# Introduction

Figure 1

Perfluorooctanoic Acid (CASRN 335-67-1; Chemical Formula C_8_HF_15_O_2_; Molecular Weight: 414.07)

## Chemical and Physical Properties

Perfluorooctanoic acid (PFOA) is a white powder at room temperature and, as a free acid, has a melting point of 54°C and a boiling point of 192°C. At 25°C, PFOA has a water solubility of 9,500 mg/L and a vapor pressure of 0.525 mm Hg.^1^ PFOA has an estimated log K_OW_ of 4.81.^2^

## Production, Use, and Human Exposure

PFOA was widely used in the manufacturing of a variety of consumer products that included many nonstick applications, such as for clothing and cookware.^3^ However, due to concerns about persistence and potential toxicity, PFOA was removed from commerce through a 2006 agreement between the U.S. Environmental Protection Agency (EPA) and U.S. manufacturers to phase it out of production by 2015.^1^ Although PFOA is no longer produced in the United States, breakdown of other per/polyfluorinated alkyl substances (PFAS) may lead to continued PFOA exposure.^4^ In addition, concentrations of PFAS can persist in the population for a long time due to a slow elimination rate in humans and persistence in the environment.

Many surveys have been conducted of PFOA exposure in humans with general findings of widespread but lower exposure concentrations in the general population, higher concentrations around communities in areas of manufacturing and use, and the highest concentrations in manufacturing plants. The U.S. National Health and Nutrition Examination Survey (NHANES) has been evaluating PFOA concentrations in the U.S. general population for nearly two decades. The geometric mean from the 1999–2000 evaluation was 5.21 μg/L serum, which dropped to 1.56 μg/L in the 2015–2016 assessment.^5^ Near areas of manufacturing or use of PFOA, community concentrations were notably higher than were those in the general population. In members of the community around the Washington Works manufacturing plant in West Virginia, median concentrations were 28.2 μg/L, but concentrations were 147.8 μg/L for those working in the plant.^6^ Prior to its discontinued use, mean serum concentrations for workers were as high as 1,030 to 1,090 μg/L in other plants.^7^

## Regulatory Status

As mentioned, PFOA is not currently used in commerce because EPA and U.S. manufacturers came to an agreement to phase out its production.^1^ However, it is still present in many areas of the environment due to its persistence, most notably in drinking water. EPA established a PFOA drinking water health advisory of 70 parts per trillion (ppt) (70 ng/L) in 2016^8^ based on decreased ossification in mice pups and accelerated male puberty.^9^ The Agency for Toxic Substances and Disease Registry (ATSDR) recently developed provisional PFOA minimal risk levels of 78 ppt (78 ng/L) for adults and 21 ppt (21 ng/L) for children^10^ given research showing increased locomotor activity in adult mouse offspring^11^ and altered mouse bone morphology.^12^ Individual states have also developed PFOA drinking water values in accordance with their assessments; New Jersey developed a drinking water guidance of 14 ppt (14 ng/L) and Minnesota developed a Health Risk Limit of 35 ppt (35 ng/L).^13,14^ Recently, the European Food Safety Authority developed provisional tolerable weekly intakes of 6 ng/kg/week for PFOA based on human endpoints.^15^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Several studies have evaluated the absorption, distribution, metabolism, and excretion properties of PFOA. PFOA is generally well absorbed and the highest concentrations are typically observed in the plasma, serum, and liver, followed by the kidney.^16^ PFOA is water soluble, and most of its elimination occurs via urine without metabolism. Very little to no accumulation has been observed in the brain.^17^ A range of elimination rates have been reported and vary across species. In addition, differences in elimination occur between the sexes, most notably in rats. In rats, half-lives of 2 to 15 days have been reported in males depending on the dose.^17,18,19-23^ In female rats, much faster half-lives have been observed in the order of 2 to 12 hours.^17,22,23^ In mice, half-lives of 22 days in males and 16 days in females were estimated after a single dose.^24^ In cynomolgus monkeys, a half-life of 14 to 42 days was estimated.^25^

Reuptake via renal absorption has been proposed to explain the differential elimination of the PFAS class across species and sexes. The notable sex difference of PFOA elimination in rats is reduced by castration of males, which increases clearance of PFOA, with evidence suggesting changes in organic anion transporter (OAT) 2 and OAT3 as the mechanism.^26^ In addition, protein binding may be another mechanism. Modeling of PFAS pharmacokinetics has included a saturable renal resorption function.^24,27-31^

### Humans

The half-life of PFOA, determined by measuring blood concentrations in retired workers (n = 26), was estimated to be 3.8 years (arithmetic mean) and 3.5 years (geometric mean).^32^ A half-life average of 2.7 years was estimated from a community (n = 106) exposed to drinking water contaminated with PFOA.^33^ A small study of ski wax technicians (n = 6), who use ski wax and wax-related products that contain PFOA, estimated a half-life average of 2.4 years.^34^

## Toxicity

### Experimental Animals

Extensive literature exists on the toxicity of PFOA in a variety of species. A common target is the liver, with findings ranging from liver hypertrophy or necrosis to alterations in liver enzymes and clinical chemistry changes. Peroxisome proliferator-activated receptor alpha (PPARα) activation by PFAS in rodents is a mechanistic pathway that is frequently attributed to PFOA exposure, and PPARα potency across the class varies with chain length.^35-40^ Gene expression profiling of the liver also suggests that constitutive androstane receptor (CAR) induction is another factor in liver toxicity and enzyme alterations,^41,42^ with additional studies showing PFOA increases liver PPARα and CAR/pregnane X receptor activation leading to increases in cytochrome P450 (Cyp) 2B1/2, Cyp3A1, and Cyp4A1 protein concentrations.^43^ In male Crl:CD BR rats exposed to ammonium perfluorooctanoate (APFO) in feed (up to 100 parts per million [ppm]) for 13 weeks, toxicity findings included increased liver weight, hepatocellular hypertrophy, increased liver palmitoyl-CoA oxidase activity, and decreased serum cholesterol.^44^ Exposure of cynomolgus monkeys to APFO for 6 months resulted in increases in triglycerides, decreases in bilirubin, increased liver weight, and decreases in thyroid hormones without histological lesions.^45^

### Humans

Numerous epidemiology studies have evaluated the relationship between health effects or outcomes and exposure to PFOA. These studies include both occupational and environmental exposure, including studies of individuals living in West Virginia’s Mid-Ohio Valley that were exposed to high concentrations of PFOA in the drinking water from an industrial plant. An expert panel^46^ and ATSDR^47^ reviewed these studies and concluded that PFOA exposure was associated with liver damage,^47^ increases in serum lipid concentrations, especially cholesterol, pregnancy-induced hypertension and/or pre-eclampsia, immune effects, and thyroid diseases.^46,47^

## Reproductive and Developmental Toxicity

### Experimental Animals

PFOA has been evaluated in several rodent studies for developmental and reproductive toxicity. Gestational exposure to PFOA in mice resulted in developmental and reproductive toxicity ranging from whole litter loss to developmental delays.^9,48^ A two-generation study in Sprague Dawley rats observed a small reduction in pup survival during lactation, decreases in body weights, and delays in pubertal markers at 30 mg/kg, with changes in organ weights and body weights occurring at lower doses.^49^

### Humans

PFOA exposure has been proposed to be associated with reproductive and developmental effects in humans. Reproductive effects include irregular and long menstrual cycles and delayed onset of menarche in adolescent females. Both ATSDR^47^ and the C8 panel reports^46^ concluded that PFOA exposure was associated with pregnancy-induced hypertension^46^ or pre-eclampsia.^47^ Several meta-analyses^50,51^ have reported that PFOA is associated with lower infant birth weight; however, ATSDR noted that the decrease in birth weight is small and may not affect the infant’s health. The interpretation of these findings is unclear as many studies are cross-sectional and the potential for confounding exists. Low glomerular filtration rate may be a confounding factor because it is related potentially to both lower birth weight and higher levels of PFOA; the potential for confounding is also more likely when maternal samples are taken later in pregnancy.^52^ A recent meta-analysis found that associations with decreased birth weight were mainly limited to studies that sampled maternal blood later in pregnancy and found little evidence of an association in studies sampling blood early in pregnancy.^53^ A systematic review identified several human health categories of concern in children with respect to exposure to PFAS, including dyslipidemia, immunity (vaccine response and asthma), renal function, and age at menarche.^54^

## Immunotoxicity

### Experimental Animals

Several studies have demonstrated the immunomodulatory effects of PFOA or APFO in mice. Across multiple strains, short-term exposure to PFOA resulted in atrophy of the spleen and thymus, reduction in splenic and thymic lymphocytes, and suppressed the T-cell dependent antibody response (TDAR). These effects occurred in the range of 9.6 to 33 mg/kg/day and were consistent across gavage, feed, and drinking water routes of exposure.^55-58^ The most sensitive effects observed were reductions in TDAR and T-cell independent antibody responses at 3.75 and 1.88 mg/kg/day, respectively, in female C57Bl6 mice exposed via drinking water for 15 days.^59,60^ Two additional studies report an increased hypersensitivity response in BALB/c mice following PFOA exposure.^61,62^

### Humans

Epidemiological studies provide evidence to suggest a link between PFOA exposure and immunomodulation. Elevated serum PFOA concentrations during development were associated with a reduced antibody response to certain vaccines (e.g., diphtheria and tetanus) in Norwegian and Faroe Island birth cohort studies^63-68^ and in a cross-sectional study of adolescents using NHANES data.^69^ Similar reductions in antibody concentrations were observed following administration of the influenza vaccine in adults in the Mid-Ohio Valley.^70^ Additional immune-related outcomes associated with PFOA exposure include increased hypersensitivity, reduced resistance to infectious disease, and an increase in autoimmune disease. In addition, the National Toxicology Program (NTP)^71^ conducted a systematic review of immune effects and concluded that PFOA is presumed to be an immune hazard based on evidence from human and animal studies. NTP concluded that there was a moderate level of evidence from studies in humans that PFOA suppresses antibody response, with evidence from developmental, childhood, and adult exposures.

## Carcinogenicity

### Experimental Animals

Two rodent studies have examined the carcinogenic activity of PFOA. The first study, conducted in the early 1980s with Sprague Dawley rats exposed to 0, 30, or 300 ppm APFO, showed increased incidences of Leydig cell adenomas of the testis in males and female mammary gland fibroadenomas in the 300 ppm groups.^72^ Further review of the mammary gland fibroadenomas from this study found that they were not in fact increased, as more were observed in the control group than initially reported.^73^ A follow-up study in male Sprague Dawley rats exposed to 300 ppm APFO reported increased incidences of hepatocellular adenomas, Leydig cell adenomas, and pancreatic acinar cell neoplasms.^74^ Review of the pancreas from the first study found increased incidences of acinar cell hyperplasia and a single incidence of an acinar cell carcinoma, which was more consistent with the follow-up study.^75^ A tumor promotion study in rainbow trout found the high dose of PFOA (1,800 ppm, or 50 mg/kg per day) increased the combined incidence of liver neoplasms in aflatoxin-initiated fish, whereas PFOA alone did not induce liver neoplasms.^76^

### Humans

The carcinogenic activity of PFOA in humans was recently reviewed by the International Agency for Research on Cancer (IARC).^77^ Approximately a dozen epidemiological studies have evaluated the possible carcinogenic effects of PFOA in different exposure scenarios (e.g., occupational, community). IARC concluded that PFOA was possibly carcinogenic to humans (Group 2B) based on limited evidence in humans of associations with cancer of the testis and kidneys and limited evidence in the previously mentioned animal carcinogenicity studies.

## Genetic Toxicity

The genetic toxicity of PFOA has been evaluated in bacterial mutagenicity assays, in vitro tests using human and rodent cells, and one animal study. Whereas bacterial mutagenicity assays using several Salmonella typhimurium test strains were uniformly negative, conflicting results were obtained for PFOA using in vitro tests with mammalian cells. In the single in vivo study, PFOA was reported to induce oxidative damage to DNA obtained from rat liver cells.^78^

PFOA was not mutagenic in S. typhimurium strains TA98, TA100, TA1535, TA1537, and TA1538 in the absence or presence of exogenous rat liver metabolic enzymes (S9 mix) at concentrations up to 5 μmol/plate.^79^ PFOA was also negative in S. typhimurium test strains TA98, TA100, TA102, and TA104 in the absence or presence of S9 mix when tested up to 500 μM.^80^

Using the comet assay, significant, dose-dependent increases in DNA damage were observed in human lymphoblastoid TK6 cells exposed to concentrations of PFOA that ranged from 125 to 500 ppm for 2 hours.^81^ Small increases in 8-hydroxy-2ʹ-deoxyguanosine DNA adducts (per 10^5^ dG) as detected using high-performance liquid chromatography (HPLC)-mass spectrometry (MS) were also reported using the same exposure protocol. In HepG2 cells, PFOA induced significant, dose-dependent increases in DNA damage in the comet assay, in 8-hydroxy-2ʹ-deoxyguanosine as detected by immunostaining, and in micronuclei after 1, 3, or 24 hours of exposure, respectively; the same concentrations, ranging from 50 to 400 μM, were used for each assay.^82^ Significant increases in DNA damage, as detected using the comet assay, were also observed in HepG2 cells exposed to PFOA at concentrations ranging from 0.2 to 20 μM for 24 hours.^83^ PFOA was negative in the comet assay when HepG2 cells were evaluated after 1 or 24 hours of exposure to concentrations ranging from 5 to 400 μM, and was negative in the micronucleus assay when HepG2 cells were evaluated 24 hours after exposure using the same conditions; however, the percentage of DMSO, a known free radical scavenger that was used for these experiments, was relatively high at 2.5%.^84^ There was no increase in DNA damage in the comet assay in Syrian hamster embryo cells after 5 or 24 hours of exposure to concentrations of PFOA of up to 300 μM.^85^ Also, negative results were obtained in the comet assay when freshly isolated Wistar rat testicular cells were exposed to 100 or 300 μM PFOA for 24 hours.^86^

One study examined the genotoxicity of PFOA in vivo. Using HPLC and an electrochemical detector (ECD) system, small increases in 8-hydroxy-2ʹ-deoxyguanosine DNA adducts (per 10^5^ dG) were detected in DNA obtained from the liver, but not the kidney, of male F344 rats exposed to 0.02% PFOA in feed for 2 weeks, or at 3, 5, or 8 days after a single intraperitoneal injection of 100 mg/kg PFOA.^78^ Increases in 8-hydroxy-2ʹ-deoxyguanosine (per 10^5^ dG) in DNA obtained from the liver or kidney were not observed at 1 day after injection. Considering that oxidative damage to DNA typically undergoes rapid repair, the small increases in 8-hydroxy-2ʹ-deoxyguanosine that were detected by Takagi et al.^78^ several days after injection may not necessarily have been due to exposure to PFOA.

In a review of unpublished genetic toxicity test data generated in industry-sponsored studies, PFOA tested as either an ammonium or sodium salt was found to be negative in bacterial mutagenicity assays, the Chinese hamster ovary HGPRT forward mutation assay, the chromosomal aberration assay when performed using Chinese hamster ovary cells or primary human lymphocytes, and in the mouse bone marrow micronucleus assay.^87^

PFOA did not show evidence of genotoxic activity in tests conducted by NTP.^88^ PFOA was negative in bacterial mutagenicity assays in S. typhimurium strain TA100 and E. coli strain WP2 uvrA pKM101, with and without 10% rat liver S9, and in strain TA98, with S9. In strain TA98 without S9, results with PFOA were equivocal. PFOA was judged to be negative in the peripheral blood micronucleus assay. There were no increases in micronucleated reticulocytes in the peripheral blood of female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats administered PFOA for 28 days via gavage. Although a positive response was indicated for male rats, the results were within the laboratory’s historical control range, and therefore the biological significance of the increase was questionable. No changes were noted in the percentage of reticulocytes in peripheral blood of either sex, suggesting that PFOA did not induce bone marrow toxicity.

## Study Rationale

The PFAS class was nominated by EPA for toxicity evaluations. Concern that exposure to PFOA could lead to unexpected carcinogenic effects due to exposures during early life development was considered in the nomination. Previous carcinogenicity studies of PFOA^72,74^ began exposure after the critical periods of in utero and early postnatal development, so it is unknown whether the carcinogenic response is altered if exposure during gestation and lactation is included. NTP tested the hypothesis that including exposure during gestation and lactation (perinatal exposure) would change the PFOA carcinogenic response quantitatively (more neoplasms) or qualitatively (different neoplasm types). Feed exposure was selected as it is a common route of exposure in the human population.

Design of this study was based on previous NTP assessments of early developmental exposures influencing carcinogenic activity.^89-91^ This approach uses a matrix-type design that evaluates different gestation/lactation doses. Comparisons were made between groups that received exposure during the perinatal and postweaning periods with groups exposed during the postweaning period only. Exposure concentrations were selected based on available literature and a 16-week interim necropsy was included to assess ongoing toxicity. Due to the identified sex differences in PFOA elimination rates, doses were increased in female rats after weaning to ensure systemic exposure. The male rat portion of this study was stopped and restarted due to observed toxicity occurring at the 16-week interim necropsy.