# Appendix F Revision Listing

## F.1 2020 Erratum

An error was identified in the NTP Technical Report on the Toxicology and Carcinogenesis Studies of Perfluorooctanoic Acid (CASRN 335-67-1) Administered in Feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats (Technical Report 598). The survival rates of female rats reported in the summary table were changed to reflect those in the corresponding results tables. [May 22, 2020]

The corrections made as part of the 2020 erratum, including the page numbers, are specified below.

Summary Table, page xx

Survival rates were corrected as outlined below:

## F.2 2022 Revisions

Errors were identified in the NTP Technical Report on the Toxicology and Carcinogenesis Studies of Perfluorooctanoic Acid (CASRN 335-67-1) Administered in Feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats (Technical Report 598). For the uterine findings, changes were made to the number of animals in the 0/1,000 ppm group with a neoplasm (overall rates) and the number of litters with animals with a neoplasm (litter rates). One animal with a squamous cell carcinoma in the 0/1,000 ppm group was inadvertently combined in the adenocarcinoma analysis of the extended evaluation. The number of animals examined during the standard, extended, and standard or extended (combined) evaluations was also corrected in the 0/300, 0/1,000, and 300/1,000 ppm groups. Due to these corrections in the incidence data, statistical analysis was rerun, and the Rao-Scott-adjusted Poly-3 test p values were updated for all exposure groups. As a result, the trend tests for uterine adenocarcinoma are no longer statistically significant (p > 0.05) for the extended and the standard or extended (combined) evaluations. In addition, the pairwise comparisons of adenocarcinoma incidence between the control and the 0/1,000 ppm groups are now p = 0.05 for the extended and the standard or extended (combined) evaluations. The original conclusion that the higher incidence of uterine adenocarcinoma may have been related to PFOA exposure (equivocal evidence) is not changed. The corrections made are specified below. [February 1, 2023]

Summary Table, page xxi

The numbers of rats examined and the overall rates of uterine adenocarcinoma were corrected as outlined below:

Page 48

The results text was updated as follows to reflect the correct table:

Table 25, pages 48–50

Tables for the statistical analysis of primary neoplasms in the uterus and statistical analysis of nonneoplastic lesions in the uterus were rerun on March 9, 2022, and March 10, 2022, respectively, to correct for the number of rats examined in the 0/300, 0/1,000, and 300/1,000 ppm groups. The resulting changes in overall rates, litter rates, and Rao-Scott-adjusted Poly-3 test p values were made as outlined below:

Table 25, page 50

Footnotes that were no longer applicable were removed from the table, and the remaining footnotes were edited for clarity and reordered as outlined below: