# Appendix E Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TR598.

## E.1 Study 1: Two-year Study in Females and 16-week Interim Evaluation in Males and Females

### E.1.1 Sixteen-week Interim Evaluation in Males and Females

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions – Females 0-0, 0-300, 0-1000

P10 – Statistical Analysis of Non-Neoplastic Lesions – Females 0-0, 150-300, 300-1000

P10 – Statistical Analysis of Non-Neoplastic Lesions – Females 0-1000, 300-1000

P10 – Statistical Analysis of Non-Neoplastic Lesions – Females 0-300, 150-300

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 0-0, 0-150, 0-300

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 0-0, 150-150, 300-300

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 0-150, 150-150

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 0-300, 300-300

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA45 – Liver Special Studies Summary

PA48 – Tissue Concentration Summary

R02 – Reproductive Performance Summary

### E.1.2 Two-year Study in Females

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves – litter (0-0, 0-150, 0-300) male

E03 – Growth Curves – litter (0-0, 0-300, 0-1000) female

E03 – Growth Curves – litter (0-0, 150-150, 300-300) male

E03 – Growth Curves – litter (0-0, 150-300, 300-1000) female

E03 – Growth Curves – litter (0-1000, 300-1000) female

E03 – Growth Curves – litter (0-150, 150-150) male

E03 – Growth Curves – litter (0-300, 150-300) female

E03 – Growth Curves – litter (0-300, 300-300) male

E04 – Mean Body Weights and Survival Table litter (0-0, 0-300, 0-1000) female

E04 – Mean Body Weights and Survival Table litter (0-0, 150-300, 300-1000) female

E04 – Mean Body Weights and Survival Table litter (0-0, 0-150, 0-300) male

E04 – Mean Body Weights and Survival Table litter (0-0, 150-150, 300-300) male

E04 – Mean Body Weights and Survival Table litter (0-1000, 300-1000) female

E04 – Mean Body Weights and Survival Table litter (0-150, 150-150) male

E04 – Mean Body Weights and Survival Table litter (0-300, 150-300) female

E04 – Mean Body Weights and Survival Table litter (0-300, 300-300) male

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

F0 Female Harlan Sprague Dawley Rats Post-Cull Pup Body Weights

F0 Female Harlan Sprague Dawley Rats Gestational Body and Body Weight Gains

F0 Female Harlan Sprague Dawley Rats Gestational and Lactational Chemical Consumption

F0 Female Harlan Sprague Dawley Rats Gestational and Lactational Food Consumption

F0 Female Harlan Sprague Dawley Rats Lactational Body and Body Weight Gains

F0 Litter Data Analysis in Female Harlan Sprague Dawley Rats: Live Litter Size and Survival

F0 Litter Data Analysis in Female Harlan Sprague Dawley Rats: PND 1 Data

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors – Uterine 0-0 0-300 0-1000

P08 – Statistical Analysis of Primary Tumors – Uterine 0-0 150-300 300-1000

P08 – Statistical Analysis of Primary Tumors – Uterine 0-1000 300-1000

P08 – Statistical Analysis of Primary Tumors – Uterine 0-300 150-300

P08 – Statistical Analysis of Primary Tumors – litter (0-0, 0-300, 0-1000)

P08 – Statistical Analysis of Primary Tumors – litter (0-0, 150-300, 300-1000)

P08 – Statistical Analysis of Primary Tumors – litter (0-1000, 300-1000)

P08 – Statistical Analysis of Primary Tumors – litter (0-300, 150-300)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions – Uterine 0-0 0-300 0-1000

P10 – Statistical Analysis of Non-Neoplastic Lesions – Uterine 0-0 150-300 300-1000

P10 – Statistical Analysis of Non-Neoplastic Lesions – Uterine 0-1000 300-1000

P10 – Statistical Analysis of Non-Neoplastic Lesions – Uterine 0-300 150-300

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (0-0, 0-300, 0-1000)

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (0-0, 150-300, 300-1000)

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (0-1000, 300-1000)

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (0-300, 150-300)

P11 – Statistical Analysis of Survival Data – litter (0-0, 0-300, 0-1000)

P11 – Statistical Analysis of Survival Data – litter (0-0, 150-300, 300-1000)

P11 – Statistical Analysis of Survival Data – litter (0-1000, 300-1000)

P11 – Statistical Analysis of Survival Data – litter (0-300, 150-300)

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades – Uterine Hyperplasia

P40 – Survival Curves – 0-0, 0-300, 0-1000

P40 – Survival Curves – 0-0, 150-300, 300-1000

P40 – Survival Curves – 0-1000, 300-1000

P40 – Survival Curves – 0-300, 150-300

P40 – Survival Curves – All Treatments

## E.2 Study 2: Two-year Study in Males with 16-week Interim Evaluation

### E.2.1 Sixteen-week Interim Evaluation in Males

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 0-0, 0-20, 0-40, 0-80

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 0-0, 300-0

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 0-20, 300-20

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 0-40, 300-40

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 0-80, 300-80

P10 – Statistical Analysis of Non-Neoplastic Lesions – Males 300-0, 300-20, 300-40, 300-80

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA45 – Liver Special Studies Summary

PA48 – Tissue Concentration Summary

R02 – Reproductive Performance Summary

### E.2.2 Two-year Study in Males

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves – litter (0-0, 0-20, 0-40, 0-80)

E03 – Growth Curves – litter (0-0, 300-0)

E03 – Growth Curves – litter (0-20, 300-20)

E03 – Growth Curves – litter (0-40, 300-40)

E03 – Growth Curves – litter (0-80, 300-80)

E03 – Growth Curves – litter (300-0, 300-20, 300-40, 300-80)

E04 – Mean Body Weights and Survival Table litter (0-0, 0-20, 0-40, 0-80)

E04 – Mean Body Weights and Survival Table litter (0-0, 300-0)

E04 – Mean Body Weights and Survival Table litter (0-20, 300-20)

E04 – Mean Body Weights and Survival Table litter (0-40, 300-40)

E04 – Mean Body Weights and Survival Table litter (0-80, 300-80)

E04 – Mean Body Weights and Survival Table litter (300-0, 300-20, 300-40, 300-80)

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

F0 Female Harlan Sprague Dawley Rats Gestational Body and Body Weight Gains

F0 Female Harlan Sprague Dawley Rats Gestational and Lactational Chemical Consumption

F0 Female Harlan Sprague Dawley Rats Gestational and Lactational Food Consumption

F0 Female Harlan Sprague Dawley Rats Lactational Body and Body Weight Gains

F0 Litter Data Analysis in Female Harlan Sprague Dawley Rats: Male Pup Body Weight

F0 Litter Data Analysis in Female Harlan Sprague Dawley Rats: PND 1 Data

F0 Litter Data Analysis in Female Harlan Sprague Dawley Rats: PND 4 Data

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors – litter (0-0, 0-20, 0-40, 0-80

P08 – Statistical Analysis of Primary Tumors – litter (0-0, 300-0)

P08 – Statistical Analysis of Primary Tumors – litter (0-20, 300-20)

P08 – Statistical Analysis of Primary Tumors – litter (0-40, 300-40)

P08 – Statistical Analysis of Primary Tumors – litter (0-80, 300-80)

P08 – Statistical Analysis of Primary Tumors – litter (300-0, 300-40, 300-60, 300-80)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (0-0, 0-20, 0-40, 0-80)

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (0-0, 300-0)

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (0-20, 300-20)

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (0-40, 300-40)

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (0-80, 300-80)

P10 – Statistical Analysis of Non-Neoplastic Lesions – litter (300-0, 300-20, 300-40, 300-80)

P11 – Statistical Analysis of Survival Data – litter (0-0, 0-20, 0-40, 0-80)

P11 – Statistical Analysis of Survival Data – litter (0-0, 300-0)

P11 – Statistical Analysis of Survival Data – litter (0-20, 300-20)

P11 – Statistical Analysis of Survival Data – litter (0-40, 300-40)

P11 – Statistical Analysis of Survival Data – litter (0-80, 300-80)

P11 – Statistical Analysis of Survival Data – litter (300-0, 300-20, 300-40, 300-80)

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves 0-0, 0-20, 0-40, 0-80

P40 – Survival Curves 0-0, 300-0

P40 – Survival Curves 0-20, 300-20

P40 – Survival Curves 0-40, 300-40

P40 – Survival Curves 0-80, 300-80

P40 – Survival Curves 300-0, 300-20, 300-40, 300-80

P40 – Survival Curves All Treatment Groups