# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals are from the same production source and weanling groups as the animals used for the studies of test compounds.

For these toxicology and carcinogenesis studies of perfluorooctanoic acid, blood samples were collected from the rodents and allowed to clot, and the serum was separated. All samples were processed appropriately with serology testing sent to IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed. Blood was collected per the following methods and as shown in Table C-1 and Table C-2.

Study 1: 10 females at arrival; 5 females, 4 weeks postarrival; 5 animals per sex at 6, 12, and 18 months; 10 females at study termination.

Study 2: 10 females at arrival; 5 females, 4 weeks postarrival; 5 males at 6, 12, and 18 months, and study termination.

Table C-1 Methods and Results for Sentinel Animal Testing (Study 1)

Method and Test | Time of Collection
Multiplex Fluorescent Immunoassay
Kilham’s Rat Virus | Arrival^a^; 4 weeks postarrival^b^; 6, 12, and 18 months; study termination
Mycoplasma pulmonis | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Parvo NS-1 | Arrival; 4 weeks postarrival; 6 and 12 months
Pneumonia Virus of Mice | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Rat Coronavirus/Sialodacryoadenitis Virus | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Rat Minute Virus | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Rat Parvovirus | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Rat Theilovirus | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Sendai | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Theiler’s Murine Encephalomyelitis Virus Strain GDVII | Arrival; 4 weeks postarrival; 6 and 12 months
Toolan’s H-1 | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination

^a^ Age-matched nonpregnant females.

^b^ Time-mated females that did not have a litter.

Table C-2 Methods and Results for Sentinel Animal Testing (Study 2)

Method and Test | Time of Collection
Multiplex Fluorescent Immunoassay
Kilham’s Rat Virus | Arrival^a^; 4 weeks postarrival^b^; 6, 12, and 18 months; study termination
Mycoplasma pulmonis | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Parvo NS-1 | Arrival; 4 weeks postarrival; 6 months
Pneumonia Virus of Mice | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Rat Coronavirus/Sialodacryoadenitis Virus | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Rat Minute Virus | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Rat Parvovirus | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Rat Theilovirus | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Sendai | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Theiler’s Murine Encephalomyelitis Virus Strain GDVII | Arrival; 4 weeks postarrival; 6 months
Toolan’s H-1 | Arrival; 4 weeks postarrival; 6, 12, and 18 months; study termination
Immunofluorescence Assay
Mycoplasma pulmonis | Study termination
Pneumocystis carinii | Study termination

^a^ Age-matched nonpregnant females.

^b^ Time-mated females that did not have a litter.

## C.2 Results

All test results were negative.