# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table B-1 Ingredients of NTP-2000 Rat Ration

Ingredient | Percent by Weight (Study 1) | Percent by Weight (Study 2)
Ground Hard Winter Wheat | 22.26 | 22.26
Ground #2 Yellow Shelled Corn | 22.18 | 22.18
Wheat Middlings | 15.0 | 15.0
Oat Hulls | 8.5 | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5 | 7.5
Purified Cellulose | 5.5 | 5.5
Soybean Meal (49% Protein) | 5.0 | 5.0
Fish Meal (60% Protein) | 4.0 | 4.0
Corn Oil (without Preservatives) | 3.0 | 3.0
Soy Oil (without Preservatives) | 3.0 | 3.0
Dried Brewer's Yeast | 1.0 | 1.0
Calcium Carbonate (USP) | 0.9 | 0.9
Vitamin Premix 1^a^ | 0.5 | 0.5
Mineral Premix 2^b^ | 0.5 | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4 | 0.4
Sodium Chloride | 0.3 | 0.3
Choline Chloride (70% Choline) | 0.26 | 0.26
Methionine | 0.2 | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as a carrier.

^b^ Calcium carbonate as a carrier.

Table B-2 Vitamins and Minerals Added to NTP-2000 Rat Ration^a^

| Study 1 | | Study 2
| Amount | Source | Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione (MSBC) | 1.0 mg | Menadione (MSBC)
α-Tocopheryl Acetate | 100 IU | – | 100 IU | –
Niacin | 23 mg | – | 23 mg | –
Folic Acid | 1.1 mg | α-Calcium pantothenate | 1.1 mg | α-Calcium pantothenate
α-Pantothenic Acid | 10 mg | – | 10 mg | –
Riboflavin | 3.3 mg | Thiamine mononitrate | 3.3 mg | Thiamine mononitrate
Thiamin | 4 mg | – | 4 mg | –
B_12_ | 52 μg | – | 52 μg | –
Pyridoxine | 6.3 mg | Pyridozine hydrochloride | 6.3 mg | Pyridozine hydrochloride
Biotin | 0.2 mg | α-Biotin | 0.2 mg | α-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate | 0.2 mg | Chromium acetate

MSBC = menadione sodium bisulfite complex.

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NTP-2000 Rat Ration

Nutrient | Study 1 | | | Study 2
Nutrient | Mean ± SD | Range | Number of Samples | Mean ± SD | Range | Number of Samples
Protein (% by Weight) | 14.57 ± 0.389 | 13.9–15.8 | 23 | 14.6 ± 0.239 | 14.1–15.0 | 24
Crude Fat (% by Weight) | 8.46 ± 0.257 | 8.1–9.0 | 23 | 8.55 ± 0.289 | 8.1–9.1 | 24
Crude Fiber (% by Weight) | 9.3 ± 0.987 | 7.5–11.6 | 23 | 9.5 ± 0.952 | 7.5–11.6 | 24
Ash (% by weight) | 5.11 ± 0.133 | 4.82–5.3 | 23 | 4.99 ± 0.184 | 4.61–5.22 | 24
Amino Acids (% of Total Diet)
Arginine | 0.802 ± 0.075 | 0.67–0.97 | 28 | 0.802 ± 0.075 | 0.67–0.97 | 28
Cystine | 0.220 ± 0.022 | 0.15–0.25 | 28 | 0.220 ± 0.022 | 0.15–0.25 | 28
Glycine | 0.703 ± 0.038 | 0.62–0.80 | 28 | 0.703 ± 0.038 | 0.62–0.80 | 28
Histidine | 0.342 ± 0.071 | 0.27–0.68 | 28 | 0.342 ± 0.071 | 0.27–0.68 | 28
Isoleucine | 0.549 ± 0.041 | 0.43–0.66 | 28 | 0.549 ± 0.041 | 0.43–0.66 | 28
Leucine | 1.097 ± 0.064 | 0.96–1.24 | 28 | 1.097 ± 0.064 | 0.96–1.24 | 28
Lysine | 0.700 ± 0.106 | 0.31–0.86 | 28 | 0.700 ± 0.106 | 0.31–0.86 | 28
Methionine | 0.410 ± 0.042 | 0.26–0.49 | 28 | 0.410 ± 0.042 | 0.26–0.49 | 28
Phenylalanine | 0.623 ± 0.047 | 0.47–0.72 | 28 | 0.623 ± 0.047 | 0.47–0.72 | 28
Threonine | 0.512 ± 0.042 | 0.43–0.61 | 28 | 0.512 ± 0.042 | 0.43–0.61 | 28
Tryptophan | 0.155 ± 0.027 | 0.11–0.20 | 28 | 0.155 ± 0.027 | 0.11–0.20 | 28
Tyrosine | 0.420 ± 0.066 | 0.28–0.54 | 28 | 0.420 ± 0.066 | 0.28–0.54 | 28
Valine | 0.666 ± 0.040 | 0.55–0.73 | 28 | 0.666 ± 0.040 | 0.55–0.73 | 28
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.88 ± 0.455 | 1.89–4.55 | 28 | 3.88 ± 0.455 | 1.89–4.55 | 28
Linolenic | 0.30 ± 0.065 | 0.007–0.368 | 28 | 0.30 ± 0.065 | 0.007–0.368 | 28
Vitamins
Vitamin A (IU/kg) | 3,731 ± 85 | 2,360–5,280 | 23 | 3,842 ± 77 | 2,360–5,290 | 24
Vitamin D (IU/kg) | 1,000^a^ | – | | 1,000^a^ | –
α-Tocopherol (ppm) | 2,543 ± 13,044 | 27.0–69,100 | 28 | 2,543 ± 13,044 | 27.0–69,100 | 28
Thiamine (ppm)^b^ | 7.45 ± 1.24 | 6.1–12.4 | 23 | 8.14 ± 1.87 | 3.9–12.5 | 24
Riboflavin (ppm) | 8.06 ± 2.83 | 4.20–17.50 | 28 | 8.06 ± 2.83 | 4.20–17.50 | 28
Niacin (ppm) | 78.6 ± 8.26 | 66.4–98.2 | 28 | 78.6 ± 8.26 | 66.4–98.2 | 28
Pantothenic Acid (ppm) | 26.6 ± 11.22 | 17.4–81.0 | 28 | 26.6 ± 11.22 | 17.4–81.0 | 28
Pyridoxine (ppm)^b^ | 9.78 ± 2.08 | 6.44–14.3 | 28 | 9.78 ± 2.08 | 6.44–14.3 | 28
Folic Acid (ppm) | 1.58 ± 0.44 | 1.15–3.27 | 28 | 1.58 ± 0.44 | 1.15–3.27 | 28
Biotin (ppm) | 0.32 ± 0.09 | 0.20–0.704 | 28 | 0.32 ± 0.09 | 0.20–0.704 | 28
Vitamin B12 (ppb) | 50.6 ± 35.5 | 18.3–174.0 | 28 | 50.6 ± 35.5 | 18.3–174.0 | 28
Choline (as Chloride) (ppm) | 2,615 ± 635 | 1,160–3,790 | 28 | 2,615 ± 635 | 1,160–3,790 | 28
Minerals
Calcium (%) | 0.915 ± 0.046 | 0.797–0.99 | 23 | 0.896 ± 0.046 | 0.797–0.99 | 24
Phosphorus (%) | 0.553 ± 0.031 | 0.487–0.613 | 23 | 0.563 ± 0.025 | 0.487–0.613 | 24
Potassium (%) | 0.667 ± 0.030 | 0.626–0.733 | 28 | 0.667 ± 0.030 | 0.626–0.733 | 28
Chloride (%) | 0.393 ± 0.045 | 0.300–0.517 | 28 | 0.393 ± 0.045 | 0.300–0.517 | 28
Sodium (%) | 0.197 ± 0.026 | 0.160–0.283 | 28 | 0.197 ± 0.026 | 0.160–0.283 | 28
Magnesium (%) | 0.217 ± 0.055 | 0.185–0.490 | 28 | 0.217 ± 0.055 | 0.185–0.490 | 28
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14 | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 191.6 ± 36.8 | 135–311 | 28 | 191.6 ± 36.8 | 135–311 | 28
Manganese (ppm) | 50.1 ± 9.59 | 21.0–73.1 | 28 | 50.1 ± 9.59 | 21.0–73.1 | 28
Zinc (ppm) | 57.4 ± 26.0 | 43.3–184.0 | 28 | 57.4 ± 26.0 | 43.3–184.0 | 28
Copper (ppm) | 7.53 ± 2.53 | 3.21–16.3 | 28 | 7.53 ± 2.53 | 3.21–16.3 | 28
Iodine (ppm) | 0.531 ± 0.201 | 0.158–0.972 | 28 | 0.531 ± 0.201 | 0.158–0.972 | 28
Chromium (ppm) | 0.684 ± 0.258 | 0.330–1.380 | 27 | 0.684 ± 0.258 | 0.330–1.380 | 27
Cobalt (ppm) | 0.225 ± 0.154 | 0.086–0.864 | 26 | 0.225 ± 0.154 | 0.086–0.864 | 26

SD = standard deviation.

^a^ From formulation.

^b^ As hydrochloride.

Table B-4 Contaminant Levels in NTP-2000 Rat Ration^a^

| Study 1 | | | Study 2
| Mean ± SD^b^ | Range | Number of Samples | Mean ± SD^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.25 ± 0.046 | 0.159–0.341 | 23 | 0.257 ± 0.059 | 0.172–0.385 | 24
Cadmium (ppm) | 0.059 ± 0.007 | 0.042–0.069 | 23 | 0.059 ± 0.011 | 0.042–0.094 | 24
Lead (ppm) | 0.086 ± 0.016 | 0.06–0.119 | 23 | 0.091 ± 0.033 | 0.06–0.194 | 24
Mercury (ppm) | 0.019 ± 0.004 | 0.019–0.004 | 23 | 0.017 ± 0.008 | 0.01–0.049 | 24
Selenium (ppm) | 0.211 ± 0.051 | 0.16–0.333 | 23 | 0.191 ± 0.049 | 0.145–0.333 | 24
Aflatoxins (ppm) | <5.00 | – | 23 | <5.00 | – | 24
Nitrate Nitrogen (ppm)^c^ | 16.64 ± 7.97 | 0.61–34.6 | 23 | 16.33 ± 6.09 | 10.0–29.6 | 24
Nitrite Nitrogen (ppm)^c^ | 0.61 | – | 23 | 0.61 | – | 24
BHA (ppm)^d^ | <1.0 | – | 23 | <1.0 | – | 24
BHT (ppm)^d^ | 1.09 ± 0.446 | 1.0–3.14 | 23 | 1.09 ± 0.437 | 1.0–3.14 | 24
Aerobic Plate Count (CFU/g) | <10.0 | – | 23 | <10.0 | – | 24
Coliform (MPN/g) | 3.0 | – | 23 | 3.0 | – | 24
Escherichia coli (MPN/g) | <10.0 | – | 23 | <10.0 | – | 24
Salmonella (MPN/g) | Negative | – | 23 | Negative | – | 24
Total Nitrosamines (ppb)^e^ | 10.0 ± 4.5 | 3.2–21.7 | 23 | 9.8 ± 4.5 | 3.2–18.9 | 24
N-Ndimethylamine (ppb)^e^ | 2.5 ± 2.6 | 0–11.8 | 23 | 2.8 ± 2.0 | 0–6.8 | 24
N-Npyrrolidine (ppb)^e^ | 7.5 ± 2.4 | 3.2–11.6 | 23 | 7.0 ± 3.1 | 2.1–15.15 | 24
Pesticides (ppm)
α-BHC | <0.01 | – | 23 | <0.01 | – | 24
β-BHC | <0.02 | – | 23 | <0.02 | – | 24
γ-BHC | <0.01 | – | 23 | <0.01 | – | 24
δ-BHC | <0.01 | – | 23 | <0.01 | – | 24
Heptachlor | <0.01 | – | 23 | <0.01 | – | 24
Aldrin | <0.01 | – | 23 | <0.01 | – | 24
Heptachlor Epoxide | <0.01 | – | 23 | <0.01 | – | 24
DDE | <0.01 | – | 23 | <0.01 | – | 24
DDD | <0.01 | – | 23 | <0.01 | – | 24
DDT | <0.01 | – | 23 | <0.01 | – | 24
HCB | <0.01 | – | 23 | <0.01 | – | 24
Mirex | <0.01 | – | 23 | <0.01 | – | 24
Methoxychlor | <0.05 | – | 23 | <0.05 | – | 24
Dieldrin | <0.01 | – | 23 | <0.01 | – | 24
Endrin | <0.01 | – | 23 | <0.01 | – | 24
Telodrin | <0.01 | – | 23 | <0.01 | – | 24
Chlordane | <0.05 | – | 23 | <0.05 | – | 24
Toxaphene | <0.10 | – | 23 | <0.10 | – | 24
Estimated PCBs | <0.20 | – | 23 | <0.20 | – | 24
Ronnel | <0.01 | – | 23 | <0.01 | – | 24
Ethion | <0.02 | – | 23 | <0.02 | – | 24
Trithion | <0.05 | – | 23 | <0.05 | – | 24
Diazinon | <0.10 | – | 23 | <0.10 | – | 24
Methyl Chlorpyrifos | 0.138 ± 0.126 | 0.02–0.567 | 23 | 0.13 ± 0.129 | 0.02–0.567 | 24
Methyl Parathion | <0.02 | – | 23 | <0.02 | – | 24
Ethyl Parathion | <0.02 | – | 23 | <0.02 | – | 24
Malathion | 0.122 ± 0.102 | 0.02–0.385 | 23 | 0.142 ± 0.101 | 0.02–0.385 | 24
Endosulfan I | <0.01 | – | 23 | <0.01 | – | 24
Endosulfan II | <0.01 | – | 23 | <0.01 | – | 24
Endosulfan Sulfate | <0.03 | – | 23 | <0.03 | – | 24

CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; PCB = polychlorinated biphenyl.

^a^ All samples were irradiated.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.