# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization of Perfluorooctanoic Acid

PFOA was obtained from Sigma-Aldrich (St Louis, MO) in a single lot (lot 03427TH). Identity, purity, and stability analyses were conducted under the analytical chemistry laboratory and study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the PFOA studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

PFOA is a white crystalline solid. The lot was identified using infrared (IR) spectroscopy. In addition, the lot was analyzed using ^19^F (including fluorine-fluorine correlation spectroscopy, COSY) and ^13^C nuclear magnetic resonance (NMR) spectroscopy and gas chromatography (GC) with mass spectrometry (MS) detection. The IR spectrum (Figure A-1) was in good agreement with the structure of PFOA and with the reference spectrum of PFOA from the National Institute of Advanced Industrial Science and Technology Spectral Database (No. 6075). Due to extensive coupling, the peak shapes in the ^19^F spectrum were broad and poorly resolved, but consistent with the structure of PFOA. The ^13^C spectrum was consistent with the structure of PFOA and also with the prediction from the Advanced Chemistry Development spectral prediction program (Version 10.02, Toronto, Ontario, Canada) for PFOA. The ^19^F and ^13^C spectra are provided in Figure A-2 and Figure A-3, respectively. GC/MS analysis, following conversion to its methyl ester, identified the major peak as PFOA using fragmentation pattern and comparison with the National Institute of Standards and Technology standard for methyl perfluorooctanoate.

The moisture content of lot 03427TH was determined by Karl Fisher titration performed at Prevalere Life Sciences, Inc. (Whitesboro, NY). The purity of lot 03427TH was evaluated using GC with electron capture detection (ECD), following conversion of PFOA to its methyl ester, and using ion chromatography (IC) with conductivity detection and by differential scanning calorimetry (DSC).

Karl Fisher titration yielded a water content of 0.24%. Purity by DSC was 98.96% with a melting point of approximately 55ºC. GC-FID analysis detected one major peak with an area of 98.3% of the total peak area, with four reportable impurities that had areas greater than or equal to 0.1% of the total peak area. IC detected one major peak with 98.8% of the total peak area, with three impurities that had areas greater than 0.1% of the total peak area. The overall purity of lot 03427TH was determined to be greater than 98%. GC with electron capture detection (ECD) showed that the impurities are likely fluorinated compounds. GC-MS analysis showed that two of the impurities representing approximately 1% were isomers of PFOA; the remaining impurities were perfluorooctenoic acid (0.51%) and a structurally dissimilar fluorinated compound (0.11%).

Accelerated stability studies of PFOA were conducted by the analytical chemistry laboratory using lot 027022E from Sigma-Aldrich (St Louis, MO) using GC-FID. Stability of PFOA was confirmed for at least 2 weeks when stored in sealed glass vials at temperatures up to 60°C. To ensure stability, PFOA lot 03427TH was stored in amber glass bottles at room temperature (25ºC). Periodic analyses of lot 03427TH of the test chemical were performed prior to and during the animal studies by the study laboratory using GC-ECD; no degradation of the test chemical was detected.

## A.2 Preparation and Analysis of Dose Formulations

The base diet was meal feed purchased from Zeigler Brothers, Inc. (Gardners, PA). The 21-week study utilized NIH-07 (single lot, milled July 2008) and NTP-2000 (four lots, milled September through December 2008). The 2-year study utilized NIH-07 (two lots milled May and April 2009) and NTP-2000 (24 lots milled June 2009 through June 2011).

Dose formulations were prepared monthly by mixing PFOA with feed (Table A-1). For the 21-week study, formulations of 0, 150, and 300 ppm were prepared in NIH-07 meal feed in September 2008, and in NTP-2000 meal feed twice (October 2008 and January 2009). For the 2-year study, formulations of 0 and 300 ppm PFOA in NIH-07 meal feed were prepared in June 2009. Formulations of 0, 20, 40, and 80 ppm PFOA in NTP-2000 meal feed were also prepared monthly for the 2-year study (28 formulations, July 2009–July 2011).

The analytical chemistry laboratory at Battelle (Columbus, OH) confirmed the homogeneity of NIH-07 and NTP-2000 dosed feed at formulations of 150 and 300 ppm PFOA with GC-FID prior to conducting studies. The homogeneity of dosed feed was also assessed by the study laboratory for NIH-07 (150 and 300 ppm PFOA) and NTP-2000 (20, 80, 150, 300, and 1,000 ppm PFOA) formulations with GC-ECD. After mixing, each formulation was sampled from three distinct locations and analysis of PFOA content was conducted using the protocols described in the above chemical procurement and characterization section and detailed in Table A-2. Formulations were determined to be homogenous and of appropriate concentration.

Remaining control and treated formulations were stored in plastic bag-lined buckets. Formulations of NIH-07 were refrigerated (approximately 5ºC), whereas formulations of NTP-2000 were stored at room temperature (approximately 25ºC). Stability was confirmed for these conditions up to 42 days.

Analysis of preadministration and postadministration (animal room) dose formulations of PFOA were each conducted every 1–3 months over the course of the study to determine purity (Table A-3, Table A-4). All preadministration formulations in both the 21-week and 2-year studies were within 10% of the target concentration. In the 21-week study, the 300 ppm formulation prepared in October 2008 was 12.7% below the target concentration when evaluated from feeders 6 weeks later, but only 6.5% below target when sampled from the remainder in the bucket at that same time. Postadministration formulation samples were analyzed five times over the course of the 2-year study. With the exception of the July 2009 formulation evaluated in September 2009 from residual feed in feeders, the postadministration formulations were within 10% of the target concentrations. These analyses provide confidence that the administered formulations were reflective of the target concentrations throughout the studies.

Table A-1 Preparation and Storage of Dose Formulations in the 21-week and Two-year Feed Study of Perfluorooctanoic Acid

Preparation
Stock solutions of PFOA were created by weighing an appropriate amount of lot 03427TH and adding it to a volumetric flask. Acetone was used to clean the weighing container until clear (at least three times) and bring the solution to volume. Flasks of stocks solution were sealed and shaken until lot 03427TH was dissolved (at least 10 inversions). An initial formulation premix was created by weighing an appropriate amount of feed (NIH-07 or NTP-2000) into a mixing bowl. The stock PFOA solution was slowly poured onto the feed while the mixture was stirred using a Hobart mixer. The formulations were mixed for approximately one hour and acetone was used twice to rinse the sides of the bowl and incorporate any residuals. The entire procedure was conducted under a nitrogen stream to encourage cyclonic flow and ensure acetone fully evaporated. In a twin shell blender, half of the remaining untreated feed was evenly covered with the premix. The sides were “rinsed” with the remaining untreated feed in two increments. The final formulation was mixed in the blender for 15 minutes. Dose formulations were prepared monthly throughout the experiments for a total of four formulations in the 21-week study and 30 formulations in the 2-year study.
Chemical Lot Number
03427TH
Maximum Storage Time
42 days
Storage Conditions
Stored in sealed plastic bag-lined buckets at ~5ºC (NIH-07) or ~25ºC (NTP-2000)
Study Laboratory
Battelle (Columbus, OH)

Table A-2 Chromatography Systems Used in the 21-week and Two-year Feed Study of Perfluorooctanoic Acid

Chromatography | Detection System | Column | Mobile Phase
System A
Gas Chromatography | Flame ionization detection | Restek RTX-5, 1.0 μm film thickness, 30 m × 0.32 mm (ID) | Helium, flow rate ~1 mL/min
System B
Gas Chromatography | Electron capture detection | Restek RTX-5, 1.0 μm film thickness, 30 m × 0.32 mm (ID) | Helium, flow rate ~1 mL/min
System C
Gas Chromatography | Mass selective detector | Restek RTX-5, 1.0 μm film thickness, 30 m × 0.32 mm (ID) | Helium, flow rate ~1 mL/min
System D
Ion Chromatography | Suppressed conductivity/ 40ºC | Dionex (Sunnyvale, CA) IonPac NG1-5 uM, 150 × 4 mm (ID) | A: 0.1 M NaOH in water B: 70% isopropanol in water C: water Flow rate: 0.6 mL/min

ID = internal diameter.

Table A-3 Results of Analyses of Dose Formulations Administered to Rats in the 21-week Feed Study of Perfluorooctanoic Acid

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
September 3, 2008 | September 5, 2008 | 0 | BLOQ | NA
September 3, 2008 | September 5, 2008 | 150 | 149.5 | −0.3
September 3, 2008 | September 5, 2008 | 300 | 296.5 | −1.2
October 14, 2008 | October 17, 2008 | 0 | BLOQ | NA
October 14, 2008 | October 17, 2008 | 150 | 148.7 | −0.9
October 14, 2008 | October 17, 2008 | 300 | 296.5 | −1.2
January 7, 2009 | January 9, 2009 | 0 | BLOQ | NA
January 7, 2009 | January 9, 2009 | 150 | 148.0 | −1.3
January 7, 2009 | January 9, 2009 | 300 | 302.3 | 0.8
Animal Room Samples^b^
September 3, 2008 | October 17, 2008 | 0 | BLOQ | NA
September 3, 2008 | October 17, 2008 | 150 | 148/149 | −1.6/−0.9
September 3, 2008 | October 17, 2008 | 300 | 310/301 | 3.5/0.3
October 14, 2008 | December 2, 2008 | 0 | BLOQ | NA
October 14, 2008 | December 2, 2008 | 150 | 140/144 | −6.9/−4.0
October 14, 2008 | December 2, 2008 | 300 | 262/281 | −12.7/−6.5

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analysis.

^b^ Value to left of slash mark is a composite sample from formulation left in feeders. Value to the right of the slash mark is for sample collected from bucket.

Table A-4 Results of Analyses of Dose Formulations Administered to Rats in the Two-year Feed Study of Perfluorooctanoic Acid

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
June 3, 2009 | June 5, 2009 | 0 | BLOQ | NA
June 3, 2009 | June 5, 2009 | 300 | 297.2 | −0.9
July 16, 2009 | July 21, 2009 | 0 | BLOQ | NA
July 16, 2009 | July 21, 2009 | 20 | 19.1 | −4.8
July 16, 2009 | July 21, 2009 | 40 | 39.0 | −2.6
July 16, 2009 | July 21, 2009 | 80 | 75.1 | −6.2
October 6, 2009 | October 9, 2009 | 0 | BLOQ | NA
October 6, 2009 | October 9, 2009 | 20 | 19.7 | −1.5
October 6, 2009 | October 9, 2009 | 40 | 40.1 | 0.2
October 6, 2009 | October 9, 2009 | 80 | 79.4 | −0.7
December 29, 2009 | December 30, 2009 | 0 | BLOQ | NA
December 29, 2009 | December 30, 2009 | 20 | 19.7 | −1.8
December 29, 2009 | December 30, 2009 | 40 | 40.8 | 2.0
December 29, 2009 | December 30, 2009 | 80 | 80.8 | 1.0
March 23, 2010 | March 24, 2010 | 0 | BLOQ | NA
March 23, 2010 | March 24, 2010 | 20 | 19.9 | −0.5
March 23, 2010 | March 24, 2010 | 40 | 40.1 | 0.1
March 23, 2010 | March 24, 2010 | 80 | 83.1 | 3.9
June 15, 2010 | June 16, 2010 | 0 | BLOQ | NA
June 15, 2010 | June 16, 2010 | 20 | 20.2 | 0.7
June 15, 2010 | June 16, 2010 | 40 | 41.8 | 4.4
June 15, 2010 | June 16, 2010 | 80 | 81.9 | 2.3
September 7, 2010 | September 10, 2010 | 0 | BLOQ | NA
September 7, 2010 | September 10, 2010 | 20 | 20.9 | 4.5
September 7, 2010 | September 10, 2010 | 40 | 41.3 | 3.2
September 7, 2010 | September 10, 2010 | 80 | 82.7 | 3.3
November 30, 2010 | December 1, 2010 | 0 | BLOQ | NA
November 30, 2010 | December 1, 2010 | 20 | 20.6 | 2.7
November 30, 2010 | December 1, 2010 | 40 | 42.3 | 5.7
November 30, 2010 | December 1, 2010 | 80 | 81.4 | 1.8
February 23, 2011 | February 24, 2011 | 0 | BLOQ | NA
February 23, 2011 | February 24, 2011 | 20 | 21.4 | 7.0
February 23, 2011 | February 24, 2011 | 40 | 41.7 | 4.3
February 23, 2011 | February 24, 2011 | 80 | 85.2 | 6.5
May 23, 2011 | May 24, 2011 | 0 | BLOQ | NA
May 23, 2011 | May 24, 2011 | 20 | 20.0 | 0.0
May 23, 2011 | May 24, 2011 | 40 | 39.2 | −2.0
May 23, 2011 | May 24, 2011 | 80 | 77.3 | −3.4
July 18, 2011 | July 19, 2011 | 0 | BLOQ | NA
July 18, 2011 | July 19, 2011 | 20 | 20.5 | 2.3
July 18, 2011 | July 19, 2011 | 40 | 40.1 | 0.1
July 18, 2011 | July 19, 2011 | 80 | 81.3 | 1.6
Animal Room Samples^b^
June 3, 2009 | July 10, 2009 | 0 | BLOQ | NA
June 3, 2009 | July 10, 2009 | 300 | 280/294 | −6.7/−1.9
July 16, 2009 | September 9, 2009 | 0 | BLOQ | NA
July 16, 2009 | September 9, 2009 | 20 | 17.7/18.3 | −11.5/−8.3
July 16, 2009 | September 9, 2009 | 40 | 35.3/37.4 | −11.9/−6.5
July 16, 2009 | September 9, 2009 | 80 | 69.3/73.5 | −13.4/−8.1
March 23, 2010 | May 5, 2010 | 0 | BLOQ | NA
March 23, 2010 | May 5, 2010 | 20 | 19.3/19.8 | −3.7/−1.2
March 23, 2010 | May 5, 2010 | 40 | 39.2/39.7 | −2.1/−0.8
March 23, 2010 | May 5, 2010 | 80 | 78.2/77.9 | −2.3/−2.7
November 30, 2010 | January 12, 2011 | 0 | BLOQ | NA
November 30, 2010 | January 12, 2011 | 20 | 19.3/19.8 | −3.7/−0.8
November 30, 2010 | January 12, 2011 | 40 | 40.1/41.5 | 0.2/3.8
November 30, 2010 | January 12, 2011 | 80 | 78.8/82.1 | −1.4/2.7
July 18, 2011 | August 31, 2011 | 0 | BLOQ | NA
July 18, 2011 | August 31, 2011 | 20 | 19.6/19.2 | −2.2/−4.2
July 18, 2011 | August 31, 2011 | 40 | 39.7/40.3 | −0.7/0.8
July 18, 2011 | August 31, 2011 | 80 | 79.0/79.9 | −1.2/−0.2

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analysis.

^b^ Value to left of slash mark is a composite sample from formulation left in feeders. Value to the right of the slash mark is for sample collected from bucket.

Figure A-1

Reference Infrared Absorption Spectrum of Perfluorooctanoic Acid

Figure A-2

^19^F-NMR Spectrum of Sample of Lot 03427TH of Perfluorooctanoic Acid

Figure A-3

^13^C NMR Spectrum of Sample of Lot 03427TH of Perfluorooctanoic Acid