# Overview

The National Toxicology Program (NTP) has assessed the potential adverse effects of sunscreens in human-relevant model systems; the data presented herein are part of that larger effort. The scope of 2-hydroxy-4-methoxybenzophenone (2H4MBP) studies includes the assessment of potential endocrine activity in the U.S. Environmental Protection Agency Endocrine Disruptor Screening Program Phase 1 studies (summary results of these data are provided in Appendix F), and characterization of the potential effects of continuous 2H4MBP exposure over multiple generations using the NTP Modified One-Generation study design. In this study design, exposure to 2H4MBP in the diet began on gestation day (GD) 6. At weaning, one and two pups per sex per litter were allocated to prenatal and reproductive performance cohorts, respectively. In addition to an assessment of reproductive performance, F_2_fetal outcomes (GD 21 fetal examinations) were assessed in one cohort and the potential effects on parturition and early growth of the F_2_ generation were assessed in the other cohort. Internal dose metrics were also assessed. Apical indicators sensitive to endocrine modulation were measured (e.g., anogenital distance, thoracic nipple retention, pubertal indices, reproductive tissue histology). The U.S. Food and Drug Administration’s National Center for Toxicological Research (NCTR), in partnership under an Interagency Agreement, has also examined the effects of maternal and lactational exposure to 2H4MBP on development and reproductive organs in male and female rat offspring, and on transcriptional changes in the testes and prostates of young rats. NCTR is also conducting fertility, embryo-fetal, and pre- and postnatal rat studies to characterize the potential effects of 2H4MBP exposure. NTP previously conducted 2- and 13-week toxicity studies by dermal and oral routes and assessed the genotoxic potential of 2H4MBP. Potential effects of 2H4MBP exposure on mouse reproduction were assessed using the Reproductive Assessment by Continuous Breeding protocol.