# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-597

Report Series: NTP Technical Report Series

Report Series Number: 597

Official citation: National Toxicology Program (NTP). 2020. NTP technical report on the toxicology and carcinogenesis studies of 2-hydroxy-4-methoxybenzophenone (CASRN 131-57-7) administered in feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Technical Report 597.