# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  B.S. McIntyre, Ph.D., Study Scientist
  S.S. Auerbach., Ph.D.
  C.R. Blystone, Ph.D.
  M.J. DeVito, Ph.D.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  G.K. Roberts, Ph.D.
  V.G. Robinson, M.S.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- Provided pathology review
  R.A. Miller, D.V.M., Ph.D.
  C.C. Shackelford, D.V.M., Ph.D.
  G.A. Willson, B.V.M.S.
- Coordinated NTP Pathology Working Groups on perinatal and 2-year rats (December 8, 2015) and on 2-year mice (February 23, 2016)
  G.A. Willson, B.V.M.S. (Rats)
  C.C. Shackelford, D.V.M., Ph.D. (Mice)
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  M.A. Buccellato, D.V.M., Ph.D.
  D.M. Fallacara, Ph.D.
  A.W. Singer, D.V.M.
- Conducted prestart chemistry activities and dose formulations
  S.W. Graves, B.S., Principal Investigator
  B.L. Burback, Ph.D.
  D.A. Contos, M.S.
  T.A. Cristy, B.A.
  N.L. South, B.S.
- CeeTox, Inc., Kalamazoo, Michigan, USA
  Conducted in vitro endocrine disruptor screening studies
  A. Hulett, B.S.
  H. Wagner, M.S.
  P. Wilga, M.S.
  J.A. Willoughby, Sr., Ph.D.
- Integrated Laboratory Systems, Inc., Research Triangle Park, North Carolina, USA
  Conducted in vivo endocrine disruptor screening studies
  Susan Borghoff, Ph.D., Principal Investigator
  Leah Zorrilla, Ph.D.
- Conducted bacterial mutagenicity assays
  L. Recio, Ph.D., Principal Investigator
  C.A. Hobbs, Ph.D.
  C.D. Swartz, D.V.M., Ph.D.
- Pathology Associates International, A Charles River Company, Research Triangle Park, North Carolina, USA
  Coordinated Pathology Peer Review on Uterine Lesions in Female Rats (April 26, 2016)
  C. Johnson, D.V.M.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  P. Brown, B.S.
  H. Gong, M.S.
  C. Martini, B.S.
  C. Myers, M.S.
  N. Sayers, B.S.
  M. Shaw, B.S.
  R. Whittlesey, M.S.