# References

1 Tarras-Wahlberg N Rosén A Stenhagen G Larkö O Wennberg A-M Wennerström O Changes in ultraviolet absorption of sunscreens after ultraviolet irradiation. J Invest Dermatol. 1999;113(4):547–553. 10.1046/j.1523-1747.1999.00721.x 10504439
2 Hazardous Substances Data Bank (HSDB). 2-Hydroxy-4-methoxybenzophenone. Bethesda, MD: National Library of Medicine, Toxnet; 2018. http://toxnet.nlm.nih.gov/cgi-bin/sis/search2/r?dbs+hsdb:@term+@DOCNO+4503 [Accessed: July 11, 2018]
3 Environmental Working Group (EWG) EWG’s guide to sunscreen. 2017. https://www.ewg.org/sunscreen/ [Accessed: July, 2017 ]
4 Iguana LLC Sunsect insect repellent sunscreen-octinoxate, oxybenzone, octisalate loction. 2015. https://dailymed.nlm.nih.gov/dailymed/getFile.cfm?setid=6ccdc093-8af9-4bd8-84b0-f229fccd2f1c&type=pdf
5 BASF AG. Technical inforation, Uvinul, T-Lite and Z-Cote grades, MEMC 050103e-00. 2005.
6 Christian M Final report on the safety assessment of benzophenones-1,-3,-4,-5,-9, and-11. J Am Coll Toxicol. 1983;2:35–73.
7 Yousif E Haddad R Photodegradation and photostabilization of polymers, especially polystyrene. Springerplus. 2013;2(1):398. 10.1186/2193-1801-2-398 25674392
8 Code of Federal Regulations (CFR). 21:§177.1010.
9 Han C Lim Y-H Hong Y-C Ten-year trends in urinary concentrations of triclosan and benzophenone-3 in the general US population from 2003 to 2012. Environ Pollut. 2016;208:803–810. 10.1016/j.envpol.2015.11.002 26602792
10 Wang L Kannan K Characteristic profiles of benzonphenone-3 and its derivatives in urine of children and adults from the United States and China. Environ Sci Technol. 2013;47(21):12532–12538. 10.1021/es4032908 24073792
11 Calafat AM Wong L-Y Ye X Reidy JA Needham LL Concentrations of the sunscreen agent benzophenone-3 in residents of the United States: National Health and Nutrition Examination Survey 2003–2004. Environ Health Perspect. 2008;116(7):893–897. 10.1289/ehp.11269 18629311
12 Code of Federal Regulations (CFR). 21:Part 352.
13 U.S. Environmental Protection Agency (USEPA). Methanone, (2-hydroxy-4-methoxyphenyl)phenyl-. 2020. https://iaspub.epa.gov/apex/pesticides/f?p=INERTFINDER:3:::NO::P3_ID:7568
14 El Dareer SM Kalin JR Tillery KF Hill DL Disposition of 2‐hydroxy‐4‐methoxybenzophenone in rats dosed orally, intravenously, or topically. J Toxicol Environ Health. 1986;19(4):491–502. 10.1080/15287398609530947 3783768
15 Mutlu E Garner CE Wegerski CJ McDonald JD McIntyre BS Doyle-Eisele M Waidyanatha S Metabolism and disposition of 2-hydroxy-4-methoxybenzophenone, a sunscreen ingredient, in Harlan Sprague Dawley rats and B6C3F1/N mice; a species and route comparison. Xenobiotica. 2019;31:1–16. [Epub ahead of print]. 10.1080/00498254.2019.1680906 31613170
16 Kadry AM Okereke CS Abdel-Rahman MS Friedman MA Davis RA Pharmacokinetics of benzophenone-3 after oral exposure in male rats. J Appl Toxicol. 1995;15(2):97–102. 10.1002/jat.2550150207 7782565
17 Jeon H-K Sarma SN Kim Y-J Ryu J-C Toxicokinetics and metabolisms of benzophenone-type UV filters in rats. Toxicology. 2008;248(2-3):89–95. 10.1016/j.tox.2008.02.009 18448226
18 Okereke CS Abdel-Rhaman MS Friedman MA Disposition of benzophenone-3 after dermal administration in male rats. Toxicol Lett. 1994;73(2):113–122. 10.1016/0378-4274(94)90101-5 8048080
19 Kamikyouden N Sugihara K Watanabe Y Uramaru N Murahashi T Kuroyanagi M Sanoh S Ohta S Kitamura S 2, 5-Dihydroxy-4-methoxybenzophenone: A novel major in vitro metabolite of benzophenone-3 formed by rat and human liver microsomes. Xenobiotica. 2013;43(6):514–519. 10.3109/00498254.2012.742217 23190297
20 Nakagawa Y Suzuki T Metabolism of 2-hydroxy-4-methoxybenzophenone in isolated rat hepatocytes and xenoestrogenic effects of its metabolites on MCF-7 human breast cancer cells. Chem Biol Interact. 2002;139(2):115–128. 10.1016/S0009-2797(01)00293-9 11823001
21 Nakamura N Inselman AL White GA Chang CW Trbojevich RA Sephr E Voris KL Patton RE Bryant MS Harrouk W Effects of Maternal and Lactational Exposure to 2‐Hydroxy‐4‐Methoxybenzone on Development and Reproductive Organs in Male and Female Rat Offspring. Birth Defects Res B Dev Reprod Toxicol. 2015;104(1):35–51. 10.1002/bdrb.21137 25707689
22 Mutlu E Pierfelice J McIntyre BS Cunny HC Kissling GE Burback B Waidyanatha S Simultaneous quantitation of 2-hydroxy-4-methoxybenzophenone, a sunscreen ingredient, and its metabolites in Harlan Sprague Dawley rat plasma following perinatal dietary exposure. J Anal Toxicol. 2017;41(9):744–754. 10.1093/jat/bkx070 28977387
23 Janjua N Kongshoj B Andersson AM Wulf HC Sunscreens in human plasma and urine after repeated whole‐body topical application. J Eur Acad Dermatol Venereol. 2008;22(4):456–461. 10.1111/j.1468-3083.2007.02492.x 18221342
24 Jiang R Roberts M Collins D Benson H Absorption of sunscreens across human skin: an evaluation of commercial products for children and adults. Br J Clin Pharmacol. 1999;48:635–637. 10.1046/j.1365-2125.1999.00056.x 10583038
25 Gonzalez H Farbrot A Larkö O Percutaneous absorption of benzophenone‐3, a common component of topical sunscreens. Clin Exp Dermatol. 2002;27(8):691–694. 10.1046/j.1365-2230.2002.01095.x 12472548
26 Tarazona I Chisvert A Salvador A Determination of benzophenone-3 and its main metabolites in human serum by dispersive liquid–liquid microextraction followed by liquid chromatography tandem mass spectrometry. Talanta. 2013;116:388–395. 10.1016/j.talanta.2013.05.075 24148420
27 Gonzalez H Farbrot A Larkö O Wennberg AM Percutaneous absorption of the sunscreen benzophenone‐3 after repeated whole‐body applications, with and without ultraviolet irradiation. Br J Dermatol. 2006;154(2):337–340. 10.1111/j.1365-2133.2005.07007.x 16433806
28 Zamoiski RD Cahoon EK Freedman DM Linet MS Self-reported sunscreen use and urinary benzophenone-3 concentrations in the United States: NHANES 2003–2006 and 2009–2012. Environ Res. 2015;142:563–567. 10.1016/j.envres.2015.08.006 26298557
29 Rodríguez-Gómez R Zafra-Gómez A Camino-Sánchez F Ballesteros O Navalón A Gas chromatography and ultra high performance liquid chromatography tandem mass spectrometry methods for the determination of selected endocrine disrupting chemicals in human breast milk after stir-bar sorptive extraction. J Chromatogr A. 2014;1349:69–79. 10.1016/j.chroma.2014.04.100 24861790
30 Lewerenz H-J Lewerenz G Plass R Akute und subchronische toxizitätsuntersuchungen des UV-absorbers MOB an ratten [In German]. Food Cosmet Toxicol. 1972;10(1):41–50. 10.1016/S0015-6264(72)80045-2
31 Hines EP Mendola P von Ehrenstein OS Ye X Calafat AM Fenton SE Concentrations of environmental phenols and parabens in milk, urine and serum of lactating North Carolina women. Reprod Toxicol. 2015;54:120–128. 10.1016/j.reprotox.2014.11.006 25463527
32 National Toxicology Program (NTP). NTP technical report on toxicity studies of 2-hydroxy-4-methoxybenzophenone (CAS number: 131-57-7) administered topically and in dosed feed to F344/N rats and B6C3F1 mice. Research Triangle Park, NC: United States Department of Health and Human Services, Public Health Service, National Institutes of Health; 1992. Toxicity Report 21. NIH Publication No. 92-3344.
33 National Toxicology Program (NTP). 2-Hydroxy-4-methoxybenzophenone: Administered topically and in dosed feed to F344/N Rats and B6C3F_1_ mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 1992. https://ntp.niehs.nih.gov/ntp/htdocs/st_rpts/tox021.pdf
34 Okereke CS Barat SA Abdel-Rahman MS Safety evaluation of benzophenone-3 after dermal administration in rats. Toxicol Lett. 1995;80(1-3):61–67. 10.1016/0378-4274(95)03334-H 7482593
35 Kunz PY Fent K Multiple hormonal activities of UV filters and comparison of in vivo and in vitro estrogenic activity of ethyl-4-aminobenzoate in fish. Aquat Toxicol. 2006;79(4):305–324. 10.1016/j.aquatox.2006.06.016 16911836
36 Miller D Wheals BB Beresford N Sumpter JP Estrogenic activity of phenolic additives determined by an in vitro yeast bioassay. Environ Health Perspect. 2001;109(2):133–138. 10.1289/ehp.109-1240632 11266322
37 Schreurs RH Sonneveld E Jansen JH Seinen W van der Burg B Interaction of polycyclic musks and UV filters with the estrogen receptor (ER), androgen receptor (AR), and progesterone receptor (PR) in reporter gene bioassays. Toxicol Sci. 2004;83(2):264–272. 10.1093/toxsci/kfi035 15537743
38 Suzuki T Kitamura S Khota R Sugihara K Fujimoto N Ohta S Estrogenic and antiandrogenic activities of 17 benzophenone derivatives used as UV stabilizers and sunscreens. Toxicol Appl Pharmacol. 2005;203(1):9–17. 10.1016/j.taap.2004.07.005 15694459
39 Schreurs R Lanser P Seinen W van der Burg B Estrogenic activity of UV filters determined by an in vitro reporter gene assay and an in vivo transgenic zebrafish assay. Arch Toxicol. 2002;76(5-6):257–261. 10.1007/s00204-002-0348-4 12107642
40 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines-OPPTS 890.1250: Estrogen receptor binding assay using rat uterine cytosol (ER-RUC) [EPA 740-C-09-005]. EPA Docket ID: EPA-HQ-OPPT-2009-0576-0005. 2009. https://www.regulations.gov/document?D=EPA-HQ-OPPT-2009-0576-0005
41 U.S. Environmental Protection Agency (USEPA). Endocrine distruptor screening program test guidelines-OPPTS 890.1300: Estrogen receptor transcriptional activation (human cell line (HeLa-9903)) [EPA 740-C-09-006]. EPA Docket ID: EPA-HQ-OPPT-2009-0576-0006. 2009. https://www.regulations.gov/document?D=EPA-HQ-OPPT-2009-0576-0006
42 Schlumpf M Cotton B Conscience M Haller V Steinmann B Lichtensteiger W In vitro and in vivo estrogenicity of UV screens. Environ Health Perspect. 2001;109(3):239–244. 10.1289/ehp.01109239 11333184
43 Coronado M De Haro H Deng X Rempel MA Lavado R Schlenk D Estrogenic activity and reproductive effects of the UV-filter oxybenzone (2-hydroxy-4-methoxyphenyl-methanone) in fish. Aquat Toxicol. 2008;90(3):182–187. 10.1016/j.aquatox.2008.08.018 18930325
44 Kim S Jung D Kho Y Choi K Effects of benzophenone-3 exposure on endocrine disruption and reproduction of Japanese medaka (Oryzias latipes)—A two generation exposure study. Aquat Toxicol. 2014;155:244–252. 10.1016/j.aquatox.2014.07.004 25064457
45 National Toxicology Program (NTP). Final report on the reproductive toxicity of 2-hydroxy-4-methoxybenzophenone in CD-1 Swiss mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1990. RACB88076. https://ntp.niehs.nih.gov/testing/types/repro/abstracts/racb88076/index-63.html
46 Daston GP Gettings SD Carlton BD Chudkowski M Davis RA Kraus AL Luke CF Oellette RE Re TA Hoberman AM Assessment of the reproductive toxic potential of dermally applied 2-hydroxy-4-methoxybenzophenone to male B6C3F1 mice. Toxicol Sci. 1993;20(1):120–124. 10.1093/toxsci/20.1.120 8432422
47 Wolff MS Engel SM Berkowitz GS Ye X Silva MJ Zhu C Wetmur J Calafat AM Prenatal phenol and phthalate exposures and birth outcomes. Environ Health Perspect. 2008;116(8):1092–1097. 10.1289/ehp.11007 18709157
48 Philippat C Mortamais M Chevrier C Petit C Calafat AM Ye X Silva MJ Brambilla C Pin I Charles M-A Exposure to phthalates and phenols during pregnancy and offspring size at birth. Environ Health Perspect. 2011;120(3):464–470. 10.1289/ehp.1103634 21900077
49 U.S. National Library of Medicine (NLM) Hirschsprung disease. 2020. https://ghr.nlm.nih.gov/condition/hirschsprung-disease#statistics
50 Huo W Cai P Chen M Li H Tang J Xu C Zhu D Tang W Xia Y The relationship between prenatal exposure to BP-3 and Hirschsprung’s disease. Chemosphere. 2016;144:1091–1097. 10.1016/j.chemosphere.2015.09.019 26454118
51 Dinardo JC Downs CA Can oxybenzone cause Hirschsprung’s disease? Reprod Toxicol. 2019;•••. 10.1016/j.reprotox.2019.02.014 30831214
52 European Chemical Agency (ECHA). Entry for: Oxybenzone (CAS No. 131-57-7). 2017. https://echa.europa.eu/registration-dossier/-/registered-dossier/5515/7/5/1
53 Trevisi P Vincenzi C Chieregato C Guerra L Tosti A Sunscreen sensitization: A three-year study. Dermatology. 1994;189(1):55–57. 10.1159/000246784 8003788
54 Agin PP Ruble K Hermansky SJ McCarthy TJ Rates of allergic sensitization and irritation to oxybenzone‐containing sunscreen products: a quantitative meta‐analysis of 64 exaggerated use studies. Photodermatol Photoimmunol Photomed. 2008;24(4):211–217. 10.1111/j.1600-0781.2008.00363.x 18717962
55 Bernard F Barrault C Deguercy A De Wever B Rosdy M Development of a highly sensitive in vitro phototoxicity assay using the SkinEthicTM reconstructed human epidermis. Cell Biol Toxicol. 2000;16(6):391–400. 10.1023/A:1007604612003 11254165
56 Jonsen J Jacobsen N Hensten-Pettersen A Bacterial muragenesis (Ames Test) as a screening method for carcinogenic substances of dental materials. In: Winter GD Leroy JL De Groot Keditors. Evaluation of Biomaterials. London, UK: John Wiley & Sons, Ltd; 1980. p. 333–339.
57 Morita K Ishigaki M Abe T Mutagenicity of materials related with cosmetics. J Soc Cosmet Chem Jpn. 1981;15(3):243–253. 10.5107/sccj.15.3_243
58 Bonin A Arlauskas A Angus D Baker R Gallagher C Greenoak G Brown ML Meher-Homji K Reeve V UV-absorbing and other sun-protecting substances: genotoxicity of 2-ethylhexyl P-methoxycinnamate. Mutat Res Lett. 1982;105(5):303–308. 10.1016/0165-7992(82)90097-5 6815524
59 Mortelmans K, Haworth S, Lawlor T, Speck W, Tainer B, Zeiger E. Salmonella mutagenicity tests: II. Results from the testing of 270 chemicals. Environ Mutagen. 1986; 8(S7 S7):56-119.
60 Dunkel VC Zeiger E Brusick D McCoy E McGregor D Mortelmans K Rosenkranz HS Simmon VF Reproducibility of microbial mutagenicity assays: II. Testing of carcinogens and noncarcinogens in Salmonella typhimurium and Escherichia coli. Environ Mutagen. 1985;7 S5:1–19. 10.1002/em.2860070902 3905369
61 Mitchell AD Rudd CJ Caspary WJ Evaluation of the L5178Y mouse lymphoma cell mutagenesis assay: intralaboratory results for sixty‐three coded chemicals tested at SRI International. Environ Mutagen. 1988;12 S13:37–101. 10.1002/em.2860120504 3416841
62 Myhr BC Caspary WJ Evaluation of the L5178Y mouse lymphoma cell mutagenesis assay: intralaboratory results for sixty‐three coded chemicals tested at Litton Bionetics, Inc. Environ Mutagen. 1988;12 S13:103–194. 10.1002/em.2860120505 3416838
63 National Cancer Institute (NCI). Bioassay of Michler’s ketone for possible carcinogenicity. CAS No. 90-94-8. Bethesda, MD: U.S. Department of Health, Education, and Welfare, Public Health Services, National Institutes of Health; 1979. NCI-CG-TR-181. NIH Publication No. 79-1737.
64 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992;19 S21:2–141. 10.1002/em.2850190603 1541260
65 Robison SH Odio MR Thompson ED Aardema MJ Kraus AL Assessment of the in vivo genotoxicity of 2‐hydroxy 4‐methoxybenzophenone. Environ Mol Mutagen. 1994;23(4):312–317. 10.1002/em.2850230409 8013479
66 Sadtler Scholl Polymer Processing Chemicals Library. HS No. 5801. Hercules, CA. Bio-Rad Laboratories; [date unknown].
67 National Institute of Advanced Industrial Science and Technology (NIAIST). Spectral Database for Organic Compunds (SDOC): Spectrum No. 5800. Tokyo, Japan; 1999. https://sdbs.db.aist.go.jp/sdbs/cgi-bin/direct_frame_top.cgi
68 Maronpot R Boorman G Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
69 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
70 Brix AE Hardisty JF McConnell EE Combining neoplasms for evaluation of rodent carcinogenesis studies. In: Hsu C-H Stedeford Teditors. Cancer Risk Assessment. Hoboken (NJ): John Wiley & Sons, Inc.; 2010. p. 699–715. 10.1002/9780470622728.ch28
71 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53(282):457–481. 10.1080/01621459.1958.10501452
72 Tarone RE Tests for trend in life table analysis. Biometrika. 1975;62(3):679–690. 10.1093/biomet/62.3.679
73 Cox DR Regression models and life‐tables. J R Stat Soc [Ser A]. 1972;34(2):187–202.
74 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;•••:417–431. 10.2307/2531856 3390507
75 Piegorsch WW, Bailer AJ. Statistics for Environmental Biology and Toxicology, Section 6.3.2. London, UK: Chapman and Hall; 1997.
76 Portier C Bailer A Testing for increased carcinogenicity using a survival-adjusted quantal response test. Toxicol Sci. 1989;12(4):731–737. 10.1093/toxsci/12.4.731 2744275
77 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986;46(9):4372–4378. 3731095
78 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;•••:793–801. 10.2307/2532200 8241374
79 Nam J-M A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987;•••:701–705. 10.2307/2532006 3663825
80 Rao J Scott A A simple method for the analysis of clustered binary data. Biometrics. 1992;•••:577–585. 10.2307/2532311 1637980
81 Fung K Krewski D Rao J Scott A Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994;14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
82 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
83 Dixon WJ Massey FJ Jr Introduction to statistical analysis. 2nd ed. New York (NY): McGraw-Hill Book Company; 1957. p. 276–278, 412.
84 Tukey JW Easy summaries – numerical and graphical. Reading (MA): Addison-Wesley; 1977.
85 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. 10.1080/01621459.1955.10501294
86 Williams D A test for differences between treatment means when several dose levels are compared with a zero-dose control. Biometrics. 1971;27:103–117. 10.2307/2528930 5547548
87 Williams D The comparison of several dose levels with a zero dose control. Biometrics. 1972;•••:519–531. 10.2307/2556164 5037867
88 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
89 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;•••:183–186. 10.2307/2531254 3719054
90 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252. 10.1080/00401706.1964.10490181
91 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1/2):133–145. 10.2307/2333011
92 Hsu JC The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992;1(2):151–168.
93 Haseman J Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992;26(2):191–200. 10.1177/009286159202600210
94 Haseman JK Data analysis: statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995;21(1):52–59. 10.1006/rtph.1995.1009 7784636
95 Haseman JK Rao GN Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992;20(1):52–60. 10.1177/019262339202000107 1411131
96 Code of Federal Regulations (CFR). 21:Part 58.
97 Miller JA Miller EC Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH Watson JD Winsten JAeditors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
98 Crawford BD Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA Flamm WG Lorentzen RJeditors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co. Inc; 1985. p. 13–59.
99 Straus DS Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67:233–241. 7021938
100 Ashby J Tennant RW Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the US NTP. Mutat Res. 1991;257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
101 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987;236(4804):933–941. 10.1126/science.3554512 3554512
102 Zeiger E Haseman JK Shelby MD Margolin BH Tennant RW Holden H Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990;16 S18:1–14. 10.1002/em.2850160502 2091921
103 Leininger JR Jokinen MP Oviduct, uterus, and vagina. In: Boorman GA Eustis SL Elwell MR Montgomery CA Jr MacKenzie WFeditors. Pathology of the Fischer Rat: Reference and Atlas. San Diego (CA): Academic Press Inc; 1990. p. 443–459.
104 Creasy D, Bube A, Rijk Ed, Kandori H, Kuwahara M, Masson R, Nolte T, Reams R, Regan K, Rehm S et al. Proliferative and Nonproliferative Lesions of the Rat and Mouse Male Reproductive System. Toxicol Pathol. 2012; 40(6_suppl):40S-121S. 10.1177/0192623312454337
105 Jokinen MP Walker NJ Brix AE Sells DM Haseman JK Nyska A Increase in cardiovascular pathology in female Sprague-Dawley rats following chronic treatment with 2, 3, 7, 8-tetrachlorodibenzo-p-dioxin and 3, 3′, 4, 4′, 5-pentachlorobiphenyl. Cardiovasc Toxicol. 2003;3(4):299. 10.1385/CT:3:4:299 14734827
106 Centers for Disease Control and Prevention (CDC). Fourth national report on human exposure to environmental chemicals: Updated tables, January 2019, volume one. Atlanta, GA: U.S. Department of Health and Human Services, National Center for Environmental Health; 2019. https://www.cdc.gov/exposurereport/pdf/FourthReport_UpdatedTables_Volume1_Jan2019-508.pdf
107 National Toxicology Program (NTP). Abstract for RACB88076: 2-hydroxy-4-methoxybenzophenone: Reproductive toxicity in CD-1 Swiss mice; dose 1.25, 2.5 & 5% in feed. Research Triangle Park: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 1990. NTIS# PB91158477.
108 Reagan-Shaw S Nihal M Ahmad N Dose translation from animal to human studies revisited. FASEB J. 2008;22(3):659–661. 10.1096/fj.07-9574LSF 17942826
109 Janjua NR Mogensen B Andersson AM Petersen JH Henriksen M Skakkebaek NE Wulf HC Systemic absorption of the sunscreens benzophenone-3, octyl-methoxycinnamate, and 3-(4-methyl-benzylidene) camphor after whole-body topical application and reproductive hormone levels in humans. J Invest Dermatol. 2004;123(1):57–61. 10.1111/j.0022-202X.2004.22725.x 15191542
110 Matta MK Zusterzeel R Pilli NR Patel V Volpe DA Florian J Oh L Bashaw E Zineh I Sanabria C Effect of sunscreen application under maximal use conditions on plasma concentration of sunscreen active ingredients. A randomized clinical trial. JAMA. 2019;321(21):2082–2091. 10.1001/jama.2019.5586 31058986
111 National Toxicology Program (NTP). DART-05: 2-Hydroxy-4-methoxybenzophenone: Growth and clinical finding tables (I), pathology tables (PA), developmental and reproductive tables (R) from NTP modified one generation dose range finding study and modified one generation main study studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2019. https://tools.niehs.nih.gov/cebs3/views/?action=main.dataReview&bin_id=14485
112 National Toxicology Program (NTP). NTP techical report on the toxicology and carcinogenesis studies of furosemide (CAS No. 54-31-9) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: National Toxicology Program, U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1989. NTP TR 356. https://ntp.niehs.nih.gov/publications/reports/tr/300s/tr356/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr356abs
113 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis study of ethinyl estradiol (CAS No. 57-63-6) in Sprague-Dawley rats (feed study). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2010. Toxicity Report 548. NIH Publication No. 10-5889. https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr548.pdf
114 Haseman JK Young E Eustis SL Hailey JR Body weight-tumor incidence correlations in long-term rodent carcinogenicity studies. Toxicol Pathol. 1997;25(3):256–263. 10.1177/019262339702500302 9210256
115 Ward J Mann P Morishima H Frith C Thymus, spleen, and lymph nodes. In: Maronpot Reditor. Pathology of the Mouse. Vienna (IL): Cache River Press; 1999. p. 333–360.
116 Seely J, Brix A. Kidney, renal tubule – Cytoplasmic alteration In: Cesta M, Herbert R, Brix A, Malarkey D, Sills R, editors. National Toxicology Program Nonneoplastic Lesion Atlas. Research Triangle Park, NC: National Toxicology Program; 2019. p.
117 Wilson CL Miller CJ Simpleaffy: A BioConductor package for Affymetrix Quality Control and data analysis. Bioinformatics. 2005;21(18):3683–3685. 10.1093/bioinformatics/bti605 16076888
118 Irizarry RA Bolstad BM Collin F Cope LM Hobbs B Speed TP Summaries of Affymetrix GeneChip probe level data. Nucleic Acids Res. 2003;31(4):e15–e15. 10.1093/nar/gng015 12582260
119 Ganter B Tugendreich S Pearson CI Ayanoglu E Baumhueter S Bostian KA Brady L Browne LJ Calvin JT Day G-J Development of a large-scale chemogenomics database to improve drug candidate selection and to understand mechanisms of chemical toxicity and action. J Biotechnol. 2005;119(3):219–244. 10.1016/j.jbiotec.2005.03.022 16005536
120 Igarashi Y Nakatsu N Yamashita T Ono A Ohno Y Urushidani T Yamada H Open TG-GATEs: A large-scale toxicogenomics database. Nucleic Acids Res. 2014;43 D1:D921–D927. 10.1093/nar/gku955 25313160
121 Kupershmidt I Su QJ Grewal A Sundaresh S Halperin I Flynn J Shekar M Wang H Park J Cui W Ontology-based meta-analysis of global collections of high-throughput public data. PLoS One. 2010;5(9):e13066. 10.1371/journal.pone.0013066 20927376
122 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines-OPPTS 890.1600: Uterotrophic assay [EPA 740-C-09-0010]. EPA Docket ID: EPA-HQ-OPPT-2009-0576-0012. 2009. https://www.regulations.gov/document?D=EPA-HQ-OPPT-2009-0576-0012
123 Code of Federal Regulations (CFR). 9:1-4.
124 National Research Council (US) Committee for the Update of the Guide for the Care and Use of Laboratory Animals Guide for the care and use of laboratory animals. Washington (D.C.): National Academies Press; 2011.
125 U.S. Environmental Protection Agency (USEPA). Endocrine distuptor screening program test guidelines-OPPTS 890.1150: Androgen receptor binding (rat prostate cytosol) [EPA 640-C-09-003]. EPA Docket ID: EPA-HQ-OPPT-2009-0576-0003. 2009. https://www.regulations.gov/document?D=EPA-HQ-OPPT-2009-0576-0003
126 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines-OPPTS 890.1400: Hershberger bioassay [EPA 740-C09-008]. EPA Docket ID: EPA-HQ-OPPT-2009-0576-0008. 2009. https://www.regulations.gov/document?D=EPA-HQ-OPPT-2009-0576-0008
127 Organisation for Economic Cooperation and Development (OECD). OECD guideline for the testing of chemicals: Hershberger bioassay in rats: A short-term screening assay for (anti)androgenic properties Paris, France: OECD; 2009. OECD Guideline 441. https://ntp.niehs.nih.gov/iccvam/suppdocs/feddocs/oecd/oecd-tg441.pdf
128 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines-OPPTS 890.1200: Aromatase (human recombinant) [EPA 740-C-09-004]. EPA Docket ID: EPA-HQ-OPPT-2009-0576-0004. 2009. https://www.regulations.gov/document?D=EPA-HQ-OPPT-2009-0576-0004