# Conclusions

Under the conditions of these 2-year studies, there was equivocal evidence of carcinogenic activity^c^ of 2H4MBP exposure in male Hsd:Sprague Dawley^®^ SD^®^ rats based on the occurrence of malignant meningiomas in the brain. There was equivocal evidence of carcinogenic activity in female Hsd:Sprague Dawley^®^ SD^®^ rats based on the increased incidence of thyroid C-cell adenomas and the increased incidence of uterine stromal polyps. There was no evidence of carcinogenic activity in male or female B6C3F1/N mice at exposure concentrations of 1,000, 3,000, and 10,000 ppm.

c See [underlined: Explanation of Levels of Evidence of Carcinogenic Activity].

Increases in the incidences of nonneoplastic lesions of the testis in male rats and of the uterus and adrenal cortex in female rats occurred with exposure to 2H4MBP. Increases in the incidences of nonneoplastic lesions of the bone marrow (males and females), spleen (males and females), kidney (males and females), and liver (males) in mice occurred with exposure to 2H4MBP.