# Discussion

These National Toxicology Program (NTP) dietary studies evaluated the toxic and carcinogenic potential of 2H4MBP. Two-year studies in Hsd:Sprague Dawley^®^ SD^®^ rats, with exposure beginning in utero, and in B6C3F1/N mice were conducted at exposure concentrations of 0, 1,000, 3,000, and 10,000 ppm 2H4MBP in feed. The initiation of F_1_ generation exposure on GD 6 (after expected implantation) in the 2-year rat study was selected to reflect potential human exposure to 2H4MBP, often present in sunscreens and cosmetics, which can occur at all human life stages, including in utero and early life.^106^ Information from previous NTP studies^32;^ ^107^ was used to aid in selection of exposure concentrations for the 2-year study. An interim evaluation at 14 weeks on a subset of rats in the control and 10,000 ppm exposure groups was conducted to confirm expected responses. The oral route of administration was selected on the basis of NTP studies that used radiolabeled 2H4MBP and that demonstrated disposition is similar between oral and dermal administration.^15;^ ^22^ Moreover, given the pragmatic challenges of topical application in young small rodents, which requires the shaving of fur, and inter- and intra-animal grooming, exposure via dietary feed was selected.

Postweaning dietary 2H4MBP was well tolerated in rats and did not adversely affect survival. Consumption of 2H4MBP in the 1,000, 3,000, and 10,000 ppm groups resulted in average daily 2H4MBP doses of approximately 58, 168, and 585 mg 2H4MBP /kg body weight for males and 60, 180, and 632 mg/kg for females. These doses translate to a range of 348 to 3,792 mg/m^2^, using a K_m_ (body weight [kg]/surface area [m^2^]) value of 6 for rats^108^ and are only 5- to 57-fold higher than those used in a repeated dermal application study (20 g/m^2^) study in postmenopausal women.^109^ NTP studies have shown previously that using plasma concentrations of 2H4MBP in rats following feed exposure of 3,000–30,000 ppm compared to humans following repeated dermal application of 20 g/m^2^ rat: human dose multiples were 0.1 to 4.^22^ Human geometric mean maximum plasma concentrations of 2H4MBP have been shown to be approximately 200 ng/mL when topically applied. This exceeds the FDA guidance of 0.5 ng/mL that would necessitate the conduct of additional nonclinical toxicity studies.^110^ Collectively, these data demonstrate similar external (5- to 57-fold) and internal (0.1- to 4-fold) exposure of 2H4MBP in rats and humans. However, the effects on body weight observed in both rats and mice precluded any higher dose levels in a chronic study.

The 14-week interim evaluation was conducted to ensure that there were no unexpected strain differences in response to 2H4MBP in feed; this interim evaluation observed similar magnitude of 2H4MBP-induced effects on female body weight in Sprague Dawley rats exposed to 10,000 ppm 2H4MBP compared to that observed in female F344/N rats exposed to 12,500 ppm 2H4MBP in the diet (12% versus 11%, respectively).^32^ F334/N male rat body weights were not affected at 12,500 ppm 2H4MBP, consistent with what was observed in Sprague Dawley males in the current study (Appendix H).^32^ The observed increases in absolute and relative kidney weights in male Sprague Dawley rats and decrease in absolute kidney weight in female Sprague Dawley rats exposed to 10,000 ppm 2H4MBP were not observed in the F344/N rats exposed to 12,500 ppm 2H4MBP (Appendix H).^32^ However, increases in absolute and relative kidney weights were observed in male F344/N rats exposed to 50,000 ppm 2H4MBP, and females exposed to 25,000 or 50,000 ppm 2H4MBP in feed.^32^ The absence of histopathological findings in the kidneys of Sprague Dawley rats at the interim evaluation is also consistent with what was previously observed at 12,500 ppm in F344/N male and female rats (Appendix H).^32^ The observed increase (~20%) in absolute and relative male Sprague Dawley rat liver weights is fairly consistent with what was previously observed in male F344/N rats (26% and 31%, respectively) exposed to 12,500 ppm (Appendix H).^32^ The increase in relative liver weight was comparable to that observed in the female F334/N rats exposed to 12,500 ppm (Appendix H).^32^ In general, 2H4MBP-induced responses in the Sprague Dawley rats were consistent with those observed previously in the F344/N rats.

At the 14-week interim evaluation in rats, the observed increase in liver weight in males exposed to 10,000 ppm 2H4MBP occurred concomitantly with a significantly increased incidence of mixed-cell cellular infiltration. However, it is unlikely that the cellular infiltrates, which were all of minimal severity, would be responsible for the changes in the liver weights observed in male rats at this time point. 2H4MBP exposure has been shown to increase hepatic Cyp1a1 and Cyp4a expression the magnitude of which is consistent with enzyme induction and moderate increase in tissue weight. In the NTP Modified One-Generation (MOG) ^111^ study, focal inflammation was observed in all F_1_ male exposure groups in the reproductive performance cohort (~8–25%), including the control group (7%), with the low exposure group of 3,000 ppm displaying the highest incidence (10/40). The incidence in F_1_ females was 5% at 30,000 ppm, the only 2H4MBP exposure group examined.

The absence of appreciable alterations in the kidneys after 14 weeks of 2H4MBP exposure was somewhat unexpected given the previous reports of 2H4MBP-induced kidney histopathology in male F344/N rats at exposure concentrations ≥12,500 ppm in the diet.^32^ This could be a function of dose, given that in the NTP MOG study, a dietary concentration of 10,000 ppm—the highest concentration used in the current study—did not result in apparent 2H4MBP-related adverse histopathological kidney findings following a similar duration of exposure. However, rats exposed to 30,000 ppm in the MOG study did display 2H4MBP-related kidney findings in renal tubules and pelvises (concretions, epithelial degeneration, and dilatation).

In the 2-year study, the incidences of malignant meningiomas in the brain in male rats were higher in the 1,000 and 3,000 ppm groups (1/50 [1/25 litters]; 3/50 [2/25 litters]) than in the control group (0/50 [0/29 litters]) or in the 10,000 ppm group (0/50 [0/28 litters]). In addition, one malignant meningioma was diagnosed in the spinal cord of a male rat in the 3,000 ppm group. Spinal cords were only examined from animals displaying clinical neurologic signs, however, so it is possible that the true incidence of spinal cord neoplasms was underreported. Although not dose responsive, these incidences of malignant meningiomas exceeded previous historical control incidences (none was observed in the control groups from six previously conducted studies) and therefore was considered equivocal evidence of carcinogenic activity. This conclusion is consistent with conclusions summarized in a previous NTP technical report (TR 356 – Toxicology and Carcinogenesis Studies of Furosemide) that found three meningiomas, all in male rats from the low-dose group, and this was considered equivocal evidence of carcinogenic activity.^112^

Although the malignant meningiomas observed in the brain in this study lacked features resembling granular cells tumors sometimes seen in benign meningiomas, the possibility that some meningiomas and granular cell tumors share a common progenitor is noteworthy. However, whereas benign granular cell tumors have been recorded in the historical controls for this study, malignant meningiomas have not. Therefore, although it may be beneficial to consider the combination of granular cell tumors and meningiomas, it is also necessary to consider malignant meningiomas on their own for the interpretation of the data in this study.

The incidences of thyroid gland C-cell adenoma in all groups of female rats exposed to dietary 2H4MBP for 2 years were higher than that in the control group, but the occurrences were not related to exposure concentration, and the higher incidence was only statistically significant at 3,000 ppm: 5/50 (5/29 litters) in the control group; 11/50 (10/25 litters); 17/50 (15/25 litters); and 10/50 (9/29 litters) in the 1,000, 3,000, and 10,000 ppm groups, respectively. This incidence exceeded the historical control incidence of recent NTP studies (38/339; range: 4% to 22%).

Along with the lack of a dose response, there were no increases in the incidences of thyroid gland C-cell hyperplasia or C-cell carcinomas when compared to the control group, nor was there any support from the males concerning proliferative lesions of the C-cells. Therefore, it was considered that thyroid gland C-cell adenomas in female rats may have been related to 2H4MBP exposure.

Female rats exposed to all dietary concentrations of 2H4MBP for 2 years had increased incidences of uterine stromal polyps (15/50 [12/25 litters]; 18/50 [16/25 litters]; 10/50 [10/29 litters]) relative to the control group (8/50 [8/29 litters]); the 3,000 ppm group was the only group that displayed a statistically significant difference from the control group. While stromal sarcomas only occurred in 2H4MBP exposed groups and not in the control group, the numbers of stromal sarcomas were not significantly different between the control group and any of the exposed groups; hence, it was considered that the increased incidences of uterine stromal polyps may have been related to 2H4MBP exposure.

The 3,000 ppm females also had a significantly higher incidence of atypical endometrial hyperplasia relative to the control group, which is considered a preneoplastic lesion of the uterine epithelium. However, that exposure group had a significantly lower incidence of uterine adenocarcinomas. These findings are inconsistent with the purported 2H4MBP estrogenic activity given that ultra-low doses (2–50 parts per billion [ppb]) of ethinyl estradiol have shown to be associated with increased incidences of both atypical uterine focal hyperplasia (6/51, 14/50, 16/49, 20/50) and squamous metaplasia (2/51, 6/50, 8/49, 13/50) in female Sprague Dawley rats.^113^

In the 2-year rat study, the incidence of mammary gland fibroadenoma in the female 10,000 ppm group (18/50 [18/29 litters]) was significantly lower than the control incidence (32/50 [23/29 litters]). Similarly, the 10,000 ppm group displayed a lower incidence of mammary gland carcinoma (1/50 [1/29 litters]) than did the control group (7/50 [6/29 litters]). The concurrent control incidence of fibroadenomas is higher than recent historical control incidences (195/340; range: 40% to 70%). The incidence of mammary gland carcinomas in the concurrent control is also higher than recent historical control incidences (30/340; range: 4% to 14%). The 10,000 ppm females had a mean body weight at terminal sacrifice that was 76% of the control group, and this lower body weight might have contributed to the lower incidences of mammary gland carcinomas and fibroadenomas in this group.^114^ These 2H4MBP findings are also inconsistent with the purported 2H4MBP estrogenic activity. Exposure to ultra-low dose (2–50 ppb) ethinyl estradiol has been reported to be associated with an increased incidence of mammary alveolar or ductal hyperplasia in male Sprague Dawley rats (1/44, 4/45, 8/47, 21/44).^113^ No changes in the incidences of mammary gland lesions were observed in males exposed to 2H4MBP.

At the end of the 2-year study, the incidences of focal hypertrophy within the adrenal cortex were significantly higher in females exposed to 1,000 (42/50) or 3,000 ppm (39/50) 2H4MBP relative to the control group (24/50). These findings were not associated with an increased incidence of adrenocortical neoplasia.

In male rats, there was an increase in the incidence of interstitial cell hyperplasia of the testes in the 10,000 ppm group, but the increase was not statistically different from controls with a pairwise comparison. No interstitial cell adenomas were observed in male rats of any group in the study.

The 2-year study was conducted in B6C3F1/N mice at dietary exposure concentrations of 0, 1,000, 3,000, and 10,000 ppm, which resulted in average daily doses of approximately 113, 339, and 1,207 mg 2H4MBP/kg body weight for males and 109, 320, and 1,278 mg/kg for females. 2H4MBP exposure did not affect survival of either sex. After several months of 2H4MBP exposure, both males and females in the 10,000 ppm groups displayed lower body weights (>10%). No 2H4MBP-related increases in the incidences of neoplastic lesions were observed in the 2-year study.

Increased incidences of bone marrow pigment (hemosiderin) were observed in both male and female mice exposed to 10,000 ppm 2H4MBP for 2 years. The incidences of pigment in the spleen were higher in males and females exposed to 3,000 and 10,000 ppm 2H4MBP. Increased levels of hemosiderin in the spleen of mice can be associated with increased erythrocyte turnover.^115^ In the current study there was no other evidence of an increase in the turnover of erythrocytes, such as changes in the cellularity of the bone marrow, or increased extramedullary hematopoiesis in the spleen. Additionally, there were no changes in hematology parameters or bone marrow histology in a 13-week dosed feed 2H4MBP mouse study.^32^

The incidences of hepatocyte syncytial alteration were significantly increased in all 2H4MBP-exposed groups of male mice. Ethylbenzene induced a similar response in the male mouse,^32^ and these compounds share some structural similarities.^32^ As with 2H4MBP no association was found between the syncytial cells and hepatocellular neoplasia in male mice in the ethylbenzene study, although there were increased incidences of hepatocellular tumors in female mice.

2H4MBP dietary exposure in male mice was associated with an increased incidence of renal tubule cytoplasmic alteration at 10,000 ppm. Vacuolation of the renal tubules, typically in the outer cortex, is a normal background finding in male mice.^116^ The presence of these vacuoles is not recorded as a lesion; however, when a decrease in the vacuolation of the renal tubules is noted, it is typically recorded. In the current study, the normal background vacuolation decreased in renal tubules in the 10,000 ppm males, and this was recorded as an increased incidence of cytoplasmic alteration.