# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-597.^b^

b National Toxicology Program (NTP). TR-597: Pathology tables, survival and growth curves from NTP long-term, genetic toxicology studies. Research Triangle Park, NC. 2020. https://doi.org/10.22427/NTP-DATA-TR-597

## Rats

### Two-year Study

#### Perinatal Exposure

Gestation body weights of dams receiving 10,000 ppm 2H4MBP in the diet were slightly lower (~3%) than those of the control group and showed statistically significant differences. Dams receiving 3,000 or 10,000 ppm 2H4MBP in the diet displayed slight decreases in GD 6–21 body weight gain (~10%) relative to the control group that attained statistical significance (Table 2). Lower body weight gain over the GD 6–9 (10,000 ppm) and 18–21 (3,000 and 10,000 ppm) intervals, which was associated with slightly lower feed consumption over the GD 18–21 interval (Table 3), likely contributed to this response. These collective effects are minimal and would not be expected to affect normal development of the offspring. Dietary concentrations of 1,000, 3,000, and 10,000 ppm 2H4MBP resulted in average daily doses of approximately 70, 206, and 660 mg 2H4MBP/kg body weight/day during gestation, and 157, 478, and 1,609 mg/kg/day over lactation days (LD) 1–14 (Appendix H).

Table 2 Mean Body Weights and Body Weight Changes of F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation and Lactation

Parameter^a^ | 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Gestation Day
6 | 231.4 ± 1.9 [40] | 231.1 ± 2.5 [34] | 232.1 ± 1.5 [32] | 231.7 ± 2.3 [36]
9 | 246.3 ± 2.4* [40] | 248.6 ± 1.9 [34] | 246.0 ± 1.4 [32] | 239.7 ± 1.8* [36]
12 | 262.5 ± 1.6* [40] | 263.2 ± 1.9 [34] | 260.3 ± 1.6 [32] | 258.8 ± 1.8 [36]
15 | 281.3 ± 1.7* [40] | 282.1 ± 2.1 [34] | 278.2 ± 1.8 [32] | 276.4 ± 2.2 [36]
18 | 321.9 ± 1.8* [40] | 322.1 ± 2.6 [34] | 316.0 ± 2.8 [32] | 314.0 ± 2.8* [36]
21 | 366.0 ± 2.4* [40] | 364.7 ± 3.5 [34] | 353.7 ± 4.9* [32] | 353.8 ± 3.8* [36]
Gestation Weight Change
6–9 | 14.9 ± 1.7** [40] | 17.5 ± 1.3 [34] | 13.9 ± 0.7 [32] | 8.0 ± 1.3** [36]
9–12 | 16.3 ± 1.6** [40] | 14.6 ± 0.6 [34] | 14.3 ± 0.5 [32] | 19.0 ± 0.8 [36]
12–15 | 18.8 ± 0.7 [40] | 19.0 ± 0.5 [34] | 17.9 ± 0.8 [32] | 17.6 ± 0.8 [36]
15–18 | 40.6 ± 1.0* [40] | 40.0 ± 1.0 [34] | 37.8 ± 1.5 [32] | 37.6 ± 1.0 [36]
18–21 | 44.1 ± 1.1* [40] | 42.6 ± 1.4 [34] | 37.6 ± 2.6* [32] | 39.9 ± 1.4 [36]
6–21 | 134.6 ± 2.4** [40] | 133.6 ± 2.9 [34] | 121.6 ± 4.4** [32] | 122.1 ± 3.2** [36]
Lactation Day
1 | 276.3 ± 1.6** [40] | 274.1 ± 2.1 [34] | 269.0 ± 2.3* [32] | 264.5 ± 2.2** [36]
4 | 289.7 ± 1.8** [40] | 287.8 ± 2.3 [34] | 279.8 ± 2.6** [32] | 274.1 ± 2.2** [36]
7 | 295.9 ± 1.8 [35] | 295.4 ± 2.5 [30] | 289.2 ± 3.6 [27] | 285.6 ± 2.5** [33]
14 | 312.9 ± 2.1* [35] | 312.7 ± 2.7 [30] | 306.9 ± 3.0 [27] | 304.2 ± 3.0* [33]
21 | 304.8 ± 2.3* [35] | 300.6 ± 2.6 [30] | 295.4 ± 2.4* [27] | 298.8 ± 2.7 [33]
Lactation Weight Change
1–4 | 13.4 ± 1.2* [40] | 13.7 ± 1.1 [34] | 10.8 ± 2.0 [32] | 9.6 ± 1.0 [36]
4–7 | 7.5 ± 1.2 [35] | 6.3 ± 1.3 [30] | 8.6 ± 1.5 [27] | 10.3 ± 1.0 [33]
7–14 | 17.0 ± 1.4 [35] | 17.3 ± 1.7 [30] | 17.7 ± 2.5 [27] | 18.6 ± 1.6 [33]
14–21 | −8.1 ± 1.5 [35] | −12.0 ± 1.7 [30] | −11.6 ± 2.1 [27] | −5.4 ± 2.1 [33]
4–21 | 16.4 ± 1.7* [35] | 11.6 ± 1.5 [30] | 14.7 ± 2.3 [27] | 23.5 ± 1.9* [33]

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Each dietary concentration was compared to the control with Williams’ test when a trend was present (p ≤ 0.01 from Jonckheere’s trend test) or with Dunnett’s test when no trend was present. Body weight data are presented in grams.

Table 3 Feed Consumption of F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation and Lactation

Parameter^a^ | 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Gestation Day
6–9 | 17.7 ± 0.5** [41] | 17.9 ± 0.2 [34] | 17.2 ± 0.3* [33] | 13.3 ± 0.4** [36]
9–12 | 18.2 ± 0.2 [41] | 18.6 ± 0.3 [34] | 18.3 ± 0.3 [33] | 19.0 ± 0.3 [36]
12–15 | 18.6 ± 0.2 [41] | 18.6 ± 0.2 [34] | 18.2 ± 0.3 [33] | 18.5 ± 0.2 [36]
15–18 | 21.1 ± 0.2* [41] | 21.3 ± 0.2 [34] | 21.0 ± 0.3 [33] | 20.2 ± 0.3 [36]
18–21 | 21.4 ± 0.2** [41] | 21.3 ± 0.2 [34] | 20.2 ± 0.5* [33] | 19.9 ± 0.3** [36]
6–21 | 19.4 ± 0.2** [41] | 19.6 ± 0.2 [34] | 19.0 ± 0.3 [33] | 18.2 ± 0.2** [36]
Lactation Day
0–4 | 35.2 ± 0.6 [40] | 35.0 ± 0.7 [34] | 33.7 ± 1.3 [32] | 37.4 ± 1.5 [35]
4–7 | 41.6 ± 0.6 [35] | 41.4 ± 0.4 [30] | 41.8 ± 1.0 [27] | 41.3 ± 0.7 [33]
7–10 | 49.6 ± 0.8 [35] | 48.4 ± 0.6 [30] | 48.5 ± 1.2 [27] | 47.9 ± 1.1 [33]
10–14 | 58.2 ± 0.8 [34] | 58.4 ± 0.6 [30] | 57.0 ± 1.1 [27] | 55.6 ± 1.1 [33]
14–17 | 61.4 ± 1.1 [35] | 62.6 ± 0.6 [30] | 62.8 ± 0.7 [27] | 59.7 ± 1.5 [33]
17–21 | 69.6 ± 1.1 [35] | 69.4 ± 1.3 [30] | 70.7 ± 1.0 [27] | 69.7 ± 1.4 [33]
1–14 | 47.1 ± 0.5 [34] | 46.9 ± 0.4 [30] | 46.5 ± 0.8 [27] | 46.5 ± 0.7 [32]

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Each dietary concentration was compared to the control group with Shirley’s test when a trend was present or with Dunn’s test when no trend was present. Feed consumption data are presented as g/animal/day.

Administration of 2H4MBP had no effects on the percentage of mated females producing pups, litter size, pup sex distribution, or numbers of male or female pups (Table 4; Table 5). The apparent decrease in the percentage of females pregnant in the 10,000 ppm group can be attributed to the seven animals that had no evidence of pregnancy as shown by the absence of implantation sites. Therefore, the lower pregnancy rate was not exposure-related given that exposure began after implantation. Dams receiving 2H4MBP did not display any adverse clinical findings before or after parturition. Litter size of the 10,000 ppm 2H4MBP group was slightly lower on PNDs 7 and 10 (Table 5).

Table 4 Summary of the Disposition of Rats during Perinatal Exposure and F_1_ Allocation in the Two-year Perinatal and Postnatal Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Reproductive Performance
Time-mated Females (GD 6) | 42 | 35 | 35 | 43
Females Pregnant (%)^a^ | 41 (98%)** | 34 (97%) | 33 (94%) | 36 (84%)
Females Not Pregnant (%) | 1 (2%) | 1 (3%) | 2 (6%) | 7 (16%)
Dams Not Delivering with Evidence of Pregnancy (%) | _1_b | 0 | _1_c | 0
Dams with Litters on PND 0 (%) | 40 (98%) | 34 (100%) | 32 (97%) | 36 (100%)
Litters Poststandardization (PND 4)^d^ | 35 | 30 | 27 | 33
Postweaning Allocation
F_1_ Males – Chronic (Litters)^e^ | 50 (30) | 50 (25) | 50 (25) | 50 (30)
F_1_ Males – Interim (Litters)^f^ | 10 (9) | – | – | 10 (8)
F_1_ Females – Chronic (Litters)^e^ | 50 (30) | 50 (25) | 50 (25) | 50 (30)
F_1_ Females – Interim (Litters)^f^ | 10 (9) | – | – | 10 (9)

Statistical significance for the control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

GD = gestation day; PND = postnatal day.

^a^ Statistical analysis performed by Cochran-Armitage (trend) and Fisher Exact (pairwise) tests.

^b^ Found dead on GD 23 (no adverse clinical signs) with a single fetus and no other apparent resorption sites.

^c^ Undelivered (2 implantations/0 resorptions).

^d^ Standardization to eight pups per litter (four pups/sex).

^e^ Total number of F_1_ rats included in the 105-week evaluation (number of litters from which they originated).

^f^ Number of F1 rats euthanized at the 14-week interim evaluation (number of litters from which they originated).

Table 5 Mean Number of Surviving F_1_ Male and Female Rats during Lactation in the Two-year Perinatal and Postnatal Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
PND 1^a,b^
Total | 12.55 ± 0.35 [40] | 12.65 ± 0.41 [34] | 11.63 ± 0.65 [32] | 12.53 ± 0.41 [36]
Live | 12.45 ± 0.36 [40] | 12.50 ± 0.41 [34] | 11.44 ± 0.66 [32] | 12.33 ± 0.43 [36]
% Male per Litter | 51.23 ± 2.29 [40] | 50.20 ± 2.34 [34] | 45.84 ± 2.89 [32] | 51.66 ± 2.54 [36]
% Male^c,d^ | 52 [498] | 50 [425] | 47 [366] | 52 [444]
PND 4 Prestandardization | 12.43 ± 0.36 [40] | 12.41 ± 0.41 [34] | 11.38 ± 0.65 [32] | 12.25 ± 0.43 [36]
Male^a,b^
PND 1 | 6.45 ± 0.35 [40] | 6.29 ± 0.36 [34] | 5.41 ± 0.40 [32] | 6.39 ± 0.38 [36]
PND 4 Prestandardization | 6.45 ± 0.35 [40] | 6.24 ± 0.36 [34] | 5.28 ± 0.40 [32] | 6.39 ± 0.39 [36]
PND 4 Poststandardization | 4.00 ± 0.00 [35] | 4.00 ± 0.05 [30] | 3.89 ± 0.08 [27] | 4.12 ± 0.08 [33]
Female^a,b^
PND 1 | 6.00 ± 0.32 [40] | 6.21 ± 0.36 [34] | 6.03 ± 0.45 [32] | 5.94 ± 0.36 [36]
PND 4 Prestandardization | 5.98 ± 0.33 [40] | 6.18 ± 0.35 [34] | 6.09 ± 0.46 [32] | 5.86 ± 0.34 [36]
PND 4 Poststandardization | 4.00 ± 0.00 [35] | 4.00 ± 0.05 [30] | 4.11 ± 0.08 [27] | 3.88 ± 0.08 [33]
Male and Female^a,b^
PND 4 Poststandardization | 8.00 ± 0.00 [35] | 8.00 ± 0.00 [30] | 8.00 ± 0.00 [27] | 8.00 ± 0.00 [33]
PND 7 | 8.00 ± 0.00* [35] | 8.00 ± 0.00 [30] | 8.00 ± 0.00 [27] | 7.82 ± 0.13* [33]
PND 10 | 8.00 ± 0.00* [35] | 8.00 ± 0.00 [30] | 8.00 ± 0.00 [27] | 7.82 ± 0.13* [33]
PND 14 | 7.94 ± 0.04 [35] | 7.97 ± 0.03 [30] | 7.96 ± 0.04 [27] | 7.82 ± 0.13 [33]
PND 17 | 7.94 ± 0.04 [35] | 7.97 ± 0.03 [30] | 7.96 ± 0.04 [27] | 7.82 ± 0.13 [33]
PND 21 | 7.91 ± 0.05 [35] | 7.97 ± 0.03 [30] | 7.93 ± 0.07 [27] | 7.82 ± 0.13 [33]
Survival per Litter
Total Dead: PND 1–4^e^ | 5 [40] | 8 [34] | 8 [32] | 10 [36]
Total Dead: PND 5–21^e^ | 3 [35] | 1 [30] | 2 [27] | 6 [33]
Dead: PND 1–4^b,f,g^ | 0.125 ± 0.064 [40] | 0.235 ± 0.095 [34] | 0.250 ± 0.162 [32] | 0.278 ± 0.102 [36]
Dead: PND 4–21^b,f,g^ | 0.086 ± 0.048 [35] | 0.033 ± 0.033 [30] | 0.074 ± 0.074 [27] | 0.182 ± 0.127 [33]
Survival Ratio: PND 1–4^b,g,h^ | 0.998 ± 0.002 [40] | 0.993 ± 0.004 [34] | 0.996 ± 0.003 [32] | 0.994 ± 0.005 [36]
Survival Ratio: PND 4–21^b,g,i^ | 0.989 ± 0.006 [35] | 0.996 ± 0.004 [30] | 0.991 ± 0.009 [27] | 0.977 ± 0.016 [33]

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

PND = postnatal day.

^a^ Each dietary concentration was compared to the control group with Shirley’s test when a trend was present or with Dunn’s test

when no trend was present.

^b^ Mean ± standard error [number of dams].

^c^ 100 × [number of live males in dietary exposure group]/[number of live males and females in dietary exposure group].

^d^ No statistics done on this endpoint.

^e^ Total dead in dietary concentration group [number of dams].

^f^ Number dead per litter.

^g^ Each dietary concentration was compared to the control group with Shirley’s test when a trend is present (p ≤ 0.01 from Jonckheere’s trend test), otherwise Dunn’s test is applied.

^h^ Survival per litter: Number of pups prestandardization on PND 4/total live pups on PND 1.

^i^ Survival per litter: Number of live pups on PND 21/number of live pups poststandardization on PND 4.

Male, female, and combined pup body weights were not significantly different across the exposure groups on PND 1. However, on PND 4, pup body weights (male, female, and both) in the 10,000 ppm exposure groups were approximately 10% lower than those of the control groups, and this response was generally observed over subsequent preweaning weights (Table 6).

Table 6 Preweaning Pup Body Weight of Rats Following Exposure during Gestation and Lactation in the Two-year Perinatal and Postnatal Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Pup Body Weights (g)^a^
Male
PND 1^b,c,d^ | 7.32 ± 0.07 [40] | 7.38 ± 0.07 [34] | 7.22 ± 0.09 [31] | 7.11 ± 0.08 [35]
PND 4^e,f,g^ | 10.65 ± 0.12** [258/40] | 10.95 ± 0.12 [212/34] | 10.54 ± 0.13 [169/31] | 10.02 ± 0.18** [231/35]
PND 7^e,h^ | 16.66 ± 0.26* [140/35] | 16.44 ± 0.26 [120/30] | 16.29 ± 0.35 [105/27] | 15.72 ± 0.28* [135/33]
PND 14^e,h^ | 33.72 ± 0.47** [139/35] | 33.79 ± 0.38 [120/30] | 32.83 ± 0.52 [104/27] | 30.99 ± 0.40** [135/33]
PND 21^e,h^ | 53.36 ± 0.84** [136/34] | 52.85 ± 0.75 [120/30] | 52.61 ± 0.77 [104/27] | 48.47 ± 0.74** [135/33]
Female
PND 1^b,c,d^ | 6.95 ± 0.07 [40] | 7.00 ± 0.08 [34] | 6.86 ± 0.09 [32] | 6.80 ± 0.07 [36]
PND 4^e,f,g^ | 10.08 ± 0.12** [239/40] | 10.42 ± 0.12 [210/34] | 9.94 ± 0.17 [195/32] | 9.51 ± 0.17* [210/36]
PND 7^e,h^ | 15.56 ± 0.28* [140/35] | 15.58 ± 0.26 [119/30] | 15.46 ± 0.35 [111/27] | 14.73 ± 0.24 [123/33]
PND 14^e,h^ | 32.27 ± 0.41** [138/35] | 32.06 ± 0.38 [119/30] | 31.37 ± 0.51 [111/27] | 29.78 ± 0.33** [123/33]
PND 21^e,h^ | 49.49 ± 0.72** [138/35] | 49.24 ± 0.79 [119/30] | 49.17 ± 0.79 [110/27] | 45.70 ± 0.55** [123/33]
Male and Female
PND 1^b,c,d^ | 7.13 ± 0.07* [40] | 7.20 ± 0.07 [34] | 7.01 ± 0.08 [32] | 6.95 ± 0.07 [36]
PND 4^e,f,g^ | 10.36 ± 0.12** [497/40] | 10.70 ± 0.10 [422/34] | 10.16 ± 0.16 [364/32] | 9.79 ± 0.17** [441/36]
PND 7^e,h^ | 16.11 ± 0.26* [280/35] | 16.02 ± 0.25 [239/30] | 15.88 ± 0.33 [216/27] | 15.23 ± 0.26 [258/33]
PND 14^e,h^ | 32.99 ± 0.42** [277/35] | 32.94 ± 0.34 [239/30] | 32.10 ± 0.49 [215/27] | 30.40 ± 0.35** [258/33]
PND 21^e,h^ | 51.39 ± 0.73** [274/35] | 51.07 ± 0.71 [239/30] | 50.90 ± 0.70 [214/27] | 47.21 ± 0.62** [258/33]

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

PND = postnatal day.

^a^ Statistical analysis was performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^b^ Mean ± standard error [number of dams].

^c^ Each dietary concentration was compared to the control group with Williams’ test when a trend was present (p ≤ 0.01 from Jonckheere’s trend test) or with Dunnett’s test when no trend was present.

^d^ Total pup weight at PND 1 divided by number of live pups at PND 1.

^e^ Mean of dam mean ± standard error [number of pups/number of dams].

^f^ PND 4 prestandardization.

^g^ Individual pup weights first adjusted for live litter size on PND 1.

^h^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

Pups were weaned on PND 21, which was considered day 1 of the 2-year exposure period.

#### Postnatal Exposure

##### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 7 and in the Kaplan-Meier survival curves (Figure 3). Survival of all exposed groups of male and female rats was not significantly different from that of the control groups.

Table 7 Survival of Rats in the Perinatal and Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Animals Initially in Study | 60 | 50 | 50 | 60
14-week Interim Evaluation^a^ | 10 | 0 | 0 | 10
Moribund | 12 | 15 | 18 | 10
Natural Deaths | 8 | 6 | 8 | 7
Animals Surviving to Study Termination | 30^b^ | 29 | 24 | 33
Percent Probability of Survival at End of Study^c^ | 60 | 58 | 48 | 66
Mean Survival (Days)^d^ | 705 | 675 | 678 | 678
Survival Analysis^e^ | p = 0.486N | p = 0.672 | p = 0.203 | p = 0.706N
Female
Animals Initially in Study | 60 | 50 | 50 | 60
14-week Interim Evaluation^a^ | 10 | 0 | 0 | 10
Moribund | 15 | 13 | 10 | 16
Natural Deaths | 5 | 4 | 6 | 8
Animals Surviving to Study Termination | 30 | 33 | 34 | 26
Percent Probability of Survival at End of Study^c^ | 60 | 66 | 68 | 52
Mean Survival (Days)^d^ | 659 | 682 | 692 | 658
Survival Analysis^e^ | p = 0.231 | p = 0.385N | p = 0.238N | p = 0.603

^a^ Excluded from survival analysis.

^b^ Includes one animal that died during the last week of the study.

^c^ Kaplan-Meier determinations.

^d^ Mean of litter means of all deaths (uncensored, censored, and study termination).

^e^ The result of the Cox proportional hazards trend tes^t67^ is in the control column, and the results of the proportional hazards pairwise comparisons with the control groups are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

Figure 3

Kaplan-Meier Survival Curves for Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed for Two Years

### Fourteen-week Interim Evaluation

Groups of 10 male and 10 female rats were exposed to 0 or 10,000 ppm 2H4MBP for 14 weeks. At the 14-week interim evaluation, the mean body weight of the 10,000 ppm males was not significantly different from that of the control males, but the mean body weight of the 10,000 ppm females was significantly decreased and was approximately 87% that of the control group (Table 8). In males, the absolute and relative liver and right kidney weights were increased in the 10,000 ppm group compared to the control group. In females, the absolute kidney weight was significantly decreased, and the relative liver weight was significantly increased relative to the control group (Table 8).

Table 8 Select Organ Weights, Organ-Weight-to-Body-Weight Ratios, and Histological Findings in Rats at the 14-week Interim of the Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 10,000 ppm
n | 10 | 10
Male
Necropsy Body Wt. (g)^a^ | 394.6 ± 7.9 | 386.8 ± 6.8
R. Kidney^a^
Absolute (g) | 1.18 ± 0.03** | 1.37 ± 0.03**
Relative (mg/g)^b^ | 3.00 ± 0.06** | 3.54 ± 0.07**
Liver^a^
Absolute (g) | 13.94 ± 0.49** | 16.41 ± 0.46**
Relative (mg/g) | 35.25 ± 0.68** | 42.38 ± 0.75**
Histological Findings^c^
Liver^d^ | 10 | 10
Infiltration cellular, mixed cell^e^ | 2 (1.0)^f^ | 8** (1.0)
Female
Necropsy Body Wt. (g) | 261.7 ± 6.3** | 228.7 ± 4.9**
R. Kidney
Absolute (g) | 0.79 ± 0.01* | 0.71 ± 0.02**
Relative (mg/g) | 3.01 ± 0.04 | 3.09 ± 0.08
Liver
Absolute (g) | 8.77 ± 0.38 | 9.64 ± 0.28
Relative (mg/g) | 33.43 ± 0.91** | 42.15 ± 0.68**
Histological Findings
Liver | (10) | (10)
Infiltration cellular, mixed cell | 2 (1.0) | 3 (1.0)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± SEM (N). Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

^c^ Statistical analysis for histological findings performed using the Poly-3 test.

^d^ Number of animals examined microscopically.

^e^ Number of animals with lesion.

^f^ Average severity grade of lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

The incidence of mixed-cell cellular infiltration in the liver was significantly increased in 10,000 ppm males relative to the control group (Table 8; Appendix H). These cellular infiltrates were composed of mononuclear cells with scarce neutrophils and had no specific predisposition to a specific area of the liver lobule. It is unlikely that the cellular infiltrates, which were all of minimal severity, would be responsible for the changes in the liver weights observed in male rats at this time point (Table 8; Appendix H). No other histologic findings were observed to explain the differences in organ weights, but in the females, body weight changes could have influenced the absolute kidney weight decrease and the relative liver weight increase. However, the increase in relative liver weight in exposed females was accompanied by a nonsignificant absolute liver weight increase, so it is unlikely that body weight was responsible for the liver weight changes (Table 8).

As a part of the 14-week interim evaluation in the F_1_ rat study, transcriptome analysis was performed on RNA extracted from microarray study male rat livers from the 10,000 ppm and control groups. The observed effects on transcription were consistent with a mild induction of xenobiotic metabolism-related processes that is likely related to the observed liver weight increases. Analysis of a subset of estrogen-responsive genes showed no change in response to 2H4MBP (Appendix E).

#### Chronic Exposure

##### Body Weights, Feed and Compound Consumption, and Clinical Observations

Male rats exposed to 10,000 ppm 2H4MBP displayed consistently lower mean body weights (~10%) after week 69 relative to the control group and were 20% lower than the control group mean at study end (Table 9; Figure 4). Females exposed to 10,000 ppm 2H4MBP displayed a similar response (~10% lower than the control group mean after week 17), but after week 45 this group displayed mean body weights that were approximately 16% lower than the control group, and mean body weights were 24% lower than the control group mean at study end. Mean body weights of females exposed to 3,000 ppm 2H4MBP were lower than the control group mean after week 77 (~10%) (Table 10).

Table 9 Mean Body Weights and Survival of Male Rats in the Perinatal and Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Day | Av. Wt. (g) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 56.2 | 30 | 56.2 | 100 | 25 | 56.0 | 100 | 25 | 51.1 | 91 | 30
8 | 85.5 | 30 | 85.1 | 100 | 25 | 84.2 | 99 | 25 | 74.5 | 87 | 30
15 | 130.9 | 30 | 127.4 | 97 | 25 | 125.2 | 96 | 25 | 109.6 | 84 | 30
22 | 177.3 | 30 | 173.5 | 98 | 25 | 170.8 | 96 | 25 | 151.7 | 86 | 30
29 | 224.2 | 30 | 218.2 | 97 | 25 | 217.2 | 97 | 25 | 194.5 | 87 | 30
36 | 270.4 | 30 | 262.5 | 97 | 25 | 260.8 | 96 | 25 | 236.9 | 88 | 30
43 | 304.2 | 30 | 295.3 | 97 | 25 | 297.4 | 98 | 25 | 272.0 | 89 | 30
50 | 332.6 | 30 | 324.4 | 98 | 25 | 324.6 | 98 | 25 | 299.4 | 90 | 30
57 | 350.4 | 30 | 342.7 | 98 | 25 | 343.4 | 98 | 25 | 321.3 | 92 | 30
64 | 368.3 | 30 | 361.0 | 98 | 25 | 358.8 | 97 | 25 | 337.4 | 92 | 30
71 | 382.9 | 30 | 372.8 | 97 | 25 | 370.9 | 97 | 25 | 351.7 | 92 | 30
78 | 395.7 | 30 | 387.2 | 98 | 25 | 384.1 | 97 | 25 | 364.4 | 92 | 30
85 | 407.4 | 30 | 398.2 | 98 | 25 | 394.7 | 97 | 25 | 374.1 | 92 | 30
92 | 416.6 | 30 | 408.0 | 98 | 25 | 404.1 | 97 | 25 | 383.1 | 92 | 30
120 | 443.8 | 29^a^ | 429.8 | 97 | 25 | 428.4 | 97 | 25 | 401.2 | 90 | 28^a^
148 | 469.2 | 29 | 447.8 | 95 | 25 | 453.6 | 97 | 25 | 423.9 | 90 | 28
176 | 482.1 | 29 | 467.6 | 97 | 25 | 467.9 | 97 | 25 | 439.1 | 91 | 28
204 | 502.2 | 29 | 490.0 | 98 | 25 | 481.8 | 96 | 25 | 458.2 | 91 | 28
232 | 511.4 | 29 | 495.2 | 97 | 25 | 496.0 | 97 | 25 | 462.8 | 91 | 28
260 | 522.1 | 29 | 512.2 | 98 | 25 | 509.5 | 98 | 25 | 479.5 | 92 | 28
288 | 538.5 | 29 | 524.4 | 97 | 25 | 518.9 | 97 | 25 | 489.0 | 91 | 28
316 | 548.5 | 29 | 533.2 | 97 | 25 | 529.2 | 97 | 25 | 495.1 | 90 | 28
344 | 555.0 | 29 | 538.3 | 97 | 25 | 541.8 | 98 | 25 | 502.8 | 91 | 28
372 | 570.2 | 29 | 551.9 | 97 | 25 | 557.0 | 98 | 25 | 521.0 | 91 | 28
400 | 579.2 | 29 | 561.6 | 97 | 25 | 563.0 | 97 | 25 | 526.5 | 91 | 28
428 | 585.1 | 29 | 557.5 | 96 | 25 | 576.1 | 99 | 25 | 531.8 | 91 | 28
456 | 594.5 | 29 | 570.4 | 96 | 25 | 587.9 | 99 | 25 | 536.8 | 90 | 28
484 | 606.6 | 29 | 575.2 | 95 | 24 | 592.7 | 98 | 25 | 543.1 | 90 | 28
512 | 610.7 | 29 | 581.6 | 95 | 24 | 598.1 | 98 | 25 | 546.2 | 89 | 28
540 | 608.6 | 29 | 573.9 | 94 | 24 | 598.7 | 98 | 25 | 543.0 | 89 | 28
568 | 613.1 | 29 | 577.9 | 94 | 24 | 597.7 | 98 | 25 | 537.9 | 88 | 28
596 | 617.6 | 29 | 590.5 | 96 | 24 | 599.1 | 97 | 23 | 538.6 | 87 | 27
624 | 613.2 | 29 | 584.4 | 95 | 23 | 594.6 | 97 | 23 | 533.1 | 87 | 27
652 | 601.5 | 28 | 584.7 | 97 | 23 | 592.9 | 99 | 22 | 528.6 | 88 | 25
680 | 590.3 | 26 | 572.0 | 97 | 23 | 590.8 | 100 | 21 | 510.1 | 86 | 25
708 | 592.2 | 23 | 547.4 | 92 | 20 | 584.5 | 99 | 21 | 486.7 | 82 | 24
EOS | 603.4 | 21 | 556.3 | 92 | 19 | 575.9 | 96 | 18 | 480.3 | 80 | 23

EOS = end of study.

^a^ Fourteen-week interim necropsy occurred between this day and the previous scheduled weigh day.

Figure 4

Growth Curves for Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed for Two Years

Table 10 Mean Body Weights and Survival of Female Rats in the Perinatal and Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Day | Av. Wt. (g) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 53.7 | 30 | 54.5 | 102 | 25 | 55.1 | 103 | 25 | 49.4 | 92 | 30
8 | 80.5 | 30 | 81.0 | 101 | 25 | 80.5 | 100 | 25 | 71.6 | 89 | 30
15 | 115.3 | 30 | 114.5 | 99 | 25 | 114.0 | 99 | 25 | 100.5 | 87 | 30
22 | 145.7 | 30 | 145.0 | 100 | 25 | 143.0 | 98 | 25 | 128.8 | 88 | 30
29 | 162.6 | 30 | 165.3 | 102 | 25 | 162.8 | 100 | 25 | 151.0 | 93 | 30
36 | 182.3 | 30 | 183.9 | 101 | 25 | 180.3 | 99 | 25 | 168.8 | 93 | 30
43 | 199.9 | 30 | 198.5 | 99 | 25 | 195.0 | 98 | 25 | 181.6 | 91 | 30
50 | 212.7 | 30 | 212.0 | 100 | 25 | 209.1 | 98 | 25 | 193.6 | 91 | 30
57 | 221.0 | 30 | 223.3 | 101 | 25 | 216.7 | 98 | 25 | 200.4 | 91 | 30
64 | 229.7 | 30 | 229.8 | 100 | 25 | 225.1 | 98 | 25 | 207.8 | 91 | 30
71 | 235.0 | 30 | 236.2 | 101 | 25 | 230.7 | 98 | 25 | 213.5 | 91 | 30
78 | 240.2 | 30 | 239.9 | 100 | 25 | 234.4 | 98 | 25 | 218.0 | 91 | 30
85 | 246.0 | 30 | 246.9 | 100 | 25 | 238.8 | 97 | 25 | 223.5 | 91 | 30
92 | 251.2 | 30 | 250.5 | 100 | 25 | 243.8 | 97 | 25 | 227.9 | 91 | 30
120 | 266.0 | 29^a^ | 262.2 | 99 | 25 | 254.3 | 97 | 25 | 237.9 | 89 | 29^a^
148 | 276.1 | 29 | 275.0 | 100 | 25 | 269.3 | 98 | 25 | 245.8 | 89 | 29
176 | 282.7 | 29 | 280.4 | 99 | 25 | 273.8 | 97 | 25 | 252.4 | 89 | 29
204 | 293.3 | 29 | 283.6 | 97 | 25 | 278.9 | 95 | 25 | 257.4 | 88 | 29
232 | 300.6 | 29 | 291.0 | 97 | 25 | 286.7 | 95 | 25 | 260.8 | 87 | 29
260 | 306.7 | 29 | 296.6 | 97 | 25 | 291.3 | 95 | 25 | 264.7 | 86 | 29
288 | 311.5 | 29 | 300.5 | 97 | 25 | 294.2 | 94 | 25 | 267.6 | 86 | 29
316 | 316.7 | 29 | 303.0 | 96 | 25 | 295.8 | 93 | 25 | 267.0 | 84 | 29
344 | 323.2 | 29 | 307.9 | 95 | 25 | 301.5 | 93 | 25 | 269.9 | 84 | 29
372 | 333.3 | 29 | 312.4 | 94 | 25 | 305.7 | 92 | 25 | 275.6 | 83 | 29
400 | 342.0 | 29 | 318.9 | 93 | 25 | 310.4 | 91 | 25 | 279.1 | 82 | 28
428 | 339.2 | 28 | 321.5 | 95 | 25 | 313.9 | 93 | 25 | 281.7 | 83 | 28
456 | 348.1 | 28 | 326.9 | 94 | 25 | 318.4 | 92 | 25 | 286.5 | 82 | 28
484 | 355.6 | 28 | 329.0 | 93 | 25 | 322.6 | 91 | 25 | 286.6 | 81 | 27
512 | 358.6 | 28 | 332.4 | 93 | 25 | 325.6 | 91 | 25 | 287.8 | 80 | 27
540 | 368.4 | 28 | 334.0 | 91 | 24 | 327.0 | 89 | 25 | 292.6 | 79 | 27
568 | 373.4 | 27 | 341.0 | 91 | 24 | 331.0 | 89 | 25 | 297.5 | 80 | 27
596 | 378.2 | 27 | 348.0 | 92 | 24 | 333.6 | 88 | 25 | 295.9 | 78 | 27
624 | 386.2 | 27 | 351.0 | 91 | 24 | 336.6 | 87 | 25 | 303.1 | 79 | 26
652 | 380.1 | 24 | 352.0 | 93 | 24 | 330.2 | 87 | 25 | 311.1 | 82 | 26
680 | 386.1 | 23 | 359.0 | 93 | 23 | 335.8 | 87 | 25 | 307.0 | 80 | 24
708 | 384.0 | 23 | 371.1 | 97 | 23 | 335.9 | 88 | 25 | 306.9 | 80 | 21
EOS | 401.4 | 23 | 367.1 | 92 | 22 | 346.0 | 87 | 25 | 303.7 | 76 | 19

EOS = end of study.

^a^ Fourteen-week interim necropsy occurred between this day and the previous scheduled weigh day.

Feed consumption by 2H4MBP-exposed male and female rats was not significantly different from that by the control groups throughout the study (Appendix H). Dietary concentrations of 1,000, 3,000, and 10,000 ppm resulted in average daily doses of approximately 58, 168, and 585 mg 2H4MBP/kg body weight for males and 60, 180, and 632 mg/kg for females. No clinical findings in exposed groups of male or female rats were considered to be related to 2H4MBP exposure (Appendix H).

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidence of neoplasms and nonneoplastic lesions of the brain and spinal cord, thyroid gland, uterus, adrenal cortex, testis, pancreas, and mammary gland. Summaries of the incidence of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms are presented in Appendix H.

Brain: Malignant meningiomas occurred only in treated animals, with incidences in males at the end of the 2-year study of 0/50, 1/50, 3/50, and 0/50 (Table 11; Appendix H). In addition, there was one malignant meningioma in the spinal cord of a 3,000 ppm animal (which did not have a meningioma in the brain). The spinal cord was examined only when an animal displayed clinical neurological signs, so the actual incidence of meningiomas in the spinal cord may be underrepresented. In females, there was one malignant meningioma (in the brain of a 3,000 ppm animal).

Table 11 Incidences of Neoplasms of the Brain in Male Rats in the Perinatal and Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n ^a^ | 50 | 50 | 50 | 50
Meningioma, Malignant^b^
Overall rate^c^ | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 0/50 (0%)
Rate per litters^d^ | 0/29 (0%) | 1/25 (4%) | 2/25 (8%) | 0/28 (0%)
Adjusted rate^e^ | 0% | 2.3% | 7% | 0%
Terminal rate^f^ | 0/30 (0%) | 0/29 (0%) | 1/24 (4%) | 0/33 (0%)
First incidence (days) | – | 162 | 430 | –
Rao-Scott-adjusted Poly-3 test^g^ | p = 0.583N | p = 0.706 | p = 0.291 | (e)

(e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Historical control incidence for all routes of 2-year studies: 0/340.

^c^ Number of animals with neoplasm per number of animals necropsied.

^d^ Number of litters with neoplasm-bearing animals per number of litters examined at site.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at study termination.

^g^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

Malignant meningiomas in the brain varied somewhat in appearance, both between neoplasms and within a single neoplasm. All of the neoplasms were poorly delineated, cellular neoplasms that were either invading into the brain parenchyma directly, or following along the meninges and vessels deep into the brain (Figure 5 and Figure 6). One neoplasm also involved the pituitary gland, and another involved the trigeminal ganglion. Within a single neoplasm, there was some variability in cell size and shape, with some of the neoplasms displaying more anisocytosis and pleomorphism than others. In some areas, neoplasms had a more sarcomatous appearance, consisting of interlacing bundles of spindle-shaped cells with indistinct cell borders. Cells in these areas tended to have indistinct cell borders, eosinophilic fibrillary cytoplasm, and oval vesicular nuclei. Other areas were characterized by sheets of cells, with round, open-faced nuclei and vacuolated cytoplasm (Figure 5 and Figure 6). In still other areas, the cells were arranged in whorls; these areas tended to have elongated nuclei and indistinct cell borders. Within some neoplasms, there were focal areas of hemorrhage and coagulative necrosis. Mitotic figures were not common in most areas of the lesions, but 1–2 per high power field could be found in some sections of a couple of the tumors. In the one case involving the spinal cord, the neoplasm appeared to be based within the meninges, with infiltration into the underlying spinal cord and spinal nerves. The neoplastic cells within the meninges appeared more epithelial than sarcomatous, although both types were present.

Figure 5

Malignant Meningioma in the Brain of a Male Sprague Dawley Rat Exposed to 1,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

This animal was humanely euthanized on study day 162. A) Widespread thickening of the meninges can be observed and is due to a highly cellular neoplasm (arrows). B) Higher magnification of panel A shows closely packed cells with oval nuclei and indistinct borders. The cells contain wispy, lightly eosinophilic cytoplasm and surround small vessels within the brain (arrows).

Figure 6

Malignant Meningioma in the Brain of a Male Sprague Dawley Rat Exposed to 3,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

A) Another example of a malignant meningioma, this one is from a male Sprague Dawley rat exposed to 3,000 ppm 2H4MBP. As in Figure 5, within the meninges is a dense proliferation of cells that can be seen surrounding blood vessels deep within the brain (arrows). B) A higher magnification of the neoplasm in panel A shows mitotic figures (arrows) among the neoplastic cells.

Thyroid gland: The incidence of C-cell adenomas in 3,000 ppm females was significantly greater than that in the control group at the end of the 2-year study (Table 12; Appendix H). Only one female rat, in the 10,000 ppm group, had bilateral C-cell adenomas; the rest were unilateral lesions. One animal (in the 1,000 ppm group) had both a C-cell adenoma and a C-cell carcinoma (in the opposite gland) but otherwise, all C-cell lesions occurred in unique animals. The incidences of C-cell carcinomas and hyperplasia in exposed groups of female rats were similar to those in the control group. There was no significant exposure concentration-related difference in the incidence of C-cell adenomas in male rats (0 ppm, 7/50; 1,000 ppm, 10/50; 3,000 ppm, 8/50; 10,000 ppm 8/50) when compared to the control group. C-cell adenomas were discrete masses of C-cells, typically larger than five thyroid gland follicles in diameter (Figure 7). The neoplasms caused some compression of adjacent follicles, but did not invade the thyroid gland capsule, and were composed of round-to-oval cells with pale cytoplasm and round nuclei. The cells were arranged in nests and clusters that were separated by a delicate fibrovascular stroma (Figure 7).

Table 12 Incidences of Neoplastic and Nonneoplastic Lesions of the Thyroid Gland in Female Rats in the Perinatal and Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n^a^ | 50 | 50 | 50 | 50
C-cell, Hyperplasia^b^ | 11 (2.0)c | 11 (2.4) | 9 (1.9) | 9 (2.4)
C-cell, Adenoma^d^
Overall rate^e^ | 5/50 (10%) | 11/50 (22%) | 17/50 (34%) | 10/50 (20%)
Rate per litters^f^ | 5/29 (17%) | 10/25 (40%) | 15/25 (60%) | 9/29 (31%)
Adjusted rate^g^ | 12.4% | 25.1% | 37.2% | 24.3%
Terminal rate^h^ | 3/30 (10%) | 9/33 (27%) | 12/34 (35%) | 6/26 (23%)
First incidence (days) | 582 | 529 | 540 | 581
Rao-Scott-adjusted Poly-3 test^i^ | p = 0.326 | p = 0.108 | p = 0.008 | p = 0.128
C-cell, Carcinoma^j^
Overall rate | 1/50 (2%) | 1/50 (2%) | 0/50 (0%) | 1/50 (2%)
Rate per litter | 1/29 (3%) | 1/25 (4%) | 0/25 (0%) | 1/29 (3%)
Adjusted rate | 2.6% | 2.3% | 0% | 2.5%
Terminal rate | 1/30 (3%) | 1/33 (3%) | 0/34 (0%) | 1/26 (4%)
First incidence (days) | 730 (T) | 730 (T) | –^k^ | 730 (T)
Rao-Scott-adjusted Poly-3 test | (n) | (n) | (n) | (n)

(T) = terminal euthanasia; (n) = no statistical test run.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 38/339 (11.85% ± 7.01%); range: 4% to 22%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with neoplasm-bearing animals per number of litters examined at site.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at study termination.

^i^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^j^ Historical control incidence: 4/339 (1.33% ± 1.63%); range: 0% to 4%.

^k^ Not applicable; no neoplasms in animal group.

Figure 7

C-cell Adenoma in the Thyroid Gland of a Female Sprague Dawley Rat Exposed to 3,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

A) The C-cell adenoma is a discrete mass of several nests, or clusters, of cells separated by a delicate fibrovascular stroma. B) Higher magnification of the C-cell adenoma; at this magnification, the fibrovascular stroma that separates the nests of C-cells is more apparent (arrows). The cells that make up the adenoma have round nuclei and pale staining cytoplasm.

Uterus: At 2 years, a significantly increased incidence of stromal polyp occurred in 3,000 ppm females when compared to the control group (Table 13; Appendix H). Incidences of stromal sarcoma, which can occasionally arise within stromal polyps,^103^ were not significantly increased relative to the control group in exposed females, and only occurred in the 1,000 and 3,000 ppm groups (Table 13; Appendix H). Stromal polyps typically were sessile or pedunculated masses of loosely organized stromal cells observed within the uterine lumen (Figure 8). Blood vessels and variable numbers of glands could be found within the polyps, which were covered by a single layer of cuboidal or columnar epithelium. A few polyps were partially lined by squamous epithelium; this was observed when the polyp arose in areas of moderate to marked squamous metaplasia of the uterus. Stromal sarcomas were poorly demarcated, highly cellular neoplasms composed of pleomorphic spindle cells with indistinct borders (Figure 9). If a stromal sarcoma arises within a stromal polyp, only the stromal sarcoma is diagnosed. In the two cases in which both were diagnosed in the same rat, the polyp and the sarcoma were considered separate, unique neoplasms.

Table 13 Incidences of Neoplastic and Nonneoplastic Lesions of the Uterus in Female Rats in the Perinatal and Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n^a^ | 50 | 50 | 50 | 50
Endometrium, Atypical Hyperplasia^b^ | 9 (2.0)^c^ | 14 (1.5) | 19* (1.4) | 14 (2.1)
Adenocarcinoma^d^
Overall rate^e^ | 5/50 (10%) | 3/50 (6%) | 0/50 (0%) | 4/50 (8%)
Rate per litters^f^ | 5/29 (17%) | 3/25 (12%) | 0/25 (0%) | 4/29 (14%)
Adjusted rate^g^ | 12.6% | 7.0% | 0.0% | 9.9%
Terminal rate^h^ | 4/30 (13%) | 3/33 (9%) | 0/34 (0%) | 4/26 (15%)
First incidence (days) | 644 | 730 (T) | –^i^ | 730 (T)
Rao-Scott-adjusted Poly-3 test^j^ | p = 0.555 | p = 0.325N | p = 0.036N | p = 0.486N
Stromal Polyp, Multiple | 1 | 3 | 3 | 0
Stromal Polyp (includes multiple)^k^
Overall rate | 8/50 (16%) | 15/50 (30%) | 18/50 (36%) | 10/50 (20%)
Rate per litters | 8/29 (28%) | 12/25 (48%) | 16/25 (64%) | 10/29 (34%)
Adjusted rate | 20.4% | 33.9% | 39.9% | 24.4%
Terminal rate | 8/30 (27%) | 12/33 (36%) | 14/34 (41%) | 7/26 (27%)
First incidence (days) | 730 (T) | 529 | 681 | 599
Rao-Scott-adjusted Poly-3 test | p = 0.415N | p = 0.132 | p = 0.049 | p = 0.424
Stromal Sarcoma | 0 | 1 | 2 | 0
Stromal Polyp or Stromal Sarcoma (Combined)^l^
Overall rate | 8/50 (16%) | 15/50 (30%) | 19/50 (38%) | 10/50 (20%)
Rate per litters | 8/29 (28%) | 12/25 (48%) | 17/25 (68%) | 10/29 (34%)
Adjusted rate | 20.4% | 33.9% | 41.5% | 24.4%
Terminal rate | 8/30 (27%) | 12/33 (36%) | 14/34 (41%) | 7/26 (27%)
First incidence (days) | 730 (T) | 529 | 525 | 599
Rao-Scott-adjusted Poly-3 test | p = 0.409N | p = 0.132 | p = 0.035 | p = 0.424

* Significantly different (p ≤ 0.05) from the control group by the Rao-Scott-adjusted Poly-3 test.

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 11/150 (7.33% ± 4.62%); range: 2% to 10%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with neoplasm-bearing animals per number of litters examined at site.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal euthanasia.

^i^ Not applicable; no neoplasms in animal group.

^j^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^k^ Historical control incidence: 34/150 (22.67% ± 8.33%); range: 16% to 32%.

^l^ Historical control incidence: 36/150 (24% ± 8%); range: 16% to 32%.

Figure 8

Stromal Polyp in the Uterus of a Female Sprague Dawley Rat Exposed to 3,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

A cross section of a stromal polyp is visible within the lumen of the uterus. This polyp (arrow) is primarily composed of connective tissue with few glands; some polyps contain more glands.

Figure 9

Stromal Sarcoma in the Uterus of Female Sprague Dawley Rat Exposed to 1,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

A) The sarcoma is a poorly demarcated, highly cellular mass. B) Magnification of panel A. A dense population of neoplastic cells is evident with oval to elongated nuclei and indistinct cell borders.

Compared to the control group, there was a significantly increased incidence of atypical endometrium hyperplasia of the uterus in 3,000 ppm females Table 13; Appendix H). Atypical hyperplasia is considered a preneoplastic lesion of the uterine epithelium,^51^ but 3,000 ppm females had a significantly decreased incidence of adenocarcinoma of the uterus (Table 13; Appendix H). Atypical hyperplasia involved both the endometrial glands and the surface epithelium (Figure 10). Affected endometrial glands were characterized by clusters of enlarged glands lined by disorganized, stratified, large epithelial cells displaying pleomorphism and anisokaryosis; thickened papillary projections and infoldings often contained clear vacuoles within the cells or spaces reminiscent of glandular lumen formation (Figure 10). Atypical hyperplasia affecting the surface epithelium consisted of branching, frond-like projections of epithelial cells on a fibrovascular stalk extending into the uterine lumen.

Figure 10

Atypical Hyperplasia of the Uterus in a Female Sprague Dawley Rat Exposed to 3,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

A) Atypical hyperplasia affected both the luminal surface epithelium (arrowheads) and the glandular epithelium (large arrows). This animal also had squamous metaplasia of the epithelium in some glands (small arrows). B) Higher magnification of hyperplasia imaged in panel A; glands are lined by enlarged, stratified, disorganized, and pleomorphic cells that frequently contain large vacuoles (arrows).

Adrenal cortex: The incidences of focal hypertrophy were significantly increased in 1,000 and 3,000 ppm females compared to the control group at the end of the 2-year study (Table 14; Appendix H). Hypertrophy in the cortex was characterized by a focal area of enlarged cells, without a concomitant increase in cell numbers. Affected cells had increased amounts of pale to brightly eosinophilic cytoplasm. Minimal to mild lesions often involved the zona glomerulosa with extension into the zona fasciculata, although some were observed only in the zona fasciculata (Figure 11). Larger lesions seemed to involve the entire thickness of the cortex, and the cells often displayed cytoplasmic vacuolation (Figure 11). One control female had bilateral lesions; all others were unilateral.

Table 14 Incidences of Nonneoplastic Lesions of the Testes, Pancreas, and Adrenal Cortex of Rats in the Perinatal and Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male ^a^ | 50 | 50 | 50 | 50
Testes
Arteriole, necrosis, fibrinoid^b^ | 16* (2.3)^c^ | 19 (2.6) | 16 (2.6) | 25* (2.4)
Interstitial cell, hyperplasia | 1* (1.0) | 0 | 0 | 5 (2.0)
Pancreas
Arteriole, inflammation, chronic active | 4 (1.5) | 15* (1.2) | 10 (1.4) | 11 (1.3)
Female ^a^ | 50 | 50 | 50 | 50
Adrenal Cortex
Hypertrophy, focal | 24 (2.0) | 42** (1.8) | 39* (1.6) | 27 (1.7)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Rao-Scott test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals; 1 = minimal; 2 = mild; 3 = moderate; 4 = marked).

Figure 11

Focal Hypertrophy in the Adrenal Cortex from a Female Sprague Dawley Rat Exposed to 3,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

A) Minimal focal hypertrophy of the adrenal cortex (arrows) is present, which involves the zona glomerulosa with extension into the zona fasciculata. B) This minimal focus of hypertrophy (arrow) was confined to the zona fasciculata. C) A large area of hypertrophy (arrows) is evident; many of the hypertrophied cells also have pronounced vacuolation.

Testes: The incidence of interstitial cell hyperplasia showed a statistically significant positive trend, but there were no significant pairwise comparisons of the exposed groups to the control group (Table 14; Appendix H). Interstitial cell hyperplasia consisted of focal proliferations of interstitial cells that did not cause compression of surrounding seminiferous tubules. Minimal lesions were typically smaller than the size of one seminiferous tubule, whereas mild lesions were somewhat larger, but still did not cause compression. All lesions were unilateral and no interstitial cell adenomas were observed in this study.

The incidence of fibrinoid necrosis of the arterioles was significantly increased in 10,000 ppm males compared to the control group (Table 14; Appendix H). Arteriole fibrinoid necrosis was characterized by vessels with a tunica media thickened by amorphous eosinophilic material. Severity grading was based on the percentage of arterioles having fibrinoid necrosis of the vessel walls: Grade 1 (minimal) was used when up to 25% of the arterioles in the testes were affected; Grade 2 (mild) when 25–50% of the arterioles were affected; Grade 3 (moderate) when 50–75% of the arterioles were affected, and Grade 4 (marked) when greater than 75% of the arterioles in the testes had fibrinoid necrosis of the vascular walls. Fibrinoid necrosis of these blood vessels was often accompanied by a mixed inflammatory cell infiltrate and was frequently found in vessels in other tissues as well. Polyarteritis nodosa involving necrosis and inflammation of arterioles and arteries is a common spontaneous age-related lesion in several strains of rats.^104^

Pancreas: The incidence of chronic active inflammation affecting the arterioles was significantly increased in 1,000 ppm males compared to the control group at the end of the 2-year study (Table 14; Appendix H). This lesion was not considered to be a primary pancreatic lesion, but rather, part of the syndrome of inflammation and necrosis of the arteries and arterioles (polyarteritis nodosa) that develops in certain strains of rats. Arteries and arterioles commonly involved in polyarteritis nodosa include those in the pancreas, mesentery, and testes.^105^ In this particular case, although the incidences of chronic active inflammation of the arterioles were increased in the 1,000 and 10,000 ppm males, the incidence of chronic active inflammation of the pancreatic arteries was not statistically different from the control group in any exposed group. The arteries, larger than the arterioles, would be easier to observe in sections of tissue and because almost every male rat that had inflammation recorded in the arterioles of the pancreas also had inflammation of the arteries of the pancreas (the exception being three 1,000 ppm males) the differences in the incidences of arteriole inflammation might simply reflect fewer observed cross sections of the smaller arterioles in some rats.

Mammary gland: The incidences of mammary gland fibroadenoma and carcinoma were significantly decreased, relative to the control group, in 10,000 ppm females at the end of the 2-year study (fibroadenoma: 32/50, 30/50, 27/50, 18/50; carcinoma: 7/50, 5/50, 7/50, 1/50; Appendix H).

## Mice

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 15 and in the Kaplan-Meier survival curves (Figure 12). Survival of all exposed groups of male and female mice was not significantly different from that of the control groups.

Table 15 Survival of Mice in the Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Animals Initially in Study | 50 | 50 | 50 | 50
Missing^a^ | 1 | 0 | 0 | 0
Moribund | 2 | 1 | 2 | 0
Natural Deaths | 13 | 9 | 5 | 8
Animals Surviving to Study Termination | 34 | 40 | 43 | 42
Percent Probability of Survival at End of Study^b^ | 69 | 80 | 86 | 84
Mean Survival (Days)^c^ | 691 | 715 | 701 | 688
Survival Analysis^d^ | p = 0.266N | p = 0.251N | p = 0.094N | p = 0.155N
Female
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 1 | 5 | 2 | 1
Natural Deaths | 7 | 6 | 4 | 3
Animals Surviving to Study Termination | 42 | 39^e^ | 44 | 46
Percent Probability of Survival at End of Study^b^ | 84 | 78 | 88 | 92
Mean Survival (Days)^c^ | 716 | 696 | 720 | 717
Survival Analysis^d^ | p = 0.135N | p = 0.492 | p = 0.724N | p = 0.369N

^a^ Censored in the survival analysis.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and study termination).

^d^ The result of the life-table trend test^72^ is in the control column, and the results of the life-table pairwise comparisons^73^ with the control group are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^e^ Includes one animal that died during the last week of the study.

Figure 12

Kaplan-Meier Survival Curves for Mice Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed for Two Years

#### Body Weights, Feed and Compound Consumption, and Clinical Observations

Mean body weights of 1,000 and 3,000 ppm males and females were within 10% of those of the control groups throughout the study (Table 16, Table 17; Figure 13). Mean body weights of 10,000 ppm males and females were at least 10% less than those of the control groups generally at weeks 17 and 12, respectively. Feed consumption by exposed groups of males and females was not significantly different from that by the control groups (Appendix H). Dietary concentrations of 1,000, 3,000, and 10,000 ppm resulted in average daily doses of approximately 113, 339, and 1,207 mg 2H4MBP /kg body weight for males and 109, 320, and 1,278 mg/kg for females. No clinical findings in exposed groups of male or female mice were considered to be related to 2H4MBP exposure (Appendix H).

Table 16 Mean Body Weights and Survival of Male Mice in the Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 21.8 | 50 | 21.8 | 100 | 50 | 21.9 | 100 | 50 | 21.9 | 100 | 50
8 | 22.6 | 50 | 22.3 | 99 | 50 | 22.4 | 99 | 50 | 21.9 | 97 | 50
15 | 23.0 | 50 | 22.9 | 100 | 50 | 23.0 | 100 | 50 | 22.4 | 97 | 50
22 | 23.4 | 50 | 23.4 | 100 | 50 | 23.3 | 100 | 50 | 22.5 | 96 | 50
29 | 24.2 | 50 | 24.4 | 101 | 50 | 23.9 | 99 | 50 | 23.1 | 95 | 50
36 | 25.0 | 50 | 25.4 | 102 | 50 | 24.8 | 99 | 50 | 23.7 | 95 | 50
43 | 25.5 | 50 | 26.0 | 102 | 50 | 25.3 | 99 | 50 | 24.2 | 95 | 50
50 | 26.5 | 50 | 26.7 | 101 | 50 | 25.8 | 97 | 50 | 24.9 | 94 | 50
57 | 27.1 | 50 | 27.3 | 101 | 50 | 26.3 | 97 | 50 | 25.3 | 93 | 50
64 | 27.9 | 50 | 28.3 | 101 | 50 | 26.9 | 97 | 50 | 25.9 | 93 | 50
71 | 28.4 | 50 | 28.8 | 101 | 50 | 27.8 | 98 | 50 | 26.7 | 94 | 50
78 | 29.1 | 50 | 29.4 | 101 | 50 | 28.3 | 97 | 50 | 26.6 | 92 | 49
85 | 28.9 | 50 | 29.3 | 101 | 50 | 27.9 | 97 | 50 | 26.5 | 92 | 49
92 | 30.0 | 50 | 30.2 | 101 | 50 | 28.4 | 95 | 50 | 27.2 | 91 | 48
120 | 33.3 | 50 | 33.4 | 100 | 50 | 31.6 | 95 | 50 | 29.4 | 88 | 48
148 | 35.3 | 50 | 35.0 | 99 | 50 | 33.2 | 94 | 50 | 30.0 | 85 | 48
176 | 37.5 | 50 | 37.6 | 100 | 50 | 35.0 | 93 | 50 | 31.4 | 84 | 48
204 | 40.4 | 50 | 40.6 | 100 | 50 | 37.8 | 94 | 50 | 33.5 | 83 | 48
232 | 42.5 | 50 | 42.2 | 99 | 50 | 39.8 | 94 | 50 | 35.1 | 83 | 48
260 | 43.6 | 50 | 43.2 | 99 | 50 | 41.0 | 94 | 50 | 35.9 | 83 | 48
288 | 43.6 | 49 | 42.9 | 98 | 50 | 42.0 | 96 | 50 | 36.8 | 84 | 48
316 | 45.5 | 49 | 44.4 | 98 | 50 | 43.1 | 95 | 50 | 37.6 | 83 | 48
344 | 46.3 | 49 | 45.9 | 99 | 50 | 44.1 | 95 | 49 | 38.6 | 83 | 48
372 | 45.6 | 49 | 44.9 | 99 | 50 | 43.4 | 95 | 49 | 38.1 | 84 | 48
400 | 46.7 | 49 | 46.6 | 100 | 50 | 44.7 | 96 | 48 | 39.3 | 84 | 48
428 | 46.0 | 49 | 46.2 | 100 | 50 | 44.6 | 97 | 48 | 39.0 | 85 | 48
456 | 46.4 | 49 | 46.7 | 101 | 50 | 44.7 | 96 | 48 | 38.9 | 84 | 48
484 | 45.9 | 49 | 46.2 | 101 | 50 | 44.7 | 97 | 48 | 38.9 | 85 | 48
512 | 46.9 | 49 | 46.5 | 99 | 50 | 45.5 | 97 | 47 | 39.1 | 83 | 47
540 | 47.4 | 49 | 47.4 | 100 | 50 | 46.6 | 98 | 46 | 40.7 | 86 | 47
568 | 47.2 | 48 | 46.8 | 99 | 50 | 45.9 | 97 | 46 | 40.1 | 85 | 46
596 | 47.6 | 45 | 47.1 | 99 | 50 | 46.6 | 98 | 46 | 40.6 | 85 | 46
624 | 47.2 | 42 | 45.7 | 97 | 48 | 45.0 | 96 | 46 | 39.2 | 83 | 46
652 | 46.6 | 39 | 46.1 | 99 | 45 | 45.0 | 97 | 45 | 39.1 | 84 | 45
680 | 46.8 | 37 | 43.9 | 94 | 44 | 45.3 | 97 | 44 | 38.7 | 83 | 43
708 | 45.8 | 36 | 44.6 | 97 | 42 | 45.5 | 99 | 43 | 38.8 | 85 | 42
Mean for Weeks
1–13 | 25.6 | – | 25.8 | 101 | – | 25.2 | 98 | – | 24.3 | 95 | –
14–52 | 39.8 | – | 39.5 | 99 | – | 37.6 | 94 | – | 33.6 | 85 | –
53–102 | 46.6 | – | 46.1 | 99 | – | 45.2 | 97 | – | 39.3 | 84 | –

Table 17 Mean Body Weights and Survival of Female Mice in the Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 18.0 | 50 | 17.7 | 98 | 50 | 17.9 | 99 | 50 | 17.7 | 99 | 50
8 | 19.0 | 50 | 18.7 | 98 | 50 | 18.8 | 99 | 50 | 18.1 | 96 | 50
15 | 20.0 | 50 | 19.6 | 98 | 50 | 19.6 | 98 | 50 | 19.0 | 95 | 50
22 | 20.8 | 50 | 20.6 | 99 | 50 | 20.3 | 98 | 50 | 19.4 | 94 | 50
29 | 21.7 | 50 | 21.3 | 98 | 50 | 20.8 | 96 | 50 | 20.2 | 93 | 50
36 | 22.5 | 50 | 22.1 | 98 | 50 | 21.9 | 97 | 50 | 20.9 | 93 | 50
43 | 22.9 | 50 | 22.5 | 98 | 50 | 22.6 | 99 | 50 | 21.2 | 93 | 50
50 | 23.6 | 50 | 22.9 | 97 | 50 | 23.0 | 98 | 50 | 21.8 | 93 | 50
57 | 24.5 | 50 | 23.9 | 98 | 50 | 23.9 | 97 | 50 | 22.6 | 92 | 50
64 | 24.8 | 50 | 24.3 | 98 | 50 | 24.7 | 100 | 50 | 22.8 | 92 | 50
71 | 25.7 | 50 | 25.3 | 98 | 50 | 24.9 | 97 | 50 | 23.1 | 90 | 50
78 | 25.5 | 50 | 25.4 | 100 | 50 | 25.3 | 99 | 50 | 23.3 | 91 | 50
85 | 26.5 | 50 | 25.9 | 98 | 50 | 26.1 | 98 | 50 | 23.8 | 90 | 50
92 | 27.1 | 50 | 26.0 | 96 | 50 | 26.3 | 97 | 50 | 23.8 | 88 | 50
120 | 29.8 | 50 | 29.2 | 98 | 50 | 28.6 | 96 | 50 | 25.1 | 84 | 50
148 | 31.9 | 50 | 30.7 | 96 | 50 | 31.1 | 98 | 50 | 26.3 | 82 | 50
176 | 34.0 | 50 | 33.3 | 98 | 50 | 32.2 | 95 | 50 | 26.9 | 79 | 50
204 | 36.8 | 50 | 35.1 | 96 | 50 | 36.0 | 98 | 50 | 27.6 | 75 | 50
232 | 38.6 | 50 | 37.0 | 96 | 50 | 37.1 | 96 | 50 | 29.7 | 77 | 50
260 | 39.9 | 50 | 38.9 | 97 | 50 | 39.6 | 99 | 50 | 30.5 | 76 | 50
288 | 42.3 | 50 | 40.3 | 95 | 50 | 40.8 | 96 | 50 | 31.5 | 75 | 50
316 | 44.3 | 50 | 42.6 | 96 | 50 | 42.4 | 96 | 50 | 33.2 | 75 | 50
344 | 45.2 | 50 | 44.3 | 98 | 50 | 43.9 | 97 | 50 | 34.2 | 76 | 50
372 | 46.0 | 50 | 44.3 | 96 | 50 | 45.1 | 98 | 50 | 34.7 | 75 | 50
400 | 47.7 | 50 | 45.8 | 96 | 50 | 46.9 | 98 | 50 | 36.1 | 76 | 50
428 | 48.7 | 50 | 47.2 | 97 | 50 | 46.5 | 95 | 50 | 36.7 | 75 | 49
456 | 48.9 | 50 | 47.9 | 98 | 50 | 46.6 | 95 | 50 | 36.7 | 75 | 49
484 | 52.0 | 50 | 49.4 | 95 | 48 | 49.5 | 95 | 50 | 37.7 | 72 | 49
512 | 53.2 | 50 | 49.2 | 93 | 48 | 50.5 | 95 | 50 | 38.4 | 72 | 49
540 | 54.5 | 50 | 51.4 | 94 | 47 | 51.8 | 95 | 50 | 39.3 | 72 | 49
568 | 54.3 | 50 | 51.7 | 95 | 46 | 50.9 | 94 | 50 | 39.3 | 72 | 49
596 | 54.7 | 48 | 51.6 | 94 | 45 | 49.5 | 91 | 49 | 39.2 | 72 | 49
624 | 54.2 | 48 | 51.2 | 94 | 43 | 50.3 | 93 | 49 | 39.3 | 72 | 49
652 | 52.3 | 48 | 50.2 | 96 | 41 | 49.8 | 95 | 48 | 38.9 | 74 | 49
680 | 52.5 | 46 | 51.0 | 97 | 39 | 50.1 | 96 | 48 | 39.5 | 75 | 47
708 | 52.5 | 43 | 50.3 | 96 | 39 | 47.2 | 90 | 46 | 39.2 | 75 | 46
Mean for Weeks
1–13 | 22.7 | – | 22.3 | 98 | – | 22.3 | 98 | – | 21.1 | 93 | –
14–52 | 37.0 | – | 35.7 | 97 | – | 35.8 | 97 | – | 28.9 | 79 | –
53–102 | 51.7 | – | 49.3 | 96 | – | 48.8 | 95 | – | 38.1 | 74 | –

Figure 13

Growth Curves for Mice Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed for Two Years

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidence of neoplasms and nonneoplastic lesions of the hematopoietic tissues (bone marrow and spleen), liver, kidney, Harderian gland, pituitary gland (pars distalis), thyroid gland, pancreatic islets, and adrenal cortex. Summaries of the incidence of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms are presented in Appendix H.

Hematopoietic tissues (bone marrow and spleen): The incidences of pigment in the bone marrow were significantly increased in 10,000 ppm males and females when compared to their respective control group (Table 18; Appendix H). Also relative to their respective control group, the incidences of pigment in the spleen were significantly increased in 10,000 ppm males and 3,000 and 10,000 ppm females (Table 18; Appendix H). In both the bone marrow and spleen, the pigment was characterized by a golden-brown to brown granular material found within the cytoplasm of macrophages (Figure 14 and Figure 15). It was consistent with hemosiderin, and the presence of iron was confirmed using a Perl’s stain on spleens from several animals (Figure 16). Some amount of pigment could be found in most animals, but pigment was only recorded as a change when it was above the threshold of that which was considered a normal background level. Typically, pigment was recorded when there were increased numbers of pigment-containing macrophages, often present in clusters of up to 10 or more macrophages, and the macrophages individually contained more pigment than what was observed at background levels. All findings of pigment in the bone marrow were of minimal severity. The majority of lesions in the spleen were of minimal severity, with only one animal each having lesions of mild or moderate severity. Mild and moderate pigment was based on a subjective increase in the amount of pigment compared to observations of minimal severity.

Table 18 Incidences of Nonneoplastic Lesions of the Bone Marrow, Spleen, Liver, and Kidney of Mice in the Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Bone Marrow^a^ | 47 | 48 | 48 | 50
Pigment^b^ | 3** (1.0)^c^ | 2 (1.0) | 9 (1.0) | 50** (1.0)
Spleen | 48 | 50 | 49 | 50
Pigment | 4** (1.0) | 5 (1.0) | 10 (1.0) | 17** (1.0)
Liver | 49 | 50 | 50 | 50
Hepatocyte, syncytial alteration | 2** (1.0) | 39** (1.0) | 45** (1.5) | 48** (1.8)
Kidney | 48 | 50 | 50 | 50
Renal tubule, cytoplasmic alteration | 0** | 0 | 0 | 46** (2.0)
Infiltration cellular, lymphocyte | 40* (1.0) | 40 (1.0) | 43 (1.0) | 46* (1.0)
Nephropathy, chronic progressive | 41* (1.1) | 48 (1.1) | 48* (1.0) | 50* (1.1)
Female
Bone Marrow | 49 | 50 | 50 | 50
Pigment | 6** (1.0) | 0* | 0* | 50** (1.0)
Spleen | 49 | 50 | 49 | 50
Pigment | 12** (1.0) | 10 (1.0) | 36** (1.0) | 38** (1.0)
Kidney | 49 | 50 | 50 | 50
Metaplasia, osseous | 0* | 1 | 3 | 5*

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals; 1 = minimal; 2 = mild; 3 = moderate; 4 = marked).

Figure 14

Pigment in the Bone Marrow from Female B6C3F1/N Mice Exposed to 0 or 10,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

A) A background level of pigment appears within macrophages in the bone marrow (arrows) of a control mouse. B) In a female mouse exposed to 10,000 ppm 2-hydroxy-4-methoxybenzophenone, an increased amount of pigment in the macrophages in the bone marrow (arrows) is apparent.

Figure 15

Pigment in the Spleen from Female B6C3F1/N Mice Exposed to 0 or 10,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

A) Similar to what was seen in the bone marrow, some pigment is present in control animals as a background observation (arrows). B) An increased amount of pigment is evident in the spleen (arrows) in a female mouse exposed to 10,000 ppm 2-hydroxy-4-methoxybenzophenone when compared to the spleen from the control mouse.

Figure 16

Pigment in the Spleen from Female B6C3F1/N Mice Exposed to 0 or 10,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (Perl’s Iron Stain)

A) The positive (blue) staining indicates that the pigment in the spleen contains iron, which is consistent with hemosiderin from a control group mouse. B) Increased iron-containing pigment in spleen of female mouse exposed to 10,000 ppm 2-hydroxy-4-methoxybenzophenone; compare the amount of positive (blue) staining in this photomicrograph to that in panel A.

Liver: The incidences of hepatocyte syncytial alteration were significantly increased in all exposed groups of males compared to the control group (Table 18; Appendix H).

Hepatocytes with two or three nuclei are common in old mice and were not included in the diagnosis of syncytial alteration. Hepatocytes recorded with syncytial alteration had four to seven or more nuclei. Affected hepatocytes were larger than normal, but the individual nuclei were typically small and densely basophilic (Figure 17). Severity grading was based upon the number of altered hepatocytes observed within a section of liver, with minimal (1) being recorded when one to three such hepatocytes were observed; mild (2) severity being recorded when four to 10 syncytial cells were observed; and moderate (3) severity being recorded when >10 were observed. No marked lesions were recorded.

Figure 17

Syncytial Alteration in the Liver from a Male B6C3F1/N Mouse Exposed to 10,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

This animal died on day 545 of the 2-year study. Enlarged hepatocytes contain multiple nuclei (arrows).

Kidney: The incidence of renal tubule cytoplasmic alteration was significantly increased in the 10,000 ppm males compared to the control group (Table 18; Appendix H). Vacuolation of the renal tubules, typically in the outer cortex, is a normal background finding in male mice (Figure 18). The presence of these vacuoles is not recorded as a lesion; however, when a decrease in the vacuolation of the renal tubules is noted, it is typically recorded. In the current study, the normal background vacuolation decreased in renal tubules in the 10,000 ppm males, and this was recorded as an increased incidence of cytoplasmic alteration. (Figure 18).

Figure 18

Renal Tubule Vacuolation in the Kidney from Male B6C3F1/N Mice Exposed to 0 or 10,000 ppm 2-Hydroxy-4-methoxybenzophenone for Two Years (H&E)

Vacuolation of the renal tubules, typically in the outer cortex, is a normal background finding in control male mice. B) The renal tubules of a male mouse exposed to 10,000 ppm 2-hydroxy-4-methoxybenzophenone show a lack of vacuoles (cytoplasmic vacuolation) compared to what is typically seen in male mice. C) Basophilic tubules (arrows) with thickened basement membranes (arrowheads) are evidence of minimal chronic progressive nephropathy in a male mouse exposed to 10,000 ppm 2-hydroxy-4-methoxybenzophenone. In addition, the normal vacuoles seen in the renal tubules of male mice are not present (cytoplasmic alteration).

Incidences of chronic progressive nephropathy were significantly increased in 3,000 and 10,000 ppm males compared to the control group In addition, the incidence of lymphocytic cellular infiltration were significantly increased in 10,000 ppm males compared to the control group (Table 18; Appendix H). Lymphocytic cellular infiltration was characterized by increased numbers of lymphocytes within the interstitium of the kidney.

Lymphocytic infiltrates are very common in aged mouse kidneys, and lymphocytes can also be associated with chronic progressive nephropathy. Therefore, lymphocytic cellular infiltration was not diagnosed unless there were larger accumulations of lymphocytes than is typically seen as a background change or what one would expect associated with chronic progressive nephropathy. Early and minimal chronic progressive nephropathy was characterized by basophilic, hyperplastic tubules with thickened basement membranes (Figure 18). Later and more severe changes were interstitial infiltrations of mononuclear cells (predominantly lymphocytes), hyaline casts, dilated tubules, and interstitial fibrosis. The vast majority of the occurrences of chronic progressive nephropathy were of minimal severity, with only a few mild or moderate (and one marked occurrence) scattered among the exposure groups.

The incidence of osseous metaplasia was significantly increased in 10,000 ppm females compared to the control group (Table 18; Appendix H). This lesion consisted of small areas of mature bone within the cortex of the kidney. Osseous metaplasia is regarded as a spontaneous lesion with unknown pathological significance.

Other tissues: In the Harderian gland, the incidence of adenoma was significantly increased in 1,000 ppm females compared to the control group (1/50, 6/50, 4/50, 3/50; Appendix H). None of these values was outside the historical control range (33/640; range: 2% to 18%),.

Relative to the control group, significantly increased incidences of focal hyperplasia in the pituitary gland (pars distalis) (15/47, 24/49, 14/47, 17/50) and follicular degeneration in the thyroid gland (20/48, 30/49, 18/48, 20/48) occurred in 1,000 ppm females (Appendix H).

In the pancreatic islets, significantly decreased incidences of hyperplasia occurred in 10,000 ppm males (29/47, 31/50, 25/48, 20/50) and 1,000 and 3,000 ppm females compared to their respective control group (11/49, 3/49, 4/49, 7/49) (Appendix H).

In the adrenal cortex, the incidences of accessory adrenal cortical nodules in 1,000 and 3,000 ppm females were significantly less than that in the control group (9/50, 2/50, 2/50, 4/50; Appendix H).

None of these lesions was considered toxicologically significant.

## Genetic Toxicology

2H4MBP (20 to 6,000 μg/plate) was not mutagenic in Salmonella typhimurium strains TA98 or TA100 or Escherichia coli strain WP2 uvrA/pKM101 when tested with and without 10% rat liver metabolic activation enzymes (S9) (Table A-1).