# Materials and Methods

## Procurement and Characterization of 2-Hydroxy-4-methoxybenzophenone

2-Hydroxy-4-methoxybenzophenone (2H4MBP) was obtained from Ivy Fine Chemicals Corporation (Cherry Hill, NJ) in one lot (20080801) that was used in the perinatal and 2-year studies. Identity and purity analyses were conducted under the analytical chemistry laboratory and study laboratory at Battelle (Columbus, OH) (Appendix B). Reports on analyses performed in support of the 2H4MBP studies are on file at the National Institute of Environmental Health Sciences.

Lot 20080801 of the chemical, a light-yellow powder, was identified as 2H4MBP by infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and gas chromatography (GC) with mass spectrometry (MS) detection. The IR spectrum was in good agreement with a reference spectrum^66^ and the structure of 2H4MBP. Proton and carbon-13 NMR spectra were consistent with computer-predicted spectra and the structure of the test article. The mass spectrum of the major peak from the GC/MS analysis matched a reference spectrum^67^ for 2H4MBP.

The purity of lot 20080801 was determined using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection and using GC with flame ionization detection (FID). Lot 20080801 was screened for common residual volatile solvents using GC with electron capture detection (ECD) and FID. Differential scanning calorimetry (DSC) was used to determine the purity of the test article. In addition, Karl Fisher titration of lot 20080801 was performed by Galbraith Laboratories, Inc. (Knoxville, TN).

Purity assessment by HPLC/UV found no reportable impurities in lot 20080801. GC/FID analysis yielded a purity of 99.8% and found one impurity with an area of 0.17% of the total peak area. No significant halogenated or nonhalogenated volatile impurities were found in the bulk chemical. Purity by DSC was 99.2%. Karl Fischer analysis indicated that no quantifiable water was present in the test article. The overall purity of lot 20080801 was determined to be greater than 99%.

To ensure stability, the bulk chemical was stored at room temperature in sealed amber glass containers. Periodic reanalyses of the bulk chemical were performed during the perinatal and 2-year studies by the study laboratory using HPLC/UV and no degradation of the bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared approximately monthly by mixing 2H4MBP with feed (Table B-1). Formulations were stored in sealed amber plastic bags at room temperature for up to 42 to 43 days.

Homogeneity studies of the 1,000 and 10,000 ppm dose formulations in NIH-07 and NTP-2000 feed were performed before the animal studies by the analytical chemistry and study laboratories. Additional homogeneity studies of the 1,000 and 10,000 ppm dose formulations in NTP-2000 feed were performed during the chronic studies by the study laboratory. Stability studies of the 1,000 ppm dose formulation in NIH-07 and NTP-2000 feed were performed by the analytical chemistry laboratory using the same analytical method. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in sealed amber plastic bags at room temperature.

Periodic analyses of the dose formulations of 2H4MBP were conducted by the study laboratory using HPLC/UV (Table B-2; Table B-3). Of the dose formulations analyzed, all were within 10% of the target concentrations; all animal room samples for rats and mice were within 10% of the target concentrations.

## Animal Source

Time-mated (F_0_) female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Harlan Laboratories (now Envigo, Indianapolis, IN). Male and female B6C3F1/N mice were obtained from Taconic (Taconic Biosciences, Germantown, NY).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle Columbus Operations (Columbus, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-year Studies

### Study Design for Rats

Exposure concentration selection was based in part on Fischer 344/N rat studies reported in Toxicity Report 21.^32^ Rats were exposed to 0, 3,125, 6,250, 12,500, 25,000, or 50,000 ppm 2H4MBP in the diet for up to 13 weeks. After 13 weeks of 2H4MBP exposure, males and females in the 25,000 ppm groups weighed approximately 10% less than rats in the control groups, whereas males and females exposed to 50,000 ppm weighed 32% and 14% less, respectively, than rats in the control groups. Both males and females in the 50,000 ppm groups had increased absolute and relative kidney weights and exhibited renal papillary necrosis and tubule dilatation. Renal tubule dilation was observed in 100% of the 25,000 ppm male rats and in 30% of the males in the 12,500 ppm group. Therefore, the 10,000 ppm exposure concentration was selected for both male and female rats, anticipating that the system would be appropriately challenged and recognizing strain differences might exist.

Beginning on GD 6, groups of 42, 35, 35, or 43 F0 time-mated female rats were fed diets containing 0, 1,000, 3,000, or 10,000 ppm 2H4MBP, respectively, throughout gestation and lactation. Groups of 50 (1,000 and 3,000 ppm) or 60 (0 and 10,000 ppm) F_1_ rats per sex continued on in the study after weaning and were fed diets containing the same respective 2H4MBP concentration for 105 weeks. An interim evaluation, using 10 F_1_ rats per sex from the 0 and 10,000 ppm groups, was conducted at 14 weeks. To evaluate transcriptional changes in the liver, liver tissue from five control and five 10,000 ppm F_1_ male rats from the 14-week interim evaluation was collected and processed for microarray analyses at the Battelle Biomedical Research Center (Columbus, OH) (Appendix E).

F_0_ female rats were 11 to 14 weeks old upon receipt. Evidence of mating is defined as GD 1; F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to exposure groups on GD 5. Randomization was performed by a body-weight-partitioning algorithm to produce similar group mean weights (PATH/TOX SYSTEM software, Xybion Medical Systems Co., Cedar Knolls, NJ).

F_0_ females were quarantined for 11 days after receipt. Ten nonmated females received with the time-mated females were designated for disease monitoring 11 days after arrival; samples were collected for serological analyses, and the rats were terminated, necropsied, and examined for the presence of disease or parasites. The health of the F_1_ rats was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix D). Pinworms (Syphacia spp.) were diagnosed in sentinel animals during routine health monitoring evaluations. Infected animals did not display clinical signs and no pathological lesions were noted in relation to the presence of the pinworms. Following this finding, NTP, in coordination with the testing laboratory, developed and implemented a successful plan of pinworm containment and eradication. NTP requires the testing laboratories to actively monitor animals to ensure the continued exclusion of pinworms from all studies going forward. All other test results were negative.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. F_0_ females were weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on PNDs 1, 4, 7, 14, and 21. The day of parturition was considered to be PND 0. Total litter weight was collected on PND 1. Individual F_1_ pups were weighed on PNDs 4, 7, 14, and 21. On apparent GD 27, all time-mated female rats that did not deliver were euthanized and the uteruses were examined and stained for evidence of implantation. On PND 1, the number of live and dead F_1_ pups, sex ratio, whole litter weights, and litter weights/sex were recorded.

F_1_ litters were standardized on PND 4 to eight pups/litter, with at least two pups of each sex and a preference for four males and four females each. Litters that did not meet the minimum of eight pups (or if they had fewer than two pups of either sex) were removed from the study. For continuation of exposure after weaning, two males and two females per litter from 30 litters in the 0 and 10,000 ppm groups and from 25 litters in the 1,000 and 3,000 ppm groups were randomly selected. During gestation and lactation, feed consumption was measured continuously by cage. On the day the last litter reached PND 18, litters were randomly selected and F_1_ pups from these litters were randomly selected for the 2-year study. On the day the last litter reached PND 21, the pups were weaned and the dams necropsied, and gross lesions collected. Weaning marked the beginning of the 2-year chronic phase of the study.

F_1_ pups were housed two (males) or four (females) per cage. Feed and water were available ad libitum. In the 2-year chronic phase of the rat study, feed consumption in F_1_ rats was measured initially, weekly for 13 weeks, then for one 7-day period every 4 weeks, and at the end of the study. Cages were changed weekly through PND 4, then changed every 2 weeks. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix C.

### Study Design for Mice

Dose selection was based primarily on the 13-week B6C3F1/N mouse data presented in Toxicity Report 21.^32^ Mice were exposed to 0, 3,125, 6,250, 12,500, 25,000, or 50,000 ppm 2H4MBP in the diet. After 13 weeks of exposure, male and female mice in the 25,000 ppm groups displayed 14% and 8% lower body weights, respectively, relative to animals in the control groups. Absolute liver weights were higher in both the males and females exposed to ≥6,250 ppm, which was associated with cytoplasmic vacuolization of the hepatocytes. Therefore, 10,000 ppm was selected as the high-exposure concentration for male and female mice.

Groups of 50 mice per sex were fed diets containing 0, 1,000, 3,000, or 10,000 ppm 2H4MBP for 104 (females) or 105 (males) weeks. Mice were quarantined for 14 days prior to study start. Mice were approximately 4 to 5 weeks old upon receipt and were randomly assigned to exposure groups using the same body-weight partitioning algorithm as was used for F_0 _female rats to produce similar group mean weights (PATH/TOX SYSTEM software).

Five male and five female mice were randomly selected for parasite evaluation and gross observation of disease. Mice were 6 to 7 weeks old on the first day of the study. The health of the mice was monitored during the study according to the protocol of the NTP Sentinel Animal Program (Appendix D). All test results were negative.

Mice were housed individually (males) or five (females) per cage. Feed and water were available ad libitum. Feed consumption was measured weekly for 13 weeks, then for one 7-day period every 4 weeks, and at the end of the study. Cages were changed once weekly (males) or twice weekly (females) and rotated every 2 weeks. Racks were changed and rotated every 2 weeks.

Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix C.

### Clinical Examinations and Pathology

For the 2-year studies in rats and mice, animals were observed twice daily for morbidity and moribundity and were weighed initially, weekly for the first 13 weeks, then at 4-week intervals, and at study termination. Clinical findings were recorded every 4 weeks and at the end of the studies.

Complete necropsies and microscopic examinations were performed on F_1_ rats and mice. At the 14-week F_1_ rat interim evaluation (control and 10,000 ppm, n = 10/sex/group), the weights of the heart, right kidney, liver, lung, right testis, and thymus were collected. At necropsy, all organs and tissues were examined for grossly visible lesions and all major tissues were fixed and preserved in 10% neutral buffered formalin except for eyes, testes, vaginal tunics, and epididymides, which were first fixed in Davidson’s solution or modified Davidson’s solution. Spinal cord was only collected from animals that had clinical neurological signs. Tissues were processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with hematoxylin and eosin (H&E) for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. In the original evaluation of the uterus, a transverse section through each uterine horn, approximately 0.5 cm cranial to cervix, was collected for histopathology evaluation. During the pathology review process, a residual tissue evaluation of the uterus of rats was performed in which all remaining uterine tissue, including the cervix, and vaginal tissue was sectioned longitudinally, processed, and examined histologically. Results from the residual uterine evaluation were combined with those from the original, transverse sections of uterus. Tissues examined microscopically are listed in Table 1

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment (QA) laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all neoplasms and all potential target organs, which included the kidney of rats and mice; the liver of male rats and male and female mice; the adrenal cortex and thyroid gland of rats; the epididymis, heart, pancreas, and testis of male rats; the uterus of female rats (including all the sections made from residual tissue); and the ovary of female mice.

The QA report and the reviewed slides were submitted to the NTP pathologist, who reviewed and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologist. The QA pathologist, who served as the coordinator of the Pathology Working Group (PWG), presented representative histopathology slides containing examples of lesions related to test agent administration, examples of disagreements in diagnoses between the laboratory and QA pathologist, or lesions of general interest to the PWG for review. The PWG consisted of the NTP pathologist and other pathologists experienced in rodent toxicologic pathology. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, QA pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^68^ and Boorman et al.^69^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of Brix et al.^70^

An additional examination to confirm lesions recorded during the QA process in the longitudinal sections of uterus, cervix, and vagina was undertaken by a pathologist that had not previously examined the tissues.

A special pathology peer review panel was convened to examine all the diagnoses of malignant meningiomas, both in the brain and spinal cord. The consensus on the tumors (both brain and spinal cord) was that they were all malignant meningiomas, confirming the diagnoses made by the study pathologist and confirmed by the QA pathologist. In addition, digital scans of the spinal cord neoplasm were also sent, without knowledge of the chemical or dose group, to eight pathologists, including two neuropathologists. The general consensus on the spinal cord lesion, which included detailed input from the neuropathologists, was that it was a malignant meningioma.

Table 1 Experimental Design and Materials and Methods in the Perinatal and Two-year Feed Studies of 2-Hydroxy-4-methoxybenzophenone

Rats | Mice
Study Laboratory
Battelle (Columbus, OH) | Same as in rats
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | B6C3F1/N
Animal Source
Harlan Laboratories (Indianapolis, IN), now Envigo | Taconic Farms (Germantown, NY)
Time Held before Studies
F_0_ females: 4 days | Males: 16 days
| Females: 15 days
Average Age When Studies Began
>F_0_ females: 11 to 14 weeks | 6 to 7 weeks
Date of First Exposure
F_0_ females: October 1, 2010 | Males: July 16, 2010
F_1_: November 8 (males) or 9 (females), 2010 | Females: July 15, 2010
Duration of Exposure
F_0_ females: GD 6 to PND 21 F_1_ (interim evaluation): 14 weeks | Males: 105 weeks
F_1_ (2-year study): 105 weeks | Females: 104 weeks
Date of Last Exposure
F_0_ females: November 8, 2010 | Males: July 13, 2012
F_1_ (14-week interim evaluation): February 8 (males) or 9 (females), 2011 | Females: July 11, 2012
F_1_ (2-year study): November 5 to 7 (males) or 7 to 9 (females), 2012
Necropsy Dates
F_1_ (2-year study): November 5 to 7 (males) or 7 to 9 (females), 2012 | Males: July 11–13, 2012
| Females: July 9–11, 2012
Size of Study Groups
F_0_ females: 42 (0 ppm), 35 (1,000 and 3,000 ppm), or 43 (10,000 ppm) | 50/sex
F_1_: 60/sex (0 and 10,000 ppm) or 50/sex (1,000 and 3,000 ppm)
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights | Same as in rats
Animals per Cage
F_0_ females: 1 (with litter) | Males: 1
F_1_: 2 (males) or 4 (females) | Females: 5
Method of Animal Identification
F_0_ females: Cage card and tail marking with permanent pen | Tail tattoo
F_1_: Cage card and tail tattoo
Diet
Irradiated NIH-07 meal feed (perinatal phase) or irradiated NTP-2000 meal feed (2-year study) (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed twice weekly | Irradiated NTP-2000 meal feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed once (males) or twice (females) weekly
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as in rats
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly through PND 4, then twice weekly, rotated every 2 weeks | Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly (males) or twice weekly (females), rotated every 2 weeks
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ) changed with cage changes | Same as in rats
Rack Filters
Spun-bonded polyester (Snow Filtration Co., Cincinnati, OH; National Filter Media, Olive Branch, MS), changed every 2 weeks | Spun-bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as in rats
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as in rats
Exposure Concentrations
0, 1,000, 3,000, or 10,000 ppm in feed | Same as in rats
Type and Frequency of Observation
F_0_ females: Observed twice daily. Weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on PNDs 1, 4, 7, 14, and 21. Feed consumption was measured continuously from GD 6 to PND 21. F_1_ rats: Observed twice daily. Litter data (litter count by sex, litter weights by sex, and litter observations) were recorded on PND 1. Pups per litter were recorded on PNDs 2 and 3. Pups were weighed on PNDs 4, 7, 14, and 21, weekly for 13 weeks, then every 4 weeks, and at the end of the study. Clinical findings were recorded every 4 weeks beginning at week 6 and at the end of the study. Feed consumption was recorded initially, continuously for 13 weeks, then for one 7-day period every 4 weeks. | Observed twice daily. Weighed initially, weekly for 13 weeks, then every 4 weeks, and at the end of the studies. Clinical findings were recorded at week 5 then every 4 weeks. Feed consumption was measured initially, continuously for 13 weeks, then every 4 weeks for a 7-day period.
Method of Euthanasia
Euthanasia solution and decapitation (≤PND 10 pups and fetuses); exsanguination (interim rats); carbon dioxide (≥PND 10 pups, F_0_ females, and adult F_1_ rats) | Carbon dioxide
Necropsy
Necropsies were performed on all animals. Organs weighed at the 14-week interim evaluation were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all animals.
Microarray Analyses
Liver tissue of five control and five 10,000 ppm F_1_ male rats was collected and processed to evaluate transcriptional changes in the liver at 14 weeks (Appendix E).
Histopathology
Complete histopathology was performed on all F_1_ rats. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. An additional extended evaluation of the uterus was performed that included all remaining cervical, vaginal, and uterine tissue remnants. | Complete histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, Harderian gland, gallbladder, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^71^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations, as are animals dying from unnatural causes within the observation period. Animals dying from natural causes are included in analyses and are treated as uncensored observations. For the two-year mouse study, dose-related trends are identified with Tarone’s life-table test,^72^ and pairwise dose-related effects are assessed using Cox’s^73^ method. For the rat perinatal study, dose-related trends and pairwise dose-related effects on survival are assessed using a Cox proportional hazards model^73^ with a random litter effect. All reported p values for the survival analyses are two-sided.

### Calculation of Incidence

The incidence of neoplasms or nonneoplastic lesions (Appendix H) is presented as the numbers of animals bearing such lesions at a specific anatomic site. For calculation of incidence rates (Appendix H), the denominator for most neoplasms and all nonneoplastic lesions is the number of animals where the site was examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, Zymbal’s gland, and spinal cord) before microscopic evaluation, the denominator consists of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominator consists of the number of animals on which a necropsy was performed. Additional study data (Appendix H) also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidence

Statistical analyses of neoplasm and nonneoplastic lesion incidence considered two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be considered. Also, up to two rats per sex were randomly selected from each litter to participate in the study. The statistical analysis of lesion incidence used the Poly-3 test to account for survival differences, with a Rao-Scott adjustment for litter effects, as described below.

The Poly-k test^74-76^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to account for survival differences. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is 1 if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died prior to terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^74^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^74^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F1 mice.^77^ Bailer and Portier^74^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^78^ Poly-3 tests used the continuity correction described by Nam.^79^

Littermates tend to be more like each other than like fetuses/pups in other litters. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Because up to two pups per sex per litter were present in the core rat study, the Poly-3 test was modified to accommodate litter effects using the Rao-Scott approach.^80^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Poly-3 test as recommended by Fung et al.,^81^ formula_^₸^RS2_.

Tests of significance included pairwise comparisons of each dosed group with control groups and a test for an overall dose-related trend. Continuity-corrected Rao-Scott-adjusted Poly-3 tests were used in the analysis of lesion incidence and reported p values are one-sided. The significance of a lower incidence or decreasing trend in lesions is represented as 1−p with the letter N added (e.g., p = 0.99 is presented as p = 0.01N). For neoplasms and nonneoplastic lesions observed without litter structure (e.g., at the interim evaluation), Poly-3 tests that included the continuity correction, but without adjustment for potential litter effects, were used for trend and pairwise comparisons to the control group.

To evaluate incidence rates by litter, the proportions of litters affected by each lesion type were tested among groups. Cochran-Armitage trend tests and Fisher exact tests^82^ were used to test for trends and pairwise differences from the control group, respectively.

### Analysis of Continuous Variables

Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey,^83^ for small samples (n < 20), and Tukey’s outer fences method,^84^ for large samples (n ≥ 20), were examined by NTP personnel, and implausible values were eliminated from the analysis. Organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^85^ and Williams.^86;^ ^87^ Dam gestational and lactational feed consumption, litter sizes, pup survival, implantations, number of resorptions, and proportions of male pups per litter for all rat endpoints were analyzed using the nonparametric multiple comparison methods of Shirley^88^ [as modified by Williams^89^] and Dunn^90^ given that these endpoints typically have skewed distributions. For all quantitative endpoints unaffected by litter structure, Jonckheere’s test^91^ was used to assess the significance of the dose-related trends and to determine at the 0.01 level of significance, whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test).

Postweaning body weights were measured on two pups per sex per litter in the 2-year study; more than two pups per sex per litter were possible in preweaning body weight measurements. The analyses of pup body weights and body weights adjusted for litter size (described below) of these animals took litter effects into account using a mixed model, where litters were the random effect. To adjust for multiple comparisons in these models, a Dunnett-Hsu adjustment was used.^92^ Dam body weights during gestation and lactation were analyzed with the parametric multiple comparison procedures of Dunnett^85^ and Williams,^86;^ ^87^ depending on whether Jonckheere’s test indicated the use of a trend-sensitive test. P values for these analyses are two-sided.

### Analysis of Gestational and Fertility Indices

Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across dose groups. The Fisher exact test was used to conduct pairwise comparisons of each dosed group with the control group. P values for these analyses are two-sided.

### Body Weight Adjustments

Preweaning pup body weights were adjusted for live litter size as follows: A linear model was fit to body weights as a function of dose and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight on the basis of the difference between its litter size and the mean litter size. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 21 were adjusted for PND 4 poststandardization litter size. Following adjustment, body weights were analyzed with a linear mixed model with a random litter effect.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control data must be generally similar. Significant factors affecting the background incidence of neoplasms at a variety of sites are diet, sex, strain/stock, vehicle and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period,^93-95^ including the concurrent control groups for comparison across multiple technical reports. Due to the sectioning of residual tissues for the rat uteri, the historical control for this organ consists of three studies at this time: Indole-3-carbinol, perfluorooctanoic acid, and this study. In general, the historical control data for a given study includes studies using the same route of administration, and the overall incidence of neoplasms in control groups for all routes of administration are included for comparison, including the current study.

## Quality Assurance Methods

The 2-year studies were conducted in compliance with FDA Good Laboratory Practice Regulations.^96^ In addition, the 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of 2H4MBP was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli. The protocol for these studies and the results are given in Appendix A.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage on the basis of the relationship between electrophilicity and mutagenicity^97^ and the somatic mutation theory of cancer.^98;^ ^99^ However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^100^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^101;^ ^102^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.