# Introduction

Figure 1

2-Hydroxy-4-methoxybenzophenone (CASRN 131-57-7; Chemical Formula: C_14_H_12_O_3_; Molecular Weight: 228.25)

Synonyms: Benzophenone-3; (2-hydroxy-4-methoxyphenyl)-phenylmethanoneoxybenzone; oxybenzone.

## Chemical and Physical Properties

2-Hydroxy-4-methoxybenzophenone (2H4MBP) is an off-white to light-yellow powder with a melting point of 62°C to 65°C. 2H4MBP is relatively insoluble in water (69 mg/kg at 25°C) and is readily soluble in most organic solvents. 2H4MBP absorbs ultraviolet (UV) A (320 to 400 nm) and UVB (290 to 320 nm) light and is photostable.^1^

## Production, Use, and Human Exposure

2H4MBP is synthesized by condensation of benzoic acid with resorcinol monomethyl ether in the presence of heat, zinc chloride, and polyphosphoric acid or by the Friedel-Crafts reaction of benzoyl chloride with 3-hydroxyanisole.^2^

2H4MBP is commonly used in sunscreens and other personal care products at concentrations of up to 6% to protect the wearer from solar erythema. Per the Environmental Working Group’s Guide to Sunscreens database,^3^ 2H4MBP is found in more than 1,000 products, including beach, sport, and baby sunscreens (619), moisturizers with SPF (150), and lip balms (109), often in combination with other sunscreens. 2H4MBP has also been combined with the insecticide repellent N,N-diethyl-meta-toluamide (DEET).^4^ 2H4MBP is also used as a photostablizer for synthetic resins and polymers, including plastics (0.05–0.5%) to prevent UV degradation.^5-7^ Exposure can occur when present in acrylic and modified acrylic plastics that come in contact with food.^8^

2H4MBP and its metabolites are typically excreted in urine. A study using National Health and Nutrition Examination Survey (NHANES) cycle data from 2004 to 2012 demonstrated more than 96% of the 10,232 samples (representing all populations) contained measurable urinary concentrations of 2H4MBP. Creatinine-adjusted urinary least square geometric mean concentrations ranged from 9 to 17 ng/mL in males, and 18 to 45 ng/mL in females. Children and adolescent concentrations ranged from 17 to 27 and 13 to 24 ng/mL, respectively.^9;^ ^10^ Higher urinary concentrations of 2H4MBP were observed in non-Hispanic whites and have been attributed to increased sunscreen use (28 versus 13 ng/L).^11^ Higher concentrations in females have been ascribed to the use of personal care products (e.g., lip balms, cosmetics) that often contain 2H4MBP.^11^

## Regulatory Status

2H4MBP is approved by the U.S. Food and Drug Administration (FDA) for use as a sunscreen when present up to 6% either alone or in combination formulations and as an indirect food additive in acrylic and modified acrylic plastics that come into contact with food.^8;^ ^12^ 2H4MBP is also approved for use as a nonfood inert pesticide additive.^13^ Section 8(a) of the Toxic Substances Control Act requires manufacturers of 2H4MBP to report preliminary assessment information concerned with production, exposure, and use to the U.S. Environmental Protection Agency.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

2H4MBP was well absorbed (≥63.9%) following a single gavage administration of [^14^C]2H4MBP (3.01 to 2,570 mg/kg) in male F344/N rats, with the administered dose excreted primarily via urine (63.9% to 72.9%) and feces (19.3% to 41.7%) by 72 hours postadministration. The radioactivity remaining in tissues 72 hours after administration was low (~0.1%) in all dose groups.^14^ Following dermal application of 51.6, 204, and 800 μg [^14^C]2H4MBP (in ethanol) in male rats, the dose was excreted mainly via urine (32.4%, 39.2%, and 13.2%) and feces (16.9%, 22.2%, and 9.15%) by 72 hours postapplication. The dose excreted in urine and feces indicated that the applied dose absorbed was 49.3%, 61.4%, and 22.4%, respectively, for 51.6, 204, and 800 μg [^14^C]2H4MBP. When the dose (50 μg) was applied in a lotion vehicle, the dose absorbed (51.8%) was similar to that in ethanol with 33.9% and 17.9% of the dose recovered in urine and feces, respectively.^14^

Absorption, distribution, metabolism, and excretion (ADME) were also investigated in male and female Sprague Dawley rats and B6C3F1/N mice following gavage administration or dermal application of [^14^C]2H4MBP.^15^ Following a single gavage administration (10, 100, or 500 mg/kg [^14^C]2H4MBP) in rats, most of the administered dose was excreted in urine (53% to 58%) and feces (38% to 42%) by 72 hours postadministration with no observable sex difference in excretion. The radioactivity in urine indicated that ≥53% of the administered dose was absorbed. Following a single 100 mg/kg gavage dose in male mice, urinary (≥34%) and fecal (≥24%) excretion was similar to that of rats. However, mice (5% to 15%) excreted a higher percentage of administered dose as exhaled CO^2^ compared to rats (~1%). The retention of dose in tissues was low at 72 hours (<1%) in all gavage groups.

ADME of 2H4MBP was investigated in rats and mice at 72 hours following dermal application of 0.1 or 10 mg/kg [^14^C]2H4MBP formulated in several vehicles. In male rats, the highest absorption was observed following application in light paraffin oil (80%). Absorption following application in ethanol, ethanol:coconut oil (1:1), or coconut oil was comparable to paraffin oil (64% to 73%). In contrast, the absorption of 2H4MBP from the lotion vehicle (olive oil:emulsifying wax:water [15:15:70 v:v:v]) in male (10 mg/kg, 46%) and female (15 mg/kg, 29%) rats was lower relative to other vehicles. Both male and female mice absorbed approximately 60–69% of 10 mg/kg dose in ethanol or acetone and 37–46% of 10 mg/kg dose when formulated in the lotion vehicle. There was no dose-related effect in absorption (0.1 versus 10 mg/kg) in either male rats or mice.^15^

Kinetics of disposition of 2H4MBP has been investigated in rats in limited studies. Following a single gavage dose of 100 mg/kg 2H4MBP in male Sprague Dawley rats, the time (T_max_) to reach the maximum concentration, C_max_ (21.21 μg/mL), was 3 hours; the elimination of 2H4MBP in plasma was biphasic with alpha and beta half-lives of 0.88 and 15.9 hours, respectively. Of the tissues examined, the liver had the highest concentration of 2H4MBP and conjugated 2H4MBP at 6 hours.^16^ In another study, following a 100 mg/kg gavage dose in male Sprague Dawley rats, similar T_max_ (2.72 hours) and C_max_ (21.21 μg/mL) were observed, with a plasma elimination half-life of 4.58 hours.^17^ Following a single gavage dose of 10 mg/kg in male and female Harlan Sprague Dawley rats, T_max_ and C_max_ were 6.0 hours and 8.5 ng/mL, respectively, for males and 2.3 hours and 2.9 ng/mL for females. The plasma elimination half-life for males was 6.4 hours and for females was 18.5 hours. The bioavailability of 2H4MBP in male and female rats was <1%, demonstrating extensive first-pass metabolism of 2H4MBP following gavage administration.^15^

2H4MBP was metabolized via numerous pathways in rodents, including demethylation, oxidation, glucuronidation, and sulfation. Products identified in bile and/or urine of rodents following administration of 2H4MBP were 2H4MBP, 2,4-dihydroxybenzophenone (DHB), 2,3,4-trihydroxybenzophenone (THB), 2,5-dihydroxy-4-methoxybenzophenone (D2H4MBP), and their corresponding glucuronide and sulfate conjugates (Figure 2).^14-16;^ ^18^ Similar metabolites were also observed in vitro following incubation of 2H4MBP with microsomes.^19;^ ^20^ 2H4MBP and DHB have been quantified in serum from pregnant rats.^21^ In a recent National Toxicology Program (NTP) study, rats were exposed in utero and postnatally to 0, 3,000, 10,000, and 30,000 parts per million (ppm) 2H4MBP in the diet, and plasma concentrations of free (unconjugated analytes) and/or total (free and all conjugated forms) 2H4MBP, DHB, THB, and D2H4MBP were quantified (Figure 2).^22^ Free D2H4MBP and THB were not detected in plasma. Mean plasma concentrations of total 2H4MBP and DHB were higher (~100- to 300-fold) than the free 2H4MBP and DHB concentrations demonstrating extensive conjugation of 2H4MBP and its metabolites. The rank order of the total concentrations were 2H4MBP ≈ DHB > D2H4MBP >> THB. Free and total analyte plasma concentrations were not sex-dependent in either PND 28 or PND 56 pup plasma.

Figure 2

Metabolism of 2-Hydroxy-4-methoxybenzophenone in Rodents

2H4MBP = 2,4-dihydroxy-4-methoxybenzophenone; D2H4MBP = 2,5-dihydroxy-4-methoxybenzophenone; THB = trihydroxybenzophenone; DHB = dihydroxybenzophenone.

*Indicates glucuronide and sulfate conjugates.

### Humans

ADME data on 2H4MBP in humans are limited. Human studies with sunscreens have demonstrated that 2H4MBP is readily absorbed from the skin.^23^ A study that used excised human epidermis in Franz diffusion cells showed that approximately 10% of the dermally applied dose of 2H4MBP is absorbed.^24^ When applied dermally, 2H4MBP and the metabolites DHB and 2,2’-dihydroxy-4-methoxybenzophenone can be detected in serum and are excreted in urine.^25;^ ^26^ A study examining the absorption of 2H4MBP, and subsequent irradiation with UV A and B rays, demonstrated that participants excreted 1.2–8.7% (mean 3.7%) of the total applied dose in the urine. 2H4MBP could be detected in the urine 3–5 days after application. UV irradiation did not affect the amount of 2H4MBP excreted.^27^ Frequency of sunscreen use is also related to urinary 2H4MBP concentrations with frequent users having much higher urinary concentrations.^28^ 2H4MBP has been detected in maternal urine and breast milk.^29;^ ^30^

## Toxicity

### Experimental Animals

The acute rat dermal LD_50_ has been reported to be greater than 16 g/kg body weight. Concomitant local skin reactions consisting of mild to moderate erythema were observed in the absence of significant pathologic findings.^5^ The rat oral LD_50_ for 2H4MBP has been reported to be greater than 12.8 g/kg.^31^ These authors also reported that administration of 0.5% or 1% 2H4MBP in rat diet for 12 weeks was associated with growth depression. Upon examination at week 6, female rats exposed to 0.5% or 1% displayed a leukocytosis with an increase in the lymphocyte count and a decrease in the neutrophil count, as well as a decrease in hemoglobin concentration. At week 12, rats exposed to either concentration displayed anemia and lymphocytosis with a reduction in granulocytes. The weights relative to brain of the pituitary gland, thymus, heart, adrenal gland, lung, and spleen were also reduced in both sexes. The 0.5% females showed an increase in the relative weight to brain of the thyroid gland and first stages of kidney degeneration. Degenerative nephrosis was diagnosed both macro- and microscopically in the kidneys of both sexes at 1%.

NTP has reported the findings of studies conducted in F344 rats and B6C3F1 mice exposed to: (1) 0, 3,125, 6,250, 12,500, 25,000, or 50,000 ppm 2H4MBP in feed for 2 or 13 weeks; (2) 0, 1.25, 2.5, 5, 10, or 20 mg/kg body weight for 2 weeks dermally in acetone or lotion; and (3) 12.5, 25, 50, 100, or 200 mg/kg body weight in acetone or lotion for 13 weeks duration.^32^ In rats and mice, dietary administration of 6,250 ppm and higher concentrations of 2H4MBP for 2 weeks were associated with increases in liver weights and with marked hepatocyte cytoplasmic vacuolization.

In the 13-week rat dietary study, 50,000 ppm of 2H4MBP was associated with lower male and female body weight gains. Liver weights were increased at 3,125 ppm and higher, whereas kidney weights were increased at the 6,250 ppm and higher dietary exposure concentrations. Males and females in the 50,000 ppm exposure groups also displayed lower weights of the heart, lungs, and thymus, and males in the 50,000 ppm exposure group displayed lower weights of the brain and testis.^33^ Histopathologic kidney findings primarily occurred in high-exposure rats, and included dilated tubules, tubular epithelial cell regeneration, papillary degeneration or necrosis, and inflammation. Although cytoplasmic vacuolization was not observed in the liver, liver enzymes remained elevated at 13 weeks.

In the 13-week mouse dietary study, there was an exposure-related decrease in body weight gains, mild increases in liver weights in both sexes, and variable increases in kidney weight in females. Histopathological findings were limited to kidneys of mice receiving 25,000 and 50,000 ppm and included eosinophilic protein casts in dilated renal tubules, and mild inflammation. In the 2-week rat and mouse dermal studies, small and variable increases in liver and kidney weights were observed primarily in the higher dose groups. In the 13-week dermal studies, kidney weights were increased in dosed groups of female rats and variably increased in dosed male mice. These weight changes were not associated with any histopathological changes.^33^ A 4-week dermal study in rats using 100 mg/kg of 2H4MBP in petroleum jelly twice a day did not affect body weight; liver, kidney, or testes weight; or histopathology.^34^ 2H4MBP exposure lowered rat blood glutathione-S-transferase levels.

### Humans

Other than the human findings summarized in the Immunotoxicity section of this report, no other significant toxicity studies in humans were identified in the public domain.

## Reproductive and Developmental Toxicity

### Models of Endocrine Activity

2H4MBP has been reported to bind to and activate estrogen receptor alpha (ERα) with an IC_50_ ranging from 3 to 20 × 10^−6^ M.^35-38^ 2H4MBP can also activate estrogen receptor beta (ERβ),^37;^ ^39^ and reports indicate that 2H4MBP can act as ERα, ERβ, and progesterone receptor antagonists.^35; 37; 39^ In NTP-sponsored ER binding and activation studies conducted under OPPTS 890.1250 and OPPTS^a^ 890.1300, maximal mean specific binding was >75% (more than 75% of the radiolabeled estradiol remained bound), which categorizes 2H4MBP as “non-interacting”; however, 2H4MBP was able to induce a luciferase response, albeit weak (>10%, log EC_50_s −3.2 and −4.0 M) (Appendix F).^40;^ ^41^ 2H4MBP acts as an estrogen in stimulating MCF7 cell proliferation (IC_50_ 3.4 × 10^−6^). 2H4MBP has been shown to induce a uterotrophic response (ED_50_: 1,000 to 1,500 mg/kg per day) in immature rats.^42^ However, 2H4MBP did not cause a uterotrophic response in ovariectomized rats when tested up to 1 g/kg in an NTP study (Appendix F). 2H4MBP was evaluated in quantitative (dose-response) high throughput screening assays by NTP in the Toxicology in the 21st Century (Tox21) program, and significant activity was observed in assays measuring stimulation of ER, progesterone receptor, constitutive androstane receptor, pregnane X receptor, retinoic acid receptor, and estrogen-related receptor signaling pathways. In addition, 2H4MBP was shown to inhibit androgen receptor signaling (https://pubchem.ncbi.nlm.nih.gov/compound/4632#section=BioAssay-Results&fullscreen=true).

a Guidelines issued before April 22, 2010, refer to “OPPTS” because the office name changed from “Office of Prevention, Pesticides and Toxic Substances” to “Office of Chemical Safety and Pollution Prevention," or “OCSPP.”

2H4MBP exposure in male rainbow trout and Japanese medaka has been shown to induce vitellogenin production, an estrogenic response, and change the number of eggs produced and egg viability/hatching.^43^ 2H4MBP has also been shown to increase plasma concentrations of testosterone in male adult Japanese medaka and to decrease the estradiol to testosterone ratio in both male and female fish with concomitant downregulation of gonadal steroidogenic genes (star, Cyp11a, Cyp17, Hsd3b, Hsd17b3, and Cyp19a).^44^

### Experimental Animals

The potential for 2H4MBP exposure to affect sperm density and vaginal cytology has been reported.^32^ Rats and mice received 0, 3,125, 12,500, or 50,000 ppm in the diet for 90 days. Male rats exposed to 50,000 ppm weighed 30% less than control animals and displayed lower epididymis (17%) and caudal epididymis (22%) weights and sperm density (27%). Female rats displayed an increase in estrous cycle length in the 12,500 and 50,000 ppm groups (>1 day).

High-exposure male mice displayed a 27% decrease in sperm density and weighed 16% less than control mice. High-exposure female mice displayed a slight increase in estrous cycle length relative to control mice (>0.5 day). NTP conducted a Reproductive Assessment by Continuous Breeding (RACB) study in mice at exposure concentrations of 12,500, 25,000, and 50,000 ppm in the diet.^45^ 2H4MBP had no effect on F_0_ fertility, but the number of live pups per litter was significantly reduced in the 25,000 and 50,000 ppm groups, which was associated with lower parental body weights. There were no changes in sperm density or estrous cyclicity; however, the cumulative days to litter were increased in the 50,000 ppm group. 2H4MBP had minimal effects on fertility in the F_1_ generation, but pup weights were significantly reduced. Collectively, it was concluded that 2H4MBP caused systemic toxicity but had minimal effects on fertility and reproduction at the exposure concentrations studied. Another study examined the effects of 0, 10, 20, 100, or 400 mg/kg body weight of 2H4MBP dermally applied to mice for 13 weeks. No effects on body weight, organ weights, sperm density, or testicular histopathology were attributed to 2H4MBP exposure.^46^

The potential effects of maternal and lactational exposure to 2H4MBP on F_1_ development and reproductive organs have been assessed.^21^ Sprague Dawley rats received 0, 1,000, 3,000, 10,000, 25,000, or 50,000 ppm 2H4MBP in the diet from gestation day (GD) 6 until weaning on postnatal day (PND) 23. Exposure to 2H4MBP was associated with increased liver and kidney weights in dams. Clinical pathology findings in the dams during GDs 10, 15, and 20 were elevation of glucose, alanine aminotransferase, alkaline phosphatase, cholesterol, total bile acids, and depression of aspartate aminotransferase, blood urea nitrogen, and creatinine. These findings occurred primarily in the higher dose groups and often at all time points. Alanine aminotransferase and cholesterol were elevated in the male and female offspring at the higher two exposure concentrations. No significant differences were observed in littering parameters. Male and female pups in the two highest dose groups displayed lower body weights. Male anogenital distance adjusted for body weight at PND 23 was decreased in the highest dose group. At necropsy on PND 23, female liver weights relative to body weight were higher at exposure concentrations ≥10,000 ppm. In the highest dose group, spermatocyte development was impaired and ovarian follicular development was delayed.

### Humans

Maternal 2H4MBP exposure, determined primarily via third trimester urinary concentrations, was associated with lower birth weight of girls and the opposite in boys.^47^ In another study, maternal gestational urinary 2H4MBP concentrations were positively associated with body weight and head circumference at birth.^48^ Maternal exposure to 2H4MBP has been postulated to be involved in the development of Hirschsprung’s disease (incidence of 1 in 5,000 newborns).^49^ One hypothesis is that this complex congenital disease is caused by gene–environment interactions that can lead to intestinal obstruction and chronic constipation in the offspring. Pregnant women that have higher 2H4MBP concentrations in urine exhibit a higher odds ratio (2.4 to 2.6:1) of having a child with Hirschsprung’s disease.^50^

In the 293T and SH-SY5Y cell migration model of Hirschsprung’s disease, 2H4MBP suppressed migration and altered the levels of key migratory proteins at both the ribonucleic acid (RNA) and transcribed protein levels in the absence of cytotoxicity.^50;^ ^51^ A study looking at the potential effect of 2H4MBP dermal application and serum hormone changes in young men and postmenopausal women concluded that the amount of 2H4MBP absorbed did not alter the endogenous reproductive hormone homeostasis.^23^

## Immunotoxicity

### Experimental Animals

A study conducted per procedures outlined by the Federal Hazardous Substances Labeling Act (FSLA) for acute skin irritation and scored for irritation per the Draize method concluded that an occlusive patch containing 0.5 mL or 0.5 mg at 2H4MBP concentrations from 4% to 100% was nonirritating to intact and abraded albino rabbit skin.^5^ 2H4MBP at 100% up to 100 mg was found not to be irritating to the rabbit eye using the modified FSLA or Draize methods. A sunscreen containing 6% 2H4MBP was found not to be photosensitizing in albino rabbits and was negative for sensitization potential in the Klingman Maximization Procedure^5^ and local lymph node assay.^52^

### Humans

Some reports have indicated that 2H4MBP might induce allergenic and sensitization responses.^6^ In a sunscreen sensitization study, researchers detected allergy and/or photoallergy to 2H4MBP in 3.7% of the human subjects, which was attributed to application of moisturizing creams that contained 2H4MBP.^53^ A subsequent study sponsored by Schering-Plough HealthCare Products reported the results of the meta-analysis of 64 unpublished studies conducted at 10 independent clinical laboratories representing the results of 19,570 individuals subjected to human repeat insult patch tests and photoallergy studies between 1992 and 2006.^54^ These studies were aggregated and analyzed to evaluate the irritancy and sensitization potential of sunscreen products containing 2H4MBP concentrations between 1% and 6%. Forty-eight dermal responses were considered suggestive of sensitization or irritation with a mean rate of response of 0.26%. The authors concluded that sunscreen products formulated with 1% to 6% oxybenzone do not possess a significant sensitization or irritation potential for the general public. 2H4MBP was also negative in an in vitro phototoxicity assay using SkinEthic^™^, a human epidermis model.^55^

## Carcinogenicity

No reports of studies that characterize the potential for 2H4MBP to induce neoplasms were found in the literature.

## Genetic Toxicity

2H4MBP was negative in tests screening for mutagenic agents in dental materials^56^ and in sunscreens.^57;^ ^58^ However, as reported in NTP Toxicity Report 21,^33^ 2H4MBP showed weak mutagenic activity in Salmonella typimurium strains TA100 and TA97 when tested in the presence of 30% hamster liver S9 mix; results from a second bacterial mutation test that tested the compound with 10% hamster liver S9 mix were negative. 2H4MBP was also positive for induction of sister chromatid exchanges and chromosomal aberrations in Chinese hamster ovary cells when testing occurred in the presence of rat liver S9 mix.^32^ The parent structure, benzophenone, also was negative in an NTP bacterial mutagenicity assay in several strains of Salmonella typhimurium, with and without exogenous metabolic activation,^59^ but both 2,2ʹ- dihydroxy-4-methoxybenzophenone and 4,4ʹ-bis(dimethylamino)benzophenone (Michler’s ketone) were mutagenic in bacterial assays conducted by NTP. Michler’s ketone also was positive in the mouse lymphoma L5178Y cell mutation assay, and in tests for induction of chromosomal aberrations and sister chromatid exchanges in Chinese hamster ovary cells.^60-64^ In vivo assessments of genotoxic potential showed no activity in the Drosophila somatic mutation and recombination test following exposure of larva to feed containing 3,500 ppm 2H4MBP, and no induction of chromosomal aberrations in male Sprague Dawley rats treated with up to 5 g/kg 2H4MBP either as a single gavage treatment or after five once-daily gavage treatments.^65^ 2H4MBP was also negative for induction of micronucleated erythrocytes in male and female mice treated via dosed feed for 90 days.^32^ No activity in any of the Tox21 deoxyribonucleic acid (DNA) damage assays was observed, consistent with the results in standard in vitro and in vivo assays for genotoxicity.

## Study Rationale

2H4MBP was nominated to NTP by the National Cancer Institute because of high exposure via use of 2H4MBP-containing sunscreen products and lack of carcinogenicity data. 2H4MBP was also nominated by a private individual to ascertain genotoxic potential. NTP designed 2-year studies in rats and mice to evaluate the potential carcinogenic activity of 2H4MBP. The initiation of F_1_ generation exposure on GD 6 (after expected implantation) in the 2-year rat study was selected to reflect potential human exposure to 2H4MBP, often present in sunscreens and cosmetics; exposure may occur at any human life stage, including in utero and early life. As the pattern of disposition is similar following oral and dermal exposure, 2H4MBP exposure via the diet was selected, rather than topical application, to sustain internal exposure. It was also recognized that if applied topically, internal dose would be influenced by intra- and inter-animal grooming behavior.