# Appendix H Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TR-597.

## H.1 Fourteen-week Interim Evaluation in Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systematic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

R02 – Reproductive Performance Summary

## H.2 Perinatal and Two-year Study in Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

HMB Chronic Perinatal Female Harlan Sprague Dawley Rats Gestational and Lactational Chemical Consumption (mg HMB/kg body weight/day)HMB Chronic Perinatal Female Harlan Sprague Dawley Rats: Gestational and Lactational Food Consumption (g/animal/day)

HMB Chronic Perinatal Female Harlan Sprague Dawley Rats: Lactational Body and Body Weight Gains

HMB Chronic Perinatal Litter Data Analysis in Female Harlan Sprague Dawley Rats: Live Litter Size

HMB Chronic Perinatal Litter Data Analysis in Female Harlan Sprague Dawley Rats: PND1 Data

HMB Chronic Perinatal Litter Data Analysis in Female Harlan Sprague Dawley Rats: Survival

HMB Chronic Perinatal: Summary Pup Body Weights

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors with Rao-Scott

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## H.3 Two-year Study in Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 –Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## H.4 Genetic Toxicology

G06 (381877) – Ames Summary Data

G06 (613844) – Ames Summary Data

G06 (G10260) – Ames Summary Data