# Appendix F Endocrine Disruptor Screening Panel Studies

## F.1 Competitive Estrogen Receptor Binding Assay

### F.1.1 Methodology

All procedures were conducted in accordance with the U.S. Environmental Protection Agency (EPA) guideline Office of Prevention, Pesticides and Toxic Substances (OPPTS) 890.1250.^40^

Briefly, 7-day postovariectomy uterine tissue from 12- to 13-week old Sprague Dawley rats was procured from Harlan Laboratories (now Envigo, Indianapolis, IN) and shipped overnight on dry ice. Uterine tissue was inspected for signs of residual ovarian tissue, and, if present, that tissue was discarded. Cytosolic fractions were prepared, pooled, and either used immediately or frozen at −80°F. If frozen, once subsequently thawed, unused aliquots were discarded. Three saturation bindings assays to support each run of the respective sunscreen ingredient were performed according to OPPTS 890.1250 and were shown to be acceptable.^40^

Radioactivity was assessed via a scintillation counter (PerkinElmer Tri-Carb 2910TR Liquid Scintillation Analyzer Model B2910) and each vial was counted for at least one minute with quench correction for determination of disintegrations per minute (DPM) per vial. Standards (^3^H, ^14^C, and background) were used to verify accurate counting. For competitive binding, 1 nM of [^3^H]-17β-estradiol was prepared on the day of assay and the specific activity was adjusted for decay over time prior to performing dilutions. The concentration of estrogen receptor (ER) was sufficient to bind 10–15% of the radioligand, and the incubation time was 16–20 hours at 4°C. The competitive binding assay was determined to be functioning correctly on the basis of criteria set forth in OPPTS 890.1250; specifically, increasing concentrations of unlabeled 17β-estradiol displaced [^3^H]-17β-estradiol from the receptor in a manner consistent with one-site competitive binding.^40^

The curve fit to the radio-inert estradiol data points using nonlinear regression descended from 90% to 10% over approximately an 81-fold increase in the concentration of the test chemicals. Ligand depletion was minimal—the ratio of total binding in the absence of competitor to the total amount of [^3^H]-17β-estradiol added per assay tube was no greater than 15%. The parameter values (Top, Bottom, and Hill slope) for 17β-estradiol and 19-norethindrone (positive control) were within the tolerance bounds outlined in the OPPTS guideline.^40^ The dimethyl sulfoxide (DMSO) solvent control did not alter the sensitivity or reliability of the assay—the acceptable limit of ethanol concentration in the assay tube—was 3%, the acceptable limit of DMSO concentration was ≤10%, and all tubes contained the same amount of solvent. The negative control substance, octyltriethoxysilane, did not displace more than 25% of the radioligand from the ER on average across all concentrations.

The sunscreen ingredients were assessed over a concentration range that fully defined the top of the curve (i.e., a range that showed that a top plateau was achieved) and the top was within 25% of either the solvent control or the value for the lowest concentration of the 17β-estradiol l standard for that run. The classification of a chemical as a binder or nonbinder was made on the basis of the average results of three nonconcurrent runs, each of which met the performance criteria and, taken together, were consistent with each other, as per OPPTS guideline 890.1250. ^40^ Each run was classified as “interactive,” “not interactive,” “equivocal,” or “equivocal up to the limit of the concentrations tested.” A run was classified as “interactive” with the ERs if the lowest point on the fitted response curve within the range of the data was less than 50%.

“Percent” (%) refers to binding of the radiolabeled estradiol. Thus, “less than 50%” means that less than 50% of the radiolabeled estradiol was bound, or, equivalently, that more than 50% of the radiolabeled estradiol had been displaced from the receptor. A run was classified as “equivocal up to the limit of concentrations tested” if there were no data points at or above sunscreen ingredient concentration of 10^−6^ M and one of the two following conditions held: (1) a binding curve could be fit but 50% or less of the radiolabeled estradiol was displaced by a concentration of 10^−6^ M; or (2) a binding curve could not be fit and the lowest average percent binding among the concentration groups in the data was above 50%. A run was classified as “not interactive” if there were usable data points at or above 10^−6^ M and either: (1) the lowest point on the fitted response curve within the range of the data was above 75%; or (2) a binding curve could not be fit and the lowest average percent binding among the concentration groups in the data was above 75%. A run was classified as “equivocal” if it fell in none of these categories.

After each run was classified, the chemical was classified by assigning the following values to each run and averaging across runs: interactive = 2, equivocal = 1, and not interactive = 0. The chemical classification, based on the average of all the runs performed for a chemical, was calculated as: interactive (average ≥ 1.5), equivocal (0.5 ≤ average < 1.5), and not interactive (average < 0.5). Data points were plotted using GraphPad curve fit for:

IC_50_: Y = Bottom + (Top−Bottom)/(1 + 10^((logIC_50_−X)*Hillslope + log((Top−Bottom)/ (50−Bottom) − 1))).

The Bottom was constrained to >0 for 2H4MBP and 2-Ethylhexyl p-methoxycinnamate (EHMC).

### F.1.2 Results

In each of the three independent ER binding experiments, the maximal mean specific binding was >75% at every soluble 2H4MBP and EHMC concentration assessed, categorizing them as “not interactive” (Figure F-1). When the specific binding was averaged using the scoring system as described in the OPPTS guideline, 2H4MBP and EHMC were classified as “not interactive.”^40^

The half maximal inhibitory concentration (IC_50_), logIC_50_, Top, Bottom, and Hill slopes of the curves were determined using the Hill model for 2H4MBP, EHMC and the reference agents (Table F-1). In general, the sunscreen ingredient-specific binding data could be fit to IC_50_ models but were often ascribed a fit of “ambiguous” by the software, likely due to the weakness of response. The IC_50_s for the “not interactive” sunscreen ingredients, 2H4MBP and EHMC, ranged from approximately 2.3 × 10^-4^ to 14.8 × 10^-4^ M and approximately 1.9 × 10^−3^ to 4.6 × 10^4^ M, respectively.

The weak positive control 19-norethindrone exhibited a logIC_50_ of approximately −5.5 to −5.6 M, whereas 17β-estradiol displayed a logIC_50_ of approximately −8.8 to −9.0 M. The Hill slope for these reference agents was between approximately −0.7 and −1.1.

## F.2 Estrogen Receptor Transcriptional Activation in a Human Cell Line (HeLa-9903)

### F.2.1 Methodology

All procedures were conducted in accordance with EPA guideline OPPTS 890.1300.^40^ Briefly, the stably transfected hERα-HeLa-9903 cell line was obtained from the Japanese Collection of Research Bioresources (JCRB) Cell Bank (Osaka, Japan). This cell line is derived from a human cervical tumor and has two stably inserted constructs—the hERα expression construct (encoding the full-length human receptor) and a firefly luciferase reporter construct bearing five tandem repeats of a vitellogenin estrogen-responsive element driven by a mouse metallothionein (MT) promoter TATA element. Consequently, the hERα-HeLa-9903 cell line can measure the ability of a test substance to induce hERα-mediated transactivation of luciferase gene expression and consequently can be used to assess the ability of a test substance to act as an agonist of hERα.

The cell line was certified to be free of mycoplasma, was passage 21 for the assay, and was maintained on phenol-red free media. The functional stability of the cell line was monitored using the following reference chemicals: 17β-estradiol, 17α-estradiol, 17α-methyltestosterone, and corticosterone. A complete concentration response curve for each reference compound was run each time the transcriptional activation assay was performed and the logPC_50_, logPC_10_, logEC_50_, Hill slope, and fold induction values calculated, compared, and deemed consistent with guideline acceptable range values.

Cell viability was monitored by a two-read propidium iodide uptake assay using a Packard Fusion fluorescence plate reader at an excitation wavelength of 544 nm and an emission wavelength of 612 nm. The first read was taken 24 hours after the addition of the control and test substances. The measured fluorescence indicates spontaneous cell death and control/test material induced cytotoxicity. The cells were then lysed, and a second read was taken, indicating 100% cell death. The first read is then subtracted from the second read and the results of the subtracted reads are directly proportional to the viability of the cells. As a positive control for inducing cell death, 125 μM digitonin was used. Dose groups were normalized to vehicle control to generate percent cell viability.

DMSO was selected as a suitable vehicle for 2H4MBP and EHMC. 2H4MBP and EHMC solutions up to 10^−4.5^ M (the limit concentration for the assay) can be prepared while limiting the final concentration of DMSO in the assay medium to 0.1% (v/v). 17α-methyltestosterone,

17α-estradiol, corticosterone, and 17β-estradiol. The limit of solubility was determined by visual inspection of the test materials and controls after preparation of the final 1x dosing solutions in culture media. A sample of the 1x dosing solution was placed into wells of a clear 96-well plate and an endoscope was used to assess precipitation in each sample. Cytotoxicity and test article precipitation were assessed at 10^−6.5^, 10^−6^, 10^−5.5^, 10^−5^, 10^−4.5^, 10^−4^, 10^−3.5^, and 10^−3^ M. If a dose level of sunscreen ingredient produced cytotoxicity or precipitation, that dose level was not used. Cytotoxicity was observed at 10^−3^ M 2H4MBP or EHMC. The final concentrations of 2H4MBP and EHMC tested in replicate in the ER transcriptional activation assay were 10^−12^, 10^−11^, 10^−10^, 10^−9^, 10^−8^, 10^−7^, 10^−6^, and 10^−5^ M. Data points were plotted using GraphPad curve fit for:

EC_50_: Y = Bottom + (Top−Bottom)/(1 + 10^((logIC_50_−X)*Hillslope))

The Bottom was constrained to zero.

### F.2.2 Results

2H4MBP at 10^−5^ M induced relative luciferase activity of 14.9% and 20.9% in each respective run (Table F-2; Figure F-2). 2H4MBP was considered a “positive” agent as per OPPTS 890.1300 because it exceeded 10% of the response of the positive control.^40^ In neither run of the ER transcriptional activation assay did EHMC exceed an increase in luciferase activity greater than 5% (RPC_max_) at any of the viable concentrations assessed. The EC_50_ (and log thereof) and Hill slopes of the curves using the Hill model constrained at 0 were generated if possible. The top of the curve was constrained to <100% for corticosterone, 17α-methyltestosterone, and the sunscreen ingredients, as they did not exhibit a full response (Table F-2). The reference agents and 2H4MBP-specific luciferase data could be fit to the EC_50_ model. The logEC_50_ for 2H4MBP was −3.2 and −4.0 M, respectively, for runs 1 and 2. The logPC_10_ for 2H4MBP was calculated to be −5.6 M for each respective individual run.

The weak positive control 17α-methyltestosterone exhibited logEC_50_s of −8.8 and −8.6 M and Hill slopes of >1. 17β-estradiol displayed logEC_50s_ of −10.5 and −10.3 M and Hill slopes of ~1.2 to 1.5. 17α-estradiol displayed logEC_50s_ of −8.8 and −8.6 M and Hill slopes of 1.5 to 2.0 (Table F-2).

## F.3 Uterotrophic Assay (OPPTS 890.1600)

### F.3.1 Methodology

All procedures were conducted in accordance with OPPTS 890.1600 and were in compliance with the Animal Welfare Act Regulations.^122;^ ^123^ Animals were handled and maintained according to the Guide for the Care and Use of Laboratory Animals.^124^ Briefly, 80 ovariectomized Sprague Dawley (Crl:CD^®^(SD) IGS) rats, 7 weeks of age, were procured from Charles River Laboratories (Raleigh, NC). Rats were acclimated to the study room for 7 days prior to randomization (body weight stratification to an N of 8/group), and initiation of dosing. Dose formulations of 2H4MBP, EHMC (320 or 1,000 mg/kg/day) and reference agent 17α-ethinyl estradiol (EE) (0.1 mg/kg/day) were prepared in corn oil. Concentrations and homogeneity were confirmed; mean concentrations were within 10% of the target concentration and the homogeneity coefficient of variation was ≤5% of the target concentration.

Rats were administered a dose volume of 5 mL/kg via oral gavage for 3 consecutive days and then humanely euthanized by carbon dioxide (followed by secondary method to confirm death). Body weights and clinical observations were performed at least once daily. At termination, uteri (with cervix) were excised. Uterine wet and blotted weights were recorded to the nearest 0.0001 g. Terminal body weight and body weight gain were analyzed by ANOVA. Uterine and blotted uterine weights were analyzed using a General Linearized Model (JMP, version 12.0.1) with terminal body weight and exposure concentration as model effects. If the probability of the p value was ≤0.05, then potential differences in least square means were identified by Dunnett’s test (compared to control). EE was compared to the vehicle using the Student’s t-test.

### F.3.2 Results

Rats administered 0.1 mg/kg EE or 1,000 mg/kg 2H4MBP displayed statistically significant body weight loss, as well as significant decreases in body weight gain, over the 3-day dosing interval. Terminal body weights of rats exposed to EE were significantly lower than control by 6.4% (Table F-3). Administration of 0.1 mg/kg EE also resulted in statistically significant (2.8- and 2.3-fold) increases in uterine wet and blotted weights, respectively, demonstrating appropriate responsiveness of the system. Neither exposure concentrations of 2H4MBP nor EHMC significantly altered uterine wet or blotted weights.

## F.4 Competitive Androgen Receptor Binding (Rat Prostate Cytosol)

### F.4.1 Methodology

DMSO is one of the recommended solvents (OPPTS 890.1150) and was selected as a suitable vehicle.^125^ 2H4MBP and EHMC solutions were prepared with concentrations up to 10^−4^ M (the limit concentration for the assay) while limiting the final concentration of DMSO in the assay media to ~3.2% (v/v). DMSO was kept at the same concentration for the controls and for the test substance and was tested as a vehicle control with the reference chemical and reference controls for the run as well. Serial dilutions were prepared in DMSO to yield the final assay concentrations of 1 × 10^−3^ to 1 × 10^−10^ M. Precipitation of 2H4MBP and EHMC was observed at final assay concentrations of 1 × 10^−3^ M. The positive control, R1881, strongly binds androgen receptors (ARs) and was included to ensure that the run was properly performed and to allow an assessment of variability in the conduct of the assay across time. R1881 stock (10 mM) was diluted 1:10 and then serial diluted. Final concentrations of unlabeled R1881 were 1 × 10^−6^ to 1 × 10^−11^ M. The weak positive control was dexamethasone prepared from a 30 mM stock solution in DMSO and then serially diluted to final concentrations of 1 × 10^−3^ to 1 × 10^−10^ M. DMSO concentrations were kept at 3.2%. Visual observation determined the limit of test chemical solubility, and initial compound solubility was determined in solvent. In addition, the solutions were watched closely when added to the experiment tube, as the test compound may precipitate upon addition to the assay tube mixtures.

Cytosol was collected, processed, and validated per EPA OPPTS 890.1150 for use in this study.^125^ Briefly, for the three independent runs, ventral prostates from SD rats (90 days old and castrated <1 day prior to collection) were removed, weighed, and sent via overnight carrier on dry ice. Upon receipt, prostates were thawed, inspected for fibrous, inflamed, edematous, or other abnormal appearance, and, if present, the organ was discarded. Prostates were trimmed of excess fascia, weighed, minced with a scalpel blade and fine scissors, and immediately homogenized with a Polytron PT2100 at 4°C in TEDG buffer. The homogenates were centrifuged at 30,000 g for 30 minutes using a Sorvall RC5B centrifuge, cooled to 4°C. The supernatant from a given run was pooled and protein concentration was determined by the Bradford method (BioRad) typical values are 1–4 mg/mL. Samples were frozen and maintained at −70°C until use. Once thawed on ice and diluted to the predetermined optimal protein concentration, they were immediately used. Triamcinolone acetonide was used to prevent progesterone-specific binding.

[^3^H]R1881 was prepared on the day of assay. The specific activity was adjusted for decay over time prior to performing dilutions, and siliconized tubes were used for the assay. Saturation AR binding assays were performed for each independent run of the assay. Increasing concentrations of unlabeled R1881 displaced [^3^H]R1881 from the receptor in a manner consistent with one-site competitive binding; the ligand depletion was held below 15%, and was acceptable as per EDSP OPPTS 890.1150.^125^ DMSO at the concentrations used did not alter assay sensitivity or reliability. Resulting data were normalized to % specific binding and plotted. Data were curve fit by weighted least squares nonlinear regression analysis with weights equal to 1/Y according to:

Y = Bottom + (Top−Bottom)/(1 + 10^((logIC_50_−X)*Hillslope + log((Top−Bottom)/ (50−Bottom) − 1))).

Relative binding activity (RBA) was calculated by dividing the IC_50_ of the positive control R-1881 by the IC_50_ of the respective sunscreen ingredient.

### F.4.2 Results

The suitable top concentration of 2H4MBP and EHMC for use in all three independent AR competitive binding assays was 10^−4^ M, as precipitation was seen with both at 10^−3^ M. In the presence of 10^−4^ M 2H4MBP, [^3^H]-R1881 specific binding was 64.9%, 62.6%, and 61.2% for each independent experiment, with a mean of 62.9%. When fitted to the 1/Y weighted Hill model, the logIC_50_ ranged from −3.7 to −1.2 M. Collectively, 2H4MBP tested up to 10^−4^ M did not displace more than 50% of the [^3^H]-R1881, categorizing 2H4MBP as “equivocal” (Table F-4; Figure F-3), as per OPPTS Guidance.^125^

In each of the three AR competitive binding assays and the averaged competition curve, the [^3^H]-R1881 specific binding at every soluble EHMC concentration tested was >75%, with logIC_50_ values ranging from −2.2 to 5.0 M. Therefore, EHMC was classified as a “nonbinder.” The weak positive control dexamethasone exhibited logIC_50_ values of −4.3 to −4.6 M, whereas R1881-1 displayed logIC_50s_ of −8.9 to −9.9 M. The Hill slopes for these reference agents were approximately −1. The mean RBA for the “equivocal” 2H4MBP UV filter was >0.0002%. The mean RBA for the weak reference agent dexamethasone was 0.0024%.

## F.5 Androgenic Transactivation Activity in MDA-kb2 Reporter Cells: Agonist and Antagonist Modes

### F.5.1 Methodology

DMSO was selected as a suitable vehicle for the test substances. Therefore, solutions with a test substance concentration of up to 10^−3^ M (the highest concentration assessed) can be prepared while limiting the final concentration of DMSO in the assay medium to 0.5% (v/v). Each test substance was prepared for addition to the cell system by making a 400 mM stock. Dilutions were prepared in DMSO up to 400x, the final target concentration. Dihydrotestosterone (DHT), nilutamide (Nil), dichlorodiphenyldichloroethylene (p,p’-DDE, or DDE), 2H4MBP, and EHMC were all prepared on the day of dosing. Considering the short-term nature of studies of this type, no analyses of stability, homogeneity, or achieved concentration(s) were carried out on preparations of the test substance or positive control chemicals, either before or after the treatment phase. Solubility limits were determined by visual observation or particulate light scattering via nephelometry with Nepheloskan. Stably transfected MDA-kb2 cell line was obtained from ATCC and confirmed to be mycoplasma-free. The MDA-kb2 cell line is derived from the MDA-MB-453 breast cancer cell line by stable transfection with a mouse mammary tumor virus luciferase-neo reporter construct containing the androgen response element. The transcriptional stability was monitored by the use of the following reference chemicals: DHT, Nil, and p,p'-DDE. A complete concentration response curve for each reference compound was run each time the transcriptional activation assay was performed. Cells were maintained in Leibovitz’s L-15 culture medium containing 10% fetal bovine serum, in an incubator at approximately 37°C. The MDA-kb2 cell line is not contact inhibited and can be grown to confluence. Cells were subcultivated at a 1:2 to 1:8 subcultivation ratio. The cells were suspended with complete medium and plated into wells of a 96-well cell culture plate at a density of approximately 1 × 10^4^ cells/100 μL/well. The cells were then placed into an incubator at approximately 37°C overnight prior to chemical exposure.

After adding the reference chemicals/test substances, the plates were incubated in an incubator at approximately 37°C for approximately 24 hours. For the agonism plates, all concentrations were tested in replicates of 6/plate. In addition, for each concentration, two replicates/plate were prepared that incorporated the AR antagonist Nil. Replicates incorporating an AR antagonist allow for the identification of nonspecific (i.e., non-AR-mediated) induction of the luciferase gene as true AR-mediated induction is inhibited by addition of an antagonist whereas nonspecific induction is not. For the antagonism plates, all concentrations were tested in replicates of 4/plate. Four replicates were co-administered 1 nM DHT and test article at each concentration. Four replicates were co-administered 1,000 nM DHT and test article at each concentration. Replicates incorporating 1,000 nM DHT allowed for the identification of assay interference. Cell viability was monitored by a two-read propidium iodide (PI) uptake assay conducted under low light conditions. Cells were seeded and exposed as described above in a black-walled 96-well cell culture plate.

Digitonin (125 μM) was used as a cell death positive control. Following chemical exposure, the growth medium was removed and 50 μL of a PI working solution (44 μM in phosphate buffered saline) was added to each well. Background fluorescence was evaluated by measuring fluorescence immediately on a Packard Fusion fluorescence plate reader at an excitation wavelength of 544 nm and an emission wavelength of 612 nm. Following this determination, 50 μL of a 2% (v/v) Triton X-100 solution was added to each well and the plate was incubated at room temperature for approximately 15 minutes to fully lyse all cells in the wells before measuring fluorescence at the same wavelengths. The background-corrected fluorescence was calculated for each well by subtracting the results of the first read from the results of the second read. The change in cell viability was determined by comparing treated wells to the vehicle control wells. A ≥20% reduction in cell viability was considered evidence of cytotoxicity.

Luciferase activity was determined as described by Wilson^116^. Acceptance criteria included: (1) background value ratio of vehicle control to antagonist control should be <10X, and (2) the ratio of positive control to vehicle control should be >3X. Each data point was normalized to the average of the vehicle-only treated control (fold induction). Where appropriate, logPC_50_, logPC_10_, logEC_50_, and Hill slope values were calculated. For the test substance, the maximum response relative to the positive control (RPC_max_) was determined. In each individual run of the transcriptional activation assay, if RPC_max_ was less than 20%, the test substance was considered a negative response for AR agonism. For each individual run of the transcriptional activation assay, the acceptability of the data was evaluated using the following criteria: (1) the mean normalized luciferase signal of the PC (10 nM DHT) should be at least fourfold that of the mean vehicle control on each plate, and (2) the results of the reference compounds, Nil and DHT, should be within the acceptable ranges. If the acceptability criteria outlined above were met, that run of the transcriptional activation assay was considered definitive. The test substance was considered negative if RPC_max_ was <20% in at least two definitive runs of the transcriptional activation assay. The test substance was considered positive if RPC_max_ was ≥20% in at least two definitive runs of the transcriptional activation assay.

To determine the relative transcriptional activity as compared to the PC (10 nM DHT), the luminescence data from each plate were analyzed as follows: wells incorporating 1 nM DHT were analyzed in an identical fashion to wells incorporating 1,000 nM DHT, except that the data were normalized to the induced control with 1 nM DHT or 1,000 nM DHT, respectively. Any cytotoxic concentrations were excluded from data analysis. The mean value for the vehicle control wells was calculated and subtracted from each well to normalize the data. The mean value for the induced control with 1 nM or 1,000 nM DHT was calculated. The wells dosed with test or control substance and 1 nM or 1,000 nM DHT were normalized to the mean value for the induced control with 1 nM or 1,000 nM DHT, respectively. Averages of antagonist or high agonist control % maximal induction were calculated (test or control substance with 1 nM or 1,000 nM DHT, respectively). Differentials were calculated (averages of high agonist % maximal induction control minus averages of antagonist % maximal induction control). Where appropriate, RIC_max_, IC_50_, and Hill slope values were calculated. If the differential between the high antagonism and the low antagonism was greater than 50% and had a dose response (more than one data point) in two of two runs, then the test substance was considered positive. If the differential between the high antagonism and the low antagonism was less than 50% and did not have a dose response (more than one data point) in two of two runs, than the test substance was considered negative. For each individual run of the transcriptional activation assay, the acceptability of the data was evaluated using the following criteria: the mean normalized luciferase signal of the PC (10 nM DHT) should have been at least fourfold that of the negative control on each plate. If the acceptability criteria outlined above were met, that run of the transcriptional activation assay was considered to be definitive.

### F.5.2 Results

In all independent runs of the agonist transcriptional activation assay, neither 2H4MBP nor EHMC resulted in an increase in luciferase activity at any of the viable soluble concentrations tested; RPC_max_ <20% (Figure F-4).

In two of three runs the decrease in DHT-induced luciferase activity resulting from 2H4MBP exposure was approximately 25% at the highest feasible dose of −4.5 M, with the first run exhibiting a luciferase activity of 72.2% of maximal (Figure F-5). EHMC had no apparent inhibitory effect on DHT-induced AR transcriptional activity. The EC_50_, IC_50_ (and logs thereof), and Hill slopes of the curves using the unconstrained Hill model were determined (Table F-5). Curves could be fit for two of the three 2H4MBP runs and both EHMC runs. The logIC_50s_ and Hill slopes for Nil and DDE were approximately −6.4 and −4.8 M, −1.3 and −1, respectively.

## F.6 Hershberger Bioassay

### F.6.1 Methodology

All procedures were conducted in accordance with OPPTS 890.1400 and in compliance with the Animal Welfare Act Regulations.^123;^ ^126^ Animals were handled and maintained according to the Guide for the Care and Use of Laboratory Animals.^124^ Briefly, 208 (total) Sprague Dawley Crl:CD(SD) IGS rats were procured from Charles River Laboratories (Raleigh, NC) one week after PND 45 castration surgery. Rats were acclimated to the study room for 7 days prior to randomization (body weight stratification; N = 8/group) and initiation of dosing. This assessment was done as two separate studies (with respective controls). For the androgen agonist assessment, 0.4 mg/kg/day of testosterone propionate (TP) was used as the positive inducer of maximal androgenic response, whereas 3 mg/kg/day of flutamide (FT) (in combination with 0.4 mg/kg/day TP) was used to induce maximal inhibition of the TP-induced androgenic response. Dose formulations of 2H4MBP, EHMC, TP, and flutamide were prepared in corn oil.

In the first study, the vehicle (corn oil) and two exposure concentrations of 2H4MBP and EHMC were used (320 and 1,000 mg/kg/day) for the assessment androgen agonism, and three exposure concentrations (100, 320, and 1,000 mg/kg/day) were used to assess potential sunscreen ingredient antagonism of TP-induced androgen action. Respective controls (vehicle, TP, TP and FT) were included in each study. OPPTS 890.1400 specifies to select doses that ensure animal survival and that are without significant toxicity or distress to the animals after 10 consecutive days of chemical administration, and the highest dose should not cause a reduction in the final body weight of the animals greater than 10% of control weight.^126^ 2H4MBP and EHMC were evaluated up to the limit exposure concentration (1,000 mg/kg/day). The test substance, FT, or corn oil dose formulations were administered by oral gavage at a dose volume of 5 mL/kg body weight. TP dose formulations were administered by subcutaneous injection into the dorsoscapular region at a dose volume of 0.5 mL/kg body weight. In co-administered animals, oral gavage preceded subcutaneous injections. Dosing occurred 24 hours (± 2 hours) from the previous dose. Dose volume was determined on individual animal daily body weight. The dosing sequence was stratified across dose groups—one animal from each group and then repeated until all animals were dosed. Selection of the route of administration was in accordance with OPPTS 890.1400 and OECD Guideline 441.^126;^ ^127^

Samples were collected for confirmation of concentration and homogeneity. Mean concentrations were within 10% of the target concentration, and the homogeneity coefficient of variation was less than ≤5% of the target concentration. Rats were orally gavaged at a dose volume of 5 mL/kg for 10 consecutive days. Body weights and clinical observations were performed at least once daily. At study termination, rats were humanely euthanized by CO_2_ asphyxiation and death confirmed by a second method in the same order as they were dosed.

Gross observations were recorded for the ventral prostate, seminal vesicle and coagulating gland with fluid, levator ani/bulbocavernosus muscle, Cowper’s gland, and glans penis. The tissues were excised, trimmed of excess adhering tissue and fat, and weighed to the nearest 0.0001 g.

Terminal body weight and body weight gain were analyzed by ANOVA. Organ weights were tested (by dose) and assumed to be normally distributed and analyzed by General Linearized Model (JMP version 12.0.1) with terminal body weight and exposure concentration as model effects. If the probability of the p value (versus the respective control) was ≤0.05 then potential differences in least square means were identified by Dunnett’s test. TP was compared to vehicle using the Student’s t-test.

### F.6.2 Results

In the absence of androgenic action, neither 2H4MBP nor EHMC had any effect on androgen dependent organ weights, demonstrating that 2H4MBP and EHMC do not exhibit any in vivo androgenic activity (Table F-6; Table F-7). In the presence of TP, EHMC did not attenuate the expected androgen-mediated increase in organ weights, demonstrating that EHMC does not exhibit any antiandrogenic activity in vivo under the exposure concentrations assessed. Rats co-administered 1,000 mg/kg/day of 2H4MBP and TP displayed statistically lower day 10 body weight and body weight gain (7 and 28%, respectively) relative to control. The mean weights of the glans penis and ventral prostate were also statistically lower (6 and 17%, respectively). The weight of the seminal vesicles was also slightly lower. However, when concurrent body weight is used as a covariate, the magnitude of the response is decreased and no longer attains statistical significance. Given that these organ weight changes only occurred in the presence of lower body weights at the highest dose assessed, these organ weight changes are likely secondary to effects on body weight.

## F.7 Human Recombinant Aromatase Assay

### F.7.1 Methodology

The potential for 2H4MBP and EHMC to as act as inhibitors of aromatase activity was assessed using human CYP19 (aromatase) and P450 reductase Supersomes^TM^ (Gentest^TM^). The substrate for the assay was [1β-^3^H]-Androstenedione (ASDN), which is then converted by aromatase to estrone. Estrone was extracted via aqueous phase and quantified utilizing liquid scintillation counting, Final concentrations of EHMC and 2H4MBP in the aromatase assay were 10^−10^, 10^−9^, 10^−8^, 10^−7^, 10^−6^, 10^−5^, 10^−4.5^, 10^−4^, and 10^−3^ M. Three independent runs of the aromatase assay were conducted. In each independent run, each concentration of test substance was tested in triplicate. In addition, the positive control inhibitor 4-hydroxyandrostenedione (4OH-ASDN) was included each time the aromatase assay was performed. Increasing concentrations of 4OH-ASDN decrease the aromatase activity in a concentration dependent manner.

### F.7.2 Results

According to the data interpretation procedure outlined by the EPA (OPPTS 890.1200), EHMC was classified as a noninhibitor, with mean aromatase activity of 100% (±6% SD).^128^ 2H4MBP was classified as equivocal, as it produced a mean aromatase activity level of 51% (±13% SD) of control activity at the highest soluble test concentration of 10^−4^ M.

## F.8 H295R Steroidogenesis Assay

### F.8.1 Methodology

The ability of 2H4MBP or EHMC to affect the steroidogenic pathway, beginning with the sequence of reactions occurring after the gonadotropin hormone receptors through the production of testosterone and estradiol/estrone was assessed using the H295R human adrenocarcinoma cell line. The final concentrations of each compound tested in the steroidogenesis assay were: 0.0001, 0.001, 0.01, 0.1, 1, 10, and 100 μM. Four independent runs of the steroidogenesis assay were conducted. Three of the four assays were analyzed for each compound. All test chemicals, reference chemicals, and solvent controls were tested in replicates of 3/plate, with the exception of the solvent controls on the quality control (QC) plate. Six solvent control wells were analyzed on the QC plate. The H295R supplemented medium used in the assay at the time of plating, dosing, and harvest contained 10 μM 22R-hydroxycholesterol. The duration of exposure was 48 hours. A QC plate containing two doses of reference chemicals forskolin and prochloraz was run each time the assay was performed. Cell viability was assessed after the 48-hour exposure using the MTT assay. Testosterone and estradiol concentrations were measured using HPLC/MS-MS by OpAns, LLC (Durham, NC). All concentrations that exhibited greater than 20% cytotoxicity in the MTT cell viability assay were excluded from the statistical analysis of testosterone and estradiol concentrations.

### F.8.2 Results

The highest concentration of 2H4MBP that could be tested in the assays was 100 μM, according to apparent solubility and cytotoxicity results. Statistically significant induction of testosterone was observed at the 100 μM concentration in all three runs of the assay. Statistically significant estradiol induction was observed at 10 and 100 μM in three runs, and at 0.1, 1, 10, and 100 μM in one run. Although statistically significant results were identified at the 100 μM 2H4MBP concentration in all three runs, precipitation was noted under the microscope after the 48-hour exposure period at this concentration. Nonetheless, 2H4MBP would be classified as positive in the steroidogenesis assay for effects on estradiol on the basis of the data interpretation criteria outlined in the OECD test guideline for the assay. Induction of testosterone production was apparently observed at 100 μM, concomitant with precipitation 2H4MBP. The criteria outlined in the OECD test indicate that the effects of 2H4MBP on testosterone in each run would be classified as equivocal.

The highest concentration of EHMC that could be tested in the assays was 0.1 μM in run 1 and 100 μM in all runs 2 and 3, as per solubility results. Precipitation was observed prior to exposure in run 1 at the 1, 10, and 100 μM concentrations. Cytotoxicity greater than 20% was not observed in any of the three runs at any of the concentrations tested. No statistically significant effects were observed on testosterone or estradiol production at any of the concentrations that were analyzed in any of the three runs. According to the data interpretation criteria outlined in the OECD test guideline, EHMC is negative in the steroidogenesis assay.

Table F-1 Uterine Estrogen Receptor Binding Assay Parameters and Curve Fit^a^

| Reference Agents | | | UV Filter
| 17β-Estradiol | 19-Norethindrone | Octyltriethoxysilane | 2H4MBP | EHMC
RPC_max_
Exp. 1 | 0.0 ± 0.4 | 0.9 ± 0.1 | 94.1 ± 1.8 | 83.2 ± 0.9 | 89.2 ± 2.9
Exp. 2 | 0.0 ± 0.2 | 0.8 ± 0.1 | 88.6 ± 1.4 | 76.5 ± 0.6 | 93.4 ± 0.8
Exp. 3 | 0.0 ± 0.1 | 1.6 ± 0.6 | 90.9 ± 1.6 | 77.2 ± 0.4 | 93.1 ± 2.1
Mean | 0.0 ± 0.0 | 1.1 ± 0.3 | 91.2 ± 1.6 | 79.0 ± 2.1 | 91.9 ± 1.4
PC_max_ (M)
Exp. 1 | _10_−7 | _10_−4 | _10_−6.5 | _10_−4 | _10_−4
Exp. 2 | _10_−7 | _10_−4 | _10_−4.5 | _10_−4 | _10_−4
Exp. 3 | _10_−7 | _10_−4 | _10_−4.5 | _10_−4 | _10_−4
R^2^
Exp. 1 | 0.9987 | 0.9993 | Ambiguous 0.2727 | Ambiguous 0.9915 | Ambiguous 0.8190
Exp. 2 | 0.9973 | 0.9981 | Ambiguous 0.1109 | 0.8872 | Ambiguous 0.5173
Exp. 3 | 0.9953 | 0.9998 | Ambiguous 0.3306 | Ambiguous 0.9843 | Ambiguous 0.3545
Top
Exp. 1 | 94.7 ± 1.9 | 93.1 ± 0.9 | ~7,305 | 95.3 ± 0.3 | 97.8 ± 2.2
Exp. 2 | 92.5 ± 2.8 | 96.6 ± 2.1 | 91.8 ± 2.2 | 97.2 ± 1.8 | 844,702
Exp. 3 | 95.7 ± 4.0 | 100.3 ± 0.5 | 98.9 ± 2.7 | 98.6 ± 0.6 | 98.7 ± 1.4
Bottom
Exp. 1 | −0.5 ± 2.0 | −0.7 ± 1.5 | ~40 | ~49 | ~50
Exp. 2 | −1.1 ± 2.9 | −7.8 ± 4.5 | ~50 | <0 | ~41
Exp. 3 | −5.0 ± 5.0 | −1.0 ± 0.8 | ~50 | ~49 | ~50
LogIC_50_
Exp. 1 | −9.0 ± 0.0 | −5.5 ± 0.0 | ~296.6 | ~−3.6 | ~4.7
Exp. 2 | −9.0 ± 0.0 | −5.5 ± 0.0 | ~−2.6 | −2.9 ± 4.0 | ~−116.6
Exp. 3 | −8.8 ± 0.1 | −5.6 ± 0.0 | ~−2.7 | ~−2.8 | ~−2.7
IC_50_
Exp. 1 | 9.9 × 10^−10^ | 2.7 × 10^−6^ | 3.7 × 10^297^ | ~2.3 × 10^−4^ | 4.6 × 10^4^
Exp. 2 | 8.8 × 10^−10^ | 2.2 × 10^−6^ | ~2.5 × 10^−3^ | 11.4 × 10^−4^ | ~0
Exp. 3 | 1.3 × 10^−9^ | 2.3 × 10^−6^ | ~1.9 × 10^−3^ | ~14.8 × 10^−4^ | ~1.9 × 10^−3^
Hill Slope
Exp. 1 | −1.1 ± 0.1 | −1.1 ± 0.1 | ~0 | ~−5.6 | −0.4 ± 1.0
Exp. 2 | −1.0 ± 0.1 | −0.7 ± 0.1 | ~−4.4 | −0.5 ± 0.9 | ~0
Exp. 3 | −0.8 ± 0.1 | −0.9 ± 0.0 | ~−4.5 | ~−1.6 | ~−4.7
Log Relative Binding Affinity
Exp. 1 | – | 1.6 | NS | 2.5 | −1.9
Exp. 2 | – | 1.6 | 3.5 | 3.1 | 0.1
Exp. 3 | – | 1.6 | 3.3 | 3.2 | 3.3
Relative Binding Affinity (%)
Exp. 1 | – | 0.0385 | – | 0.0004 | 0.0000
Exp. 2 | – | 0.0409 | 0.0001 | 0.0001 | –
Exp. 3 | – | 0.0565 | 0.0002 | 0.0001 | 0.0001

2H4MBP = 2,4-dihydroxy-4-methoxybenzophenone; EHMC = 2-ethylhexyl p-methoxycinnamate.

RPC _max_ = maximum level of response induced by test chemical compared to positive control; PC_max_ = maximum response of test chemical relative to response induced by 1 nM 17β-Estradiol.

^a^ Values reported as average ± SEM.

Curve Fit: Y = Bottom + (Top−Bottom)/(1 + 10^((logIC_50_−X)*Hillslope + log((Top−Bottom)/(50−Bottom) −1))); Bottom > 0 for sunscreen ingredients.

Table F-2 Estrogen Receptor Transcriptional Activation, Assay Parameters, and Curve Fit^a^

| Reference Agents | | | | UV Filters
| 17β-Estradiol | 17α-Ethynyl Estradiol | Corticosterone | 17α-Methyltestosterone | 2H4MBP | EHMC
RPC_max_
Exp. 1 | 125.8 ± 9.4 | 103.8 ± 11.6 | 2.3 ± 0.5 | 43.9 ± 8.0 | 14.9 ± 1.1 | 4.1 ± 0.8
Exp. 2 | 135.3 ± 10.4 | 101.5 ± 7.0 | 0.0 ± 0.0 | 35.4 ± 4.0 | 20.9 ± 3.1 | 3.2 ± 0.4
PC_max_
Exp. 1 | _10_−8 | _10_−7 | _10_−7 | _10_−5 | _10_−5 | _10_−8
Exp. 2 | _10_−9 | _10_−8 | _10_−7 | _10_−5 | _10_−5 | _10_−8
_R_2
Exp. 1 | 0.9966 | 0.9962 | Not converged | 0.9588 | 0.8897 | Interrupted
Exp. 2 | 0.9930 | 0.9959 | Not converged | 0.9602 | 0.9062 | Interrupted
Top
Exp. 1 | 120.8 ± 2.9 | 99.0 ± 2.5 | – | – | – | –
Exp. 2 | 129.3 ± 4.6 | 115.0 ± 3.0 | – | – | – | –
LogEC_50_
Exp. 1 | −10.5 ± 0.1 | −8.8 ± 0.1 | – | −4.9 ± 0.1 | −3.2 ± 0.5 | ~−6.6 × 10^5^
Exp. 2 | −10.3 ± 0.1 | −8.6 ± 0.1 | – | −4.6 ± 0.1 | −4.0 ± 0.3 | ~−4 × 10^5^
EC_50_
Exp. 1 | 3.3 × 10^−11^ | 1.6 × 10^−9^ | – | 1.4 × 10^−5^ | 6.4 × 10^−4^ | ~0
Exp. 2 | 4.6 × 10^−11^ | 2.6 × 10^−9^ | – | 2.3 × 10^−5^ | 1.0 × 10^−4^ | ~0
Hill Slope
Exp. 1 | 1.5 ± 0.2 | 2.0 ± 0.8 | – | 0.9 ± 0.2 | 0.4 ± 0.1 | ~0
Exp. 2 | 1.2 ± 0.2 | 1.5 ± 0.2 | – | 0.7 ± 0.1 | 0.6 ± 0.2 | ~0
LogPC_10_
Exp. 1 | −11.5 | −9.7 | NC | −6.0 | −5.6 | NC
Exp. 2 | −11.6 | −9.7 | NC | −6.0 | −5.6 | NC
PC_10_
Exp. 1 | 7.6 × 10^−12^ | 4.8 × 10^−10^ | NC | 1.1 × 10^−6^ | 2.6 × 10^−6^ | NC
Exp. 2 | 6.6 × 10^−12^ | 6.4 × 10^−10^ | NC | 1.1 × 10^−6^ | 2.6 × 10^−6^ | NC

2H4MBP = 2,4-dihydroxy-4-methoxybenzophenone; EHMC = 2-ethylhexyl p-methoxycinnamate; NC = Not calculated.

^a^ Values reported as average ± SEM.

Curve Fit: Y = Bottom + (Top−Bottom)/(1 + 10^((logEC_50_−X)*Hillslope)). Constrained at 0 (17β-estradiol, 17α-ethynyl estradiol) or 0 and 100 (corticosterone, 17α-methyltestosterone, 2H4MBP, EHMC).

Table F-3 Uterine and Body Weights of Ovariectomized Sprague Dawley Rats Administered UV Sunscreen Ingredients via Gavage for Three Days^a^

| 0 mg/kg | EE 0.1 mg/kg^b^ | 2H4MBP 320 mg/kg | 2H4MBP 1,000 mg/kg | EHMC 320 mg/kg | EHMC 1,000 mg/kg
n | 8 | 8 | 8 | 8 | 8 | 8
Uterine Weight (mg)^c^ | 94.3 ± 14.5 | 277.1 ± 76.3* | 94.3 ± 11.2 | 103.8 ± 19.0 | 89.1 ± 11.2 | 94.4 ± 9.5
Uterine Weight, Blotted (mg)^c^ | 86.8 ± 13.7 | 210.1 ± 27.5* | 87.5 ± 10.5 | 96.3 ± 17.9 | 82.2 ± 11.5 | 87.5 ± 9.7
Body Weight (Day 1) (g) | 257.7 ± 12.9 | 260.9 ± 12.8 | 257.8 ± 13.4 | 256.2 ± 11.6 | 260.7 ± 10.6 | 259.5 ± 14.5
Terminal Body Weight (g)^d^ | 268.1 ± 10.2 | 251.4 ± 12.7* | 268.8 ± 13.1 | 254.6 ± 9.4 | 271.5 ± 9.0 | 264.8 ± 12.0
Body Weight Gain (g)^d^ | 10.4 ± 6.6 | −7.0 ± 5.7* | 11.1 ± 2.9 | −1.6 ± 5.8* | 10.8 ± 6.3 | 5.3 ± 6.3

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control.

* Statistically significantly at p ≤ 0.05.

2H4MBP = 2,4-dihydroxy-4-methoxybenzophenone; EHMC = 2-ethylhexyl p-methoxycinnamate.

Initial mean body weights were ~260 g.

^a^ Data presented as mean ± SD.

^b^ EE was compared to control using the Student’s t-test.

^c^ Uterine and blotted uterine weights were analyzed by MS Excel and SAS version 9.1 (SAS Institute, Cary, NC) with terminal body weight and exposure concentration as model effects. If the probability of the p value was <0.05 then potential differences in least square means were identified by Dunnett’s test (compared to control).

^d^ Terminal body weight and body weight gain were analyzed by ANOVA.

Table F-4 Prostate Androgen Receptor Binding Assay Parameters and Curve Fit^a^

| Reference Agents | | UV Filter
| R1881-1 | Dexamethasone | 2H4MBP | EHMC
Specific Binding Response_max_
Exp. 1 | 1.2 ± 1.0 | 2.9 ± 1.6 | 64.9 ± 1.4 | 84.5 ± 2.1
Exp. 2 | 1.9 ± 1.0 | 5.1 ± 1.2 | 62.5 ± 0.4 | 81.9 ± 2.2
Exp. 3 | 0.0 ± 0.8 | 0.5 ± 0.7 | 61.3 ± 4.0 | 89.3 ± 1.4
Concentration_max_ (M)
Exp. 1 | _10_−6 | _10_−3 | _10_−4 | _10_−4
Exp. 2 | _10_−6 | _10_−3 | _10_−4 | _10_−4
Exp. 3 | _10_−6 | _10_−3 | _10_−4 | _10_−4
R^2^
Exp. 1 | 0.9993 | 0.9990 | Ambiguous 0.9927 | Ambiguous 0.9769
Exp. 2 | 0.9993 | 0.9996 | Ambiguous 0.9645 | Ambiguous 0.9445
Exp. 3 | 0.9890 | 0.9997 | Hit constraint 0.9872 | 0.9360
Top
Exp. 1 | 98.7 ± 2.6 | 98.6 ± 1.7 | 99.9 ± 1.0 | 100.1 ± 1.1
Exp. 2 | 113.3 ± 4.9 | 98.7 ± 0.9 | 92.6 ± 1.4 | 95.8 ± 0.8
Exp. 3 | 99.0 ± 11.5 | 94.0 ± 1.0 | 100.4 ± 1.2 | 100.0 ± 0.9
Bottom
Exp. 1 | 1.2 ± 0.3 | −2.9 ± 2.1 | ~50.0 | ~50.0
Exp. 2 | 1.8 ± 0.2 | −0.1 ± 1.2 | ~50.0 | ~50.0
Exp. 3 | −0.3 ± 0.4 | −2.0 ± 0.5 | ~0 | ~0
LogIC_50_
Exp. 1 | −8.9 ± 0.0 | −4.4 ± 0.0 | ~−1.2 | ~5.0
Exp. 2 | −9.9 ± 0.0 | −4.3 ± 0.0 | ~−3.1 | ~−0.7
Exp. 3 | −9.1 ± 0.1 | −4.6 ± 0.0 | −3.7 ± 0.5 | −2.2 ± 9.5
IC_50_
Exp. 1 | 1.3 × 10^−9^ | 3.8 × 10^−5^ | 6.7 × 10^−2^ | ~9.5 × 10^4^
Exp. 2 | 1.1 × 10^−10^ | 4.7 × 10^−5^ | 8.1 × 10^−4^ | ~0.2
Exp. 3 | 0.9 × 10^−9^ | 2.5 × 10^−5^ | 1.8 × 10^−4^ | ~6.2 × 10^−3^
Hill Slope
Exp. 1 | −0.9 ± 0.1 | −0.9 ± 0.1 | −1.1 ± 0.2 | −0.4 ± 0.1
Exp. 2 | −0.9 ± 0.0 | −1.0 ± 0.1 | ~−3.1 | ~−1.2 ± 1.7
Exp. 3 | −0.9 ± 0.2 | −1.0 ± 0.1 | −0.8 ± 0.8 | −0.5 ± 0.3
LogRBA
Exp. 1 | – | 2.0 | 7.4 | −1.8
Exp. 2 | – | 2.3 | 3.2 | 14.1
Exp. 3 | – | 2.0 | 2.4 | 4.1
Mean (Exp. 1–3) | – | 2.1 | 4.3 | 5.5
RBA (%)
Exp. 1 | – | 0.0034 | <0.0000 | <0.0000
Exp. 2 | – | 0.0002 | <0.0000 | <0.0000
Exp. 3 | – | 0.0036 | 0.0005 | <0.0000
Mean (Exp. 1–3) | – | 0.0024 | 0.0002 | <0.0000

2H4MBP = 2,4-dihydroxy-4-methoxybenzophenone; EHMC = 2-ethylhexyl p-methoxycinnamate.

^a^ Data presented mean ± SEM.

Curve Fit: Y = Bottom + (Top−Bottom)/(1 + 10^((logIC50−X)*Hillslope + log((Top−Bottom)/(50−Bottom) −1))). 1/Y weighed; constrained at Bottom >0 for 2H4MBP and EHMC.

Table F-5 Androgen Receptor Transactivation: Antagonist Mode Parameters and Curve Fit

| Reference Agents | | UV Filter
| DDE | Nilutamide | 2H4MBP | EHMC
RPC_min_
Exp. 1 | 10.3 ± 0.3 | −1.9 ± 0.0 | 72.2 ± 4.6 | 98.5 ± 7.9
Exp. 2 | 13.2 ± 1.0 | −2.1 ± 0.0 | 89.0 ± 2.8 | 83.3 ± 5.2
Exp. 3 | 13.9 ± 1.0 | −1.0 ± 0.4 | 75.6 ± 5.0 | –
PC_max_
Exp. 1 | _10_−4 | _10_−4 | _10_−4.5 | _10_−4.5
Exp. 2 | _10_−4 | _10_−4 | _10_−4.5 | _10_−4.5
Exp. 3 | _10_−4 | _10_−4 | _10_−4.5 | –
R^2^
Exp. 1 | 0.9992 | 0.9979 | Ambiguous 0.7991 | Ambiguous 0.3451
Exp. 2 | 0.9795 | 0.9960 | Not converged | Ambiguous 0.3581
Exp. 3 | 0.9808 | 0.9879 | Ambiguous 0.5396 | –
Top
Exp. 1 | 111.8 ± 1.1 | 97.8 ± 2.6 | 108.6 ± 11.6 | 114.4 ± 22.0
Exp. 2 | 94.6 ± 3.2 | 101.5 ± 3.7 | – | 94.3 ± 4.4
Exp. 3 | 110.8 ± 4.1 | 116.1 ± 15.3 | 110.6 ± 7.7 | –
Bottom
Exp. 1 | 8.4 ± 2.3 | 2.0 ± 1.4 | ~50.0 | ~50.0
Exp. 2 | 14.7 ± 7.4 | 1.6 ± 2.0 | – | ~50.0
Exp. 3 | 11.2 ± 10.7 | 2.3 ± 3.8 | ~50.0 | –
LogIC_50_
Exp. 1 | −4.9 ± 0.0 | −6.4 ± 0.0 | ~−3.2 | ~−1.2
Exp. 2 | −4.9 ± 0.1 | −6.3 ± 0.0 | – | ~−1.9
Exp. 3 | −4.8 ± 0.1 | −6.5 ± 0.1 | ~−4.3 | –
IC_50_
Exp. 1 | 1.4 × 10^−5^ | 4.3 × 10^−7^ | ~0.7 × 10^−4^ | ~6.7 × 10^−2^
Exp. 2 | 1.3 × 10^−5^ | 4.6 × 10^−7^ | – | ~1.2 × 10^−2^
Exp. 3 | 1.5 × 10^−5^ | 3.1 × 10^−7^ | ~5.1 × 10^−5^ | –
Hill Slope
Exp. 1 | −1.6 ± 0.1 | −1.6 ± 0.2 | −2.6 ± 3.9 | −1.2 ± 4.8
Exp. 2 | −2.1 ± 0.8 | −1.7 ± 0.2 | – | −1.6 ± 3.4
Exp. 3 | −1.5 ± 0.5 | −1.0 ± 0.3 | ~−16.7 | –

DDE = dichlorodiphenyldichloroethylene; 2H4MBP = 2,4-dihydroxy-4-methoxybenzophenone; EHMC = 2-ethylhexyl p-methoxycinnamate.

Curve Fit: Y = Bottom + (Top−Bottom)/(1 + 10^((logIC50−X)*Hillslope + log((Top−Bottom)/(50−Bottom) −1))); unconstrained.

Table F-6 Reproductive Organ and Body Weights of Rats Administered 2H4MBP or EHMC via Gavage for 10 Days (Agonist Assessment)^a^

| 0 mg/kg | TP 0.4 mg/kg | 2H4MBP 320 mg/kg | 2H4MBP 1,000 mg/kg | EHMC 320 mg/kg | EHMC 1,000 mg/kg
n | 7^b^ | 8 | 8 | 8 | 8 | 8
Organ Weight (mg)
Glans Penis^c^ | 47.4 ± 6.1 | 92.7 ± 5.0* | 52.4 ± 7.3 | 50.7 ± 5.2 | 49.4 ± 7.0 | 50.4 ± 5.9
Cowper’s Gland^d^ | 5.4 ± 1.5 | 39.0 ± 5.6* | 5.2 ± 2.6 | 5.1 ± 1.6 | 4.6 ± 1.5 | 5.6 ± 2.0
LABC^d^ | 133.4 ± 34.9 | 384.5 ± 51.7* | 133.4 ± 19.1 | 123.4 ± 32.0 | 143.3 ± 28.9 | 129.1 ± 25.6
Ventral Prostate^c^ | 15.8 ± 3.1 | 186.2 ± 57.2* | 15.2 ± 3.0 | 14.0 ± 1.6 | 16.1 ± 2.4 | 15.6 ± 2.8
Seminal Vesicles^c^ | 31.1 ± 5.3 | 542.5 ± 63.2* | 39.2 ± 9.0 | 33.6 ± 9.6 | 34.1 ± 6.4 | 33.9 ± 7.6
Body Weight (g)
Day 1 | 255.5 ± 14.3^e^ | 259.3 ± 11.9 | 255.9 ± 17.7 | 258.7 ± 12.4 | 256.8 ± 14.4 | 257.4 ± 9.3
Day 11 | 302.2 ± 24.9 | 335.1 ± 24.1* | 299.0 ± 27.7 | 298.0 ± 20.3 | 313.6 ± 29.4 | 298.3 ± 14.0
Weight Gain | 47.3 ± 16.6 | 75.8 ± 16.7* | 43.1 ± 10.6 | 39.4 ± 11.2 | 56.8 ± 17.6 | 40.9 ± 10.4

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p < 0.05 when compared to the respective vehicle control group.

^ Statistically significant at p < 0.05 when compared to the respective TP control.

2H4MBP = 2,4-dihydroxy-4-methoxybenzophenone; EHMC = 2-ethylhexyl p-methoxycinnamate; LABC = levator ani/bulbocavernosus muscle; TP = testosterone propionate.

^a^ Data presented as mean ± SD.

^b^ Decrease in N due to animal removal.

^c^ Statistical analysis performed by ANOVA. If significant, the means were subjected to Dunnett’s test (compared to vehicle control) using JMP version 12.0.1.

^d^ Statistical analysis performed using Kruskal Wallace nonparametric analyses. If significant, the means were subjected to Dunn’s test (compared to vehicle control).

^e^ Average weight of all eight animals in the 0 mg/kg group at study initiation.

Table F-7 Reproductive Organ and Body Weights of Rats Administered 2H4MBP or EHMC via Gavage for 10 Days (Antagonist Assessment)^a^

| 0 mg/kg (+ TP)b | FT 3 mg/kg (+ TP) | 2H4MBP 100 mg/kg (+ TP) | 2H4MBP 320 mg/kg (+ TP) | 2H4MBP 1,000 mg/kg (+ TP) | EHMC 100 mg/kg (+ TP) | EHMC 320 mg/kg (+ TP) | EHMC 1,000 mg/kg (+ TP)
n | 8 | 8 | 8 | 8 | 8 | 8 | 6^c^ | 8
Organ Weight (mg)
Glans Penis^d^ | 92.7 ± 5.0* | 62.5 ± 3.8^^d^ | 95.6 ± 4.7 | 94.0 ± 4.5 | 87.5 ± 3.8^ | 94.7 ± 7.8 | 94.6 ± 3.2 | 91.6 ± 5.0
Cowper’s Gland^e^ | 39.0 ± 5.6* | 12.2 ± 3.9^ | 38.1 ± 5.2 | 37.2 ± 5.6 | 37.3 ± 9.8 | 39.4 ± 5.7 | 36.7 ± 7.7 | 32.1 ± 5.0
LABC^e^ | 384.5 ± 51.7* | 181.7 ± 25.6^ | 419.5 ± 41.9 | 428.0 ± 55.1 | 387.9 ± 41.1 | 415.9 ± 46.3 | 419.1 ± 42.6 | 359.4 ± 47.3
Ventral Prostate^d^ | 186.2 ± 57.2* | 37.0 ± 7.7^ | 206.2 ± 38.6 | 195.8 ± 32.1 | 155.0 ± 21.3^ | 182.4 ± 47.6 | 176.9 ± 47.2 | 147.6 ± 39.7
Seminal Vesicles^d^ | 542.5 ± 63.2* | 58.5 ± 16.7^ | 594.7 ± 54.5 | 618.8 ± 97.3 | 506.5 ± 39.9 | 562.3 ± 74.4 | 610.1 ± 99.1 | 465.5 ± 80.2
Body Weight (g)
Day 1 | 259.3 ± 11.9 | 258.1 ± 14.4 | 257.9 ± 14.2 | 260.8 ± 9.5 | 256.8 ± 13.4 | 259.9 ± 14.7 | 259.4 ± 11.1 | 259.3 ± 13.3
Day 11 | 335.1 ± 24.1* | 324.0 ± 24.3 | 338.1 ± 17.7 | 339.2 ± 15.9 | 311.2 ± 16.7^ | 330.2 ± 42.3 | 343.7 ± 26.5 | 319.7 ± 24.8
Weight Gain | 75.8 ± 16.7* | 65.9 ± 14.2 | 80.2 ± 9.0 | 78.4 ± 10.1 | 54.4 ± 12.4^ | 70.3 ± 30.9 | 85.2 ± 23.9 | 60.4 ± 16.4

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p < 0.05 when compared to the respective vehicle control group.

^ Statistically significant at p < 0.05 when compared to the respective TP control.

2H4MBP = 2,4-dihydroxy-4-methoxybenzophenone; EHMC = 2-ethylhexyl p-methoxycinnamate; LABC = levator ani/bulbocavernosus muscle; TP = testosterone propionate; FT = flutamide.

^a^ Data presented as mean ± SD.

^b^ For the androgen antagonist assessment, all exposure groups were co-administered 0.4 mg/kg/day TP.

^c^ Decrease in N due to animal removal.

^d^ Statistical analysis performed by ANOVA. If significant, the means were subjected to Dunnett’s test (compared to vehicle control) using JMP version 12.0.1. mean ± SD.

^e^ Statistical analysis performed using Kruskal Wallace nonparametric analyses. If significant, the means were subjects to Dunn’s test (compared to vehicle control).

Figure F-1

Uterine Estrogen Receptor Binding

Figure F-2

Estrogen Receptorα Transcriptional Activation Assay

Figure F-3

Prostate Androgen Receptor Binding

Figure F-4

Androgen Receptor Transactivation – Agonist Mode

Figure F-5

Androgen Receptor Transactivation – Antagonist Mode