# Appendix E Microarray Analysis

## E.1 Objective

The objective of the microarray study was to evaluate the transcriptional changes in liver from rats exposed to 0 or 10,000 ppm 2H4MBP. At the 14-week interim evaluation, livers were analyzed from male Sprague Dawley rats.

## E.2 Methods

### E.2.1 RNA Isolation, cDNA Synthesis, and Array Hybridization

Liver tissues were excised from five vehicle control F_1_ male rats and five 10,000 ppm F_1_ male rats from the 14-week interim evaluation performed as a part of the 2-year carcinogenicity study. Tissues were immediately frozen in liquid nitrogen at collection and transported to the Battelle Biomedical Research Center (Columbus, OH). The liver tissues were removed and added to lysis buffer, and each sample was then homogenized using OmniTip™ plastic disposable probes (Omni International, Marietta, GA). Following homogenization samples were centrifuged and the RNA was extracted from the supernatant using the Qiagen RNeasy Midi Kit (Qiagen, Valencia, CA). RNA concentration and purity were determined by UV analysis using a NanoDrop 1000 spectrophotometer (NanoDrop Technologies, Wilmington, DE). All samples were assessed for RNA integrity using an RNA 6000 Nano Chip kit with an Agilent 2100 Bioanalyzer (Agilent, Santa Clara, CA). Total RNA (100 ng) was used to synthesize single-stranded DNA, which was subsequently converted into a double stranded eDNA template for transcription. An in vitro transcription (IVT) reaction, which incorporates biotinylated ribonucleotide analogs, was then used to create labeled amplified RNA (aRNA). This RNA target preparation was performed using the Affymetrix GeneChip^®^ 3' IVT Express Kit (Affymetrix Inc., Santa Clara, CA) according to the manufacturer’s protocol. All incubation steps during this preparation were completed using an Eppendorf Mastercycler^®^ thermal cycler (Eppendorf, Hamburg, Germany). Labeled aRNA was fragmented and hybridized to the Affymetrix Rat Genome 230 2.0 Array (31,099 probe sets) using an Affymetrix GeneChip Hybridization Oven 640. Washing and staining of the arrays were completed using the Affymetrix GeneChip Hybridization Wash and Stain kit and performed using the Fluidics Station 450 according to the Affymetrix recommended protocol (FS450_0001). After washing and staining, the arrays were scanned using an Affymetrix GeneChip Scanner 3000 7G and the raw microarray data (.CEL files) were acquired using Affymetrix GeneChip Command Console^®^ Software (AGCC).

### E.2.2 Microarray Analysis

#### E.2.2.1 Analysis of GeneChip Data Quality

Quality control (QC) measurements from each Affymetrix GeneChip array were evaluated to determine the quality of the microarray data generated. Affymetrix recommended guidelines for evaluating quality were used to evaluate the output files for each GeneChip array using the R/Bioconductor package, Simpleaffy.^117^ The following QC parameters were evaluated for each chip: average background, scale factor, percent of genes scored as present, 3' to 5' ratios for the internal control genes beta-actin and glyceraldehyde-3-phosphate dehydrogenase (GAPDH), values for hybridization control transcripts, and values for poly (A) controls. In addition, the data were visually assessed outliers using intensity distribution histograms and principal component analysis. These assessments contributed to the determination that the quality of the GeneChip array data obtained from all 10 RNA samples is sufficient to proceed with statistical analysis and biological interpretation.

#### E.2.2.2 Statistical Analysis

The 10 .CEL files representing the 10 liver samples from the study were normalized using the robust multiarray algorithm (RMA)^118^ using Patek Genomics Suite v 6.6 (Partek, Inc, St. Louis, MO) using the commented settings in the software. Probe sets showing differential expression between the two dose groups were identified using an ANOVA (p < 0.05) combined with a fold change of >|1.5|.

#### E.2.2.3 Biological Interpretation

Ingenuity Pathway Analysis™ (IPA) (Ingenuity Systems^®^, Inc., Redwood City, CA) was used to facilitate biological interpretation of the transcriptional changes produced by 2H4MBP treatment.

The IPA Core Analysis was performed on June 11, 2019. Enrichment and activation analysis was carried out for IPA disease/biological/toxicity functions. In addition, an IPA Upstream Analysis was performed. Enrichment p values were calculated using a right-tailed Fisher’s Exact Test combined with a Benjamini-Hochberg method of multiple testing correction. The p value (p < 0.05) was determined by how many differentially expressed genes (DEGs) overlapped that are annotated into gene groups (e.g., canonical pathways, biological functions).

Activation/inhibition analysis was performed using the annotation in the IPA Knowledge Base. To determine if there was plausible activation/inhibition of disease/biological/toxicity functions, transcription factors, and chemical signaling signatures, a Z-score was calculated. The Z-score was determined by concordance of observed patterns of regulation (up or down) with known effects on biological functions or effects of transcription factors/chemicals (activation or inhibition of target genes) as annotated in the Ingenuity Knowledge Base. A gene set was deemed to be activated (Z-score >2), inhibited (Z-score <−2), or not affected on the basis of the Z-score.

## E.3 Results

### E.3.1 Differential Gene Expression

Whole-rat genome Affymetrix 230 2.0 microarrays were used to assess the effect of 10,000 ppm of 2H4MBP in the diet for 14 weeks on male Sprague Dawley rat liver. Treatment with 2H4MBP led to the differential expression of 357 probe sets (67 up-regulated, 290 down-regulated) that mapped to 273 unique genes. Overall the effect on the transcriptome was deemed to be weak relative to high-dose studies that are typical of most toxicogenomics assessments. Notably Cyp2b1/2, Cyp1a1, and Cyp4a1 were all moderately up-regulated along with other biotransformation-related genes such as Gsta2, Aldh1a7, and Abcc3. Up-regulation of these genes suggests the liver was adapting to the presence of chemical stressor by up-regulating metabolic pathways to facilitate clearance. The top five up- and down-regulated probe sets as determined by fold change are shown in Table E-1.

Five hundred twenty-seven IPA disease/biological/toxicity functions showed significant enrichment, however only a small set were also determined to be activated or inhibited by 2H4MBP treatment. Those that were activated include hepatic steatosis, hypoplasia of organ, and G2 phase. Several functions, all primarily related to cell cycle and growth, were inhibited by 2H4MBP treatment. The enriched and activated/inhibited functions are listed in Table E-2.

Twenty-six IPA canonical pathways showed significant enrichment following 2H4MBP treatment. Of the 26 pathways, only a small subset showed inhibition and all were related to cell cycle/proliferation. The enriched and activated/inhibited pathways are listed in Table E‑3.

The IPA Upstream Analysis identified >700 enriched regulatory agents, however, only 32 showed patterns that were suggestive of activation of inhibition. A sizable number of the regulatory agents were prototype chemicals that effect specific processes (e.g., PXR activation) and lead to specific patterns of transcriptional response (i.e., signatures). Identification of these patterns in the 2H4MBP transcriptional response data suggests that 2H4MBP may be interacting with the same biological targets as the prototype agents. Caution must be used when interpreting these results because genes are often shared across the signatures, hence differentiating between highly redundant upstream regulatory processes that are driving transcriptomic changes is challenging.

Findings for 2H4MBP are suggestive of effects on glucocorticoid (dexamethasone) and vitamin D (calcitriol) signaling and potentially on estrogen signaling (raloxifene). Other potential regulatory features in the 2H4MBP signaling cascade include miR-30c-5p and let-7 microRNAs and some inhibitory effects on cytokine signaling (i.e., TNF, IL1β, and IFNβ1). Notably, there is a suggestion that estrogen receptor (Esr1) signaling was inhibited by 2H4MBP, although an effect on Esr1 is unlikely based on additional analysis that was performed (see the Other Notable Findings section in this appendix, below). The enriched and activated/inhibited pathways are listed in Table E-4.

### E.3.2 Other Notable Findings

Due to the potential estrogenic properties of 2H4MBP, a specific analysis of estrogen response genes was performed. A subset of genes is known to be strongly up-regulated in male rat liver by pharmacological estrogens. The up-regulation of these genes in response to estrogens has been documented in both the DrugMatrix and TG-Gates data sets,^119;^ ^120^ which are accessible through the Illumina Correlation Engine.^121^ The up-regulated genes include Rbp7, Lifr, Cited4, Ksr1, and Ctr9. None of these genes was identified as differentially expressed in the liver of male rats following 2H4MBP exposure. This observation suggests that it is unlikely that 2H4MBP produced a systemic estrogenic effect within the context of the 14-week study.

## E.4 Conclusions

The overall transcriptomic response of rat liver to 14 weeks of exposure to 10,000 ppm 2H4MBP was weak. This is consistent with the absence of pathological findings in the liver following 2 years of exposure at this dose. The biological interpretation suggests there may be marginal, nonspecific effects on steroid hormone homeostasis that may be related findings in the adrenal cortex, testis, uterus, and ovary in the 2-year study. Notably, these effects do not appear to be related to direct effects on the estrogen receptor as opposed to other potential mechanisms that have yet to be characterized. One generally consistent observation was the inhibition of cell cycle-related processes, which could potentially be related to the decreased body weight observed in the 10,000 ppm groups from the 14-week interim evaluation. Finally, the weak induction of some of the nuclear receptor regulated P450s (e.g., Cyp2b1/2) are likely associated with microsomal enzyme induction and the observed liver weight increase at 10,000 ppm 2H4MBP.

Table E-1 Top Five Up- and Down-regulated Probesets in the Liver of Male Sprague Dawley Rats Administered 10,000 ppm 2H4MBP in Feed for 14 Weeks

Probeset ID | Gene Symbol | Entrez Gene | Fold Change
Up-regulated
1368718_at | Aldh1a7 | 29651 | 21.9409
1378249_x_at | LOC102554740 /// LOC103693750 | 102554740 /// 103693750 | 2.83937
1371076_at | Cyp2b1 /// Cyp2b2 | 24300 /// 361523 | 2.63343
1368321_at | Egr1 | 24330 | 2.43895
1394541_at | Unknown | Unknown | 2.37995
Down-regulated
1390317_at | RGD1561849 | 500393 | −2.6521
1369415_at | Bhlhe40 | 79431 | −3.11306
1395255_at | Onecut1 | 25231 | −3.16945
1387760_a_at | Onecut1 | 25231 | −3.77045
1371034_at | Onecut1 | 25231 | −3.98444

Table E-2 Ingenuity Pathway Analysis Enriched Disease and Biological/Toxicity Functions that Exhibit Activation/Inhibition in the Liver of Male Sprague Dawley Rats Administered 10,000 ppm 2H4MBP in Feed for 14 Weeks

Diseases or Biological/Toxicity Functions | Enrichment P Value | Activation Z-Score | Predicted Activation State
Hepatic Steatosis | 0.00116 | 2.327 | Activate
Hypoplasia of Organ | 0.00299 | 2.138 | Activate
G2 Phase | 0.00229 | 2 | Activate
Increased Levels of Red Blood Cells | 0.00139 | −2 | Inhibited
S Phase | 0.00183 | −2.01 | Inhibited
Vasculogenesis | 0.00665 | −2.092 | Inhibited
Mitosis | 0.00373 | −2.098 | Inhibited
Formation of Gonadal Cells | 0.00475 | −2.169 | Inhibited
Maturation of Myeloid Cells | 0.00096 | −2.181 | Inhibited
Development of Genitourinary System | 0.00114 | −2.189 | Inhibited
Angiogenesis | 0.00172 | −2.221 | Inhibited
Development of Vasculature | 0.00178 | −2.223 | Inhibited
Hyperplasia of Exocrine Gland | 0.00395 | −2.236 | Inhibited
Genitourinary Tumor | 0.00313 | −2.358 | Inhibited
Cell Cycle Progression | 6.54E^−06^ | −2.376 | Inhibited
Development of Genital Organ | 0.000931 | −2.376 | Inhibited
Transactivation of RNA | 0.00258 | −2.399 | Inhibited
Cell Proliferation of Tumor Cell Lines | 0.00153 | −2.595 | Inhibited
Development of Reproductive System | 0.000378 | −2.91 | Inhibited
Growth of Organism | 0.00696 | −3.468 | Inhibited

Table E-3 Ingenuity Pathway Analysis Enriched Canonical Pathways that Exhibit Activation/Inhibition in the Liver of Male Sprague Dawley Rats Administered 10,000 ppm 2H4MBP in Feed for 14 Weeks

Ingenuity Canonical Pathways | Enrichment P Value | Activation Z-Score | Predicted Activation State
Acute Myeloid Leukemia Signaling | 0.0355 | −2.236 | Inhibition
ERK5 Signaling | 0.0372 | −2 | Inhibition
Melanocyte Development and Pigmentation Signaling | 0.0380 | −2.236 | Inhibition
ErbB2–ErbB3 Signaling | 0.0490 | −2 | Inhibition
Mouse Embryonic Stem Cell Pluripotency | 0.0490 | −2.236 | Inhibition

Table E-4 Ingenuity Pathway Analysis Enriched Upstream Regulators that Exhibit Activation/Inhibition in the Liver of Male Sprague Dawley Rats Administered 10,000 ppm 2H4MBP in Feed for 14 Weeks

Upstream Regulator | Molecule Type | Enrichment P Value | Activation Z-Score | Predicted Activation State
MiR-30c-5p (and Other MiRNAs w/ Seed GUAAACA) | Mature microRNA | 0.000422 | 2.828 | Activated
Let-7 | MicroRNA | 0.019 | 2.763 | Activated
U0126 | Chemical – kinase inhibitor | 0.0368 | 2.314 | Activated
Sulindac Sulfide | Chemical drug | 1.92E−05 | 2.209 | Activated
Calcitriol | Chemical drug | 0.0411 | 2.173 | Activated
Dexamethasone | Chemical drug | 0.000916 | 2.096 | Activated
LY294002 | Chemical – kinase inhibitor | 0.00632 | 2.058 | Activated
Cigarette Smoke | Chemical toxicant | 0.00578 | 2.007 | Activated
ZBED6 | Transcription regulator | 0.000273 | 2 | Activated
Ursolic Acid | Chemical drug | 0.00175 | 2 | Activated
Salirasib | Chemical drug | 0.00961 | 2 | Activated
MiR-199a-5p (and Other MiRNAs w/ Seed CCAGUGU) | Mature microRNA | 0.0245 | 2 | Activated
EHHADH | Enzyme | 0.000111 | −2 | Inhibited
HSD17B4 | Enzyme | 0.000718 | −2 | Inhibited
NORAD | Other | 0.0027 | −2 | Inhibited
Esr1 | Ligand-dependent nuclear receptor | 0.0136 | −2.04 | Inhibited
Lipopolysaccharide | Chemical drug | 0.000845 | −2.12 | Inhibited
Tgf Beta | Group | 0.0234 | −2.126 | Inhibited
IFNB1 | Cytokine | 0.036 | −2.162 | Inhibited
Bucladesine | Chemical toxicant | 0.0481 | −2.19 | Inhibited
E2F1 | Transcription regulator | 0.0453 | −2.191 | Inhibited
TGFB2 | Growth factor | 0.00702 | −2.205 | Inhibited
CSHL1 | Growth factor | 0.00302 | −2.207 | Inhibited
E2F3 | Transcription regulator | 0.0292 | −2.219 | Inhibited
Tributyrin | Chemical drug | 0.00418 | −2.236 | Inhibited
Mycophenolic Acid | Chemical drug | 0.00949 | −2.236 | Inhibited
IL1B | Cytokine | 0.00709 | −2.36 | Inhibited
PDGF BB | Complex | 0.00181 | −2.381 | Inhibited
Raloxifene | Chemical drug | 0.0272 | −2.433 | Inhibited
Insulin | Group | 0.000964 | −2.446 | Inhibited
TNF | Cytokine | 0.00658 | −2.672 | Inhibited
HGF | Growth factor | 0.0154 | −2.745 | Inhibited