# Appendix D Sentinel Animal Program

## D.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For these toxicology and carcinogenesis studies, blood samples were collected from the rodents and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately with serology testing and sent to IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected per the following:

- Rats: 10 females at end of quarantine, and 4 weeks postarrival; 5 animals per sex at 6, 15, and 18 months, and study termination
- Mice: 5 animals per sex per time period

## D.2 Results

Rats: Positive for pinworms (Syphacia spp.) All other test results were negative. Mice: All test results were negative.

Table D-1 Methods and Results for Sentinel Animal Testing

Method and Test | Time of Collection
Rats
Multiplex Fluorescent Immunoassay
Kilham Rat Virus | End of quarantine^a^; 4 weeks postarrival^b^; 6, 15, and 18 months; stud termination
Mycoplasma Pulmonis | End of quarantine; 4 weeks postarrival; 6, 15, and 18 months; study termination
Pneumonia Virus of Mice | End of quarantine; 4 weeks postarrival; 6, 15, and 18 months; study termination
Rat Coronavirus/Sialodacryoadenitis Virus | End of quarantine; 4 weeks postarrival; 6, 15, and 18 months; study termination
Rat Minute Virus | End of quarantine; 4 weeks postarrival; 6, 15, and 18 months; study termination
Rat Parvo Virus | End of quarantine; 4 weeks postarrival; 6, 15, and 18 months; study termination
Rat Theilovirus | End of quarantine; 4 weeks postarrival; 6, 15, and 18 months; study termination
Sendai | End of quarantine; 4 weeks postarrival; 6, 15, and 18 months; study termination
Toolan's H-1 | End of quarantine; 4 weeks postarrival; 6, 15, and 18 months; study termination
Immunofluorescence Assay
Pneumocystis carinii | 6 months
Mice
Multiplex Fluorescent Immunoassay
Ectromelia Virus | 6 weeks postarrival; 6, 12, and 18 months; study termination
Epizootic Diarrhea of Infant Mice | 6 weeks postarrival; 6, 12, and 18 months; study termination
Lymphocytic Choriomeningitis Virus | 6 weeks postarrival; 6, 12, and 18 months; study termination
Mycoplasma Pulmonis | 6 weeks postarrival; 6, 12, and 18 months; study termination
Mouse Hepatitis Virus | 6 weeks postarrival; 6, 12, and 18 months; study termination
Mouse Norovirus | 6 weeks postarrival; 6, 12, and 18 months; study termination
Mouse Parvovirus | 6 weeks postarrival; 6, 12, and 18 months; study termination
Minute Virus of Mice | 6 weeks postarrival; 6, 12, and 18 months; study termination
Pneumonia Virus of Mice | 6 weeks postarrival; 6, 12, and 18 months; study termination
Reovirus | 6 weeks postarrival; 6, 12, and 18 months; study termination
Sendai | 6 weeks postarrival; 6, 12, and 18 months; study termination
Theiler's Murine Encephalomyelitis Virus GDVII | 6 weeks postarrival; 6, 12, and 18 months; study termination
Immunofluorescence Assay
Ectromelia Virus | 6 months
Epizootic Diarrhea of Infant Mice | 6 weeks postarrival; 6 months
Mouse Hepatitis Virus | Study termination
Mouse Norovirus | 6 and 12 months
Polymerase Chain Reaction
Helicobacter species | 18 months

^a^ Age-matched nonpregnant females.

^b^ Time-mated females that did not have a litter.