# Appendix C Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table C-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 22.26
Ground #2 Yellow Shelled Corn | 22.18
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 5.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table C-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| | Amount | Source
Vitamins
Vitamin A | | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | | 1,000 IU | D-activated animal sterol
Vitamin K | | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | | 100 IU | –
Niacin | | 23 mg | –
Folic Acid | | 1.1 mg | –
α-Pantothenic Acid | | 10 mg | α-Calcium pantothenate
Riboflavin | | 3.3 mg | –
Thiamine | | 4 mg | Thiamine mononitrate
B12 | | 52 μg | –
Pyridoxine | | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | | α-Biotin
Minerals
Magnesium | 514 mg | | Magnesium oxide
Iron | 35 mg | | Iron sulfate
Zinc | 12 mg | | Zinc oxide
Manganese | 10 mg | | Manganese oxide
Copper | 2.0 mg | | Copper sulfate
Iodine | 0.2 mg | | Calcium iodate
Chromium | 0.2 mg | | Chromium acetate

^a^ Per kg of finished product.

Table C-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 14.8 ± 0.516 | 14.2–16.8 | 28
Crude Fat (% by weight) | 8.69 ± 0.357 | 8.0–9.7 | 28
Crude Fiber (% by weight) | 9.47 ± 0.594 | 8.34–11.6 | 28
Ash (% by weight) | 5.25 ± 1.76 | 4.6–14.2 | 28
Amino Acids (% of Total Diet)
Arginine | 0.802 ± 0.075 | 0.67–0.97 | 28
Cystine | 0.220 ± 0.022 | 0.15–0.25 | 28
Glycine | 0.703 ± 0.038 | 0.62–0.80 | 28
Histidine | 0.342 ± 0.071 | 0.27–0.68 | 28
Isoleucine | 0.549 ± 0.041 | 0.43–0.66 | 28
Leucine | 1.097 ± 0.064 | 0.96–1.24 | 28
Lysine | 0.700 ± 0.106 | 0.31–0.86 | 28
Methionine | 0.410 ± 0.042 | 0.26–0.49 | 28
Phenylalanine | 0.623 ± 0.047 | 0.47–0.72 | 28
Threonine | 0.512 ± 0.042 | 0.43–0.61 | 28
Tryptophan | 0.155 ± 0.027 | 0.11–0.20 | 28
Tyrosine | 0.420 ± 0.066 | 0.28–0.54 | 28
Valine | 0.666 ± 0.040 | 0.55–0.73 | 28
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.95 ± 0.234 | 3.49–4.55 | 28
Linolenic | 0.31 ± 0.031 | 0.021–0.368 | 28
Vitamins
Vitamin A (IU/kg) | 378 ± 79.35 | 203–529 | 28
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 2,543 ± 13,044 | 27.0–69,100 | 28
Thiamine (ppm)b | 8.39 ± 1.87 | 3.9–12.5 | 28
Riboflavin (ppm) | 8.06 ± 2.83 | 4.20–17.50 | 28
Niacin (ppm) | 78.6 ± 8.26 | 66.4–98.2 | 28
Pantothenic Acid (ppm) | 26.6 ± 11.22 | 17.4–81.0 | 28
Pyridoxine (ppm)b | 9.78 ± 2.08 | 6.44–14.3 | 28
Folic Acid (ppm) | 1.58 ± 0.44 | 1.15–3.27 | 28
Biotin (ppm) | 0.32 ± 0.09 | 0.20–0.704 | 28
B12 (ppb) | 50.6 ± 35.5 | 18.3–174.0 | 28
Choline (as Chloride) (ppm) | 2,615 ± 635 | 1,160–3,790 | 28
Minerals
Calcium (%) | 0.913 ± 0.046 | 0.831–1.03 | 28
Phosphorus (%) | 0.550 ± 0.099 | 0.053–0.613 | 28
Potassium (%) | 0.667 ± 0.030 | 0.626–0.733 | 28
Chloride (%) | 0.393 ± 0.045 | 0.300–0.517 | 28
Sodium (%) | 0.197 ± 0.026 | 0.160–0.283 | 28
Magnesium (%) | 0.217 ± 0.055 | 0.185–0.490 | 28
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 191.6 ± 36.8 | 135–311 | 28
Manganese (ppm) | 50.1 ± 9.59 | 21.0–73.1 | 28
Zinc (ppm) | 57.4 ± 26.0 | 23.3–184.0 | 28
Copper (ppm) | 7.53 ± 2.53 | 3.21–16.3 | 28
Iodine (ppm) | 0.531 ± 0.201 | 0.158–0.972 | 28
Chromium (ppm) | 0.916 ± 0.908 | 0.330–3.97 | 27
Cobalt (ppm) | 0.225 ± 0.154 | 0.086–0.964 | 26

^a^ From formulation.

^b^ As hydrochloride.

Table C-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.223 ± 0.063 | 0.149–0.385 | 28
Cadmium (ppm) | 0.053 ± 0.012 | 0.038–0.094 | 28
Lead (ppm) | 0.138 ± 0.108 | 0.064–0.474 | 28
Mercury (ppm)^a^ | 0.014 ± 0.008 | 0.01–0.049 | 28
Selenium (ppm) | 0.162 ± 0.030 | 0.029–0.209 | 28
Aflatoxins (ppb)^a^ | 5 ± 0.00 | 5.0–5.0 | 28
Nitrate Nitrogen (ppm)^b^ | 15.62 ± 6.125 | 10.0–35.1 | 28
Nitrite Nitrogen (ppm)^a,b^ | 0.61 ± 0.002 | 0.60–0.61 | 28
BHA (ppm)^a,c^ | 1 ± 0.00 | 1.0–1.0 | 28
BHT (ppm)^a,c^ | 1.08 ± 0.40 | 1.0–3.14 | 28
Aerobic Plate Count (CFU/gm) | 10 ± 0.00 | 10.0–10.0 | 28
Coliform (MPN/gm) | 3.0 ± 0.00 | 3.0–3.0 | 28
E. coli (MPN/gm)^a^ | 10 ± 0.00 | 10.0–10.0 | 28
Salmonella (MPN/gm) | Negative | – | –
Total Nitrosamines (ppb)^d^ | 11.1 ± 5.55 | 3.2–24.5 | 28
N-Ndimethylamine (ppb)^d^ | 2.5 ± 1.6 | 1.0–6.8 | 28
N-Npyrrolidine (ppb)^d^ | 8.7 ± 5.1 | 2.1–20.0 | 28
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 28
β-BHC^a^ | <0.02 | – | 28
γ-BHC^a^ | <0.01 | – | 28
δ-BHC^a^ | <0.01 | – | 28
Heptachlor^a^ | <0.01 | – | 28
Aldrin^a^ | <0.01 | – | 28
Heptachlor Epoxide^a^ | <0.01 | – | 28
DDE^a^ | <0.01 | – | 28
DDD^a^ | <0.01 | – | 28
DDT^a^ | <0.01 | – | 28
HCB^a^ | <0.01 | – | 28
Mirex^a^ | <0.01 | – | 28
Methoxychlor^a^ | <0.05 | – | 28
Dieldrin^a^ | <0.01 | – | 28
Endrin^a^ | <0.01 | – | 28
Telodrin^a^ | <0.01 | – | 28
Chlordane^a^ | <0.05 | – | 28
Toxaphene^a^ | <0.10 | – | 28
Estimated PCBs^a^ | <0.20 | – | 28
Ronnel^a^ | <0.01 | – | 28
Ethion^a^ | <0.02 | – | 28
Trithion^a^ | <0.05 | – | 28
Diazinon^a^ | <0.10 | – | 28
Methyl Chlorpyrifos | 0.09 ± 0.073 | 0.02–0.315 | 28
Methyl Parathion^a^ | <0.02 | – | 28
Ethyl Parathion^a^ | <0.02 | – | 28
Malathion | 0.1 ± 0.093 | 0.02–0.355 | 28
Endosulfan I^a^ | <0.01 | – | 28
Endosulfan II^a^ | <0.01 | – | 28
Endosulfane Sulfate^a^ | <0.03 | – | 28

CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; PCB = polychlorinated biphenyl.

^a^ All values were less than the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.