# Appendix B Chemical Characterization and Dose Formulation Studies

## B.1 Procurement and Characterization of 2-Hydroxy-4-methoxybenzophenone

2-Hydroxy-4-methoxybenzophenone (2H4MBP) was obtained from Ivy Fine Chemicals Corporation (Cherry Hill, NJ) in one lot (20080801) that was used in the perinatal and 2-year studies. Identity and purity analyses were conducted under the analytical chemistry laboratory and study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the 2H4MBP studies are on file at the National Institute of Environmental Health Sciences.

Lot 20080801 of the chemical, a light-yellow powder, was identified as 2H4MBP by infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and gas chromatography (GC) with mass spectrometry (MS) detection. The IR spectrum was in good agreement with a reference spectrum ^66^ and the structure of 2H4MBP. Proton and carbon-13 NMR spectra were consistent with computer-predicted spectra and the structure of the test article. The mass spectrum of the major peak from the GC/MS analysis matched a reference spectrum^67^ for 2H4MBP. A representative IR spectrum is presented in Table B-1 and Figure B-1.

The purity of lot 20080801 was determined using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection by system A and using GC with flame ionization detection (FID) by system B. Lot 20080801 was screened for common residual volatile solvents using GC system C with electron capture detection (ECD) and FID. Differential scanning calorimetry (DSC) was used to determine the purity of the test article using a PerkinElmer (Shelton, CT) Diamond differential scanning calorimeter scanning 1°C per minute over the range of 40°C to 75°C. In addition, Karl Fisher titration of lot 20080801 was performed by Galbraith Laboratories, Inc. (Knoxville, TN).

A. For HPLC/UV analysis, the system included an Agilent 110 high-performance liquid chromatograph (Agilent Technologies, Inc., Santa Clara, CA) with UV detection (289 nm); a Synergi™ Fusion-RP column (100 mm × 3 mm, 2.5 μm particle size or 100 mm × 4.6 mm, 4 μm particle size; Phenomenex, Torrance, CA); and an isocratic mobile phase of acetonitrile:ASTM Type 1 water (40:60) at a flow rate of 0.8 mL/minute.
B. For GC/FID analysis of initial bulk chemical purity, the system included an Agilent 6890 gas chromatograph (Agilent Technologies, Inc., Santa Clara, CA) with FID; a Rtx-5, 30 m × 0.32 mm, 1.0 μm film thickness column (Restek, Bellefonte, PA), helium carrier gas at a flow rate of 3 mL/minute; and an oven temperature program of 80°C for 1 minute, then 20°C/minute to 200°C, then 10°C/minute to 280°C, held for 10 minutes.
C. For GC analysis of residual volatiles in the test article, the system included an Agilent 6890 instrument (Agilent Technologies, Inc., Santa Clara, CA) with either ECD for halogenated volatiles or FID for non-halogenated volatiles; a Restek Rtx-624, 30 m × 0.53 mm, 3 μm film thickness column, helium carrier gas at a flow rate of 5 mL/minute; and an oven temperature program of 35°C for 14 minutes, then 15°C/minute to 40°C, held for 3 minutes, then 15°C/minute to 240°C, held for 2 minutes.

Purity assessment by HPLC/UV system A found no reportable impurities in lot 20080801. GC/FID analysis by system B yielded a purity of 99.8% and found one impurity with an area of 0.17% of the total peak area. No significant halogenated or nonhalogenated volatile impurities were found in the bulk chemical using GC/ECD or GC/FID by system C, respectively. Purity by DSC was 99.2%. Karl Fischer analysis indicated that no quantifiable water was present in the test article. The overall purity of lot 20080801 was determined to be greater than 99%.

To ensure stability, the bulk chemical was stored at room temperature, in sealed amber glass containers. Periodic reanalyses of the bulk chemical were performed during the perinatal and 2-year studies by the study laboratory using HPLC/UV by system A and no degradation of the bulk chemical was detected.

## B.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared approximately monthly by mixing 2H4MBP with feed (Table B-1). Formulations were stored in sealed amber plastic bags at room temperature for up to 43 days.

Homogeneity studies of the 1,000 and 10,000 ppm dose formulations in NIH-07 and NTP-2000 feed were performed before the animal studies by the analytical chemistry and study laboratories with HPLC/UV by system A. Additional homogeneity studies of the 1,000 and 10,000 ppm dose formulations in NTP-2000 feed were performed during the chronic studies by the study laboratory with the same HPLC/UV system. Stability studies of the 1,000 ppm dose formulation in NIH-07 and NTP-2000 feed were performed by the analytical chemistry laboratory using the same analytical method. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in sealed amber plastic bags at room temperature.

Periodic analyses of the dose formulations of 2H4MBP were conducted by the study laboratory using HPLC/UV system A. During the perinatal and 2-year studies, the dose formulations were analyzed 14 times; animal room samples were also analyzed (Table B-2; Table B-3). Of the dose formulations analyzed, all 65 for rats and all 67 for mice were within 10% of the target concentrations; all 18 animal room samples for rats and all 15 for mice were within 10% of the target concentrations.

Table B-1 Preparation and Storage of Dose Formulations in the Perinatal and Two-year Feed Studies of 2-Hydroxy-4-methoxybenzophenone

Rats | Mice
Preparation
A premix of NIH-07 or NTP-2000 meal feed and 2-hydroxy-4-methoxybenzophenone was prepared in a Hobart processor, then layered into the remaining feed and blended in a Patterson Kelly twin-shell blender for approximately 15 minutes. The dose formulations were prepared approximately every 4 weeks. | Same as rats except that dose formulations were only prepared in NTP-2000 feed
Chemical Lot Number
20080801 | 20080801
Maximum Storage Time
42 days | 43 days
Storage Conditions
Stored in sealed amber plastic bags at room temperature | Stored in sealed amber plastic bags at room temperature
Study Laboratory
Battelle (Columbus, OH) | Battelle (Columbus, OH)

Table B-2 Results of Analyses of Dose Formulations Administered to Rats in the Perinatal and Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
September 22, 2010 | September 24, 2010 | 1,000 | 981 | −2
| | 3,000 | 2,920 | −3
| | 10,000 | 9,910 | −1
| October 26, 2010^b^ | 1,000 | 945 | −6
| | 3,000 | 2,740 | −9
| | 10,000 | 9,550 | −5
October 7, 2010 | October 8, 2010 | 1,000 | 1,000 | 0
| | 1,000 | 989 | −1
| | 3,000 | 3,020 | 1
| | 3,000 | 3,020 | 1
| | 10,000 | 10,000 | 0
| | 10,000 | 9,730 | −3
| November 15, 2010^b^ | 1,000 | 950 | −5
| | 3,000 | 2,840 | −5
| | 10,000 | 9,450 | −6
December 2, 2010 | December 3, 2010 | 1,000 | 1,040 | 4
| | 1,000 | 1,030 | 3
| | 3,000 | 3,050 | 2
| | 3,000 | 3,070 | 2
| | 10,000 | 10,200 | 2
| | 10,000 | 10,100 | 1
January 26, 2011 | January 26, 2011 | 1,000 | 998 | 0
| | 3,000 | 2,940 | −2
| | 3,000 | 2,950 | −2
| | 10,000 | 9,820 | −2
| March 11, 2011^b^ | 1,000 | 971 | −3
| | 3,000 | 3,020 | +1
| | 10,000 | 9,550 | −5
April 15, 2011 | April 18, 2011 | 1,000 | 996 | 0
| | 1,000 | 992 | −1
| | 3,000 | 2,970 | −1
| | 3,000 | 2,960 | −1
| | 10,000 | 9,860 | −1
| | 10,000 | 9,890 | −1
June 10, 2011 | June 14, 2011 | 1,000 | 1,010 | 1
| | 1,000 | 1,010 | 1
| | 3,000 | 2,970 | −1
| | 3,000 | 3,020 | 1
| | 10,000 | 9,890 | −1
| | 10,000 | 9,790 | −2
| July 25, 2011^b^ | 1,000 | 967 | −3
| | 3,000 | 2,790 | −7
| | 10,000 | 9,140 | −9
September 7, 2011 | September 9, 2011 | 1,000 | 1,020 | 2
| | 1,000 | 1,010 | 1
| | 3,000 | 2,910 | −3
| | 3,000 | 2,960 | −2
| | 10,000 | 9,830 | −2
| | 10,000 | 9,730 | −3
October 28, 2011 | October 28, 2011 | 1,000 | 988 | −1
| | 1,000 | 993 | −1
| | 3,000 | 2,950 | −2
| | 3,000 | 2,900 | −3
| | 10,000 | 9,710 | −3
| | 10,000 | 9,800 | −2
January 20, 2012 | January 20, 2012 | 1,000 | 1,010 | 1
| | 1,000 | 1,020 | 2
| | 3,000 | 2,960 | −1
| | 3,000 | 2,930 | −2
| | 10,000 | 9,750 | −3
| | 10,000 | 9,730 | −3
| March 6, 2012^b^ | 1,000 | 929 | −7
| | 3,000 | 2,850 | −5
| | 10,000 | 9,370 | −6
March 16, 2012 | March 16, 2012 | 1,000 | 1,030 | 3
| | 1,000 | 996 | 0
| | 3,000 | 3,020 | 1
| | 3,000 | 3,050 | 2
| | 10,000 | 9,960 | 0
| | 10,000 | 9,990 | 0
June 8, 2012 | June 11, 2012 | 1,000 | 974 | −3
| | 1,000 | 990 | −1
| | 3,000 | 3,030 | 1
| | 3,000 | 2,950 | −2
| | 10,000 | 9,960 | 0
| | 10,000 | 9,880 | −1
August 31, 2012 | August 31, 2012 | 1,000 | 984 | −2
| | 3,000 | 3,010 | 0
| | 10,000 | 10,300 | 3
| | 10,000 | 10,200 | 2
| October 16, 2012^b^ | 1,000 | 974 | −3
| | 3,000 | 2,860 | −5
| | 10,000 | 9,600 | −4

^a^ Results of triplicate analyses.

^b^ Animal room samples.

Table B-3 Results of Analyses of Dose Formulations Administered to Mice in the Two-year Feed Study of 2-Hydroxy-4-methoxybenzophenone

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
June 17, 2010 | June 19, 2010 | 1,000 | 1,030 | +3
| | 3,000 | 2,940 | −2
| | 10,000 | 9,600 | −4
| July 27, 2010^b^ | 1,000 | 951 | −5
| | 3,000 | 2,770 | −8
| | 10,000 | 9,120 | −9
July 15, 2010 | July 16, 2010 | 1,000 | 997 | 0
| | 1,000 | 993 | −1
| | 3,000 | 2,920 | −3
| | 3,000 | 2,930 | −2
| | 10,000 | 9,770 | −2
| | 10,000 | 9,770 | −2
October 7, 2010 | October 8, 2010 | 1,000 | 1,000 | 0
| | 1,000 | 989 | −1
| | 3,000 | 3,020 | 1
| | 3,000 | 3,020 | 1
| | 10,000 | 10,000 | 0
| | 10,000 | 9,730 | −3
December 2, 2010 | December 3, 2010 | 1,000 | 1,040 | 4
| | 1,000 | 1,030 | 3
| | 3,000 | 3,050 | 2
| | 3,000 | 3,070 | 2
| | 10,000 | 10,200 | 2
| | 10,000 | 10,100 | 1
| January 13, 2011^b^ | 1,000 | 943 | −6
| | 3,000 | 2,760 | −8
| | 10,000 | 9,260 | −7
January 26, 2011 | January 26, 2011 | 1,000 | 998 | 0
| | 3,000 | 2,940 | −2
| | 3,000 | 2,950 | −2
| | 10,000 | 9,820 | −2
| March 11, 2011^b^ | 1,000 | 977 | −2
| | 3,000 | 2,910 | −3
| | 10,000 | 9,920 | −1
April 15, 2011 | April 18, 2011 | 1,000 | 996 | 0
| | 1,000 | 992 | −1
| | 3,000 | 2,970 | −1
| | 3,000 | 2,960 | −1
| | 10,000 | 9,860 | −1
| | 10,000 | 9,890 | −1
June 10, 2011 | June 14, 2011 | 1,000 | 1,010 | 1
| | 1,000 | 1,010 | 1
| | 3,000 | 2,970 | −1
| | 3,000 | 3,020 | 1
| | 10,000 | 9,890 | −1
| | 10,000 | 9,790 | −2
| July 25, 2011^b^ | 1,000 | 967 | −3
| | 3,000 | 2,870 | −4
| | 10,000 | 9,560 | −4
September 7, 2011 | September 9, 2011 | 1,000 | 1,020 | 2
| | 1,000 | 1,010 | 1
| | 3,000 | 2,910 | −3
| | 3,000 | 2,960 | −2
| | 10,000 | 9,830 | −2
| | 10,000 | 9,730 | −3
October 28, 2011 | October 28, 2011 | 1,000 | 988 | −1
| | 1,000 | 993 | −1
| | 3,000 | 2,950 | −2
| | 3,000 | 2,900 | −3
| | 10,000 | 9,710 | −3
| | 10,000 | 9,800 | −2
January 20, 2012 | January 20, 2012 | 1,000 | 1,010 | 1
| | 1,000 | 1,020 | 2
| | 3,000 | 2,960 | −1
| | 3,000 | 2,930 | −2
| | 10,000 | 9,750 | −3
| | 10,000 | 9,730 | −3
| March 6, 2012^b^ | 1,000 | 975 | −3
| | 3,000 | 2,840 | −5
| | 10,000 | 9,360 | −6
March 16, 2012 | March 16, 2012 | 1,000 | 1,030 | 3
| | 1,000 | 996 | 0
| | 3,000 | 3,020 | 1
| | 3,000 | 3,050 | 2
| | 10,000 | 9,960 | 0
| | 10,000 | 9,990 | 0
June 8, 2012 | June 11, 2012 | 1,000 | 974 | −3
| | 1,000 | 990 | −1
| | 3,000 | 3,030 | 1
| | 3,000 | 2,950 | −2
| | 10,000 | 9,960 | 0
| | 10,000 | 9,880 | −1

^a^ Results of triplicate analyses.

^b^ Animal room samples.

Figure B-1

Infrared Absorption Spectrum of 2-Hydroxy-4-methoxybenzophenone