# Appendix A Genetic Toxicology

## A.1 Bacterial Mutagenicity Test Protocol

Testing procedures were modified from those originally reported by Zeiger et al.^64^ Coded samples of 2-hydroxy-4-methoxybenzophenone (2H4MBP) (the same chemical lot that was used in the 2-year bioassays) were incubated with the Salmonella typhimurium (TA98, TA100) or Escherichia coli (WP2 uvrA pKM101) tester strains either in buffer or S9 mix (metabolic activation enzymes and cofactors from phenobarbital/benzoflavone-induced male Sprague Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine (or tryptophan for the E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and at least five doses of 2H4MBP. The highest concentration tested was limited by toxicity in strain TA100; the other two strains were tested up to the assay limit dose of 6,000 μg/plate. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not related to dose, not reproducible, or not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. No minimum percentage or fold increase is required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## A.2 Results

2H4MBP (20 to 6,000 μg/plate) was not mutagenic in S. typhimurium strains TA98 or TA100 or E. coli strain WP2 uvrA pKM101 when tested with and without 10% rat liver metabolic activation enzymes (S9) (Table A-1).

Table A-1 Mutagenicity of 2-Hydroxy-4-methoxybenzophenone in Bacterial Tester Strains^a^

Strain | Concentration (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 92.7 ± 4.1 | 111.7 ± 10.7 | 101.7 ± 1.3 | 156.3 ± 3.3
| 20 | 95.0 ± 9.2 | 120.3 ± 9.8 | – | –
| 50 | 86.7 ± 2.9 | 115.0 ± 6.0 | 99.7 ± 1.9 | 157.7 ± 7.9
| 125 | 82.3 ± 4.9 | 126.0 ± 4.6 | 88.0 ± 9.6 | 147.3 ± 10.3
| 250 | 80.7 ± 4.3 | 83.3 ± 1.9^c^ | 76.7 ± 2.0 | 128.0 ± 15.2
| 500 | 56.0 ± 4.0 | 51.3 ± 6.0^c^ | 58.3 ± 1.3 | 84.7 ± 6.7^c^
| 1,000 | 14.3 ± 1.9^c^ | 54.3 ± 16.3^c^ | 25.7 ± 3.3^c^ | 55.7 ± 3.3^c^
| 3,000 | – | – | 30.3 ± 3.0^c^ | 56.3 ± 3.4^c^
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control^b^ | | 658.3 ± 14.4 | 573.3 ± 10.4 | 542.0 ± 9.5 | 554.0 ± 20.1
TA98
| 0 | 16.7 ± 2.9 | 17.7 ± 3.3 | 23.7 ± 4.6 | 22.0 ± 1.0
| 125 | 9.0 ± 1.7 | 10.3 ± 3.7 | 14.7 ± 2.4 | 27.0 ± 2.3
| 250 | 9.7 ± 0.7 | 15.7 ± 1.9 | 14.7 ± 0.7 | 17.7 ± 0.7
| 500 | 6.0 ± 1.5 | 10.3 ± 1.9 | 11.3 ± 2.3 | 14.3 ± 0.9
| 1,000 | 2.7 ± 0.3^c^ | 3.3 ± 0.3^c^ | 12.0 ± 2.3 | 13.0 ± 1.7^c^
| 3,000 | 2.0 ± 0.6^c^ | 2.3 ± 1.3^c^ | 4.7 ± 1.5^c^ | 12.3 ± 1.8^c^
| 6,000 | 2.3 ± 0.3^c^ | 9.7 ± 1.5^c^ | 10.7 ± 4.4^c^ | 17.3 ± 0.3^c^
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 537.7 ± 9.8 | 519.0 ± 24.6 | 1,485.7 ± 67.2 | 2,016.7 ± 34.7
Escherichia coli WP2 uvrA/pKM101
| 0 | 116.0 ± 11.5 | 109.3 ± 9.5 | 155.0 ± 9.3 | 152.7 ± 4.2
| 125 | 106.0 ± 7.1 | 127.7 ± 10.3 | 161.0 ± 3.1 | 153.0 ± 6.1
| 250 | 118.7 ± 8.1 | 119.7 ± 9.2 | 145.3 ± 11.9 | 166.3 ± 11.7
| 500 | 99.7 ± 5.5 | 111.7 ± 6.2 | 137.3 ± 12.0 | 139.0 ± 9.5
| 1,000 | 90.3 ± 2.8 | 106.0 ± 5.6 | 117.0 ± 8.0 | 109.7 ± 17.1^c^
| 3,000 | 86.0 ± 2.3^c^ | 101.0 ± 7.2^c^ | 105.3 ± 1.7 | 122.7 ± 5.0^c^
| 6,000 | 102.0 ± 11.2^c^ | 116.0 ± 12.5^c^ | 110.3 ± 16.4^c,d^ | 97.3 ± 9.6^c^
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 1,751.3 ± 68.7 | 1,984.0 ± 82.4 | 1,391.3 ± 37.1 | 1,178.0 ± 35.4

^a^ Studies performed at ILS, Inc. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate served as the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

^c^ Precipitate on plate.

^d^ Contamination.