# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-596

Report Series: NTP Technical Report Series

Report Series Number: 596

Official citation: National Toxicology Program (NTP). 2018. NTP technical report on the toxicology and carcinogenesis studies in B6C3F1/N mice exposed to whole-body radio frequency radiation at a frequency (1,900 MHz) and modulations (GSM and CDMA) used by cell phones. Research Triangle Park, NC: National Toxicology Program. Technical Report 596.