# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M.E. Wyde, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  J.R. Bucher, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  S.A. Elmore, D.V.M.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  G.K. Roberts, Ph.D.
  K.R. Shockley, Ph.D.
  R.C. Sills, D.V.M., Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Management of peer review of draft document
  M.S. Wolfe, Ph.D.
- Oversight for data management
  J.M. Fostel, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- IIT Research Institute, Chicago, Illinois, USA
  Conducted studies and evaluated pathology findings
  D.L. McCormick, Ph.D., Principal Investigator
  T.L. Horn, Ph.D., Study Director
  J.R. Gauger, B.S., Engineer
- IT’IS Foundation, Zurich, Switzerland
  Constructed and maintained exposure system
  M. Capstick, Ph.D.
  N. Kuster, Ph.D. M.
- National Institute of Standards and Technology, Boulder, Colorado, USA
  Conducted independent validation of the exposure system
  P.F. Wilson, Ph.D., Principal Investigator
  G. Koepke, M.S.
  J.M. Ladbury, M.S.
- Pathology Associates International, A Charles River Company, Research Triangle Park, North Carolina, USA
  Evaluated pathology findings
  J.S. Hoane, D.V.M., Ph.D., Principal Investigator
  J.M. Pletcher, D.V.M., Principal Investigator
  L.H. Brennecke, D.V.M.
  C. Detrisac, D.V.M., Ph.D.
  R.M. Kovatch, D.V.M.
- Evaluated sperm motility
  F.T. Les, M.S.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  E.T. Adams, D.V.M., Ph.D., Principal Investigator
  G.D. Hill, D.V.M., Ph.D.
  R.R. Moore, D.V.M.
- Coordinated the NTP Pathology Peer Review on mice exposed to GSM- and CDMA-modulated cell phone RFR for 28 days (June 13, 2016)
  R.R. Moore, D.V.M., Coordinated CDMA studies
  G.D. Hill, D.V.M., Ph.D., Coordinated GSM studies
- Coordinated the NTP Pathology Working Group on male mice (May 2, 2017) or female mice (May 1, 2017) exposed to GSM- or CDMA-modulated cell phone RFR for 2 years
  R.R. Moore, D.V.M., Coordinated male mice (May 2, 2017)
  G.D. Hill, D.V.M., Ph.D., Coordinated female mice (May 1, 2017)
- Conducted comet and micronucleus assays for male and female mice exposed to GSM- or CDMA-modulated cell phone RFR for 14 weeks
  L. Recio, Ph.D., Principle Investigator
  C.A. Hobbs, Ph.D., Laboratory Director
  P.V. Garibaldi, B.S.
  A.S. Green, B.S.
  C.A. Lentz, B.S.
  K.G. Shepard, B.S.
  J.W. Winters, B.S.
- RTI International, Research Triangle Park, North Carolina, USA
  Provided SCVCE analysis
  R.W. Tyl, Ph.D., Principal Investigator
  M.C. Marr, B.A.
  C.S. Sloan, M.S.