# References

1 Office of Engineering and Technology (OET). Questions and answers about biological effects and potential hazards of radiofrequency electromagnetic fields. Washington, DC: Federal Communications Comission; 1999. OET Bulletin 56, 4th ed.
2 Buddhikot MM, Kennedy I, Mullany F, Viswanathan H. Ultra‐broadband femtocells via opportunistic reuse of multi‐operator and multi‐service spectrum. Bell Labs Tech J. 2009;13(4):129–143.10.1002/bltj.20340
3 National Toxicology Program (NTP). Peer review of the draft NTP Technical Reports on cell phone radiofrequency radiation – March 26-28, 2018. 2018. https://ntp.niehs.nih.gov/about/org/sep/trpanel/meetings/docs/2018/march/videos/capstick-ladbury/index.html
4 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of carcinogenic risks to humans. Non-ionizing radiation, part 2: Radiofrequency electromagnetic fields. Vol. 102. Lyon, France: IARC; 2013.
5 Pew Research Center Survey. Mobile fact sheet. Internet and technology. Washington, DC: Pew Research Center; 2017. http://www.pewinternet.org/fact-sheet/mobile
6 Cellular Telecommunications Industry Association (CTIA). Annual wireless industry survey. 2017. https://www.ctia.org/industry-data/ctia-annual-wireless-industry-survey
7 Code of Federal Regulations (CFR). 47:§1.1310.
8 Adair RK. Biophysical limits on athermal effects of RF and microwave radiation. Bioelectromagnetics. 2003;24(1):39–48. 10.1002/bem.10061 12483664
9 Prohofsky EW. RF absorption involving biological macromolecules. Bioelectromagnetics. 2004;25(6):441–451. 10.1002/bem.20013 15300730
10 Sheppard AR, Swicord ML, Balzano Q. Quantitative evaluations of mechanisms of radio-frequency interactions with biological molecules and processes. Health Phys. 2008;95(4):365–396. 10.1097/01.HP.0000319903.20660.37 18784511
11 Manna D, Ghosh R. Effect of radiofrequency radiation in cultured mammalian cells: A review. Electromagn Biol Med. 2016;35(3):265–301. 10.3109/15368378.2015.1092158 27053138
12 Smialowicz RJ, Rogers RR, Garner RJ, Riddle MM, Luebke RW, Rowe DG. Microwaves (2,450 MHz) suppress murine natural killer cell activity. Bioelectromagnetics. 1983;4(4):371–381. 10.1002/bem.2250040408 6651889
13 Guy AW, Chou C-K, Kunz LL, Crowley J, Krupp J. Summary. Vol. 9. Seattle (WA): University of Washington, School of Medicine, Department of Rehabilitation Medicine, Bioelectromagnetics Research Laboratory; 1985. (Effects of long-term low-level radiofrequency radiation exposure on rats.). http://www.dtic.mil/docs/citations/ADA159512.
14 Veyret B, Bouthet C, Deschaux P, De Seze R, Geffard M, Joussot‐Dubien J, Le Diraison M, Moreau JM, Caristan A. Antibody responses of mice exposed to low‐power microwaves under combined, pulse‐and‐amplitude modulation. Bioelectromagnetics. 1991;12(1):47–56. 10.1002/bem.2250120107 2012621
15 Novoselova EG, Fesenko EE, Makar VR, Sadovnikov VB. Microwaves and cellular immunity. II. Immunostimulating effects of microwaves and naturally occurring antioxidant nutrients. Bioelectrochem Bioenerg. 1999;49(1):37–41. 10.1016/S0302-4598(99)00059-8 10619446
16 Lushnikov KV, Gapeev AB, Sadovnikov VB, Cheremis NK. Effect of extremely high frequency electromagnetic radiation of low intensity on parameters of humoral immunity in healthy mice [In Russian]. Biofizika. 2001;46(4):753–760. 11558390
17 Kolomytseva MP, Gapeev AB, Sadovnikov VB, Chemeris NK. Suppression of nonspecific resistance of the body under the effect of extremely high frequency electromagnetic radiation of low intensity [In Russian]. Biofizika. 2002;47(1):71–77. 11855293
18 Elekes E, Thuróczy G, Szabó LD. Effect on the immune system of mice exposed chronically to 50 Hz amplitude modulated 2.45 GHz microwaves. Bioelectromagnetics. 1996;17(3):246–248. 10.1002/(SICI)1521-186X(1996)17:3<246::AID-BEM11>3.0.CO;2-O 8809365
19 Chagnaud JL, Veyret B. In vivo exposure of rats to GSM-modulated microwaves: flow cytometry analysis of lymphocyte subpopulations and of mitogen stimulation. Int J Radiat Biol. 1999;75(1):111–113. 10.1080/095530099140861 9972797
20 Gatta L, Pinto R, Ubaldi V, Pace L, Galloni P, Lovisolo GA, Marino C, Pioli C. Effects of in vivo exposure to GSM-modulated 900 MHz radiation on mouse peripheral lymphocytes. Radiat Res. 2003;160(5):600–605. 10.1667/RR3078 14565821
21 Nasta F, Prisco MG, Pinto R, Lovisolo GA, Marino C, Pioli C. Effects of GSM-modulated radiofrequency electromagnetic fields on B cell peripheral differentiation and antibody production. Radiat Res. 2006;165(6):664–670. 10.1667/RR3555.1 16802866
22 Ohtani S, Ushiyama A, Maeda M, Ogasawara Y, Wang J, Kunugita N, Ishii K. The effects of radio-frequency electromagnetic fields on T cell function during development. J Radiat Res (Tokyo). 2015;56(3):467–474. 10.1093/jrr/rru126 25835473
23 Fritze K, Wiessner C, Kuster N, Sommer C, Gass P, Hermann DM, Kiessling M, Hossmann KA. Effect of global system for mobile communication microwave exposure on the genomic response of the rat brain. Neuroscience. 1997;81(3):627–639. 10.1016/S0306-4522(97)00228-5 9316016
24 Belyaev IY, Koch CB, Terenius O, Roxström-Lindquist K, Malmgren LO, Sommer WH, Salford LG, Persson BR. Exposure of rat brain to 915 MHz GSM microwaves induces changes in gene expression but not double stranded DNA breaks or effects on chromatin conformation. Bioelectromagnetics. 2006;27(4):295–306. 10.1002/bem.20216 16511873
25 Nittby H, Widegren B, Krogh M, Grafström G, Berlin H, Rehn G, Eberhardt JL, Malmgren L, Persson BRR, Salford LG. Exposure to radiation from global system for mobile communications at 1,800 MHz significantly changes gene expression in rat hippocampus and cortex. Environmentalist. 2008;28:458–465.10.1007/s10669-008-9170-8
26 Stagg RB, Hawel LH 3rd, Pastorian K, Cain C, Adey WR, Byus CV. Effect of immobilization and concurrent exposure to a pulse-modulated microwave field on core body temperature, plasma ACTH and corticosteroid, and brain ornithine decarboxylase, Fos and Jun mRNA. Radiat Res. 2001;155(4):584–592. 10.1667/0033-7587(2001)155[0584:EOIACE]2.0.CO;2 11260660
27 Paparini A, Rossi P, Gianfranceschi G, Brugaletta V, Falsaperla R, De Luca P, Romano Spica V. No evidence of major transcriptional changes in the brain of mice exposed to 1800 MHz GSM signal. Bioelectromagnetics. 2008;29(4):312–323. 10.1002/bem.20399 18175331
28 McNamee JP, Bellier PV, Konkle AT, Thomas R, Wasoontarajaroen S, Lemay E, Gajda GB. Analysis of gene expression in mouse brain regions after exposure to 1.9 GHz radiofrequency fields. Int J Radiat Biol. 2016;92(6):338–350. 10.3109/09553002.2016.1159353 27028625
29 Ammari M, Lecomte A, Sakly M, Abdelmelek H, de-Seze R. Exposure to GSM 900 MHz electromagnetic fields affects cerebral cytochrome c oxidase activity. Toxicology. 2008;250(1):70–74. 10.1016/j.tox.2008.05.019 18585429
30 Ammari M, Gamez C, Lecomte A, Sakly M, Abdelmelek H, De Seze R. GFAP expression in the rat brain following sub-chronic exposure to a 900 MHz electromagnetic field signal. Int J Radiat Biol. 2010;86(5):367–375. 10.3109/09553000903567946 20397841
31 Dasdag S, Akdag MZ, Ulukaya E, Uzunlar AK, Ocak AR. Effect of mobile phone exposure on apoptotic glial cells and status of oxidative stress in rat brain. Electromagn Biol Med. 2009;28(4):342–354. 10.3109/15368370903206556 20017625
32 Lee HJ, Pack JK, Kim TH, Kim N, Choi SY, Lee JS, Kim SH, Lee YS. The lack of histological changes of CDMA cellular phone-based radio frequency on rat testis. Bioelectromagnetics. 2010;31(7):528–534. 10.1002/bem.20589 20607737
33 Masuda H, Sanchez S, Dulou PE, Haro E, Anane R, Billaudel B, Lévêque P, Veyret B. Effect of GSM-900 and -1800 signals on the skin of hairless rats. I: 2-hour acute exposures. Int J Radiat Biol. 2006;82(9):669–674. 10.1080/09553000600930079 17050479
34 Sanchez S, Masuda H, Billaudel B, Haro E, Anane R, Lévêque P, Ruffie G, Lagroye I, Veyret B. Effect of GSM-900 and -1800 signals on the skin of hairless rats. II: 12-week chronic exposures. Int J Radiat Biol. 2006;82(9):675–680. 10.1080/09553000600930087 17050480
35 Sanchez S, Masuda H, Ruffie G, De Gannes FP, Billaudel B, Haro E, Lévêque P, Lagroye I, Veyret B. Effect of GSM-900 and -1800 signals on the skin of hairless rats. III: expression of heat shock proteins. Int J Radiat Biol. 2008;84(1):61–68. 10.1080/09553000701616098 17852563
36 Liu Q, Si T, Xu X, Liang F, Wang L, Pan S. Electromagnetic radiation at 900 MHz induces sperm apoptosis through bcl-2, bax and caspase-3 signaling pathways in rats. Reprod Health. 2015;12:65. 10.1186/s12978-015-0062-3 26239320
37 Pyrpasopoulou A, Kotoula V, Cheva A, Hytiroglou P, Nikolakaki E, Magras IN, Xenos TD, Tsiboukis TD, Karkavelas G. Bone morphogenetic protein expression in newborn rat kidneys after prenatal exposure to radiofrequency radiation. Bioelectromagnetics. 2004;25(3):216–227. 10.1002/bem.10185 15042631
38 Eşmekaya MA, Seyhan N, Ömeroğlu S. Pulse modulated 900 MHz radiation induces hypothyroidism and apoptosis in thyroid cells: A light, electron microscopy and immunohistochemical study. Int J Radiat Biol. 2010;86(12):1106–1116. 10.3109/09553002.2010.502960 20807179
39 Ohtani S, Ushiyama A, Maeda M, Hattori K, Kunugita N, Wang J, Ishii K. Exposure time-dependent thermal effects of radiofrequency electromagnetic field exposure on the whole body of rats. J Toxicol Sci. 2016;41(5):655–666. 10.2131/jts.41.655 27665775
40 Ilhan A, Gurel A, Armutcu F, Kamisli S, Iraz M, Akyol O, Ozen S. Ginkgo biloba prevents mobile phone-induced oxidative stress in rat brain. Clin Chim Acta. 2004;340(1-2):153–162. 10.1016/j.cccn.2003.10.012 14734207
41 Meral I, Mert H, Mert N, Deger Y, Yoruk I, Yetkin A, Keskin S. Effects of 900-MHz electromagnetic field emitted from cellular phone on brain oxidative stress and some vitamin levels of guinea pigs. Brain Res. 2007;1169:120–124. 10.1016/j.brainres.2007.07.015 17674954
42 Sokolovic D, Djindjic B, Nikolic J, Bjelakovic G, Pavlovic D, Kocic G, Krstic D, Cvetkovic T, Pavlovic V. Melatonin reduces oxidative stress induced by chronic exposure of microwave radiation from mobile phones in rat brain. J Radiat Res (Tokyo). 2008;49(6):579–586. 10.1269/jrr.07077 18827438
43 İmge EB, Kiliçoğlu B, Devrim E, Cetin R, Durak I. Effects of mobile phone use on brain tissue from the rat and a possible protective role of vitamin C - A preliminary study. Int J Radiat Biol. 2010;86(12):1044–1049. 10.3109/09553002.2010.501838 20698742
44 Ozguner F, Altinbas A, Ozaydin M, Dogan A, Vural H, Kisioglu AN, Cesur G, Yildirim NG. Mobile phone-induced myocardial oxidative stress: protection by a novel antioxidant agent caffeic acid phenethyl ester. Toxicol Ind Health. 2005;21(7-8):223–230. 10.1191/0748233705th228oa 16342473
45 Oktem F, Ozguner F, Mollaoglu H, Koyu A, Uz E. Oxidative damage in the kidney induced by 900-MHz-emitted mobile phone: protection by melatonin. Arch Med Res. 2005;36(4):350–355. 10.1016/j.arcmed.2005.03.021 15950073
46 Ozguner F, Oktem F, Armagan A, Yilmaz R, Koyu A, Demirel R, Vural H, Uz E. Comparative analysis of the protective effects of melatonin and caffeic acid phenethyl ester (CAPE) on mobile phone-induced renal impairment in rat. Mol Cell Biochem. 2005;276(1-2):31–37. 10.1007/s11010-005-2734-8 16132682
47 Ozguner F, Bardak Y, Comlekci S. Protective effects of melatonin and caffeic acid phenethyl ester against retinal oxidative stress in long-term use of mobile phone: A comparative study. Mol Cell Biochem. 2006;282(1-2):83–88. 10.1007/s11010-006-1267-0 16317515
48 Ozgur E, Güler G, Seyhan N. Mobile phone radiation-induced free radical damage in the liver is inhibited by the antioxidants N-acetyl cysteine and epigallocatechin-gallate. Int J Radiat Biol. 2010;86(11):935–945. 10.3109/09553002.2010.496029 20807176
49 Tomruk A, Güler G, Dincel AS. The influence of 1800 MHz GSM-like signals on hepatic oxidative DNA and lipid damage in nonpregnant, pregnant, and newly born rabbits. Cell Biochem Biophys. 2010;56(1):39. 10.1007/s12013-009-9068-1 19851891
50 Oral B, Guney M, Ozguner F, Karahan N, Mungan T, Comlekci S, Cesur G. Endometrial apoptosis induced by a 900-MHz mobile phone: preventive effects of vitamins E and C. Adv Ther. 2006;23(6):957–973. 10.1007/BF02850217 17276964
51 Guney M, Ozguner F, Oral B, Karahan N, Mungan T. 900 MHz radiofrequency-induced histopathologic changes and oxidative stress in rat endometrium: Protection by vitamins E and C. Toxicol Ind Health. 2007;23(7):411–420. 10.1177/0748233707080906 18536493
52 Mailankot M, Kunnath AP, Jayalekshmi H, Koduru B, Valsalan R. Radio frequency electromagnetic radiation (RF-EMR) from GSM (0.9/1.8GHz) mobile phones induces oxidative stress and reduces sperm motility in rats. Clinics (Sao Paulo, Brazil). 2009; 64(6):561-565. 10.1590/S1807-59322009000600011
53 Yakymenko I, Tsybulin O, Sidorik E, Henshel D, Kyrylenko O, Kyrylenko S. Oxidative mechanisms of biological activity of low-intensity radiofrequency radiation. Electromagn Biol Med. 2016;35(2):186–202. 10.3109/15368378.2015.1043557 26151230
54 Sonmez OF, Odaci E, Bas O, Kaplan S. Purkinje cell number decreases in the adult female rat cerebellum following exposure to 900 MHz electromagnetic field. Brain Res. 2010;1356:95–101. 10.1016/j.brainres.2010.07.103 20691167
55 Eberhardt JL, Persson BR, Brun AE, Salford LG, Malmgren LO. Blood-brain barrier permeability and nerve cell damage in rat brain 14 and 28 days after exposure to microwaves from GSM mobile phones. Electromagn Biol Med. 2008;27(3):215–229. 10.1080/15368370802344037 18821198
56 Nittby H, Brun A, Eberhardt J, Malmgren L, Persson BR, Salford LG. Increased blood-brain barrier permeability in mammalian brain 7 days after exposure to the radiation from a GSM-900 mobile phone. Pathophysiology. 2009;16(2-3):103–112. 10.1016/j.pathophys.2009.01.001 19345073
57 Nittby H, Brun A, Strömblad S, Moghadam MK, Sun W, Malmgren L, Eberhardt J, Persson BR, Salford LG. Nonthermal GSM RF and ELF EMF effects upon rat BBB permeability. Environmentalist. 2011;31:140–148.10.1007/s10669-011-9307-z
58 Grafström G, Nittby H, Brun A, Malmgren L, Persson BR, Salford LG, Eberhardt J. Histopathological examinations of rat brains after long-term exposure to GSM-900 mobile phone radiation. Brain Res Bull. 2008;77(5):257–263. 10.1016/j.brainresbull.2008.08.004 18782606
59 de Gannes FP, Billaudel B, Taxile M, Haro E, Ruffié G, Lévêque P, Veyret B, Lagroye I. Effects of head-only exposure of rats to GSM-900 on blood-brain barrier permeability and neuronal degeneration. Radiat Res. 2009;172(3):359–367. 10.1667/RR1578.1 19708785
60 McQuade JM, Merritt JH, Miller SA, Scholin T, Cook MC, Salazar A, Rahimi OB, Murphy MR, Mason PA. Radiofrequency-radiation exposure does not induce detectable leakage of albumin across the blood-brain barrier. Radiat Res. 2009;171(5):615–621. 10.1667/RR1507.1 19580497
61 Masuda H, Ushiyama A, Takahashi M, Wang J, Fujiwara O, Hikage T, Nojima T, Fujita K, Kudo M, Ohkubo C. Effects of 915 MHz electromagnetic-field radiation in TEM cell on the blood-brain barrier and neurons in the rat brain. Radiat Res. 2009;172(1):66–73. 10.1667/RR1542.1 19580508
62 Frey AH. Headaches from cellular telephones: are they real and what are the implications? Environ Health Perspect. 1998;106(3):101–103. 10.1289/ehp.98106101 9441959
63 Chia SE, Chia HP, Tan JS. Prevalence of headache among handheld cellular telephone users in Singapore: A community study. Environ Health Perspect. 2000;108(11):1059–1062. 10.1289/ehp.001081059 11102297
64 Hocking B, Westerman R. Neurological abnormalities associated with mobile phone use. Occup Med (Lond). 2000;50(5):366–368. 10.1093/occmed/50.5.366 10975136
65 Sandström M, Wilen J, Oftedal G, Hansson Mild K. Mobile phone use and subjective symptoms. Comparison of symptoms experienced by users of analogue and digital mobile phones. Occup Med (Lond). 2001;51(1):25–35. 10.1093/occmed/51.1.25 11235824
66 Santini R, Seigne M, Bonhomme-Faivre L, Bouffet S, Defrasne E, Sage M. Symptoms experienced by users of digital cellular phones: A study of a French engineering school. Electromagn Biol Med. 2002;21(1):81–88.10.1081/JBC-120003113
67 Santini R, Santini P, Danze JM, Le Ruz P, Seigne M. Investigation on the health of people living near mobile telephone relay stations: I/Incidence according to distance and sex [In French]. Pathol Biol (Paris). 2002;50(6):369–373. 10.1016/S0369-8114(02)00311-5 12168254
68 Kwon MS, Hämäläinen H. Effects of mobile phone electromagnetic fields: critical evaluation of behavioral and neurophysiological studies. Bioelectromagnetics. 2011;32(4):253–272. 10.1002/bem.20635 21452356
69 Mann K, Röschke J. Effects of pulsed high-frequency electromagnetic fields on human sleep. Neuropsychobiology. 1996;33(1):41–47. 10.1159/000119247 8821374
70 Wagner P, Röschke J, Mann K, Hiller W, Frank C. Human sleep under the influence of pulsed radiofrequency electromagnetic fields: A polysomnographic study using standardized conditions. Bioelectromagnetics. 1998;19(3):199–202. 10.1002/(SICI)1521-186X(1998)19:3<199::AID-BEM8>3.0.CO;2-X 9554698
71 Wagner P, Röschke J, Mann K, Fell J, Hiller W, Frank C, Grözinger M. Human sleep EEG under the influence of pulsed radio frequency electromagnetic fields: results from polysomnographies using submaximal high power flux densities. Neuropsychobiology. 2000;42(4):207–212. 10.1159/000026695 11096337
72 Borbély AA, Huber R, Graf T, Fuchs B, Gallmann E, Achermann P. Pulsed high-frequency electromagnetic field affects human sleep and sleep electroencephalogram. Neurosci Lett. 1999;275(3):207–210. 10.1016/S0304-3940(99)00770-3 10580711
73 Huber R, Graf T, Cote KA, Wittmann L, Gallmann E, Matter D, Schuderer J, Kuster N, Borbély AA, Achermann P. Exposure to pulsed high-frequency electromagnetic field during waking affects human sleep EEG. Neuroreport. 2000;11(15):3321–3325. 10.1097/00001756-200010200-00012 11059895
74 Huber R, Treyer V. A. BA, Schuderer J, Gottselig JM, Landolt HP, Werth E, Berthold T, Kuster N, Buck A et al. Electromagnetic fields, such as those from mobile phones, alter regional cerebral blood flow and sleep and waking EEG. J Sleep Res. 2002; 11(4):289-295. 10.1046/j.1365-2869.2002.00314.x
75 Huber R, Schuderer J, Graf T, Jütz K, Borbély AA, Kuster N, Achermann P. Radio frequency electromagnetic field exposure in humans: estimation of SAR distribution in the brain, effects on sleep and heart rate. Bioelectromagnetics. 2003;24(4):262–276. 10.1002/bem.10103 12696086
76 Loughran SP, Wood AW, Barton JM, Croft RJ, Thompson B, Stough C. The effect of electromagnetic fields emitted by mobile phones on human sleep. Neuroreport. 2005;16(17):1973–1976. 10.1097/01.wnr.0000186593.79705.3c 16272890
77 Hung CS, Anderson C, Horne JA, McEvoy P. Mobile phone ‘talk-mode’ signal delays EEG-determined sleep onset. Neurosci Lett. 2007;421(1):82–86. 10.1016/j.neulet.2007.05.027 17548154
78 Regel SJ, Tinguely G, Schuderer J, Adam M, Kuster N, Landolt HP, Achermann P. Pulsed radio-frequency electromagnetic fields: dose-dependent effects on sleep, the sleep EEG and cognitive performance. J Sleep Res. 2007;16(3):253–258. 10.1111/j.1365-2869.2007.00603.x 17716273
79 Lowden A, Åkerstedt T, Ingre M, Wiholm C, Hillert L, Kuster N, Nilsson JP, Arnetz B. Sleep after mobile phone exposure in subjects with mobile phone-related symptoms. Bioelectromagnetics. 2011;32(1):4–14. 10.1002/bem.20609 20857453
80 Volkow ND, Tomasi D, Wang G-J, Vaska P, Fowler JS, Telang F, Alexoff D, Logan J, Wong C. Effects of cell phone radiofrequency signal exposure on brain glucose metabolism. JAMA. 2011;305(8):808–813. 10.1001/jama.2011.186 21343580
81 Lin JC. Cancer occurrences in laboratory rats from exposure to RF and microwave radiation. IEEE J Electromagn RF Microw Med Biol. 2017;1(1):2–13.10.1109/JERM.2017.2721427
82 Repacholi MH, Lerchl A, Röösli M, Sienkiewicz Z, Auvinen A, Breckenkamp J, d’Inzeo G, Elliott P, Frei P, Heinrich S, Systematic review of wireless phone use and brain cancer and other head tumors. Bioelectromagnetics. 2012;33(3):187–206. 10.1002/bem.20716 22021071
83 Yang M, Guo W, Yang C, Tang J, Huang Q, Feng S, Jiang A, Xu X, Jiang G. Mobile phone use and glioma risk: A systematic review and meta-analysis. PLoS One. 2017;12(5):e0175136. 10.1371/journal.pone.0175136 28472042
84 Tillmann T, Ernst H, Ebert S, Kuster N, Behnke W, Rittinghausen S, Dasenbrock C. Carcinogenicity study of GSM and DCS wireless communication signals in B6C3F1 mice. Bioelectromagnetics. 2007;28(3):173–187. 10.1002/bem.20283 17019729
85 La Regina M, Moros EG, Pickard WF, Straube WL, Baty J, Roti Roti JL. The effect of chronic exposure to 835.62 MHz FDMA or 847.74 MHz CDMA radiofrequency radiation on the incidence of spontaneous tumors in rats. Radiat Res. 2003;160(2):143–151. 10.1667/RR3028 12859224
86 Smith P, Kuster N, Ebert S, Chevalier HJ. GSM and DCS wireless communication signals: combined chronic toxicity/carcinogenicity study in the Wistar rat. Radiat Res. 2007;168(4):480–492. 10.1667/RR0680.1 17903030
87 Utteridge TD, Gebski V, Finnie JW, Vernon-Roberts B, Kuchel TR. Long-term exposure of Eμ-Pim1 transgenic mice to 898.4 MHz microwaves does not increase lymphoma incidence. Radiat Res. 2002;158(3):357–364. 10.1667/0033-7587(2002)158[0357:LTEOEP]2.0.CO;2 12175314
88 Sommer AM, Streckert J, Bitz AK, Hansen VW, Lerchl A. No effects of GSM-modulated 900 MHz electromagnetic fields on survival rate and spontaneous development of lymphoma in female AKR/J mice. BMC Cancer. 2004;4:77. 10.1186/1471-2407-4-77 15538947
89 Sommer AM, Bitz AK, Streckert J, Hansen VW, Lerchl A. Lymphoma development in mice chronically exposed to UMTS-modulated radiofrequency electromagnetic fields. Radiat Res. 2007;168(1):72–80. 10.1667/RR0857.1 17723000
90 Oberto G, Rolfo K, Yu P, Carbonatto M, Peano S, Kuster N, Ebert S, Tofani S. Carcinogenicity study of 217 Hz pulsed 900 MHz electromagnetic fields in Pim1 transgenic mice. Radiat Res. 2007;168(3):316–326. 10.1667/rr0425.1 17705642
91 Lee HJ, Jin YB, Lee JS, Choi SY, Kim TH, Pack JK, Choi HD, Kim N, Lee YS. Lymphoma development of simultaneously combined exposure to two radiofrequency signals in AKR/J mice. Bioelectromagnetics. 2011;32(6):485–492. 10.1002/bem.20655 21437920
92 International Agency for Research on Cancer (IARC). IARC report to the Union for International Cancer Control (UICC) on the Interphone Study. Lyon, France: IARC; 2011. http://interphone.iarc.fr/UICC_Report_Final_03102011.pdf
93 Cardis E, Richardson L, Deltour I, Armstrong B, Feychting M, Johansen C, Kilkenny M, McKinney P, Modan B, Sadetzki S, The INTERPHONE study: Design, epidemiological methods, and description of the study population. Eur J Epidemiol. 2007;22(9):647–664. 10.1007/s10654-007-9152-z 17636416
94 INTERPHONE Study Group. Brain tumour risk in relation to mobile telephone use: results of the INTERPHONE international case-control study. Int J Epidemiol. 2010;39(3):675–694. 10.1093/ije/dyq079 20483835
95 INTERPHONE Study Group. Acoustic neuroma risk in relation to mobile telephone use: results of the INTERPHONE international case-control study. Cancer Epidemiol. 2011;35(5):453–464. 10.1016/j.canep.2011.05.012 21862434
96 Saika K, Katanoda K. Comparison of time trends in brain and central nervous system cancer mortality (1990-2006) between countries based on the WHO mortality database. Jap J Clin Oncol. 2011; 41(2):304-305. 10.1093/jjco/hyr004
97 Lönn S, Klaeboe L, Hall P, Mathiesen T, Auvinen A, Christensen HC, Johansen C, Salminen T, Tynes T, Feychting M. Incidence trends of adult primary intracerebral tumors in four Nordic countries. Int J Cancer. 2004;108(3):450–455. 10.1002/ijc.11578 14648713
98 Nelson PD, Toledano MB, McConville J, Quinn MJ, Cooper N, Elliott P. Trends in acoustic neuroma and cellular phones: is there a link? Neurology. 2006;66(2):284–285. 10.1212/01.wnl.0000194218.79519.ea 16434678
99 Röösli M, Michel G, Kuehni CE, Spoerri A. Cellular telephone use and time trends in brain tumour mortality in Switzerland from 1969 to 2002. Eur J Cancer Prev. 2007;16(1):77–82. 10.1097/01.cej.0000203618.61936.cd 17220708
100 Deltour I, Johansen C, Auvinen A, Feychting M, Klaeboe L, Schüz J. Time trends in brain tumor incidence rates in Denmark, Finland, Norway, and Sweden, 1974-2003. J Natl Cancer Inst. 2009;101(24):1721–1724. 10.1093/jnci/djp415 19959779
101 de Vocht F, Burstyn I, Cherrie JW. Time trends (1998-2007) in brain cancer incidence rates in relation to mobile phone use in England. Bioelectromagnetics. 2011;32(5):334–339. 10.1002/bem.20648 21280060
102 Muscat JE, Hinsvark M, Malkin M. Mobile telephones and rates of brain cancer. Neuroepidemiology. 2006;27(1):55–56. 10.1159/000094381 16825795
103 Propp JM, McCarthy BJ, Davis FG, Preston-Martin S. Descriptive epidemiology of vestibular schwannomas. Neuro-oncol. 2006;8(1):1–11. 10.1215/S1522851704001097 16443943
104 Inskip PD, Hoover RN, Devesa SS. Brain cancer incidence trends in relation to cellular telephone use in the United States. Neuro-oncol. 2010;12(11):1147–1151. 10.1093/neuonc/noq077 20639214
105 Nomura E, Ioka A, Tsukuma H. Trends in the incidence of primary intracranial tumors in Osaka, Japan. Jap J Clin Oncol. 2011; 41(2):291-294. 10.1093/jjco/hyq204
106 Cook A, Woodward A, Pearce N, Marshall C. Cellular telephone use and time trends for brain, head and neck tumours. N Z Med J. 2003;116(1175):U457. 12838353
107 Czerninski R, Zini A, Sgan-Cohen HD. Risk of parotid malignant tumors in Israel (1970-2006). Epidemiology. 2011;22(1):130–131. 10.1097/EDE.0b013e3181feb9f0 21150362
108 Johansen C, Boice J Jr, McLaughlin J, Olsen J. Cellular telephones and cancer: A nationwide cohort study in Denmark. J Natl Cancer Inst. 2001;93(3):203–207. 10.1093/jnci/93.3.203 11158188
109 Schüz J, Jacobsen R, Olsen JH, Boice JD Jr, McLaughlin JK, Johansen C. Cellular telephone use and cancer risk: update of a nationwide Danish cohort. J Natl Cancer Inst. 2006;98(23):1707–1713. 10.1093/jnci/djj464 17148772
110 Schüz J, Elliott P, Auvinen A, Kromhout H, Poulsen AH, Johansen C, Olsen JH, Hillert L, Feychting M, Fremling K, An international prospective cohort study of mobile phone users and health (Cosmos): design considerations and enrolment. Cancer Epidemiol. 2011;35(1):37–43. 10.1016/j.canep.2010.08.001 20810339
111 Takebayashi T, Varsier N, Kikuchi Y, Wake K, Taki M, Watanabe S, Akiba S, Yamaguchi N. Mobile phone use, exposure to radiofrequency electromagnetic field, and brain tumour: A case-control study. Br J Cancer. 2008;98(3):652–659. 10.1038/sj.bjc.6604214 18256587
112 Schoemaker MJ, Swerdlow AJ. Risk of pituitary tumors in cellular phone users: a case-control study. Epidemiology. 2009;20(3):348–354. 10.1097/EDE.0b013e31819c7ba8 19279493
113 Hardell L, Carlberg M, Ohlson CG, Westberg H, Eriksson M, Hansson Mild K. Use of cellular and cordless telephones and risk of testicular cancer. Int J Androl. 2007;30(2):115–122. 10.1111/j.1365-2605.2006.00721.x 17209885
114 Hardell L, Hallquist A, Hansson Mild K, Carlberg M, Gertzén H, Schildt EB, Dahlqvist A. No association between the use of cellular or cordless telephones and salivary gland tumours. Occup Environ Med. 2004;61(8):675–679. 10.1136/oem.2003.011262 15258273
115 Lönn S, Ahlbom A, Christensen HC, Johansen C, Schüz J, Edström S, Henriksson G, Lundgren J, Wennerberg J, Feychting M. Mobile phone use and risk of parotid gland tumor. Am J Epidemiol. 2006;164(7):637–643. 10.1093/aje/kwj242 16818464
116 Stang A, Schmidt-Pokrzywniak A, Lash TL, Lommatzsch PK, Taubert G, Bornfeld N. H. JK. Mobile phone use and risk of uveal melanoma: results of the risk factors for uveal melanoma case-control study. J Natl Cancer Inst. 2009;101(2):120–123. 10.1093/jnci/djn441 19141780
117 Hardell L, Carlberg M, Hansson Mild K, Eriksson M. Case-control study on the use of mobile and cordless phones and the risk for malignant melanoma in the head and neck region. Pathophysiology. 2011;18(4):325–333. 10.1016/j.pathophys.2011.06.001 21764571
118 Hardell L, Eriksson M, Carlberg M, Sundström C, Mild KH. Use of cellular or cordless telephones and the risk for non-Hodgkin’s lymphoma. Int Arch Occup Environ Health. 2005;78(8):625–632. 10.1007/s00420-005-0003-5 16001209
119 Linet MS, Taggart T, Severson RK, Cerhan JR, Cozen W, Hartge P, Colt J. Cellular telephones and non-Hodgkin lymphoma. Int J Cancer. 2006;119(10):2382–2388. 10.1002/ijc.22151 16894556
120 Kaufman DW, Anderson TE, Issaragrisil S. Risk factors for leukemia in Thailand. Ann Hematol. 2009;88(11):1079–1088. 10.1007/s00277-009-0731-9 19294385
121 Aydin D, Feychting M, Schüz J, Tynes T, Andersen TV, Schmidt LS, Poulsen AH, Johansen C, Prochazka M, Lannering B, Mobile phone use and brain tumors in children and adolescents: A multicenter case-control study. J Natl Cancer Inst. 2011;103(16):1264–1276. 10.1093/jnci/djr244 21795665
122 Hardell L, Carlberg M, Hansson Mild K. Use of mobile phones and cordless phones is associated with increased risk for glioma and acoustic neuroma. Pathophysiology. 2013;20(2):85–110. 10.1016/j.pathophys.2012.11.001 23261330
123 Hardell L, Carlberg M. Using the Hill viewpoints from 1965 for evaluating strengths of evidence of the risk for brain tumors associated with use of mobile and cordless phones. Rev Environ Health. 2013;28(2-3):97–106. 10.1515/reveh-2013-0006 24192496
124 Hardell L, Carlberg M. Mobile phone and cordless phone use and the risk for glioma - Analysis of pooled case-control studies in Sweden, 1997-2003 and 2007-2009. Pathophysiology. 2015;22(1):1–13. 10.1016/j.pathophys.2014.10.001 25466607
125 Carlberg M, Hardell L. Pooled analysis of Swedish case-control studies during 1997-2003 and 2007-2009 on meningioma risk associated with the use of mobile and cordless phones. Oncol Rep. 2015;33(6):3093–3098. 10.3892/or.2015.3930 25963528
126 Coureau G, Bouvier G, Lebailly P, Fabbro-Peray P, Gruber A, Leffondre K, Guillamo JS, Loiseau H, Mathoulin-Pélissier S, Salamon R, Mobile phone use and brain tumours in the CERENAT case-control study. Occup Environ Med. 2014;71(7):514–522. 10.1136/oemed-2013-101754 24816517
127 Yoon S, Choi J-W, Lee E, An H, Do Choi H, Kim N. Mobile phone use and risk of glioma: A case-control study in Korea for 2002-2007. Environ Health Toxicol. 2015;30:e2015015. 10.5620/eht.e2015015 26726040
128 Pettersson D, Mathiesen T, Prochazka M, Bergenheim T, Florentzson R, Harder H, Nyberg G, Siesjö P, Feychting M. Long-term mobile phone use and acoustic neuroma risk. Epidemiology. 2014;25(2):233–241. 10.1097/EDE.0000000000000058 24434752
129 Benson VS, Pirie K, Schüz J, Reeves GK, Beral V, Green J. Mobile phone use and risk of brain neoplasms and other cancers: prospective study. Int J Epidemiol. 2013;42(3):792–802. 10.1093/ije/dyt072 23657200
130 Benson VS, Pirie K, Schüz J, Reeves GK, Beral V, Green J. Authors’ response to: The case of acoustic neuroma: Comment on mobile phone use and risk of brain neoplasms and other cancers. Int J Epidemiol. 2014;43(1):275. 10.1093/ije/dyt186 24078152
131 Prasad M, Kathuria P, Nair P, Kumar A, Prasad K. Mobile phone use and risk of brain tumours: A systematic review of association between study quality, source of funding, and research outcomes. Neurol Sci. 2017;38(5):797–810. 10.1007/s10072-017-2850-8 28213724
132 Lagorio S, Röösli M. Mobile phone use and risk of intracranial tumors: A consistency analysis. Bioelectromagnetics. 2014;35(2):79–90. 10.1002/bem.21829 24375548
133 Ioannidis JPA. Meta-analyses in environmental and occupational health. Occup Environ Med. 2018;75(6):443–445. 10.1136/oemed-2016-104128 29574405
134 Brusick D, Albertini R, McRee D, Peterson D, Williams G, Hanawalt P, Preston J. Genotoxicity of radiofrequency radiation. DNA/Genetox Expert Panel. Environ Mol Mutag. 1997; 29(1):1-9. 10.1002/(SICI)1098-2280(1998)32:1<1::AID-EM1>3.0.CO;2-Q
135 Verschaeve L, Juutilainen J, Lagroye I, Miyakoshi J, Saunders R, De Seze R, Tenforde T, Van Rongen E, Veyret B, Xu Z. In vitro and in vivo genotoxicity of radiofrequency fields. Mutat Res Rev Mutat Res. 2010;705(3):252–268. 10.1016/j.mrrev.2010.10.001 20955816
136 Vijayalaxmi, Prihoda TJ. Genetic damage in human cells exposed to non-ionizing radiofrequency fields: A meta-analysis of the data from 88 publications (1990–2011). Mutat Res Genet Toxicol Environ Mutagen. 2012;749(1-2):1–16.10.1016/j.mrgentox.2012.09.007
137 Speit G, Gminski R, Tauber R. Genotoxic effects of exposure to radiofrequency electromagnetic fields (RF-EMF) in HL-60 cells are not reproducible. Mutat Res. 2013;755(2):163–166. 10.1016/j.mrgentox.2013.06.014 23817106
138 Speit G, Schutz P, Hoffmann H. Genotoxic effects of exposure to radiofrequency electromagnetic fields (RF-EMF) in cultured mammalian cells are not independently reproducible. Mutat Res. 2007;626(1-2):42–47. 10.1016/j.mrgentox.2006.08.003 16997616
139 Asanami S, Shimono K. High body temperature induces micronuclei in mouse bone marrow. Mutat Res. 1997;390(1-2):79–83. 10.1016/S0165-1218(97)00002-5 9150755
140 Komae N, Hibino Y, Sugano N. Analysis of micronuclei induced under hyperthermic conditions in human lymphocyte culture by fluorescence in situ hybridization (FISH) and spectral karyotyping (SKY) methods [In Japanese]. Yakugaku Zasshi. 1999;119(10):763–772. 10.1248/yakushi1947.119.10_763 10518460
141 Speit G, Schutz P. Hyperthermia-induced genotoxic effects in human A549 cells. Mutat Res. 2013;747-748:1–5. 10.1016/j.mrfmmm.2013.04.008 23643703
142 Kampinga HH, Dikomey E. Hyperthermic radiosensitization: mode of action and clinical relevance. Int J Radiat Biol. 2001;77(4):399–408. 10.1080/09553000010024687 11304434
143 Hunt CR, Pandita RK, Laszlo A, Higashikubo R, Agarwal M, Kitamura T, Gupta A, Rief N, Horikoshi N, Baskaran R, Hyperthermia activates a subset of ataxia-telangiectasia mutated effectors independent of DNA strand breaks and heat shock protein 70 status. Cancer Res. 2007;67(7):3010–3017. 10.1158/0008-5472.CAN-06-4328 17409407
144 Wyde ME, Horn TL, Capstick MH, Ladbury JM, Koepke G, Wilson PF, Kissling GE, Stout MD, Kuster N, Melnick RL et al. Pilot studies of the National Toxicology Program’s cell phone radiofrequency radiation reverberation chamber exposure system (publication pending). 2018.
145 Gong Y, Capstick M, Kuehn S, Wilson P, Ladbury J, Koepke G, McCormick DL, Melnick RL, Kuster N. Life-time dosimetric assessment for mice and rats exposed in reverberation chambers of the 2-year NTP cancer bioassay study on cell phone radiation. IEEE Trans Electromagn Compat. 2017;59(6):1798–1808. 10.1109/TEMC.2017.2665039 29217849
146 Capstick M, Kuehn S, Berdinas-Torres V, Gong Y, Wilson PF, Ladbury JM, Koepke G, McCormick DL, Gauger J, Melnick RL, A radio frequency radiation exposure system for rodents based on reverberation chambers. IEEE Trans Electromagn Compat. 2017;59(4):1041–1052. 10.1109/TEMC.2017.2649885 29217848
147 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
148 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
149 Weinberger MA. How valuable is blind evaluation in histopathologic examinations in conjunction with animal toxicity studies? Toxicol Pathol. 1979;7(2):14–17.10.1177/019262337900700204
150 Prasse K, Hildebrandt P, Dodd D. Microscopic evaluation slides from toxicity and carcinogenicity studies. Toxicol Pathol. 1986;14(2):274–275. 10.1177/019262338601400218 3764324
151 Society of Toxicologic Pathology. Editorial: society of Toxicologic Pathologists’ position paper on blinded slide reading. Toxicol Pathol. 1986;14(4):493–494. 10.1177/019262338601400419 3809899
152 Iatropoulos MJ. Society of Toxicologic Pathologists position paper: “Blinded” microscopic examination of tissues from toxicologic or oncogenic studies In: Grice HC, Ciminera JL, editors. Carcinogenicity. Berlin, Heidelberg: ILSI Monographs; 1988. 10.1007/978-3-642-61364-7_16
153 Crissman JW, Goodman DG, Hildebrandt PK, Maronpot RR, Prater DA, Riley JH, Seaman WJ, Thake DC. Best practices guideline: toxicologic histopathology. Toxicol Pathol. 2004;32(1):126–131. 10.1080/01926230490268756 14713558
154 Neef N, Nikula KJ, Francke-Carroll S, Boone L. Regulatory forum opinion piece: blind reading of histopathology slides in general toxicology studies. Toxicol Pathol. 2012;40(4):697–699. 10.1177/0192623312438737 22407309
155 Brix AE, Hardisty JF, McConnell EE. Combining neoplasms for evaluation of rodent carcinogenesis studies. In: Hsu C-H, Stedeford T, editors. Cancer Risk Assessment: Chemical Carcinogenesis, Hazard Evaluation, and Risk Quantification. Hoboken (NJ): John Wiley & Sons, Inc; 2010. p. 699–715.10.1002/9780470622728.ch28
156 Kaplan E, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53:457–481. 10.1080/01621459.1958.10501452
157 Cox DR. Regression models and life-tables. J R Stat Soc [Ser A]. 1972;34:187–220.
158 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975;62(3):679–690.10.1093/biomet/62.3.679
159 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. 10.2307/2531856 3390507
160 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989;12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
161 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology, Section 6.3.2. London, UK: Chapman and Hall; 1997.
162 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986;46(9):4372–4378. 3731095
163 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. 10.2307/2532200 8241374
164 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
165 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121.10.1080/01621459.1955.10501294
166 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
167 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
168 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
169 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
170 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252.10.1080/00401706.1964.10490181
171 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145.10.1093/biomet/41.1-2.133
172 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York (NY): McGraw-Hill Book Company; 1957. p. 276–278, 412.
173 Girard DM, Sager DB. The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. 10.2307/2531963 3567307
174 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharm. 1995; 21(1):52-59. 10.1006/rtph.1995.1009
175 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992;26(2):191–200.10.1177/009286159202600210
176 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992;20(1):52–60. 10.1177/019262339202000107 1411131
177 Code of Federal Regulations (CFR). 21:Part 58.
178 Schmid W. The micronucleus test. Mutat Res. 1975;31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
179 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983;123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
180 Organisation for Economic Cooperation and Development (OECD). OECD Guideline for the testing of chemicals. In vivo mammalian alkaline comet assay. Paris, France: OECD Publishing; 2014. Testing Guideline 489.
181 Tice RR, Agurell E, Anderson D, Burlinson B, Hartmann A, Kobayashi H, Miyamae Y, Rojas E, Ryu JC, Sasaki YF. Single cell gel/comet assay: Guidelines for in vitro and in vivo genetic toxicology testing. Environ Mol Mutag. 2000; 35(3):206-221. 10.1002/(SICI)1098-2280(2000)35:3<206::AID-EM8>3.0.CO;2-J
182 Collins AR. The comet assay for DNA damage and repair: Principles, applications, and limitations. Mol Biotechnol. 2004;26(3):249–261. 10.1385/MB:26:3:249 15004294
183 Brendler-Schwaab S, Hartmann A, Pfuhler S, Speit G. The in vivo comet assay: use and status in genotoxicity testing. Mutagenesis. 2005;20(4):245–254. 10.1093/mutage/gei033 15899933
184 Burlinson B, Tice RR, Speit G, Agurell E, Brendler-Schwaab SY, Collins AR, Escobar P, Honma M, Kumaravel TS, Nakajima M, Fourth International Workgroup on Genotoxicity testing: results of the in vivo Comet assay workgroup. Mutat Res Genet Toxicol Environ Mutagen. 2007;627(1):31–35. 10.1016/j.mrgentox.2006.08.011 17118697
185 Pfuhler S, Wolf HU. Detection of DNA-crosslinking agents with the alkaline comet assay. Environ Mol Mutag. 1996; 27(3):196-201. 10.1002/(SICI)1098-2280(1996)27:3<196::AID-EM4>3.0.CO;2-D
186 Hartmann A, Agurell E, Beevers C, Brendler-Schwaab S, Burlinson B, Clay P, Collins A, Smith A, Speit G, Thybaud V, Recommendations for conducting the in vivo alkaline Comet assay. 4th International Comet Assay Workshop. Mutagenesis. 2003;18(1):45–51. 10.1093/mutage/18.1.45 12473734
187 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
188 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67(2):233–241. 7021938
189 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co; 1985. p. 13–59.
190 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short‐term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutag. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
191 Sasaki YF, Sekihashi K, Izumiyama F, Nishidate E, Saga A, Ishida K, Tsuda S. The comet assay with multiple mouse organs: comparison of comet assay results and carcinogenicity with 208 chemicals selected from the IARC monographs and U.S. NTP Carcinogenicity Database. Crit Rev Toxicol. 2000;30(6):629–799. 10.1080/10408440008951123 11145306
192 Alison RH, Morgan KT, Haseman JK, Boorman GA. Morphology and classification of ovarian neoplasms in F344 rats and (C57BL/6 X C3H)F1 mice. J Natl Cancer Inst. 1987;78(6):1229–1243. 3473260
193 Recio L, Kissling GE, Hobbs CA, Witt KL. Comparison of Comet assay dose-response for ethyl methanesulfonate using freshly prepared versus cryopreserved tissues. Environ Mol Mutag. 2012; 53(2):101-113. 10.1002/em.20694
194 Ruediger HW. Genotoxic effects of radiofrequency electromagnetic fields. Pathophysiology. 2009;16(2-3):89–102. 10.1016/j.pathophys.2008.11.004 19285841
195 Recio L, Hobbs C, Caspary W, Witt KL. Dose-response assessment of four genotoxic chemicals in a combined mouse and rat micronucleus (MN) and Comet assay protocol. J Toxicol Sci. 2010;35(2):149–162. 10.2131/jts.35.149 20371966
196 Rundell MS, Wagner ED, Plewa MJ. The comet assay: Genotoxic damage or nuclear fragmentation? Environ Mol Mutag. 2003; 42(2):61-67. 10.1002/em.10175
197 Lorenzo Y, Costa S, Collins AR, Azqueta A. The comet assay, DNA damage, DNA repair and cytotoxicity: hedgehogs are not always dead. Mutagenesis. 2013;28(4):427–432. 10.1093/mutage/get018 23630247
198 National Toxicology Program (NTP). Toxicology and carcinogenesis studies in Hsd:Sprague Dawley SD rats exposed to whole-body radio frequency radiation at a frequency (900 MHz) and modulations (GSM and CDMA) used by cell phones. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2018. Technical Report Series No. 595.
199 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry-and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res Genet Toxicol Environ Mutagen. 2008;649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
200 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007;634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117