# Discussion

The Food and Drug Administration (FDA) nominated the radio frequency radiation (RFR) emissions of wireless communication devices for toxicology and carcinogenicity testing based on several factors. Current exposure guidelines are based on protection from acute injury from thermal effects, and little is known about the potential for health effects of long-term exposure. Epidemiology and toxicology studies have not definitively demonstrated an association between cell phone RFR exposure and any specific health problems in humans; however, the results of these studies are mixed and further complicated by confounding factors (including potential recall biases of the study participants that could impact the assessment of exposure). For epidemiology studies, exposures in the general population may not have occurred for a long enough period of time to accommodate the long latency period for some types of cancers in humans. Studies in laboratory animals have been complicated by limitations that researchers have faced in conducting robust studies designed to characterize the toxicity and carcinogenicity of RFR used by cell phones.

To improve on the existing methods of exposing laboratory animals to RFR, NTP worked in collaboration with experts from the Radio-Frequency Fields Group at the National Institute of Standards and Technology (NIST, Boulder, CO), IT’IS Foundation (Zurich, Switzerland), and IIT Research Institute (Chicago, IL) to design, construct, and validate a novel system of delivering RFR exposure that improved on the designs of previous exposure systems. Together with NIST and the IT’IS Foundation, NTP identified and constructed an exposure system designed to uniformly expose unrestrained, individually housed animals to a uniform field of RFR at frequencies and modulations that reflect those currently in use in wireless communication devices (GSM and CDMA). The exposure facility was installed at IIT Research Institute where all animal studies were conducted following system testing and RFR exposure validation.

Studies were designed to evaluate the toxicology and carcinogenicity of whole-body exposure to cell phone RFR in individually housed, unrestrained animals. Studies for both GSM- and CDMA-modulated RFR were conducted simultaneously with a common control group in a sham chamber. Exposures were conducted in 10-minute periods, followed by 10 minutes of rest with no RFR exposure. The exposure system ran continuously, alternating each 10 minute block of active exposure between the GSM- and CDMA-exposed mice over the course of approximately 18 hours a day, 7 days per week. Based on the on/off cycling scheme, the actual daily exposure time to RFR was approximately 9 hours per day.

Studies were conducted in multiple phases. The first phase comprised a series of short-term toxicity studies conducted in young and aged B6C3F1/N mice and Hsd:Harlan Sprague Dawley^®^ SD^®^ rats to characterize the effects of RFR exposure on body temperature and the potential impact of animal size. The impact of RFR exposure during pregnancy was also evaluated in rats. These studies demonstrated that rats were more sensitive to the heating effects of RFR than were the mice^144^. In both young and aged male and female mice, body temperatures were only sporadically increased at exposures to RFR up to 12 W/kg (GSM and CDMA). These data suggest that exposures of up to 12 W/kg did not markedly alter the thermoregulatory capacity in mice. It must be noted, however, that core body temperature is a general surrogate for the heating effects of RFR and that these results do not address the issue of potential changes in temperature that may occur in localized areas within some tissues.

The findings from these short-term studies were used to guide the selection of RFR exposure levels for the 28-day and 2-year studies. Because no significant effect of RFR exposure up to 12 W/kg was observed in the body temperature of mice in these thermal pilot studies, a higher level of RFR exposure (15 W/kg) was selected for the highest exposure group in the 28-day studies. The selection of 15 W/kg was determined by the technical limitations of the exposure system to deliver higher RFR fields in the 28-day studies. Results from the 28-day studies demonstrated some increases in core body temperature at various time points at 10 and 15 W/kg. Based on the observed increases in body temperature and the power limitations of the system to generate maximum RFR fields for the large numbers of mice that were required for the 2-year studies, the highest exposure level for the 2-year studies was 10 W/kg.

The effects of whole-body exposure to GSM- or CDMA-modulated cell phone RFR at 1,900 MHz for 14 weeks or 2 years were studied in B6C3F1/N mice at specific absorption rates (SARs) of 2.5, 5, and 10 W/kg, with a common sham control group for both GSM- and CDMA-modulated signals. At SAR exposures up to 10 W/kg, there were no exposure-related effects on survival or mean body weights in either modulation (GSM or CDMA).

In both the GSM and CDMA studies, the incidences of malignant lymphoma in all exposed female groups were higher than that in the sham controls. These incidences were significantly increased only in the GSM groups at 2.5 and 5 W/kg, and in the CDMA group at 2.5 W/kg compared to sham controls. The 2% incidence of lymphoma in the concurrent sham controls was the lowest incidence observed thus far in female B6C3F1/N mice. The incidence is well below the overall historical control mean of 16%, and appreciably lower than the lower end of the range of overall historical control values in other studies (10% to 36%). Additionally, the incidences of malignant lymphoma in all exposed groups were within the range observed in overall historical controls. These considerations reduce the confidence that these increases in incidences were attributable to the RFR exposure, so these were considered equivocal findings. In NTP conclusions, such uncertain responses in the absence of other clearer effects on carcinogenicity would be referred to as equivocal evidence of carcinogenicity (i.e., may have been related to exposure).

In males, there were no common lesions observed between the two modulations. Potential RFR-mediated effects observed in the lung and the skin of males were specific to the GSM modulation. In the lung, there was a positive trend in the combined incidence of alveolar/ bronchiolar adenoma or carcinoma in male mice, but there was no significant effect in any of the individual groups compared to the sham controls. The combined incidences at the upper two exposure levels exceeded the historical control range (16% to 34%). Despite a significant trend in the combined incidence of alveolar/bronchiolar adenoma or carcinoma, the observation that the incidences were only marginally outside the historical range, and the fact that the incidences of focal alveolar epithelial hyperplasia, a potential preneoplastic lesion, were similar in all dose groups, reduces the confidence that the increased incidences were attributable to the RFR exposure. Therefore, these were considered equivocal findings.

The combined incidences of fibrosarcoma, sarcoma, or malignant fibrous histiocytoma in the skin were higher in the 5 and 10 W/kg GSM males but were not statistically different than that of the sham controls. Malignant fibrous histiocytoma was the predominant neoplasm in this combination. There was also a lack of an increased exposure level response. However, the incidences in both groups were above the historical control range for malignant fibrous histiocytoma. Additionally, there was one occurrence of a sarcoma in the 2.5 W/kg GSM males and one occurrence of a fibrosarcoma in the 10 W/kg GSM males. While the incidences in the 5 and 10 W/kg GSM males were not significant versus the current sham controls, the increases were seen in the top two exposure groups and were outside the historical range. None of the malignant fibrous histiocytomas in these groups showed evidence of metastasis, and most of the neoplasms were restricted to single occurrences on the tail. The increases in incidences observed may have been attributable to the RFR exposure, so these were considered equivocal findings.

At 2 years in the CDMA study only, there was a significantly increased incidence of hepatoblastoma in males exposed to 5 W/kg. The incidence at 5 W/kg exceeded the historical control; however, no increases were observed in males at 10 W/kg. Additionally, when all liver neoplasms (hepatocellular adenoma, hepatocellular carcinoma, or hepatoblastoma) were combined, there were no significant differences between any of the exposed groups compared to the sham controls. The isolated increase in only the 5 W/kg group and overall lack of exposure response reduces the confidence that the increase in incidence of hepatoblastoma observed was attributable to the RFR exposure, therefore, this was considered an equivocal finding.

Subsets of male and female mice from the 2-year studies were examined at 14 weeks to evaluate biomarkers of genotoxicity. Chromosomal damage was evaluated using the peripheral blood erythrocyte micronucleus (MN) assay, and DNA damage was evaluated in the frontal cortex, hippocampus, cerebellum, liver, and peripheral blood using the comet assay. Results of the MN assays were negative, but significantly higher levels of DNA damage were observed in cells of the frontal cortex of male mice exposed to both modulations (GSM and CDMA) and in blood leukocytes of female mice (CDMA only).

Unlike ionizing radiation or ultraviolet radiation, RFR is not sufficiently energetic, by several orders of magnitude, to directly damage macromolecules,^4^ and little is known about the mechanisms by which RFR could induce DNA damage in the absence of thermal effects. Proposed mechanisms include, for example, induction of oxygen radicals and interference with DNA repair mechanisms^53; 194^.

No histopathologic assessments of cytotoxicity (apoptosis and necrosis) were conducted in the male mouse brain tissues that were examined for DNA damage, which leaves open the possibility that apoptosis or necrosis may have confounded the comet assay results. However, this seems unlikely as brain sections from other groups of mice in this interim 14-week study and in the 2-year study did undergo histopathologic assessment and no significant evidence of cytotoxicity was observed.

Although increases in DNA damage were observed in the frontal cortex of male mice, there were no increases observed in the incidences of any type of neoplasm in the brain of males in the 2-year study. Similarly, while increased DNA damage was observed in blood leukocytes of female mice exposed to CDMA-modulated cell phone RFR, there were no increased incidences of related neoplasms. Therefore, no association was established between DNA damage appearing early in the studies and neoplasm development in these tissues.