# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-596.

## GSM

### Twenty-eight-day Study

All mice survived to the end of the study (Table 2). Weekly mean body weights of exposed groups of males and females were similar to those of the sham controls at all time points (Table 2; Figure 6). There were no clinical signs related to exposure to GSM-modulated RFR.

Table 2 Mean Body Weights and Survival of Mice Exposed to GSM-modulated Cell Phone RFR for 28 Days

Day | Sham Control | | 5 W/kg | | | 10 W/kg | | | 15 W/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 20.2 | 10 | 20.0 | 98.9 | 10 | 20.4 | 100.8 | 10 | 21.1 | 104.7 | 10
8 | 21.8 | 10 | 22.2 | 101.5 | 10 | 21.8 | 99.8 | 10 | 22.6 | 103.3 | 10
15 | 22.8 | 10 | 23.1 | 101.4 | 10 | 22.7 | 99.4 | 10 | 23.2 | 101.7 | 10
22 | 24.0 | 10 | 24.2 | 101.0 | 10 | 23.8 | 99.4 | 10 | 24.1 | 100.5 | 10
29 | 24.9 | 10 | 25.2 | 101.2 | 10 | 24.7 | 99.5 | 10 | 25.0 | 100.5 | 10
Female
1 | 18.1 | 10 | 17.8 | 98.3 | 10 | 17.4 | 96.1 | 10 | 17.9 | 98.9 | 10
8 | 18.9 | 10 | 19.0 | 100.7 | 10 | 18.4 | 97.3 | 10 | 18.5 | 98.0 | 10
15 | 20.1 | 10 | 20.1 | 100.0 | 10 | 19.5 | 97.0 | 10 | 19.6 | 97.3 | 10
22 | 21.0 | 10 | 21.1 | 100.4 | 10 | 20.4 | 97.1 | 10 | 20.3 | 96.8 | 10
30 | 21.7 | 10 | 21.9 | 100.9 | 10 | 21.2 | 97.5 | 10 | 21.0 | 96.6 | 10

Figure 6

Growth Curves for Mice Exposed to GSM-modulated Cell Phone RFR for 28 Days

Body temperatures were significantly higher in RFR-exposed male mice at several time points (Table 3). In female mice, there were a few occurrences of significantly lower body temperatures in the exposed groups, but no significantly higher body temperatures. These changes in body temperature were inconsistent and not SAR-related.

Table 3 Mean Body Temperatures of Mice Exposed to GSM-modulated Cell Phone RFR for 28 Days^a^

Day | Sham Control | | 5 W/kg | | 10 W/kg | | 15 W/kg
Day | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured
Male
0 | 37.0 ± 0.2 | 10 | 38.5 ± 0.2 | 10 | 37.3 ± 0.3 | 10 | 36.2 ± 0.2* | 10
2 | 35.7 ± 0.1 | 10 | 37.2 ± 0.3** | 10 | 37.1 ± 0.3** | 10 | 37.0 ± 0.3** | 10
4 | 36.2 ± 0.2 | 10 | 37.0 ± 0.2 | 10 | 37.1 ± 0.3* | 10 | 37.1 ± 0.2* | 10
7^b^ | 36.6 ± 0.2 | 9 | 37.4 ± 0.2 | 10 | 37.7 ± 0.4* | 10 | 36.8 ± 0.1 | 10
14^b^ | 35.5 ± 0.3 | 10 | 36.0 ± 0.1 | 10 | 36.1 ± 0.4 | 10 | 35.9 ± 0.1 | 10
17 | 36.0 ± 0.3 | 10 | 37.2 ± 0.3* | 10 | 36.7 ± 0.3 | 10 | 36.8 ± 0.4 | 10
20 | 36.5 ± 0.3 | 10 | 37.0 ± 0.3 | 10 | 37.6 ± 0.3* | 10 | 37.2 ± 0.2 | 10
27 | 35.8 ± 0.4 | 9 | 37.6 ± 0.3** | 10 | 37.4 ± 0.2** | 10 | 37.2 ± 0.3** | 10
2–27^c^ | 36.0 ± 0.2 | 10 | 37.1 ± 0.1** | 10 | 37.1 ± 0.2** | 10 | 36.9 ± 0.2** | 10
Female
0 | 38.1 ± 0.1 | 10 | 37.9 ± 0.1 | 9 | 37.2 ± 0.3** | 9 | 37.2 ± 0.1** | 10
2 | 37.5 ± 0.2 | 10 | 37.4 ± 0.2 | 9 | 37.3 ± 0.3 | 9 | 37.5 ± 0.1 | 10
4 | 37.0 ± 0.2 | 10 | 37.5 ± 0.2 | 10 | 37.1 ± 0.5 | 10 | 37.6 ± 0.1 | 10
7^b^ | 38.6 ± 0.1 | 10 | 38.1 ± 0.2 | 10 | 37.8 ± 0.5 | 10 | 38.5 ± 0.1 | 10
14^b^ | 36.9 ± 0.1 | 10 | 36.4 ± 0.1 | 10 | 36.6 ± 0.2 | 9 | 37.0 ± 0.2 | 10
17 | 37.9 ± 0.1 | 10 | 37.3 ± 0.2** | 10 | 37.7 ± 0.1 | 9 | 37.6 ± 0.1 | 10
20 | 37.7 ± 0.2 | 10 | 37.6 ± 0.2 | 10 | 37.6 ± 0.1 | 9 | 37.8 ± 0.1 | 10
27 | 37.8 ± 0.1 | 10 | 38.2 ± 0.1 | 10 | 37.2 ± 0.2* | 9 | 37.5 ± 0.2 | 10
2–27^c^ | 37.6 ± 0.1 | 10 | 37.5 ± 0.1 | 10 | 37.3 ± 0.2 | 10 | 37.6 ± 0.1 | 10

* Significantly different (P ≤ 0.05) from the sham control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Temperatures are given as mean ± standard error.

^b^ All temperatures were recorded within 5 minutes of the exposure cessation, except for the measurements on days 7 and 14, which were recorded at least 1 hour after exposure.

^c^ Average of days 2 to 27, excluding days 7 and 14.

There were no exposure-related effects on the organ weights of males exposed to GSM-modulated RFR (Table G-1). The absolute heart weight of 15 W/kg females was significantly less than that of the sham controls, and there were negative trends in the absolute weights of the brain, right kidney, and liver, all of which were considered to be due to minor reductions in body weight. There were no significantly lower relative organ weights and no associated histopathologic findings, therefore, these organ weight changes were considered sporadic and not related to GSM-modulated RFR exposure.

There were no histopathologic lesions related to the effects of exposure to GSM-modulated RFR.

Exposure Level Selection Rationale: In male and female mice exposed for 5 days to RFR up to 12 W/kg, only sporadic increases were observed in body temperature, regardless of the sex or age of the animals^144^. Because no significant effects of RFR were observed in body temperature at 12 W/kg, a higher upper exposure level was selected for the 28-day studies. Due to limits on the maximum capacity of the exposure system to generate high RF fields, the maximum achievable exposure level capacity was 15 W/kg, which was selected as the highest exposure level for the 28-day studies. Selection of the highest exposure level for the 2-year studies was also limited by the power capacity of the exposure system to generate maximum RF fields. Based on these limitations and increased body temperature at various time points that were similarly observed at 10 and 15 W/kg in the 28-day studies, the exposure levels selected for the 2-year studies were 2.5, 5, and 10 W/kg.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 4 and in the Kaplan-Meier survival curves (Figure 7). Survival was significantly higher for the 5 W/kg males than the sham control group. Survival of the rest of the exposed groups of males and females was generally similar to that of the sham controls.

Table 4 Survival of Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Male
Animals initially in study | 105 | 105 | 105 | 105
14-week interim evaluation^a^ | 15 | 15 | 15 | 15
Accidental death^b^ | 0 | 1 | 0 | 0
Missing^b^ | 0 | 1 | 0 | 0
Moribund | 8 | 6 | 2 | 6
Natural deaths | 16 | 19 | 8 | 12
Animals surviving to study termination | 66 | 63 | 80^f^ | 72^g^
Percent probability of survival at end of study^c^ | 73 | 72 | 89 | 80
Mean survival (days)^d^ | 687 | 693 | 717 | 707
Survival analysis^e^ | P = 0.135N | P = 0.959 | P = 0.013N | P = 0.360N
Female
Animals initially in study | 105 | 105 | 105 | 105
14-week interim evaluation^a^ | 15 | 15 | 15 | 15
Moribund | 9 | 9 | 9 | 6
Natural deaths | 14 | 7 | 11 | 11
Animals surviving to study termination | 67^f^ | 74^h^ | 70^i^ | 73^j^
Percent probability of survival at end of study^c^ | 74 | 80 | 77 | 80
Mean survival (days)^d^ | 704 | 715 | 711 | 712
Survival analysis^e^ | P = 0.476N | P = 0.420N | P = 0.709N | P = 0.405N

^a^ Excluded from survival analysis.

^b^ Censored in the survival analysis.

^c^ Kaplan-Meier determinations.

^d^ Mean of all deaths (uncensored, censored, and terminal euthanasia).

^e^ The result of the life table trend test^158^ is in the sham control column, and the results of the life table pairwise comparisons^157^ with the sham controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^f^ Includes one animal that died during the last week of the study.

^g^ Includes four animals that died during the last week of the study.

^h^ Includes four animals that died during the last week of the study; two of these were censored in the survival analysis.

^i^ Includes two animals that died during the last week of the study; one of these was censored in the survival analysis.

^j^ Includes one animal that died during the last week of the study; this animal was censored in the survival analysis.

Figure 7

Kaplan-Meier Survival Curves for Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

#### Body Weights and Clinical Observations

Mean body weights of exposed groups of males and females were similar to those of the sham controls throughout the study (Table 5, Table 6; Figure 8). Clinical signs included more occurrences of thin and ruffled fur in 10 W/kg males and thin, ruffled fur, and mass-torso/ventral in 5 and 10 W/kg females. These findings were not correlated with differences in body weights or incidences of neoplasms in exposed animals.

Table 5 Mean Body Weights and Survival of Male Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

Day | Sham Control | | 2.5 W/kg | | | 5 W/kg | | | 10 W/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
0 | 20.6 | 105 | 20.4 | 99.1 | 105 | 20.4 | 99.4 | 105 | 20.4 | 99.0 | 105
8 | 21.9 | 104 | 22.0 | 100.4 | 104 | 21.8 | 99.5 | 105 | 21.9 | 100.2 | 105
15 | 22.9 | 104 | 23.1 | 100.7 | 104 | 22.8 | 99.4 | 105 | 23.1 | 100.6 | 105
22 | 24.1 | 104 | 24.4 | 101.4 | 104 | 24.0 | 99.7 | 105 | 23.9 | 99.1 | 105
29 | 25.1 | 104 | 25.4 | 101.2 | 104 | 25.0 | 99.6 | 105 | 24.8 | 98.5 | 105
36 | 26.3 | 104 | 26.2 | 99.9 | 104 | 26.1 | 99.5 | 105 | 25.7 | 98.0 | 105
43 | 27.3 | 104 | 27.1 | 99.3 | 104 | 27.2 | 99.5 | 105 | 26.4 | 96.7 | 105
50 | 28.1 | 104 | 27.8 | 99.1 | 104 | 28.1 | 100.2 | 105 | 27.5 | 98.1 | 105
57 | 29.3 | 104 | 28.9 | 98.5 | 104 | 29.3 | 99.9 | 105 | 28.7 | 97.8 | 105
64 | 30.5 | 104 | 29.6 | 97.2 | 104 | 30.3 | 99.4 | 105 | 29.7 | 97.2 | 105
71 | 31.7 | 104 | 30.8 | 97.3 | 104 | 31.7 | 100.1 | 105 | 30.9 | 97.5 | 105
79 | 32.9 | 104 | 31.8 | 96.6 | 104 | 32.9 | 100.1 | 105 | 32.1 | 97.5 | 105
86 | 33.6 | 104 | 33.0 | 98.3 | 104 | 33.8 | 100.5 | 105 | 32.7 | 97.2 | 105
93 | 34.3 | 94 | 34.0 | 99.0 | 94 | 34.7 | 101.2 | 95 | 33.6 | 98.0 | 95
121 | 38.6 | 89 | 38.5 | 99.5 | 89 | 39.4 | 101.9 | 90 | 38.5 | 99.7 | 90
149 | 42.0 | 89 | 42.2 | 100.6 | 89 | 42.1 | 100.2 | 90 | 42.8 | 101.9 | 90
177 | 44.3 | 89 | 44.4 | 100.3 | 89 | 44.7 | 100.9 | 90 | 44.8 | 101.0 | 90
205 | 46.0 | 89 | 46.3 | 100.7 | 89 | 46.4 | 100.8 | 90 | 46.1 | 100.3 | 90
233 | 47.3 | 89 | 47.1 | 99.7 | 89 | 47.3 | 100.1 | 90 | 46.7 | 98.8 | 90
261 | 47.6 | 89 | 47.9 | 100.8 | 89 | 47.9 | 100.6 | 90 | 47.1 | 99.0 | 90
289 | 48.2 | 88 | 48.6 | 100.7 | 89 | 48.5 | 100.6 | 90 | 47.7 | 98.9 | 90
317 | 48.8 | 88 | 49.1 | 100.7 | 89 | 49.1 | 100.6 | 90 | 48.2 | 98.8 | 90
345 | 49.4 | 88 | 49.7 | 100.7 | 89 | 49.7 | 100.6 | 90 | 48.6 | 98.4 | 90
373 | 50.0 | 87 | 50.3 | 100.6 | 88 | 50.2 | 100.4 | 90 | 49.2 | 98.3 | 89
401 | 50.4 | 86 | 51.0 | 101.0 | 88 | 51.0 | 101.0 | 90 | 49.7 | 98.4 | 89
429 | 50.7 | 85 | 51.2 | 100.9 | 88 | 51.5 | 101.4 | 90 | 50.1 | 98.8 | 89
457 | 51.1 | 84 | 51.7 | 101.1 | 88 | 51.9 | 101.5 | 90 | 50.3 | 98.4 | 89
485 | 51.5 | 84 | 52.1 | 101.3 | 88 | 52.3 | 101.5 | 90 | 51.1 | 99.3 | 88
513 | 50.5 | 83 | 51.4 | 101.8 | 88 | 52.0 | 103.0 | 89 | 50.6 | 100.2 | 87
541 | 49.7 | 83 | 50.7 | 102.0 | 86 | 51.2 | 103.0 | 89 | 50.6 | 101.7 | 85
569 | 50.4 | 82 | 51.1 | 101.5 | 85 | 51.8 | 102.8 | 88 | 51.2 | 101.8 | 85
597 | 50.9 | 81 | 51.8 | 101.7 | 83 | 52.1 | 102.3 | 88 | 51.5 | 101.3 | 85
625 | 50.7 | 78 | 51.6 | 101.7 | 79 | 52.1 | 102.7 | 86 | 51.5 | 101.5 | 82
639 | 49.8 | 78 | 51.5 | 103.6 | 78 | 51.9 | 104.3 | 85 | 51.1 | 102.7 | 82
653 | 49.0 | 78 | 51.1 | 104.3 | 75 | 51.9 | 105.8 | 84 | 50.8 | 103.6 | 82
667 | 49.0 | 76 | 51.0 | 104.0 | 71 | 52.0 | 106.1 | 82 | 50.5 | 103.0 | 81
681 | 49.2 | 74 | 51.1 | 103.9 | 69 | 51.7 | 105.0 | 82 | 49.8 | 101.2 | 77
695 | 48.7 | 71 | 50.6 | 104.0 | 68 | 51.1 | 104.9 | 81 | 50.0 | 102.7 | 74
709 | 48.5 | 69 | 50.3 | 103.6 | 67 | 50.6 | 104.3 | 80 | 49.1 | 101.3 | 74
723 | 48.4 | 67 | 50.6 | 104.6 | 65 | 50.0 | 103.4 | 80 | 48.9 | 101.1 | 73
Mean for Weeks
1–13 | 27.3 | | 27.0 | 99.2 | | 27.2 | 99.8 | | 26.8 | 98.3
14–52 | 44.7 | | 44.8 | 100.3 | | 45.0 | 100.8 | | 44.4 | 99.5
53–105 | 49.9 | | 51.1 | 102.4 | | 51.5 | 103.1 | | 50.4 | 100.9

Table 6 Mean Body Weights and Survival of Female Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

Day | Sham Control | | 2.5 W/kg | | | 5 W/kg | | | 10 W/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
0 | 17.4 | 105 | 17.2 | 99.1 | 105 | 17.5^a^ | 100.3 | 104 | 17.3 | 99.6 | 105
8 | 18.4 | 105 | 18.3 | 99.5 | 105 | 18.5 | 100.9 | 105 | 18.4 | 100.3 | 105
15 | 19.4 | 105 | 19.4 | 99.6 | 105 | 19.4 | 99.6 | 105 | 19.3 | 99.3 | 105
22 | 20.2 | 105 | 20.3 | 100.4 | 105 | 20.2 | 99.8 | 105 | 20.2 | 99.8 | 105
29 | 20.8 | 105 | 20.9 | 100.5 | 105 | 20.9 | 100.4 | 105 | 20.8 | 99.8 | 105
36 | 21.5 | 105 | 21.5 | 99.9 | 105 | 21.7 | 100.9 | 105 | 21.5 | 99.9 | 105
43 | 22.0 | 105 | 21.9 | 99.4 | 105 | 21.9 | 99.8 | 105 | 21.8 | 99.4 | 105
50 | 22.5 | 105 | 22.3 | 98.8 | 105 | 22.5 | 99.9 | 105 | 22.5 | 100.1 | 105
57 | 22.8 | 105 | 22.6 | 99.0 | 105 | 22.9 | 100.6 | 105 | 22.7 | 99.8 | 105
64 | 23.3 | 105 | 23.3 | 99.7 | 105 | 23.7 | 101.4 | 105 | 23.5 | 100.7 | 105
71 | 23.4 | 105 | 23.6 | 101.0 | 105 | 24.1 | 102.9 | 105 | 24.1 | 102.9 | 105
79 | 23.9 | 105 | 24.2 | 101.0 | 105 | 24.4 | 102.1 | 105 | 24.6 | 102.9 | 105
86 | 24.0 | 105 | 24.3 | 101.4 | 105 | 24.5 | 101.9 | 104 | 24.7 | 102.8 | 105
93 | 24.3 | 95 | 24.4 | 100.3 | 95 | 25.2 | 103.6 | 94 | 25.0 | 103.0 | 95
121 | 26.3 | 90 | 26.8 | 101.7 | 90 | 28.2 | 107.2 | 89 | 27.3 | 103.6 | 89
149 | 28.8 | 90 | 29.3 | 101.6 | 90 | 30.6 | 106.2 | 89 | 30.4 | 105.5 | 89
177 | 30.8 | 90 | 31.7 | 103.1 | 90 | 33.6 | 109.3 | 89 | 33.4 | 108.5 | 89
205 | 33.4 | 90 | 34.9 | 104.6 | 90 | 36.7 | 109.9 | 89 | 36.1 | 108.2 | 89
233 | 36.8 | 90 | 37.3 | 101.5 | 90 | 39.7 | 108.0 | 89 | 39.0 | 106.0 | 89
261 | 38.4 | 90 | 38.9 | 101.3 | 90 | 41.5 | 107.9 | 89 | 41.6 | 108.2 | 89
289 | 40.3 | 90 | 40.3 | 100.1 | 90 | 43.2 | 107.1 | 89 | 42.7 | 106.0 | 89
317 | 42.3 | 90 | 42.8 | 101.4 | 90 | 45.4 | 107.6 | 89 | 45.3 | 107.2 | 89
345 | 45.0 | 90 | 45.3 | 100.7 | 90 | 47.7 | 106.0 | 88 | 47.2 | 104.8 | 89
373 | 47.6 | 90 | 47.7 | 100.1 | 90 | 49.6 | 104.2 | 88 | 49.1 | 103.0 | 89
401 | 49.9 | 90 | 49.3 | 98.7 | 90 | 51.9 | 103.9 | 88 | 51.2 | 102.5 | 88
429 | 51.4 | 90 | 51.3 | 99.9 | 89 | 53.4 | 103.9 | 88 | 52.4 | 102.1 | 88
457 | 53.3 | 89 | 52.6 | 98.7 | 88 | 54.5 | 102.3 | 88 | 53.7 | 100.8 | 87
485 | 55.0 | 89 | 53.9 | 98.1 | 87 | 55.6 | 101.1 | 88 | 55.4 | 100.7 | 87
513 | 54.5 | 87 | 53.3 | 97.8 | 87 | 54.1 | 99.3 | 88 | 54.1 | 99.2 | 87
541 | 51.9 | 87 | 51.4 | 99.1 | 86 | 52.6 | 101.4 | 87 | 52.2 | 100.7 | 86
569 | 52.2 | 83 | 52.0 | 99.7 | 84 | 53.6 | 102.7 | 87 | 53.0 | 101.5 | 85
597 | 55.3 | 80 | 54.4 | 98.4 | 84 | 55.0 | 99.5 | 87 | 54.8 | 99.2 | 84
625 | 56.3 | 76 | 55.0 | 97.8 | 83 | 55.5 | 98.6 | 85 | 56.0 | 99.6 | 83
639 | 54.8 | 75 | 54.0 | 98.6 | 82 | 54.6 | 99.6 | 83 | 54.5 | 99.6 | 83
653 | 54.5 | 71 | 53.4 | 97.9 | 80 | 54.9 | 100.8 | 80 | 53.8 | 98.7 | 83
667 | 55.1 | 70 | 53.2 | 96.6 | 79 | 54.8 | 99.6 | 80 | 53.5 | 97.2 | 81
681 | 54.6 | 70 | 52.7 | 96.5 | 78 | 54.2 | 99.2 | 76 | 53.4 | 97.8 | 77
695 | 54.0 | 69 | 52.1 | 96.3 | 77 | 53.1 | 98.2 | 76 | 52.8 | 97.7 | 76
709 | 53.7 | 68 | 52.1 | 96.9 | 76 | 52.0 | 96.8 | 74 | 51.8 | 96.5 | 75
723 | 53.0 | 68 | 51.7 | 97.6 | 74 | 51.8 | 97.7 | 71 | 52.0 | 98.1 | 74
737 | 52.2 | 67 | 51.2 | 98.1 | 72 | 51.1 | 97.8 | 69 | 51.6 | 98.9 | 72
Mean for Weeks
1-13 | 21.5 | | 21.5 | 99.9 | | 21.7 | 100.8 | | 21.6 | 100.6
14-52 | 34.6 | | 35.2 | 101.6 | | 37.2 | 107.3 | | 36.8 | 106.1
53-107 | 53.3 | | 52.3 | 98.2 | | 53.5 | 100.4 | | 53.1 | 99.7

^a^ One animal not weighed.

Figure 8

Growth Curves for Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

#### 14-week Interim Evaluation

There were no changes to the hematology variables attributable to GSM-modulated RFR exposure (Table F-1).

At the 14-week interim evaluation, mean body weights of exposed groups of males and females were similar to those of the sham controls (Table G-2). In males, the absolute right kidney weights were significantly lower (7%) in the 5 and 10 W/kg groups compared to the sham controls, and the absolute left kidney weight was significantly lower (12%) in the 10 W/kg group (Table G-2). The absolute liver weights of 5 and 10 W/kg males were significantly lower (10%) and the relative liver weight was significantly lower in 5 W/kg males. These organ weight changes were considered small changes and were not accompanied by exposure-related histopathologic lesions. In 10 W/kg females, there were significantly lower relative weights in the brain and right kidney (Table G-2); these changes were not accompanied by significant changes in absolute weights and were not considered toxicologically important. The absolute thymus weight of 10 W/kg females was 20% higher compared to the sham controls, but this was not correlated with any histopathologic lesions in the thymus.

In males, there were no exposure-related effects on reproductive organ weights, testis spermatid concentrations, caudal epididymal sperm concentrations, or sperm motility (Table H-1). In females, there were no exposure-related effects on estrous cycle length, number of cycling females, or relative amount of time spent in the estrous stages (Table H-2, Table H-3; Figure H-1).

In the liver, a significantly higher incidence of focal inflammation occurred in 5 W/kg males (sham control, 0/10; 2.5 W/kg, 2/10; 5 W/kg, 4/10; 10 W/kg, 0/10; Table A-5). Focal inflammation is commonly seen in B6C3F1/N mice, and consisted of small clusters of mixed inflammatory cells, predominantly lymphocytes with fewer macrophages and an occasional neutrophil. There was no zonal pattern to this finding and the inflammation was randomly scattered within the hepatic parenchyma. All of the lesions were of minimal severity that typically consisted of one to three small areas of inflammation, and they were not considered biologically relevant.

#### Pathology and Statistical Analyses

This section describes the statistically significant or potentially biologically noteworthy changes in the incidences of malignant lymphoma and neoplasms and/or nonneoplastic lesions of the skin, lung, mediastinum, and ovary in the 2-year study. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix A for male mice and Appendix B for female mice.

Skin (Subcutaneous Tissue): Fibrosarcoma, sarcoma, and malignant fibrous histiocytoma are all neoplasms of mesenchymal stem cell origin, and as such, the combined incidences of these tumors were evaluated, as well as the incidences of malignant fibrous histiocytoma alone. The International Harmonization of Nomenclature and Diagnostic Criteria for Lesions in Rats and Mice (INHAND) project currently refers to malignant fibrous histiocytomas as pleomorphic fibrosarcomas, furthering the concept that these neoplasms should be considered together. The incidences of malignant fibrous histiocytoma were higher in 5 and 10 W/kg males, although not significantly or in an exposure concentration-related manner (Table 7, Table A-1, Table A-2); however, the incidences exceeded the overall historical control ranges for malignant fibrous histiocytoma (Table 7, Table A-3). The combined incidences of fibrosarcoma, sarcoma, or malignant fibrous histiocytoma were also increased in the 5 and 10 W/kg males, although still not in a statistically significant or exposure concentration-dependent manner. In males, all but one of the malignant fibrous histiocytomas occurred on the tail; the remaining neoplasm (in a 5 W/kg animal) was located on the pinna of the ear; this animal also had a neoplasm on the tail and was recorded as having malignant fibrous histiocytoma, multiple. The two tumors in that one animal were small, well circumscribed lesions, distinct in appearance from one another, and lacking in features that would indicate metastatic lesions; hence they were recorded as multiple rather than one neoplasm with a metastasis. Malignant fibrous histiocytomas can have a variable appearance. In general, all the malignant fibrous histiocytomas had a portion of the neoplasm that was composed of spindle-shaped cells arranged in interlacing or irregular bundles or whorls amongst a background of varying amounts of collagen and a sizable population of cells resembling histiocytes – large cells with abundant eosinophilic cytoplasm and small basophilic nuclei. Multinucleated cells were present in most of the tumors, but were more abundant in the neoplasm on the ear. Several of the neoplasms on the tail had areas of pigment in the section – possibly from the tail tattoo. The single malignant fibrous histiocytoma that occurred in a sham control male metastasized throughout the abdominal cavity, involving the liver, stomach, mesentery, adrenal gland, and seminal vesicle, as well as being found in the mesenteric lymph nodes and skeletal muscle. None of the other neoplasms had distant metastases.

Table 7 Incidences of Neoplasms of the Skin (Subcutaneous Tissue) in Male Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Number Examined Microscopically | 90 | 89 | 90 | 90
Malignant Fibrous Histiocytoma, Multiple^a^ | 0 | 0 | 1 (1%) | 0
Malignant Fibrous Histiocytoma (includes multiple)^b^
Overall rate^c^ | 1/90 (1%) | 0/89 (0%) | 5/90 (6%) | 3/90 (3%)
Adjusted rate^d^ | 1.2% | 0.0% | 5.8% | 3.6%
Terminal rate^e^ | 0/66 (0%) | 0/63 (0%) | 4/80 (5%) | 3/72 (4%)
First incidence (days) | 674 | –^g^ | 654 | 729 (T)
Poly-3 test^f^ | P = 0.127 | P = 0.499N | P = 0.124 | P = 0.321
Fibrosarcoma, Sarcoma, or Malignant Fibrous Histiocytoma^h^
Overall rate | 1/90 (1%) | 1/89 (1%) | 5/90 (6%) | 4/90 (4%)
Adjusted rate | 1.2% | 1.2% | 5.8% | 4.7%
Terminal rate | 0/66 (0%) | 0/63 (0%) | 4/80 (5%) | 3/72 (4%)
First incidence (days) | 674 | 523 | 654 | 488
Poly-3 test | P = 0.093 | P = 0.758N | P = 0.124 | P = 0.197

T = terminal euthanasia.

^a^ Number of animals with neoplasm.

^b^ Historical control incidence for 2-year studies (all studies except RFR) (mean ± standard deviation): 1/499 (0.2% ± 0.6%), range 0%–2%.

^c^ Number of animals with neoplasm per number of animals necropsied.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal euthanasia.

^f^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A lower incidence in an exposure group is indicated by N.

^g^ Not applicable; no neoplasms in animal group.

^h^ Historical control incidence: 4/499 (0.8% ± 1.0%), range 0%–2%.

The single occurrences of sarcoma in a 2.5 W/kg male (sham control, 0/90; 2.5 W/kg, 1/89; 5 W/kg, 0/90; 10 W/kg, 0/90) and fibrosarcoma in a 10 W/kg male (0/90, 0/89, 0/90, 1/90) were histologically much different from the malignant fibrous histiocytomas (Table A-1). They were much larger neoplasms, with large areas of necrosis. They were poorly circumscribed and consisted of interlacing bundles of elongated cells. Nuclei were long and oval and typically vesicular, in comparison to the small, often round, densely basophilic nuclei found in the malignant fibrous histiocytomas. There was no population of histiocyte-like cells in the sarcoma or the fibrosarcoma. The fibrosarcoma had evidence of collagen fibers within the neoplasm, indicating a fibrosarcoma, but in the case of the sarcoma, the tumor was anaplastic and lacked any kind of specific diagnostic features allowing it to be classified any further than sarcoma. Neither of these neoplasms occurred on the tail.

Lung: There was a significant positive trend in the incidences of alveolar/bronchiolar adenoma or carcinoma (combined) in males (Table 8, Table A-2). The incidences of focal alveolar epithelial hyperplasia were similar in all groups of males (6/90, 8/89, 8/90, 7/90; Table A-5). Alveolar/bronchiolar adenomas were discrete, expansile proliferations of cuboidal to columnar cells supported by a fine fibrovascular stroma arranged in solid nests or papillary fronds projecting into alveolar spaces and causing compression of the surrounding parenchyma.

Table 8 Incidences of Alveolar/bronchiolar Neoplasms in Male Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Number Examined Microscopically | 90 | 89 | 90 | 90
Alveolar/bronchiolar Adenoma, Multiple^a^ | 2 | 0 | 2 | 1
Alveolar/bronchiolar Adenoma (includes multiple)^b^
Overall rate^c^ | 13/90 (14%) | 13/89 (15%) | 18/90 (20%) | 16/90 (18%)
Adjusted rate^d^ | 16.0% | 16.0% | 20.7% | 19.0%
Terminal rate^e^ | 9/66 (14%) | 10/63 (16%) | 16/80 (20%) | 14/72 (19%)
First incidence (days) | 488 | 663 | 604 | 658
Poly-3 test^f^ | P = 0.297 | P = 0.583 | P = 0.279 | P = 0.380
Alveolar/bronchiolar Carcinoma, Multiple | 2 | 0 | 1 | 1
Alveolar/bronchiolar Carcinoma (includes multiple)^g^
Overall rate | 13/90 (14%) | 12/89 (13%) | 16/90 (18%) | 18/90 (20%)
Adjusted rate | 16.1% | 14.7% | 18.5% | 21.2%
Terminal rate | 12/66 (18%) | 8/63 (13%) | 16/80 (20%) | 14/72 (19%)
First incidence (days) | 568 | 594 | 729 (T) | 614
Poly-3 test | P = 0.165 | P = 0.488N | P = 0.418 | P = 0.259
Alveolar/bronchiolar Adenoma or Carcinoma^h^
Overall rate | 23/90 (26%) | 24/89 (27%) | 32/90 (36%) | 34/90 (38%)
Adjusted rate | 28.1% | 29.2% | 36.8% | 39.9%
Terminal rate | 18/66 (27%) | 17/63 (27%) | 30/80 (38%) | 28/72 (39%)
First incidence (days) | 488 | 594 | 604 | 614
Poly-3 test | P = 0.040 | P = 0.506 | P = 0.149 | P = 0.074

T = terminal euthanasia.

^a^ Number of animals with neoplasm.

^b^ Historical control incidence for 2-year studies (all studies except RFR) (mean ± standard deviation): 71/499 (14.2% ± 5.7%), range 8%–24%.

^c^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal euthanasia.

^f^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A lower incidence in an exposure group is indicated by N.

^g^ Historical control incidence: 53/499 (10.6% ± 4.5%), range 4%–20%.

^h^ Historical control incidence: 119/499 (23.8% ± 5.5%), range 16%–34%.

Alveolar/bronchiolar carcinomas were usually larger than adenomas and tended to be poorly demarcated and locally invasive. They were composed of cuboidal to columnar epithelial cells that displayed moderate to marked pleomorphism and lacked a normal orderly arrangement, with multiple layers and piling up of cells. The neoplastic cells were arranged in papillary arrangements or solid sheets of cells; most carcinomas contained both growth patterns. Occasional mitoses were present.

Malignant Lymphoma: Compared to the sham controls, all exposed groups of females had higher incidences of malignant lymphoma and the incidences in the 2.5 and 5 W/kg groups were significantly higher (Table 9, Table B-1, Table B-2). The sham control group had a low incidence of malignant lymphoma compared to the range seen in historical controls (Table 9, Table B-3). All of the incidences in the exposed groups fell within the overall historical control range. Malignant lymphoma involved many organs, most frequently the spleen, lymph nodes, thymus, lung, kidney, liver, and bone marrow, and was characterized by the effacement of normal architecture by a monomorphic population of neoplastic lymphocytes, which tended to be larger than normal lymphocytes. In spleens with malignant lymphoma, there was a loss of individual follicles and periarteriolar lymphoid sheaths, as the enlarged white pulp became one solid sheet of neoplastic cells sometimes leading to the gross enlargement of the organ. In the lymph nodes and thymus, malignant lymphoma led to the loss of distinguishable cortical and medullary regions, with the entire node appearing to contain only a single type of cell. Involved lymph nodes were typically grossly enlarged. In the liver and kidney, aggregates of neoplastic lymphocytes disrupted the normal arrangement of the paren-chyma, and in the lungs, neoplastic lymphocytes were often found expanding the bronchial-associated lymphoid tissue. Malignant lymphoma in the bone marrow resulted in a hypercellular marrow cavity with a monotonous population of malignant lymphocytes rather than the typical mix of erythrocytes and leukocytes in various stages of maturity.

Table 9 Incidences of Malignant Lymphoma in Female Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Malignant Lymphoma^a^
Overall rate^b^ | 2/90 (2%) | 13/90 (14%) | 9/90 (10%) | 6/90 (7%)
Adjusted rate^c^ | 2.5% | 15.6% | 10.7% | 7.1%
Terminal rate^d^ | 1/67 (1%) | 12/72 (17%) | 5/69 (7%) | 3/72 (4%)
First incidence (days) | 604 | 731 | 516 | 590
Poly-3 test^e^ | P = 0.474 | P = 0.004 | P = 0.035 | P = 0.153

^a^ Historical control incidence for 2-year studies (all studies except RFR) (mean ± standard deviation): 87/500 (17.4% ± 7.2%), range 10%–36%.

^b^ Number of animals with neoplasm per number of animals necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal euthanasia.

^e^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia.

Other Tissues: Several tissues had significantly increased incidences of lesions in one, or even two exposed groups of males or females. Many of them, such as lymphocytic infiltration or inflammation in various tissues, are common findings in aged mice and the incidences and severities recorded in this study were not considered exposure related. The incidence of other lesions lacked an exposure concentration response and were considered sporadic occurrences or of unknown importance.

Two hibernomas of the mediastinum occurred in 5 W/kg males (0, 0, 2, 0; Table A-1). These are unusual neoplasms of brown adipose tissue. Hibernomas were grossly observed tumors; histologically they were composed of round cells with moderate amounts of cytoplasm filled with tiny vacuoles, and small, round nuclei. Two benign ovarian teratomas occurred in 5 W/kg females, and one in 10 W/kg females (0/75, 0/86, 2/82, 1/80; Table B-1). Neither of these neoplasms occurred in the sham controls, nor have they occurred in the overall (except RFR study) historical control populations [males: mediastinum, hibernoma (0/499); females: ovary, benign teratoma (0/495)]. However, benign teratomas have been reported in the literature to occur in B6C3F1 mice^192^. Both the hibernomas and the teratomas were considered sporadic occurrences of rare neoplasms, and while unusual, were not considered exposure related.

## CDMA

### Twenty-eight-day Study

All mice survived to the end of the study (Table 10). Weekly mean body weights of exposed groups of males and females were similar to those of the sham controls at all time points (Table 10; Figure 9). There were no clinical signs related to exposure to CDMA-modulated RFR.

Table 10 Mean Body Weights and Survival of Mice Exposed to CDMA-modulated Cell Phone RFR for 28 Days

Day | Sham Control | | 5 W/kg | | | 10 W/kg | | | 15 W/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 20.2 | 10 | 20.4 | 100.7 | 10 | 20.4 | 101.0 | 10 | 20.9 | 103.2 | 10
8 | 21.8 | 10 | 21.8 | 100.0 | 10 | 22.2 | 101.6 | 10 | 22.4 | 102.4 | 10
15 | 22.8 | 10 | 22.4 | 98.3 | 10 | 23.0 | 100.9 | 10 | 23.3 | 102.3 | 10
22 | 24.0 | 10 | 23.5 | 98.0 | 10 | 23.9 | 99.6 | 10 | 24.2 | 101.0 | 10
29 | 24.9 | 10 | 24.3 | 97.6 | 10 | 25.2 | 101.2 | 10 | 25.1 | 101.1 | 10
Female
1 | 18.1 | 10 | 18.2 | 100.5 | 10 | 17.9 | 99.2 | 10 | 17.6 | 97.5 | 10
8 | 18.9 | 10 | 19.0 | 100.8 | 10 | 18.7 | 99.3 | 10 | 18.7 | 99.0 | 10
15 | 20.1 | 10 | 20.1 | 99.6 | 10 | 20.0 | 99.4 | 10 | 19.8 | 98.2 | 10
22 | 21.0 | 10 | 21.0 | 99.9 | 10 | 20.8 | 99.1 | 10 | 20.5 | 97.4 | 10
30 | 21.7 | 10 | 21.7 | 99.7 | 10 | 21.6 | 99.4 | 10 | 21.2 | 97.5 | 10

Figure 9

Growth Curves for Mice Exposed to CDMA-modulated Cell Phone RFR for 28 Days

Similar to what was seen in mice exposed to GSM-modulated RFR, body temperatures were significantly higher in males and significantly lower in females at several time points (Table 11).

Table 11 Mean Body Temperatures of Mice Exposed to CDMA-modulated Cell Phone RFR for 28 Days^a^

Day | Sham Control | | 5 W/kg | | 10 W/kg | | 15 W/kg
Day | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured
Male
0 | 37.0 ± 0.2 | 10 | 37.0 ± 0.1 | 10 | 38.0 ± 0.2** | 10 | 37.8 ± 0.2** | 10
2 | 35.7 ± 0.1 | 10 | 36.1 ± 0.1 | 10 | 37.0 ± 0.3** | 10 | 36.5 ± 0.2** | 10
4 | 36.2 ± 0.2 | 10 | 36.7 ± 0.2 | 10 | 37.0 ± 0.2** | 10 | 37.1 ± 0.2** | 10
7^b^ | 36.6 ± 0.2 | 9 | 36.4 ± 0.2 | 10 | 37.3 ± 0.3 | 10 | 37.3 ± 0.2 | 10
14^b^ | 35.5 ± 0.3 | 10 | 35.8 ± 0.1 | 10 | 36.1 ± 0.2 | 10 | 36.0 ± 0.1 | 10
17 | 36.0 ± 0.3 | 10 | 36.2 ± 0.3 | 10 | 36.8 ± 0.4 | 10 | 37.2 ± 0.3* | 10
20 | 36.5 ± 0.3 | 10 | 36.4 ± 0.2 | 10 | 37.3 ± 0.3* | 10 | 37.6 ± 0.2** | 10
27 | 35.8 ± 0.4 | 9 | 36.5 ± 0.3 | 10 | 37.4 ± 0.3** | 10 | 36.8 ± 0.3 | 10
2–27^c^ | 36.0 ± 0.2 | 10 | 36.3 ± 0.1 | 10 | 37.1 ± 0.1** | 10 | 36.9 ± 0.1** | 10
Female
0 | 38.1 ± 0.1 | 10 | 37.5 ± 0.1* | 9 | 38.3 ± 0.1 | 10 | 38.0 ± 0.2 | 10
2 | 37.5 ± 0.2 | 10 | 37.0 ± 0.2 | 9 | 38.1 ± 0.2 | 10 | 37.5 ± 0.2 | 10
4 | 37.0 ± 0.2 | 10 | 37.2 ± 0.2 | 10 | 37.7 ± 0.2 | 10 | 37.5 ± 0.2 | 10
7^b^ | 38.6 ± 0.1 | 10 | 37.9 ± 0.2** | 9 | 38.0 ± 0.1* | 10 | 38.3 ± 0.1 | 10
14^b^ | 36.9 ± 0.1 | 10 | 36.5 ± 0.2 | 9 | 37.0 ± 0.1 | 10 | 37.0 ± 0.2 | 10
17 | 37.9 ± 0.1 | 10 | 37.1 ± 0.2** | 10 | 37.6 ± 0.1 | 10 | 37.4 ± 0.2 | 10
20 | 37.7 ± 0.2 | 10 | 37.2 ± 0.1 | 10 | 37.5 ± 0.2 | 10 | 37.9 ± 0.1 | 10
27 | 37.8 ± 0.1 | 10 | 37.4 ± 0.3 | 10 | 37.9 ± 0.2 | 10 | 38.0 ± 0.3 | 10
2–27^c^ | 37.6 ± 0.1 | 10 | 37.2 ± 0.1** | 10 | 37.7 ± 0.1 | 10 | 37.7 ± 0.1 | 10

* Significantly different (P ≤ 0.05) from the sham control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Temperatures are given as mean ± standard error.

^b^ All temperatures were recorded within 5 minutes of the exposure cessation, except for the measurements on days 7 and 14, which were recorded at least 1 hour after exposure.

^c^ Average of days 2 to 27, excluding days 7 and 14.

There were no exposure-related effects on organ weights of males exposed to CDMA-modulated RFR (Table G-3). The absolute kidney weight of 15 W/kg females was significantly less (12%) than that of the sham controls (Table G-3); however, because there was no similar effect on relative kidney weight and no associated histopathologic findings, the biological significance of this finding was unknown.

There were no histopathologic lesions related to the effects of exposure to CDMA-modulated RFR.

Exposure Level Selection Rationale: In male and female mice exposed for 5 days to RFR up to 12 W/kg, only sporadic increases were observed in body temperature, regardless of the sex or age of the animals^144^. Because no significant effects of RFR were observed in body temperature at 12 W/kg, a higher upper exposure level was selected for the 28-day studies. Due to limits on the maximum capacity of the exposure system to generate high RF fields, the maximum achievable exposure level capacity was 15 W/kg, which was selected as the highest exposure level for the 28-day studies. Selection of the highest exposure level for the 2-year studies was also limited by the power capacity of the exposure system to generate maximum RF fields. Based on these limitations and increased body temperatures at various time points that were similarly observed at 10 and 15 W/kg in the 28-day studies, the exposure levels selected for the 2-year studies were 2.5, 5, and 10 W/kg.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 12 and in the Kaplan-Meier survival curves (Figure 10). Survival was significantly higher in 2.5 W/kg males compared to that in the sham controls. Survival of males and females in all other exposed groups was generally similar to that of the sham controls.

Table 12 Survival of Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Male
Animals initially in study | 105 | 106 | 105 | 105
14-week interim evaluation^a^ | 15 | 15 | 15 | 15
Accidental death^b^ | 0 | 0 | 1 | 0
Moribund | 8 | 2 | 5 | 3
Natural deaths | 16 | 6 | 13 | 16
Animals surviving to study termination | 66 | 83 | 71 | 71
Percent probability of survival at end of study^c^ | 73 | 91 | 80 | 79
Mean survival (days)^d^ | 687 | 715 | 706 | 704
Survival analysis^e^ | P = 1.000N | P = 0.003N | P = 0.343N | P = 0.482N
Female
Animals initially in study | 105 | 104 | 105 | 105
14-week interim evaluation^a^ | 15 | 15 | 15 | 15
Moribund | 9 | 5 | 4 | 4
Natural deaths | 14 | 9 | 16 | 14
Animals surviving to study termination | 67^f^ | 75^g^ | 70^h^ | 72^h^
Percent probability of survival at end of study^c^ | 74 | 83 | 77 | 79
Mean survival (days)^d^ | 704 | 715 | 715 | 712
Survival analysis^e^ | P = 0.758N | P = 0.168N | P = 0.702N | P = 0.517N

^a^ Excluded from survival analysis.

^b^ Censored in the survival analysis.

^c^ Kaplan-Meier determinations.

^d^ Mean of all deaths (uncensored, censored, and terminal euthanasia).

^e^ The result of the life table trend test^158^ is in the sham control column, and the results of the life table pairwise comparisons^157^ with the sham controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^f^ Includes one animal that died during the last week of the study.

^g^ Includes three animals that died during the last week of the study; one of these was censored in the survival analysis.

^h^ Includes one animal that died during the last week of the study; this animal was censored in the survival analysis.

Figure 10

Kaplan-Meier Survival Curves for Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

#### Body Weights and Clinical Observations

Mean body weights of exposed groups of males and females were similar to those of the sham controls throughout the study (Table 13, Table 14; Figure 11). In males, there were higher occurrences of the clinical signs mass-torso/lateral and mass-torso/ventral in the 10 W/kg group. In females, more occurrences of ruffled fur were recorded in the 5 and 10 W/kg groups and more occurrences of thin were recorded in all exposed groups. These findings were not correlated with differences in body weights or incidences of neoplasms in exposed animals.

Table 13 Mean Body Weights and Survival of Male Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

Day | Sham Control | | 2.5 W/kg | | | 5 W/kg | | | 10 W/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
0 | 20.6 | 105 | 20.4 | 99.1 | 106 | 20.3 | 99.0 | 105 | 20.4 | 99.3 | 105
8 | 21.9 | 104 | 21.7 | 99.0 | 106 | 21.9 | 100.0 | 105 | 21.9 | 100.2 | 105
15 | 22.9 | 104 | 22.9 | 99.9 | 106 | 23.2 | 101.3 | 105 | 22.7 | 99.2 | 105
22 | 24.1 | 104 | 24.1 | 100.0 | 106 | 24.4 | 101.2 | 105 | 24.0 | 99.6 | 105
29 | 25.1 | 104 | 25.1 | 99.9 | 106 | 25.2 | 100.3 | 105 | 25.1 | 99.8 | 105
36 | 26.3 | 104 | 26.2 | 99.9 | 106 | 26.2 | 100.0 | 104 | 26.3 | 100.1 | 105
43 | 27.3 | 104 | 27.3 | 99.8 | 106 | 27.2 | 99.7 | 104 | 27.4 | 100.3 | 105
50 | 28.1 | 104 | 28.2 | 100.5 | 106 | 28.0 | 99.8 | 104 | 28.3 | 100.8 | 105
57 | 29.3 | 104 | 29.4 | 100.2 | 106 | 28.9 | 98.5 | 104 | 29.5 | 100.5 | 105
64 | 30.5 | 104 | 30.2 | 99.1 | 106 | 29.8 | 97.8 | 104 | 30.7 | 100.5 | 105
71 | 31.7 | 104 | 31.3 | 98.9 | 106 | 31.2 | 98.3 | 104 | 32.2 | 101.7 | 105
79 | 32.9 | 104 | 32.6 | 99.0 | 106 | 32.3 | 98.1 | 104 | 33.4 | 101.6 | 105
86 | 33.6 | 104 | 33.4 | 99.2 | 106 | 33.0 | 98.0 | 104 | 34.6 | 102.8 | 105
93 | 34.3 | 94 | 33.8 | 98.5 | 96 | 33.6 | 98.0 | 94 | 35.3 | 102.8 | 95
121 | 38.6 | 89 | 38.3 | 99.0 | 91 | 38.3 | 99.1 | 89 | 39.5 | 102.4 | 90
149 | 42.0 | 89 | 41.4 | 98.6 | 91 | 42.2 | 100.6 | 89 | 43.2 | 103.0 | 90
177 | 44.3 | 89 | 44.0 | 99.4 | 91 | 44.6 | 100.7 | 89 | 45.2 | 102.0 | 90
205 | 46.0 | 89 | 45.8 | 99.6 | 91 | 46.5 | 101.0 | 89 | 46.4 | 101.0 | 90
233 | 47.3 | 89 | 46.8 | 99.1 | 91 | 47.1 | 99.6 | 89 | 47.0 | 99.4 | 90
261 | 47.6 | 89 | 47.5 | 99.8 | 90 | 47.8 | 100.5 | 89 | 47.7 | 100.3 | 90
289 | 48.2 | 88 | 48.3 | 100.2 | 90 | 48.5 | 100.5 | 89 | 48.1 | 99.8 | 90
317 | 48.8 | 88 | 48.7 | 99.7 | 90 | 49.0 | 100.4 | 89 | 48.7 | 99.8 | 90
345 | 49.4 | 88 | 49.0 | 99.1 | 90 | 49.4 | 100.1 | 89 | 49.3 | 99.7 | 90
373 | 50.0 | 87 | 49.9 | 99.9 | 90 | 50.1 | 100.1 | 89 | 49.7 | 99.4 | 90
401 | 50.4 | 86 | 50.4 | 99.8 | 90 | 50.7 | 100.5 | 89 | 50.5 | 100.2 | 90
429 | 50.7 | 85 | 50.8 | 100.1 | 90 | 51.1 | 100.8 | 89 | 50.8 | 100.1 | 89
457 | 51.1 | 84 | 51.5 | 100.7 | 90 | 51.4 | 100.5 | 89 | 51.1 | 100.1 | 89
485 | 51.5 | 84 | 51.9 | 100.8 | 90 | 51.6 | 100.3 | 89 | 51.6 | 100.3 | 87
513 | 50.5 | 83 | 51.7 | 102.4 | 90 | 51.5 | 102.0 | 89 | 51.2 | 101.3 | 86
541 | 49.7 | 83 | 51.2 | 103.0 | 89 | 50.8 | 102.3 | 89 | 50.5 | 101.7 | 85
569 | 50.4 | 82 | 51.7 | 102.7 | 88 | 51.5 | 102.3 | 87 | 50.8 | 101.0 | 85
597 | 50.9 | 81 | 52.4 | 103.0 | 87 | 52.1 | 102.4 | 84 | 51.4 | 101.1 | 84
625 | 50.7 | 78 | 52.5 | 103.4 | 86 | 52.1 | 102.7 | 84 | 50.9 | 100.3 | 83
639 | 49.8 | 78 | 52.5 | 105.5 | 85 | 51.3 | 103.1 | 83 | 50.3 | 101.0 | 80
653 | 49.0 | 78 | 52.1 | 106.4 | 85 | 50.9 | 103.8 | 82 | 49.9 | 101.8 | 79
667 | 49.0 | 76 | 52.3 | 106.6 | 84 | 51.3 | 104.6 | 80 | 49.9 | 101.7 | 76
681 | 49.2 | 74 | 51.9 | 105.6 | 84 | 51.1 | 104.0 | 78 | 49.8 | 101.3 | 75
695 | 48.7 | 71 | 51.4 | 105.5 | 84 | 50.5 | 103.8 | 76 | 49.3 | 101.2 | 73
709 | 48.5 | 69 | 51.0 | 105.2 | 84 | 49.5 | 102.0 | 75 | 48.8 | 100.5 | 72
723 | 48.4 | 67 | 51.0 | 105.5 | 83 | 48.6 | 100.5 | 73 | 48.3 | 99.9 | 71
Mean for Weeks
1–13 | 27.3 | | 27.1 | 99.6 | | 27.0 | 99.4 | | 27.4 | 100.5
14–52 | 44.7 | | 44.4 | 99.3 | | 44.7 | 100.1 | | 45.0 | 101.0
53–105 | 49.9 | | 51.5 | 103.3 | | 50.9 | 102.1 | | 50.3 | 100.8

Table 14 Mean Body Weights and Survival of Female Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

Day | Sham Control | | 2.5 W/kg | | | 5 W/kg | | | 10 W/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
0 | 17.4 | 105 | 17.4 | 99.7 | 104 | 17.4 | 100.2 | 105 | 17.5 | 100.4 | 105
8 | 18.4 | 105 | 18.4 | 100.0 | 104 | 18.5 | 100.5 | 105 | 18.4 | 100.2 | 105
15 | 19.4 | 105 | 19.6 | 100.7 | 104 | 19.5 | 100.3 | 105 | 19.3 | 99.0 | 105
22 | 20.2 | 105 | 20.3 | 100.5 | 104 | 20.2 | 99.7 | 105 | 20.1 | 99.6 | 105
29 | 20.8 | 105 | 21.0 | 100.8 | 104 | 20.8 | 99.8 | 105 | 20.7 | 99.6 | 105
36 | 21.5 | 105 | 21.6 | 100.4 | 103 | 21.5 | 99.9 | 105 | 21.5 | 99.8 | 105
43 | 22.0 | 105 | 22.0 | 100.0 | 103 | 21.9 | 99.7 | 105 | 21.8 | 99.4 | 105
50 | 22.5 | 105 | 22.4 | 99.4 | 103 | 22.3 | 99.0 | 105 | 22.0 | 97.8 | 105
57 | 22.8 | 105 | 22.7 | 99.8 | 103 | 22.9 | 100.3 | 105 | 22.6 | 99.1 | 105
64 | 23.3 | 105 | 23.4 | 100.2 | 103 | 23.4 | 100.4 | 105 | 23.2 | 99.4 | 105
71 | 23.4 | 105 | 23.7 | 101.2 | 103 | 23.9 | 102.2 | 105 | 23.8 | 101.6 | 105
79 | 23.9 | 105 | 24.4 | 101.8 | 103 | 24.7 | 103.1 | 105 | 24.5 | 102.4 | 105
86 | 24.0 | 105 | 24.1 | 100.5 | 103 | 24.6 | 102.6 | 105 | 24.5 | 102.2 | 105
93 | 24.3 | 95 | 24.1 | 99.2 | 93 | 24.9 | 102.4 | 95 | 24.8 | 102.2 | 95
121 | 26.3 | 90 | 26.4 | 100.2 | 88 | 26.9 | 102.2 | 90 | 27.0 | 102.5 | 90
149 | 28.8 | 90 | 29.5 | 102.3 | 88 | 29.9 | 103.9 | 90 | 30.2 | 104.8 | 90
177 | 30.8 | 90 | 32.2 | 104.6 | 88 | 32.3 | 105.0 | 90 | 33.0 | 107.1 | 90
205 | 33.4 | 90 | 35.6 | 106.5 | 88 | 35.1 | 105.2 | 90 | 35.8 | 107.1 | 90
233 | 36.8 | 90 | 38.2 | 103.7 | 88 | 38.2 | 103.9 | 89 | 39.1 | 106.3 | 89
261 | 38.4 | 90 | 40.4 | 105.1 | 88 | 40.8 | 106.1 | 89 | 42.1 | 109.5 | 89
289 | 40.3 | 90 | 43.6 | 108.1 | 87 | 43.3 | 107.4 | 89 | 44.1 | 109.4 | 89
317 | 42.3 | 90 | 45.6 | 108.0 | 87 | 46.0 | 108.9 | 89 | 46.8 | 110.8 | 89
345 | 45.0 | 90 | 48.0 | 106.7 | 87 | 48.7 | 108.3 | 89 | 49.0 | 109.0 | 89
373 | 47.6 | 90 | 50.4 | 105.8 | 87 | 50.7 | 106.4 | 89 | 51.0 | 107.0 | 89
401 | 49.9 | 90 | 52.2 | 104.5 | 87 | 52.6 | 105.3 | 89 | 52.7 | 105.6 | 89
429 | 51.4 | 90 | 53.5 | 104.2 | 87 | 54.3 | 105.8 | 89 | 53.6 | 104.3 | 89
457 | 53.3 | 89 | 55.2 | 103.7 | 87 | 55.6 | 104.5 | 89 | 54.8 | 102.9 | 89
485 | 55.0 | 89 | 56.2 | 102.3 | 87 | 56.8 | 103.3 | 89 | 56.0 | 102.0 | 88
513 | 54.5 | 87 | 55.9 | 102.6 | 86 | 56.8 | 104.3 | 87 | 56.7 | 104.1 | 86
541 | 51.9 | 87 | 54.0 | 104.1 | 86 | 54.7 | 105.4 | 86 | 54.1 | 104.4 | 85
569 | 52.2 | 83 | 54.2 | 103.8 | 86 | 55.2 | 105.7 | 85 | 54.5 | 104.5 | 85
597 | 55.3 | 80 | 56.8 | 102.7 | 85 | 57.5 | 104.0 | 84 | 56.7 | 102.5 | 84
625 | 56.3 | 76 | 56.9 | 101.1 | 85 | 57.7 | 102.6 | 84 | 57.1 | 101.5 | 83
639 | 54.8 | 75 | 55.8 | 101.9 | 83 | 56.2 | 102.5 | 84 | 55.7 | 101.6 | 82
653 | 54.5 | 71 | 55.3 | 101.4 | 83 | 55.5 | 101.8 | 82 | 55.7 | 102.1 | 81
667 | 55.1 | 70 | 55.3 | 100.5 | 82 | 55.1 | 100.1 | 81 | 55.0 | 99.9 | 81
681 | 54.6 | 70 | 54.6 | 99.9 | 82 | 54.7 | 100.1 | 80 | 53.9 | 98.6 | 77
695 | 54.0 | 69 | 54.0 | 99.9 | 80 | 53.6 | 99.1 | 77 | 53.7 | 99.3 | 73
709 | 53.7 | 68 | 53.2 | 99.1 | 77 | 53.3 | 99.3 | 76 | 53.2 | 99.0 | 72
723 | 53.0 | 68 | 52.3 | 98.7 | 75 | 53.4 | 100.7 | 72 | 52.7 | 99.4 | 72
737 | 52.2 | 67 | 51.3 | 98.3 | 75 | 53.2 | 101.9 | 69 | 52.2 | 99.9 | 71
Mean for Weeks
1–13 | 21.5 | | 21.6 | 100.4 | | 21.7 | 100.6 | | 21.5 | 100.0
14–52 | 34.6 | | 36.4 | 104.4 | | 36.6 | 105.3 | | 37.2 | 106.9
53–107 | 53.3 | | 54.3 | 101.9 | | 54.8 | 102.9 | | 54.4 | 102.1

Figure 11

Growth Curves for Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

#### 14-week Interim Evaluation

There were no changes to the hematology variables attributable to CDMA-modulated RFR exposure (Table F-2).

At the 14-week interim evaluation, mean body weights of exposed groups of males and females were similar to those of the sham controls (Table G-4). The absolute right and left kidney weights were significantly lower (7% and 8%, respectively) in 5 W/kg males, and the absolute left kidney weight was significantly lower (8%) in 10 W/kg males (Table G-4). The relative right and left kidney weights were significantly lower in 10 W/kg males. The histologic changes observed in the kidneys were not thought to be responsible for the changes in organ weights. The absolute liver weight was significantly lower (10%) in 5 W/kg males, and the relative liver weight was significantly lower in 10 W/kg males. The changes in the liver weights were considered small and sporadic and therefore not toxicologically relevant; there were no histopathologic lesions that would account for changes in liver weights. Although the absolute thymus weight of 10 W/kg males was 22% higher than that of the sham controls, the relative thymus weight was not higher in the 10 W/kg males, nor were there any histopathologic lesions in the thymus. There were no significant changes in organ weights in females.

In males, there were no exposure-related effects on reproductive organ weights, testis spermatid concentrations, caudal epididymal sperm concentrations, or sperm motility (Table H-4). In females, there were no exposure-related effects on estrous cyclicity (Table H-5, Table H-6; Figure H-2). Compared to the sham controls, there were statistically significant differences for extended estrous in the 2.5 W/kg group and extended diestrus in the 5 W/kg group; however, these changes were considered sporadic due to the lack of an exposure-related response.

In the kidney of 10 W/kg females, there was a significantly higher incidence of interstitial lymphocytic cellular infiltration (sham control, 0/10; 2.5 W/kg, 1/10, 5 W/kg, 1/10; 10 W/kg, 5/10; Table D-4). The lesions were minimal to mild in severity, and consisted of clusters of lymphocytes within the interstitium.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of malignant lymphoma and neoplasms and/or nonneoplastic lesions of the liver, pituitary gland, and uterus in the 2-year study. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Liver: There was a significantly higher incidence of hepatoblastoma in 5 W/kg males (Table 15, Table C-1, Table C-2). In 2.5 W/kg males, there was a significantly higher incidence of hepatocellular adenoma and a significantly lower incidence of hepatocellular carcinoma. When these neoplasms were combined (hepatocellular adenoma, hepatocellular carcinoma, or hepatoblastoma), there were no significant differences in the incidences between exposed and sham control groups of males. Hepatocellular adenomas were well-circumscribed lesions that compressed the surrounding liver parenchyma. Most were considerably larger than a hepatic lobule, and when located at the edge of the liver would usually cause an outward protrusion of the liver surface. They were made up of hepatocytes that lacked the normal architectural arrangement; while portal areas might be found near the edge of a hepatocellular adenoma, they were typically lacking within the center of the neoplasm. Most adenomas lacked cellular pleomorphism and contained few, if any, mitotic figures. Hepatocellular carcinomas were usually large lesions, typically larger than hepatocellular adenomas, and frequently contained areas of necrosis. They were often multinodular and compressive, and were composed of trabeculae of neoplastic hepatocytes that were arranged at least three cells wide (in contrast to normal hepatic trabeculae, which are a single hepatocyte wide). Cells within hepatocellular carcinomas had higher mitotic rates and more pleomorphism when compared to hepatocellular adenomas. Hepatoblastomas were composed of small cells with scant cytoplasm and hyperchromatic, oval nuclei, often arranged in nests and whorls. Hepatoblastomas frequently arose from within a hepatocellular adenoma or carcinoma; when this occurred, only the hepatoblastoma was recorded.

Table 15 Incidences of Neoplasms of the Liver in Male Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Number Examined Microscopically | 90 | 89 | 90 | 90
Hepatocellular Adenoma^a^
Overall rate^b^ | 52/90 (58%) | 66/89 (74%) | 55/90 (61%) | 62/90 (69%)
Adjusted rate^c^ | 62.3% | 75.4% | 64.9% | 72.7%
Terminal rate^d^ | 45/66 (68%) | 64/83 (77%) | 51/71 (72%) | 54/71 (76%)
First incidence (days) | 393 | 625 | 656 | 478
Poly-3 test^e^ | P = 0.199 | P = 0.043 | P = 0.428 | P = 0.096
Hepatocellular Carcinoma^f^
Overall rate | 28/90 (31%) | 18/89 (20%) | 25/90 (28%) | 31/90 (34%)
Adjusted rate | 34.2% | 20.6% | 29.0% | 36.2%
Terminal rate | 18/66 (27%) | 16/83 (19%) | 18/71 (25%) | 22/71 (31%)
First incidence (days) | 608 | 629 | 559 | 461
Poly-3 test | P = 0.177 | P = 0.033N | P = 0.287N | P = 0.459
Hepatoblastoma, Multiple^g^ | 0 | 0 | 1 | 0
Hepatoblastoma (includes multiple)^h^
Overall rate | 6/90 (7%) | 6/89 (7%) | 16/90 (18%) | 7/90 (8%)
Adjusted rate | 7.5% | 6.9% | 18.9% | 8.5%
Terminal rate | 5/66 (8%) | 6/83 (7%) | 14/71 (20%) | 7/71 (10%)
First incidence (days) | 711 | 729 (T) | 679 | 729 (T)
Poly-3 test | P = 0.328 | P = 0.562N | P = 0.026 | P = 0.523
Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma^i^
Overall rate | 68/90 (76%) | 70/89 (79%) | 69/90 (77%) | 75/90 (83%)
Adjusted rate | 80.3% | 79.6% | 79.8% | 85.6%
Terminal rate | 52/66 (79%) | 67/83 (81%) | 59/71 (83%) | 61/71 (86%)
First incidence (days) | 393 | 625 | 559 | 461
Poly-3 test | P = 0.175 | P = 0.532N | P = 0.548N | P = 0.230

T = terminal euthanasia.

^a^ Historical control incidence for 2-year studies (all studies except RFR) (mean ± standard deviation): 256/499 (51.3% ± 10.7%), range 34%–70%.

^b^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal euthanasia.

^e^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A lower incidence in an exposure group is indicated by N.

^f^ Historical control incidence: 136/499 (27.2% ± 8.6%), range 16%–42%.

^g^ Number of animals with neoplasm.

^h^ Historical control incidence: 13/499 (2.6% ± 1.9%), range 0%–6%.

^i^ Historical control incidence: 340/499 (68.1% ± 8.7%), range 53%–80%.

Malignant Lymphoma: Compared to the sham controls, the incidences of malignant lymphoma were higher in all exposed groups of females, and the increase in the 2.5 W/kg group was statistically significant (Table 16, Table D-1, Table D-2). This was similar to the pattern seen in females exposed to GSM-modulated RFR in that the incidences of malignant lymphoma in groups exposed to RFR (either CDMA or GSM) were similar, and increasingly higher exposures did not have increasingly higher incidences. The incidence in the sham control group, shared by the GSM- and CDMA-modulated RFR studies, was at the low end of the range for malignant lymphoma in historical controls (Table 16, Table D-3). Malignant lymphoma in the CDMA-modulated RFR-exposed groups was similar in appearance, and in the organs that were involved, to that observed in the sham controls and the GSM-modulated RFR-exposed groups.

Table 16 Incidences of Malignant Lymphoma in Female Mice Exposed to CDMA-Modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Malignant Lymphoma^a^
Overall rate^b^ | 2/90 (2%) | 9/89 (10%) | 6/90 (7%) | 7/90 (8%)
Adjusted rate^c^ | 2.5% | 10.7% | 7.2% | 8.4%
Terminal rate^d^ | 1/67 (2%) | 8/74 (11%) | 4/69 (6%) | 4/71 (6%)
First incidence (days) | 604 | 689 | 716 | 635
Poly-3 test^e^ | P = 0.220 | P = 0.035 | P = 0.152 | P = 0.094

^a^ Historical control incidence for 2-year studies (all studies except RFR) (mean ± standard deviation): 87/500 (17.4% ± 7.2%), range 10%–36%.

^b^ Number of animals with neoplasm per number of animals necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal euthanasia.

^e^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia.

Other Tissues: Several tissues had significantly increased incidences of lesions in one, or even two, exposed groups of males or females. Some of these lesions are common background lesions and were not considered toxicologically important; the incidences of others lacked a dose response and were considered sporadic occurrences and not related to treatment.

In 5 W/kg males, two adenomas (0/86, 0/84, 2/89, 0/83) and one carcinoma (0/86, 0/84, 1/89, 0/83) occurred in the pars distalis of the pituitary gland (Table C-1); no neoplasms of the pituitary gland pars distalis occurred in the sham control group or in the other exposed groups of males, including those in the GSM study (Table A-1). Only two adenomas of the pituitary gland (pars distalis) have been recorded in the current (August 2017) historical control database of 490 male mice (all studies except RFR), and no carcinomas of the pars distalis have been recorded in male mice.

In the uterus of female mice, there were one or two occurrences of adenocarcinoma (sham control, 0/89; 2.5 W/kg, 2/89; 5 W/kg, 0/88; 10 W/kg, 1/90) or leiomyosarcoma (0/89, 1/89, 1/88, 2/90) in most of the exposed groups; these neoplasms did not occur in the sham control group (Table D-1). Neither uterine adenocarcinomas nor leiomyosarcomas have been recorded in the current historical control database (0/590). These neoplasms were considered sporadic occurrences, and not related to exposure.

## Genetic Toxicology

Twenty tissue samples obtained from animals in the 14-week interim evaluation study were evaluated for DNA damage using the comet assay (two sexes, two RFR modulations, five tissues). Results are based on the standard 100-cell scoring approach in use at the time these data were collected; data obtained using a 150-cell scoring approach, recommended in a recently adopted international guideline for the in vivo comet assay, are noted here for the few instances where results differed between the two methods. The complete 100-cell and 150-cell data are presented in Appendix E data tables. Significant increases in DNA damage (percent tail DNA) were observed in cells of the frontal cortex of male mice exposed to both modulations, CDMA and GSM (Table E-1, Table E-2). Positive results were also obtained for male mouse frontal cortex (CDMA and GSM) (Table E-3) using the 150-cell approach. Of note is the low percent comet tail DNA value in the frontal cortex of sham control mice. There is no appropriate historical control database to provide context for this response, but bonafide changes in DNA damage levels in a treatment group should remain constant relative the control value. No technical aspects of the study that may have influenced this control value independently of the treated group values (e.g., % agarose gel, duration of electrophoresis, electromagnetic field strength, slide position in the electrophoresis tank) were identified. Technical factors that influence control levels have not been shown to alter sensitivity to detect effects in treated groups^193^. No other tissues showed evidence of a treatment-related effect in male mice. In female mice exposed to the CDMA modulation, significant increases in DNA damage were seen in blood leukocytes using both scoring approaches (Table E-4, Table E-6). In female mouse liver samples exposed to either modulation, the mean percent comet tail DNA was elevated above the sham control for all exposures when evaluated using either scoring approach. Results of the 100-cell scoring approach were judged to be negative (Table E-4, Table E-5); scoring 150 cells resulted in a negative call for GSM-exposed female mice (Table E-6) but in CDMA-exposed female mouse liver, significant increases (P = 0.009) in percent comet tail DNA were seen in the 5 and 10 W/kg groups, resulting in a positive call for this dataset.

In the micronucleus assay for male mice exposed to CDMA (Table E-7), although a significant trend was observed for micronucleated polychromatic erythrocytes (PCEs) (P = 0.013), the absolute increase was quite small and fell within the laboratory’s historical control range. In addition, no corresponding increase in micronucleated normochromatic erythrocytes was observed; the mature erythrocyte population ought to be in steady state equilibrium after continuous 14 weeks of exposure, such as occurred in this study. Thus, the overall result in the micronucleus assay for male mice exposed to CDMA was judged to be negative. No other significant effects on either micronucleus frequency or % PCEs were seen in male or female mice exposed to either modulation of RFR.