# Materials and Methods

## Overview

The establishment of the National Toxicology Program (NTP) research program on radio frequency radiation (RFR) has required the coordination of expertise from multiple scientific and engineering disciplines. At the initiation of the RFR research program, a collaboration was established with technical experts from the Radio-Frequency Fields Group in the Radio Frequency (RF) Technology Division, which is part of the Communications Technology Laboratory (CTL) at the National Institute of Standards and Technology (NIST, Boulder, CO). NIST evaluated the existing exposure systems and identified the types of improvements that would be required to provide a system of sufficient size and power to conduct robust toxicology and carcinogenicity studies with uniform RFR exposures in unrestrained, individually housed animals for a minimum of 6 hours a day at frequencies and modulations that reflected those in use at the time. The design of the chambers and toxicology studies required special consideration of logistical, financial, and engineering limitations.

NIST tested the feasibility of a reverberation chamber-type exposure system by conducting a series of studies on field strengths, field uniformity, and power requirements under various conditions of RFR exposure in such chambers. These studies provided critical information for the design of experimental studies with respect to the number of cages that could be placed in specific size chambers, the arrangement of cages within each chamber, and the input power requirements.

Concurrent with the collaboration with NIST, NTP also worked with the Foundation for Research on Information Technologies in Society (IT’IS, Zurich, Switzerland), which conducted studies using computational models that simulated RFR dosimetry to provide estimates of whole-body and organ-specific internal field strengths and specific absorption rates (SARs) during exposure. Based on information and parameters obtained during the NIST feasibility studies, IT’IS built a prototype reverberation chamber as the basis for an exposure system to study health effects of long-term exposure of laboratory animals. Following completion, NIST evaluated the prototype exposure chamber to determine if it met the requirements specified by NTP.

The role of each institution collaborated with is outlined below:

- National Institute of Standards and Technology (NIST), Boulder, CO.
  - Suggested reverberation chamber exposure system.
  - Conducted feasibility studies for reverberation chambers.
  - Established various technical parameters for chambers.
  - Evaluated the prototype chamber built by IT’IS Foundation.
  - Validated the system prior to the conduct of studies at IITRI.
  - Reevaluated RFR exposures prior to and after 2-year studies.
- IT’IS Foundation, Zurich, Switzerland.
  - Constructed and tested prototype chamber.
  - Refined technical parameters.
  - Built the chambers for the NTP exposure facility.
  - Installed chambers at IITRI.
  - Monitored system performance throughout all phases of the studies.
  - Conducted maintenance on exposure system hardware and software.
- IIT Research Institute (IITRI), Chicago, IL.
  - Tested exposure system after installation.
  - Conducted maintenance of exposure system hardware.
  - Conducted all toxicology and carcinogenicity studies.
  - Conducted day-to-day operations.

After prototype-testing by IT’IS Foundation and NIST, the IT’IS Foundation built the reverberation chambers required for the NTP RFR exposure facility. Chambers were installed at the Illinois Institute of Technology (IIT) Research Institute (IITRI, Chicago, IL). Following the installation and initial testing of the exposure system by IT’IS and IITRI, technical experts from NIST conducted an independent validation of the system. NIST confirmed that the probe readings in the system were consistent, that field uniformity was within expected specifications, and that the signal quality was acceptable. NIST performed additional evaluations prior to initiation of the 2-year studies and after completion of the studies to determine if any changes occurred in the signal quality, field uniformity, or consistency of in-chamber field measurements. All studies were conducted at IITRI with real-time monitoring of the system performance at IT’IS Foundation.

## Reverberation Chamber Method of Exposure

The use of the reverberation exposure chamber as a method for exposing rats and mice to cell phone RFR was conceptualized by NIST and further designed and tested by NIST and the IT’IS Foundation. A reverberation chamber is a resonant box where the resonances and field structure are continuously modified under the influence of metallic stirrers, introduced to change the effective geometry, such that when averaged over time, the field strength is uniform over the entire exposure volume. A reverberation chamber exposure system was selected by NTP for the primary benefit that controlled exposures can be achieved in unrestrained animals (rats and mice) with extended daily RFR exposure periods compared to other methods of exposure for up to 2 years.

Preliminary studies were first conducted at NIST to test the concept of reverberation chambers. In these studies, field strengths and field uniformity were measured under various conditions of RFR exposure, including an empty chamber and a chamber loaded with water bottles (simulating animals) at different locations in the chamber. Power requirements were evaluated to achieve desired SAR levels. The effects of proximity between water bottles were also investigated to avoid electromagnetic coupling. These studies provided critical information for the design of experimental studies with respect to the number of cages that could be placed in specific size chambers, the arrangement of cages within each chamber, and the input power requirements. The results of these investigations demonstrated that while variations occurred over time and space the average RFR field was uniform over the large volume of the chamber. These studies also demonstrated that RFR field exposure occurred from all directions and all polarizations, and that there was uniformity of SAR in reverberation chambers. Based on the information and parameters obtained during the NIST feasibility studies, a custom-built prototype reverberation chamber was constructed and tested by the IT’IS Foundation. The development of the prototype chamber involved the design of amplifiers and antennas for signal generation, the design of vertical and horizontal stirrers to improve the homogeneity of experimentally generated RF fields, the development of both hardware and software for the control and monitoring of experimentally generated RF signals, and testing of chamber performance. During the design of the prototype exposure chamber, engineering studies were performed to optimize the following prior to construction:

- The uniform field volume within each chamber to minimize spatial variability in the characteristics of generated RF fields within a chamber such that all animals housed within the chamber space were exposed to comparable RF field strengths.
- The design and placement of stirrers in each chamber in order to maximize homogeneity of experimentally-generated RF fields.
- The design and location of RF antennas in each chamber.
- The location of cage racks within the exposure chamber in order to provide appropriate separation of individual animal cages and cage racks from all reflective surfaces (chamber walls, chamber floor and ceiling, antennas, and stirrers) in the reverberation chamber.
- Chamber volume to provide adequate space for staff to observe animals, collect data, and perform routine animal husbandry operations, while minimizing overall chamber volume to minimize the chamber size/footprint and the RF power required to maintain target SARs.

The final reverberation chamber design for use in these studies was a fully-shielded room constructed of stainless steel, equipped with a shielded room door to eliminate leakage of RFR signals, two rotating stirrers (one horizontal and one vertical), ventilation structures, and RFR excitation antennas. A detailed rationale for the selection of reverberation chambers for exposure to RFR and a full description of the exposure system are provided in Capstick et al.^146^ and Gong et al.^145^ and in a video^c^ (day 1 a.m. at 54 minutes) on the NTP website.^3^

c https://doi.org/10.22427/NTP-VIDEO-41

As part of the validation of the reverberation chamber exposure system design, a team of engineers from NIST conducted an independent evaluation of chamber design and exposure system operation in order to evaluate the suitability of the reverberation chamber model for use in the program. NIST engineers evaluated the design and operation of the prototype chamber and performed an extensive series of RF measurements to support an evaluation of system performance. Further information on the exposure verification is found in the video^d^ (day 1 p.m. at 0 minutes) by John Ladbury^3^.

d https://doi.org/10.22427/NTP-VIDEO-42

## RFR Exposure Facility

The exposure facility was specifically designed to expose mice in reverberation chambers to three different power levels of modulated cell phone RFR [Global System for Mobile Communications (GSM) or Code Division Multiple Access (CDMA)] at 1,900 MHz for up to 2 years to evaluate toxicity and carcinogenicity. The completed exposure facility consisted of a total of 21 RFR reverberation exposure chambers (seven designated for mice); the RFR signal generation, amplification, and monitoring systems; software for chamber operation; and hardware and software for monitoring of environmental and exposure conditions within each chamber. All system hardware and software were installed by the IT’IS Foundation.

During exposures, modulated (GSM or CDMA) RFR signals were generated by a signal generator, amplifiers amplified the signals, and the signals were delivered by antennas in the reverberation chambers. RFR field strengths were monitored in real time and were adjusted throughout the studies to achieve specific exposure levels [based on SARs quantitated in watts (W) per kg body weight]. Environmental conditions were also monitored and controlled in real time throughout the study. RFR exposures and environmental conditions were monitored and controlled by a computer in a control room at the study laboratory at IITRI; the IT’IS Foundation was also capable of remote system monitoring and control.

### Facility Design and Reverberation Chambers

Each reverberation chamber was permanently programmed for a specified modulation (GSM or CDMA) of the 1,900 MHz RFR specified for the mouse studies. Designated SARs for each chamber were selected prior to exposures. The field strengths required to achieve a given target SAR (W/kg) exposure level are a function of animal body weight (kg) and were adjusted to provide consistent SARs as the animals grew. However, separate chambers were not required for male and female B6C3F1/N mice because their body weights and growth curves are sufficiently similar to yield similar SARs. To conduct robust toxicology studies with three exposure groups (low, medium, and high), three chambers were required for different levels of exposures for GSM modulation and three for CDMA modulation. A sham exposure chamber without any RFR signal provided shared control groups for the parallel studies of the two modulations. As per these requirements, the RFR exposure facility consisted of seven reverberation chambers for exposures in mice including:

- Three power levels for mice exposed to GSM-modulated cell phone RFR at 1,900 MHz
- Three power levels for mice exposed to CDMA-modulated cell phone RFR at 1,900 MHz
- One sham control chamber for mice with no RFR exposure

The chamber size was designed to accommodate the RF field stirring paddles (described below), approximately 220 individually housed mice, and a minimum distance (3/4 of a wavelength) between the cages and the walls, floor, ceiling and stirrers, respectively. The interior of the chamber was suitable for cleaning using high-pressure water (after the RF antennas were protected). The internal dimensions of the chambers were 2.2 m (width) × 3.7 m (length) × 2.6 m (height); the exterior dimensions were 2.3 m (width) × 3.8 m (length) × 2.85 m (height). A floorplan for the exposure facility and images of the interior and exterior of the chambers are presented in Figure 4 and Figure 5.

Figure 4

Exposure Facility Floor Plan for the Cell Phone RFR Studies

(Not shown are the Ethernet connections to computers in the control room.)

Mouse chamber designations: low GSM=14; medium GSM=12; high GSM=11; low CDMA=3; medium CDMA=2; high CDMA=1; sham control=13. The 14 other chambers (including 12 for cell phone RFR exposure and two for sham control) were designated for concurrent rat studies.

Figure 5

Exterior View of Chambers, Empty Chamber Showing the Vertical and Horizontal Stirrers, and Chamber with Cage Racks in Place

Each chamber contained two motor-controlled stirring paddles (one vertical and one horizontal) with adjustable speed control (1 to 50 rpm) and large asymmetrical reflecting surfaces. Stirring paddles were placed off center in the chamber for maximum scattering of the RFR fields to generate a statistically homogeneous field distribution when averaged over time. The horizontal stirrer was mounted on the ceiling of the chamber. The vertical stirrer was at the rear of the chamber, and was protected by rack guides that prevented contact with the animal cage racks.

### Cage Racks and Watering System

Cages, cage racks, and watering systems for standard laboratory use contain elements that have the ability to alter the exposure of the animals or introduce potential confounding factors. Because cage racks and the drinking water delivery system were contained inside the chambers during exposure periods, it was required that these components be constructed of durable materials that had essentially no impact on the RF fields generated in the chamber. Metallic cage rack components, cage lids, feed dispensers, and cage grommets all needed to be eliminated. Hence, custom engineering was required to overcome the challenges regarding potential RFR exposure-altering aspects of the caging and cage racks used to house the animals during the studies. The safe provision of drinking water provided the largest challenge for the studies.

The absorption of RFR energy by water, if supplied by nonmetallic sipper tubes and distribution systems or bottles, could lead to dose-dependent elevated water temperatures. At the same time, the potential for enhanced exposure fields by metallic sipper tubes or lixits precluded the use of water bottles or a standard automatic watering system in the reverberation chambers. The absorption of RFR energy by water could result in significant heating of the drinking water, thereby decreasing water palatability and increasing the required RFR power to achieve the desired exposure field strength, potentially to the extent that the exposure levels could not be met. To overcome these challenges, adaptations were made to an automatic watering system so that the delivery of drinking water to the animals would not interfere with RFR dosimetry. The water system was constructed from stainless steel ensuring no dose-dependent energy absorption in the water (avoiding exposure-dependent water temperature) and in structures around the lixits to ensure no enhanced fields that could lead to excessive SAR in the animals while drinking.

Customized, nonmetallic animal cage racks for the reverberation chambers were designed by IITRI to minimize any absorption of RFR or disruption of RF field homogeneity. Cage racks were constructed primarily of box beam fiberglass (with some angle beam fiberglass used in nonweight-bearing areas of the rack). The shelves/cage lids were constructed of a clear polycarbonate sheet with slots for increased airflow. The potential impact of the racks on RF fields was evaluated in the prototype reverberation chamber by the IT’IS Foundation. Cage racks were designed to accommodate the automatic watering system and position the perimeter of each animal cage at least one-half wavelength from any reflecting surface. The specific considerations for design and further details of the custom-designed cage racks and adapted automated watering system are provided in Capstick et al.^146^ and in the video presentation^e^ by Dr. Myles Capstick^3^.

e https://doi.org/10.22427/NTP-VIDEO-41

### RFR Exposure System Control

The hardware and chambers designated for mice (using an exposure frequency of 1,900 MHz) were connected to a dedicated computer control system using an Ethernet protocol. The computerized control system managed and monitored the RFR exposures and environmental conditions in the chambers. A more detailed description of the computer control of RFR exposure is provided in Capstick et al.^146^.

The control computer managed the exposure schedule, stirrer rotation speeds, exposure signal and level, and monitored air flow, temperature, humidity, light, and the electric and magnetic fields (E- and H-fields, respectively) in each chamber. The hardware for the exposure system consisted of the control computer and a rack containing communications interfaces and instrumentation for signal generation, data acquisition, signal monitoring, signal amplifiers, and the chamber hardware (which included the stirrer motors and environmental and RFR sensors). The instrumentation rack contained the equipment that generated the RFR signal, acquired RFR field strengths and environmental data, and provided an interface between the components and the control computer.

## RFR Signal Generation

GSM-modulated and CDMA-modulated cell phone RFR signals were generated experimentally via a SMIQ02B vector signal generator with options SMIQB11 and SMIQB20 and software options 100421–100423 (Rohde and Schwarz, Munich, Germany). Signals were amplified using six LSE^™^ amplifiers (LSE, Spanga, Sweden) in the exposure system. The outputs of each individual amplifier were set by real-time controllers on a slot-by-slot basis for GSM or CDMA modulation to control the E-field strength in each chamber. Each chamber contained at least one standard gain antenna (two half-wave dipoles) that was mounted a quarter of a wavelength in front of a reflector plate. Antennas were directed towards one of the two stirrers to maximize scattering and obtain acceptable E-field homogeneity within the chamber space. The computerized control system managed the exposure schedule, stirrer rotation speeds, and exposure signal type and level.

The RFR power introduced into a given chamber was adjusted to achieve target field strengths; to maintain constant exposure levels (W/kg) in a given chamber, the field strengths [measured in volts (V) per meter] were regularly adjusted to reflect changes in the average mass of the exposed animals. The relationship between animal mass, field strength, and SAR was determined from numerical dosimetry and programmed into the control software, hence the required exposure field strength was computed from the average animal weights entered for each exposure group. The interval at which animal weights were updated was determined on how rapidly the animals were growing, at the start of the exposure period this was once per week, and as long as up to every 4 weeks later in the studies.

## Verification of RFR Exposure

Prior to initiation of the animal studies, the RF Fields Group in the Communications Technology Laboratory at the NIST performed an independent, detailed evaluation of each of the reverberation chambers (excluding the sham control chambers; Figure 4) to verify the RFR exposure fields, chamber characteristics (field uniformity), and signal quality to determine the accuracy of field values reported by the developers of the exposure system (IT’IS Foundation). This information provided in the video^f^ (day 1 p.m. at 0 minutes) by John Ladbury^3^. Full reports detailing the procedures for measurements and calculations are available from NTP.

f https://doi.org/10.22427/NTP-VIDEO-42

All E-field measurements agreed within the estimated uncertainty bounds, indicating that the chamber fields measured by the NIST agreed with the measurements provided by the IT’IS Foundation probes. During validation, it was determined that the H-field probes at higher signal levels in the mid- and high-power GSM chambers reported higher fields than indicated by other measurements, potentially leading to a modest overestimation of chamber field strengths. In these chambers, H-field probes were replaced with E-field probes, which provided more accurate measurements of the RF fields. The magnitude of field variation throughout the volume of a fully loaded chamber was consistent with earlier values reported for the prototype chamber. However, it was determined that there may have been up to ± 2.5 dB of variation in the exposure field depending on location in the cage racks. To mitigate this positional variation, cages were routinely rotated to various locations within and between the cage racks. The quality of the modulated signals was found to be acceptable with regard to distortion and harmonic content.

Overall, the NIST confirmed that the RFR reverberation chamber exposure system was operating correctly and RFR exposures were within specifications.

## RFR Exposure Monitoring

During all exposure periods, experimentally generated RFR was continuously monitored by the control system via two RF sensors (E-field and/or H-field probes) in each exposure chamber that measured real-time signal strengths. The use of two probes provided two independent measurements of RF field strengths and ensured that appropriate quantitation of experimentally generated RF fields continued even in the unlikely event that one probe failed. The E-field sensor measured electric field strength (V/m). The H-field sensor measured magnetic field strength [measured in amperes (A) per meter]. All chambers were instrumented with one E-field sensor (ER3DV6) and one H-field sensor (H3DV6) [both from Schmid and Partner Engineering AG (SPEAG), Zurich, Switzerland], except for the medium and high power GSM chambers. These chambers were instrumented with two E-field probes because H-field probes saturated at high field strengths. This change in hardware did not result in the loss of monitoring capability. The measured E- and H-fields were communicated to the control computer in order to maintain exposure to selected levels of RFR. During daily shutdown periods when RFR exposures were not active, RF sensors monitored ambient RF fields in the exposure chambers. RF sensors were calibrated twice by the manufacturer (SPEAG); once prior to initiation of any of the animal studies and once prior to initiation of the 2-year studies. All E-field probes were calibrated in air from 100 MHz to 3.0 GHz, and had an absolute accuracy of ± 6.0% (k=2) with a spherical isotropy of better than ± 0.4 dB. All H-field probes were calibrated in air from 200 MHz to 3.0 GHz and had an absolute accuracy of ± 6.0% (k=2) with a spherical isotropy of better than ± 0.2 dB. Placement of probes within the chambers is discussed in the video^g^ (day 1 a.m. at 1 hours, 31 minutes)^3^.

g https://doi.org/10.22427/NTP-VIDEO-41

Data collected by the RF sensors were transmitted to the exposure and monitoring system on a real-time basis and were recorded throughout the study. Chamber field strengths are reported as V/m and animal exposure levels (SAR values) are reported as W/kg. The chamber field strength is the average effective E-field strength from both probes. E-field and H-field strengths are related by the impedance of free space which is ~377 Ohms. Where an H-field probe was used, the value in A/m was multiplied by 377 to calculate the equivalent E-field strength in V/m; it is this effective E-field value that was used to report the chamber field strength. Field strength data reported for each day of exposure included mean ± standard deviation, minimum field strength, maximum field strength, total number of readings in range/total number of readings for the period, and percentage of readings in range. After each exposure day, RFR exposure data were downloaded onto DVDs for long-term archival. Summaries of the 2-year RFR exposure data from the studies are presented in Appendix I. The SAR and chamber-fields in the exposure chambers were within the target ranges (defined as ± 2 dB) for >99.85% of recorded measurements over the course of the 2-year study; ≥99.70% of recorded E-field and H-field measurements were within the target ranges for all but one chamber (97.35% within range). All recorded broadband field measurements (<40 MHz to >6 GHz) were below the limit of detection of the probes within the sham chamber showing that there was no significant confounding exposure. In the 28-day studies, the performance of the sham control and exposure chambers was similar for SAR and field measurements as in the 2-year studies (data not shown).

As previously stated, the performance of the RFR exposure and monitoring system was independently validated by engineers from the NIST prior to the initiation of the animal studies.

## Monitoring and Maintenance of Environmental Conditions

Environmental conditions including temperature, humidity, and airflow in all exposure chambers, as well as in other areas of the IITRI RFR exposure facility, were maintained by a computer-controlled environmental management system (Siemens Industries, Inc.). Monitoring instrumentation for each chamber was located in the air exhaust duct. Each chamber was fitted by the IT’IS Foundation with a sensor box that contained sensors for temperature and humidity (Type EE06; E + E Elektronik GmbH, Engerwitzdorf, Austria), oxygen level (Pewatron Type FCX-MC25; Zurich, Switzerland), air speed (model EE65A; E + E Elektronik GmbH), light (light-dependent resistor), noise (design based on WL-93 microphone; Shure Brothers, Inc., Evanston, IL), and RFR. Outputs from the sensor box were monitored using Agilent data acquisition units, with the exception of the RF sensor. The RF sensor was directly wired to a warning light as a safety precaution to indicate active RFR exposures and not intended to quantitatively measure RFR field strengths.

Exposure chambers were equipped with incandescent lights located on light bars in each corner of the chamber. All connections were RF-filtered. Chamber lighting was controlled using an adjustable daily cycle of 12 hours on, 12 hours off. In order to minimize the heat load generated by the incandescent lights, low wattage bulbs were used that maintained chamber lighting within a range that was sufficient to support normal in vivo operations, while minimally affecting chamber temperature. Further discussion of chamber lighting is found in the video^h^ (day 1 a.m. at 1 hours, 27 minutes)^3^.

h https://doi.org/10.22427/NTP-VIDEO-41

Differences in noise levels in the exposure chambers resulting from the heating, ventilation, and air conditioning system were equalized by the installation of sound baffles in various ducts within the system. An audible signal generated by the high intensity GSM signal was detected and equalized in all chambers by the introduction of a “pink noise” masking sound; this masking noise equalized sound levels in all chambers. As a result of the combination of these efforts, noise levels in all chambers were essentially equivalent at approximately 62 dBA, and met the NC-35 noise specification. The noise criterion (NC) is a widely accepted numerical index commonly used to define the maximum allowable noise. It primarily applies to the noise produced by ventilation systems, but is applied to other noise sources, as well. Standards organizations, such as the American National Standards Institute (ANSI), Acoustical Society of America (ASA), and International Standards Organization, provide definitions of various NCs for ambient noise in enclosed spaces. The ANSI/ASA standard (S12.2-2008) recommends NCs for various types of rooms, including private residences (NC 25-40), schools (NC 25-35), offices (NC 25-40), libraries (NC 30-35), and restaurants (NC 40-45). For further discussion of noise control in these studies see the video^8^ (day 1 a.m. at 2 hours, 0 minutes)^3^.

## Animal Source

Male and female B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY), for the 28-day and 2-year studies.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the IITRI Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Twenty-eight-day Studies

The 28-day studies were conducted to evaluate the cumulative effects of repeated GSM- or CDMA-modulated cell phone RFR exposure and to determine the appropriate RFR power levels to be used in the 2-year studies. The exposure levels in these studies were selected based on the findings of minimal increases in body temperature observed in 5-day studies at exposures up to 12 W/kg RFR^144^.

Groups of 10 male and 10 female mice were housed in reverberation chambers and received whole-body exposures to GSM- or CDMA-modulated cell phone RFR at power levels of 0 (sham control), 5, 10, or 15 W/kg, for 9 hours and 10 minutes per day for 5 or 7 (last week of study) days per week for at least 28 days with continuous cycling of 10 minutes on and 10 minutes off during a period of 18 hours and 20 minutes each day. The sham control animals were housed in a reverberation chamber identical to those used for the exposed groups, but they were not exposed to RFR; a shared group of unexposed mice of each sex served as sham controls for both RFR modulations.

Animals were observed twice daily and were weighed once during quarantine, initially, and weekly thereafter. Clinical signs were recorded once during quarantine and then weekly. In core study mice, subcutaneously implanted temperature microchips and monitoring equipment (Bio Medic Data Systems, Seaford, DE) were used to monitor individual animal body temperatures. Body temperature measurements were taken prior to initial exposure at the beginning of the study, on days 7 and 14 during inactive shutdown periods with no exposure, and on days 2, 4, 17, 20, and 27 within 5 minutes of exposure pauses at the end of the second to the last “on” cycle at the same time each day.

Mice were quarantined for 9 or 3 days (first and second shipment, respectively) before the beginning of the studies. Ten mice (two males and eight females) that were not assigned during randomization were selected for parasite evaluation and gross observation of disease. Mice were approximately 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K). All test results were negative.

Mice were housed individually. Feed and water were available ad libitum. To avoid interference with RFR dosimetry, feed was provided in ceramic (nonmetallic) bowls and water was delivered in an adapted automatic watering system^146^. Cages were changed weekly and rotated within the racks weekly; racks were changed biweekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix J.

Table 1 Experimental Design and Materials and Methods in the Whole-Body Exposure Studies of GSM- and CDMA-modulated Cell Phone RFR

Twenty-eight-day Studies | Two-year Studies
Study Laboratory
IIT Research Institute (Chicago, IL) | Same as 28-day studies
Strain and Species
B6C3F1/N mice | Same as 28-day studies
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Same as 28-day studies
Time Held Before Studies
9 and 3 days (first and second shipment, respectively) | 9 days
Average Age When Studies Began
Approximately 5 to 6 weeks | 5 to 6 weeks
Date of First Exposure
September 6, 2010 | June 18, 2012
Duration of Exposure
9 hours and 10 minutes per day, 7 days per week, over the course of 18 hours and 20 minutes, in 10-minute-on, 10-minute-off intervals for 28 days. | 9 hours and 10 minutes per day, 7 days per week, over the course of 18 hours and 20 minutes, in 10-minute-on, 10-minute-off intervals for 14 weeks (interim evaluation) or 106 (males) or 108 (females) weeks (2-year studies).
Date of Last Exposure
October 3 or 4, 2010 | Males: June 26, 2014 Females: July 9, 2014
Necropsy Dates
October 4 or 5, 2010 | Males: June 16 to 26, 2014 Females: June 26 to July 9, 2014
Age at Necropsy
Approximately 9 to 10 weeks | Males: 110 to 112 weeks Females: 111 to 114 weeks
Size of Study Groups
10 males and 10 females | Core study: 90 males and 90 females Interim evaluation: 10 male and 10 females Genetic toxicity: Five male and five females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 28-day studies
Animals per Cage
1 | Same as 28-day studies
Method of Animal Identification
Tail tattoo | Same as 28-day studies
Diet
Certified, irradiated NTP-2000 rodent diet wafer (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, ceramic feed bowls changed weekly | Same as 28-day studies
Water
Tap water (Chicago municipal supply) via an adapted automatic watering system (SE Lab Group, Cincinnati, OH), available ad libitum | Same as 28-day studies
Cages
Polycarbonate, solid bottom “shoebox” cages (Allentown Caging, Allentown, NJ), changed and rotated within the rack weekly | Same as 28-day studies, except changed weekly and rotated within the rack biweekly
Bedding
Certified, irradiated hardwood bedding (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly | Same as 28-day studies
Racks
Custom-designed fiberglass cage racks (Ultra, Inc., Milwaukee, WI), changed biweekly | Same as 28-day studies
Reverberation Chambers
Fully-shielded, stainless steel room equipped with a stainless steel door to eliminate leakage of RFR signals, RFR excitation antennas, and two rotating stirrers; chambers were cleaned at least once weekly. | Same as 28-day studies
Reverberation Chamber Environment
Temperature: 72° ± 3° F Relative humidity: 50% ± 15% Room incandescent light: 12 hours/day Chamber air changes: at least 10/hour | Same as 28-day studies
Exposure Concentrations
Time-averaged whole-body SARs of 0 (sham control), 5, 10, and 15 W/kg GSM- or CDMA-modulated cell phone RFR | Time-averaged whole-body SARs of 0 (sham control), 2.5, 5, and 10 W/kg GSM- or CDMA-modulated cell phone RFR
Type and Frequency of Observation
Observed twice daily; animals were weighed once during quarantine, initially, and weekly thereafter. Clinical signs were recorded once during quarantine and then weekly. Body temperature measurements were taken on core study mice prior to initial exposure at the beginning of the study, on days 7 and 14 during inactive exposures, and on days 2, 4, 17, 20, and 27 within 5 minutes of exposure pauses at the end of the second to the last “on” cycle. | Observed twice daily; animals were weighed initially, weekly for the first 14 weeks, at 4-week intervals during weeks 14 to 86, and then every 2 weeks from week 90 until the end of the studies. Clinical signs were recorded once during quarantine and at least once every 4 weeks during the studies.
Method of Euthanasia
Carbon dioxide asphyxiation | Same as 28-day studies
Necropsy
Necropsies were performed on all core study mice on day 29 or 30. Organs weighed were the right adrenal gland, brain, heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all mice. Organs weighed in 10 mice per exposure group at 14 weeks were the brain, heart, kidneys (right and left), liver, lung, ovaries (right and left), testes (right and left) with epididymides (right and left), and thymus.
Clinical Pathology
None | Blood was collected from the retroorbital sinus of 10 mice per group at 14 weeks for hematology. Hematology: hematocrit (auto and manual); hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; erythrocyte, leukocyte, and platelet morphology; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials
Histopathology
Complete histopathology was performed on all 0 (sham control) and 15 W/kg groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, aorta, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, muscle, nerve (sciatic), nose, oral cavity, ovary, pancreas, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spinal cord, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, tongue, trachea, urinary bladder, and uterus. | Complete histopathology was performed on 10 mice from each group at 14 weeks, on all mice that died early, and on all mice surviving to the end of the studies. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, aorta, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung with bronchi, lymph nodes (mandibular and mesenteric), mammary gland, muscle, nerve (sciatic, trigeminal, and ganglion), nose, ovary, pancreas, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spinal cord, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Count and Vaginal Cytology
None | Spermatid and sperm samples were collected from 10 male mice in each group at 14 weeks. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected from 10 females in each group for 15 or 16 days prior to the 14-week interim evaluation.

Necropsies were performed on all core study mice on day 29 or 30. Organs weighed were the right adrenal gland, brain, heart, right kidney, liver, lung, right testis, and thymus. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, testis with epididymis, and vaginal tunics were first fixed in Davidson’s solution or modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on all 0 (sham control) and 15 W/kg GSM- and 15 W/kg CDMA-modulated cell phone RFR core study mice. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist (QAP), the findings and differences of opinions between the study pathologist (SP) and the QAP were reviewed by the NTP pathologist. Slides containing representative lesions of exposure-related lesions or differences of opinions between pathologists were brought to a Pathology Peer Review (PPR). A pathology peer review typically consists of a small group (three to eight) of pathologists who examine the lesions around a multiheaded microscope. It is frequently used to review lesions in short term studies, issues of terminology, or examine single issues that have arisen during a pathology working group (PWG – see below). Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologist, NTP pathologist, and the QAP(s). Details of these review procedures have been described, in part, by Maronpot and Boorman^147^ and Boorman et al.^148^.

A further discussion of pathology review procedures is found in the video^i^ (day 2 a.m. at 1 hours, 0 minutes)^3^.

i https://doi.org/10.22427/NTP-VIDEO-43

## Two-year Studies

### Study Design

Groups of 105 male and 105 female mice were housed in reverberation chambers and received whole-body exposures to GSM- or CDMA-modulated cell phone RFR at power levels of 0 (sham control), 2.5, 5, or 10 W/kg, 9 hours and 10 minutes per day, 7 days per week for 106 (males) or 108 (females) weeks with continuous cycling of 10 minutes on and 10 minutes off during a period of 18 hours and 20 minutes each day. The sham control animals were housed in reverberation chambers identical to those used for the exposed groups, but were not exposed to RFR; shared groups of unexposed mice of each sex served as sham controls for both RFR modulations. Fifteen mice per group were randomly selected from the core group after 10 weeks of study; ten mice per group were randomly selected for interim evaluation at 14 weeks, and five mice per group were used for genetic toxicity testing at 14 weeks.

Mice were quarantined for 9 days before the beginning of the studies. An additional five male and five female mice not assigned during randomization were selected for parasite evaluation and gross observation of disease. Mice were approximately 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K). All test results were negative.

Mice were housed individually. Feed and water were available ad libitum. To avoid interference with RFR dosimetry, feed was provided in ceramic (nonmetallic) bowls and water was delivered in an adapted automatic watering system (see video^j^, day 1 a.m. at 2 hours, 5 minutes)^3; 146^. Cages were changed weekly and rotated within the racks biweekly; racks were changed biweekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix J.

j https://doi.org/10.22427/NTP-VIDEO-41

### Clinical Examinations and Pathology

Animals were observed twice daily and were weighed initially, weekly for the first 14 weeks, at 4-week intervals during weeks 14 to 86, and then every 2 weeks from week 90 until the end of the studies. Clinical signs were recorded once during quarantine and at least every 4 weeks during the studies.

Hematology evaluations were performed on 10 male and 10 female interim evaluation mice from each group at 14 weeks. Mice were anesthetized with 70% CO_2_/30% O_2_ and blood was collected from the retroorbital sinus and placed into tubes containing EDTA as an anticoagulant. Hematology parameters were determined on an ADVIA^™^ 120 automated hematology analyzer (Bayer Diagnostic Division, Tarrytown, NY). The parameters measured are listed in Table 1. Wright Giemsa stained peripheral blood smears were prepared and evaluated for any blood cell abnormalities. Blood was collected from the remaining five male and five female interim evaluation mice per exposure group at 14 weeks for use in the comet and micronucleus assays; methods for these assays are presented in Appendix E.

At 14 weeks, samples were collected for sperm motility and count and vaginal cytology evaluations on 10 male and 10 female interim evaluation mice from each group. The parameters evaluated are listed in Table 1. For 15 or 16 consecutive days prior to scheduled euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Modified Tyrode’s buffer was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

All mice were necropsied. The cerebrum, frontal cortex, hippocampus, and liver were collected from five male and five female interim sacrifice animals per exposure group at 14 weeks for use in the comet assay; methods for this assay are presented in Appendix E. Microscopic examinations were performed on 10 male and 10 female interim evaluation mice in each group at 14 weeks and all core study mice, including those found dead or euthanized moribund. At the interim evaluation, the brain, right and left epididymides, heart, right and left kidneys, liver, lung, right and left ovaries, right and left testes, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory and NTP PPR. All data and materials are available for review upon request from the NTP Archives.

## NTP Pathology Review Process

Typically, the initial reading of the slides and the first steps of the pathology review are done by an open, or non-blinded, evaluation by the pathologists involved. This is standard practice for NTP, as well as the toxicologic pathology industry as a whole, and is in accordance with the recommendations of the Society of Toxicologic Pathologists^149-154^. If issues arise where subtle lesions need to be identified or graded by a blinded evaluation, the pathologist will perform this.

The primary goals of the NTP pathology review are to reach consensus agreement on the diagnosis of all potentially treatment-related findings, confirm the diagnoses of all neoplasms, confirm that consistent and acceptable nomenclature is being used, and confirm the diagnosis of any unusual lesions. There are several elements in this process:

Pathology Data Review (PDR) is a complete review of the pathology data generated by the study laboratory to identify potential target organs and discrepant data and to harmonize terminology. The review involves a multidisciplinary meeting by the NTP staff and pathology support-contract pathologists to determine the organs and lesions to be reviewed by the quality assessment pathologist (QAP), including all neoplasms.

Audit of Pathology Specimens (APS) is a review of the physical data and residual wet tissues (typically from 10% of the animals) to ensure all gross lesions were evaluated microscopically; of the slides and blocks (typically from 10% of the animals) to ensure correct labeling and quality of sections; and of the submitted reports to ensure accuracy. Also evaluated is whether or not the study laboratory adhered to NTP pathology specifications.

Quality Assessment is a review of the slides of target organs and lesions identified in the PDR by a pathologist from one of NTP’s pathology support contract laboratories not involved with the initial pathology evaluation of the study. For the 2-year mouse RFR studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the brain, spinal cord, heart, and kidney. In addition, the liver, large intestine (cecum and colon), small intestine (duodenum, jejunum, and ileum), lung, testis, urinary bladder, and Harderian gland were reviewed from all male mice for specific lesions; and the bronchial and mesenteric lymph nodes, spleen, ovary, urinary bladder, Harderian gland, and thyroid gland were reviewed from all female mice for specific lesions. All differences in diagnoses between the study pathologist (SP) and QAP are identified in the Differences Report prepared by the QAP. The NTP pathologist attempts to resolve the discrepant diagnoses between the SP and QAP; those that are not resolved are reviewed by the pathology working group (PWG).

Pathology Working Group is a review of selected slides by a panel of pathologists in order to confirm the diagnoses of all treatment-related neoplastic and nonneoplastic lesions and unusual lesions, resolve discrepancies between the SP, QAP, and NTP pathologist, harmonize nomenclature, propose further characterization of the lesions, and address possible mechanisms. The QAP, with oversight from the NTP pathologist, selects slides for the PWG and conducts the PWG. Typically, experts in a particular organ of interest are invited to participate.

A Pathology Peer Review (PPR) is a peer review meeting that convenes to resolve minor issues or issues limited in scope (such as review of short-term studies with limited findings), or review findings of post-PWG actions. Reports are prepared for all these activities. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, QA pathologist(s), and the PWG.

Once the PWG and/or PPR is complete, all written documentation of data changes is reviewed for accuracy and the study data are updated. The pathology data and all written documentation of data changes are then submitted to an outside independent auditor to ensure the accuracy of the updated data. Once all issues identified by the independent auditor have been addressed, the final pathology data tables are generated. For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of Brix et al.^155^.

## Statistical Methods

For all analyses, P values less than 0.05 were considered statistically significant. Statistical significance is one component of the “weight of evidence” approach to evaluate carcinogenicity (described in Explanation of Levels of Evidence of Carcinogenic Activity).

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^156^ and is presented in the form of graphs. Animals found dead of other than natural causes or missing were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^157^ method for testing two groups for equality and Tarone’s^158^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-5, Table B-1, Table B-4, Table C-1, Table C-4, Table D-1, and Table D-4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^159-161^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died prior to terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time^159^. Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^159^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F1 mice^162^. Bailer and Portier^159^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams^163^.

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N). For neoplasms and nonneoplastic lesions detected at the interim evaluation, the Fisher exact test^164^, a procedure based on the overall proportion of affected animals, was used.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions and body temperatures, were analyzed with the parametric multiple comparison procedures of Dunnett^165^ and Williams^166; 167^. Hematology, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^168^ (as modified by Williams^169^) and Dunn^170^. Jonckheere’s test^171^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^172^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager^173^. For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics. P values for these analyses are two-sided.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^174-176^. In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison. Because the two mouse studies presented in this report are the only two using this whole-body exposure method, only the overall incidences for all routes are included. A list of the specific NTP studies included in this database and a summary of the historical control data for the lesions of interest are presented in the Appendices (Table A-3, Table B-3, Table C-3, Table D-3).

## Quality Assurance Methods

The 28-day and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations^177^. In addition, the 28-day and 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of GSM- and CDMA-modulated RFR was assessed by measuring the frequency of micronucleated erythrocytes in peripheral blood and DNA damage in five different tissues of male and female mice following 14 weeks of exposure. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division^178; 179^. The alkaline (pH>13) comet assay^180^ (also known as the single cell gel electrophoresis assay) detects DNA damage in any of a variety of eukaryotic cell types^181-184^; cell division is not required. The type of DNA damage detected includes nicks, adducts, strand breaks, and abasic sites that are converted to DNA strand breaks after treatment of cells in an alkaline (pH>13) solution. Transient DNA strand breaks generated by the process of DNA excision repair may also be detected. DNA damage caused by crosslinking agents has been detected as a reduction of DNA migration^185; 186^. The fate of the DNA damage detected by the comet assay is varied; most of the damage is rapidly repaired resulting in no sustained impact on the tissue but some may result in cell death or may be incorrectly processed by the repair proteins and result in a fixed mutation or chromosomal alteration. The detailed protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have grown out of an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a test article’s carcinogenicity in experimental animals based on the results from a number of in vitro and in vivo short-term tests measuring functionally distinct genotoxicity endpoints. The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^187^ and the somatic mutation theory of cancer^188; 189^. However, it should be noted that not all cancers arise through genotoxic mechanisms, and in these studies, the test article is not a chemical. Many studies have established the genotoxicity of some forms of radiation including, for example, ultraviolet radiation and X-ray radiation, which are both forms of ionizing radiation. Because exposure to RFR requires specialized and highly technical exposure protocols, only in vivo biomarkers associated with genotoxicity could be investigated.

Clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies^190^. The relationship between comet assay results and rodent carcinogenicity was investigated previously and a close association was observed^191^; however, this assay is best employed as a hazard identification assay. Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular test article.

Further discussion of the genetic toxicology assays used in these studies can be found in the video^k^ (day 2 a.m. at 2 hours, 48 minutes)^3^.

k https://doi.org/10.22427/NTP-VIDEO-43