# Appendix K Sentinel Animal Program

## K.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test agents. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test agents.

Blood samples were collected and allowed to clot, and the serum was separated. All samples were processed appropriately with serology testing performed by IDEXX BioResearch [formerly Research Animal Diagnostic Laboratory (RADIL), University of Missouri, Columbia, MO] for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five mice per sex per time point except for the following:

- 28-day studies, study termination collection: Two males and eight females
- 2-year studies, study termination collection: 10 males and 10 females

Table K-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
28-day Studies
Multiplex Fluorescent Immunoassay
Ectromelia virus | Study termination
EDIM (epizootic diarrhea of infant mice) | Study termination
LCMV (lymphocytic choriomeningitis virus) | Study termination
Mycoplasma pulmonis | Study termination
MHV (mouse hepatitis virus) | Study termination
MNV (mouse norovirus) | Study termination
MPV (mouse parvovirus) | Study termination
MVM (minute virus of mice) | Study termination
PVM (pneumonia virus of mice) | Study termination
REO3 (reovirus) | Study termination
Sendai | Study termination
TMEV (Theiler’s murine encephalomyelitis virus) | Study termination
Two-Year Studies
Multiplex Fluorescent Immunoassay
Ectromelia virus | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
EDIM | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
LCMV | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
M. pulmonis | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
MHV | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
MNV | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
MPV | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
MVM | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
PVM | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
REO3 | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
Sendai | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
TMEV | End of quarantine, 4 weeks, 6, 12, and 18 months, study termination
Immunofluorescence Assay
MNV | Study termination
Polymerase Chain Reaction
Helicobacter species | 18 months

## K.2 Results

All test results were negative.