# Appendix I GSM- and CDMA-modulated Cell Phone RFR Exposure Data

Exposure data include SAR (W/kg) (Table I-1, Table I-5), chamber field strength (V/m) (Tables I2 and I6), and E- and H-field measurements (V/m) (Table I-3, Table I-4, Table I-7, Table I-8). For the medium and high dose GSM chambers, where a second E-field probe was used, the H-field measurements were converted from E-field measurements (E-field divided by 377). Fields were measured continuously throughout the study and measurements were automatically recorded approximately every 20 seconds. For every 20-second interval, the SAR was calculated based on the average H- and/or E-field data. The data presented for each exposure parameter include the mean and standard deviation [expressed in decibels (dB), W/kg, or V/m]; the total number of measurements recorded during the identified period of exposure (>44,000 calculated SAR per month and more than 1.1 million over the course of the 2-year study); the lowest (min) and highest (max) measurement recorded during the given exposure period; the number of measurements that were within the acceptable range; and the ratio of all measurements within range. The data reported for SAR also include the range of animal body weights (g) over the indicated time period of exposure, as well as the selected target SAR for each group. The data reported for field strengths (chamber, E-field, and H-field) include the target range of the field required to maintain appropriate SAR exposures. The minimum and maximum exposure values reported represent a single recorded measurement over the 2-year exposure period. The SAR and chamber-field in the sham and exposure chambers were within the target ranges (defined as ± 2 dB) for >99.85% of recorded measurements over the course of the 2-year study; ≥99.70% of E-field and H-field exposures in the sham and exposure chambers were within the target ranges for all but one chamber (97.35% within range).

The dB is a mathematical transformation of a number or numerical ratio using base 10 logarithms. Multiplication of ratios is transformed into addition of dBs; raising a number to a power is transformed into multiplication of dBs.

In general, dB(power) = 10 × log(R), and dB(field) = 20 × log(R). The formulas differ by a factor of two because power or SAR varies as the square of the fields. For SAR (in watts/kg), the decibel formula is calculated as:

SAR(dB) = 10 × log(SAR_M_/SAR_T_)

where SAR_M_ is the measured value and SAR_T_ is the target value, and

–2 dB = 10 × log(SARL/SART), where SARL (low) = SART × 10–0.2

+2 dB = 10 × log(SARH/SART), where SARH (high) = SART × 100.2

On this basis, the ± 2 dB range specified by NTP translates to the following ranges for each SAR used in the 2-year study:

Target SAR (W/kg): Acceptable SAR Range (W/kg; ± 2 dB)

2.5: 1.58 to 3.96

5: 3.15 to 7.92

10: 6.31 to 15.85

Table I-1 Summary of GSM-modulated Cell Phone RFR Exposure Data—SAR^a^

Chamber | Weight Range [g] | Target [W/kg] | Mean [W/kg] | Stdev [dB]/[W/kg] | Min [W/kg] | Max [W/kg] | In Range/ Total | Ratio
June 18 to 30, 2012
Ch11 Mouse GSM High | 18.9 to 20.2 | 10.00 | 10.08 | 0.23/0.05 | 3.944 | 23.576 | 19472/19475 | 1.000
Ch12 Mouse GSM Med | 18.9 to 20.2 | 5.00 | 5.04 | 0.21/0.05 | 2.105 | 11.918 | 19472/19475 | 1.000
Ch14 Mouse GSM Low | 18.8 to 20.2 | 2.50 | 2.51 | 0.20/0.05 | 1.948 | 3.175 | 19475/19475 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 19475/19475 | 1.000
July 1 to 31, 2012
Ch11 Mouse GSM High | 20.2 to 24.1 | 10.00 | 10.01 | 0.23/0.05 | 7.430 | 13.279 | 48731/48731 | 1.000
Ch12 Mouse GSM Med | 20.2 to 24.6 | 5.00 | 5.01 | 0.21/0.05 | 3.349 | 7.170 | 48731/48731 | 1.000
Ch14 Mouse GSM Low | 20.2 to 24.5 | 2.50 | 2.50 | 0.18/0.04 | 2.103 | 3.135 | 48731/48731 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48731/48731 | 1.000
August 1 to 31, 2012
Ch11 Mouse GSM High | 24.1 to 27.5 | 10.00 | 10.02 | 0.20/0.05 | 6.893 | 13.910 | 47488/47488 | 1.000
Ch12 Mouse GSM Med | 24.6 to 27.9 | 5.00 | 5.03 | 0.20/0.05 | 3.911 | 6.803 | 47488/47488 | 1.000
Ch14 Mouse GSM Low | 24.5 to 27.2 | 2.50 | 2.50 | 0.18/0.04 | 1.900 | 3.441 | 47488/47488 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 47488/47488 | 1.000
September 1 to 30, 2012
Ch11 Mouse GSM High | 27.5 to 29.3 | 10.00 | 10.01 | 0.21/0.05 | 5.187 | 12.693 | 47186/47187 | 1.000
Ch12 Mouse GSM Med | 27.9 to 30.0 | 5.00 | 5.01 | 0.19/0.04 | 2.558 | 6.280 | 47184/47185 | 1.000
Ch14 Mouse GSM Low | 27.2 to 29.2 | 2.50 | 2.51 | 0.18/0.04 | 1.444 | 3.129 | 47184/47185 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 47185/47185 | 1.000
October 1 to 31, 2012
Ch11 Mouse GSM High | 29.3 to 32.9 | 10.00 | 10.02 | 0.19/0.05 | 3.290 | 12.620 | 48801/48802 | 1.000
Ch12 Mouse GSM Med | 30.0 to 33.8 | 5.00 | 5.02 | 0.18/0.04 | 3.828 | 6.511 | 48801/48801 | 1.000
Ch14 Mouse GSM Low | 29.2 to 32.7 | 2.50 | 2.51 | 0.17/0.04 | 2.017 | 3.080 | 48801/48801 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48801/48801 | 1.000
November 1 to 30, 2012
Ch11 Mouse GSM High | 32.9 to 36.6 | 10.00 | 10.03 | 0.19/0.04 | 7.649 | 13.824 | 47314/47314 | 1.000
Ch12 Mouse GSM Med | 33.8 to 36.4 | 5.00 | 5.02 | 0.17/0.04 | 3.724 | 6.537 | 47314/47314 | 1.000
Ch14 Mouse GSM Low | 32.7 to 35.8 | 2.50 | 2.51 | 0.17/0.04 | 2.054 | 3.110 | 47314/47314 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 47314/47314 | 1.000
December 1 to 31, 2012
Ch11 Mouse GSM High | 36.6 to 39.1 | 10.00 | 10.07 | 0.20/0.05 | 7.992 | 12.863 | 48750/48750 | 1.000
Ch12 Mouse GSM Med | 36.4 to 39.2 | 5.00 | 5.04 | 0.18/0.04 | 4.145 | 6.028 | 48748/48748 | 1.000
Ch14 Mouse GSM Low | 35.8 to 38.1 | 2.50 | 2.52 | 0.17/0.04 | 2.139 | 3.109 | 48748/48748 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48748/48748 | 1.000
January 1 to 31, 2013
Ch11 Mouse GSM High | 39.1 to 41.1 | 10.00 | 9.78 | 0.30/0.07 | 7.230 | 13.516 | 48689/48689 | 1.000
Ch12 Mouse GSM Med | 39.2 to 41.6 | 5.00 | 5.02 | 0.20/0.05 | 3.121 | 7.619 | 48681/48682 | 1.000
Ch14 Mouse GSM Low | 38.1 to 40.6 | 2.50 | 2.51 | 0.17/0.04 | 2.037 | 2.987 | 48682/48682 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48682/48682 | 1.000
February 1 to 28, 2013
Ch11 Mouse GSM High | 41.1 to 42.9 | 10.00 | 8.23 | 0.22/0.05 | 6.187 | 10.364 | 44057/44058 | 1.000
Ch12 Mouse GSM Med | 41.6 to 43.5 | 5.00 | 5.02 | 0.17/0.04 | 3.872 | 5.967 | 44058/44058 | 1.000
Ch14 Mouse GSM Low | 40.6 to 42.2 | 2.50 | 2.52 | 0.17/0.04 | 1.851 | 3.048 | 44058/44058 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 44058/44058 | 1.000
March 1 to 31, 2013
Ch11 Mouse GSM High | 42.9 to 44.4 | 10.00 | 8.25 | 0.24/0.06 | 6.753 | 10.627 | 48892/48892 | 1.000
Ch12 Mouse GSM Med | 43.5 to 44.7 | 5.00 | 5.04 | 0.17/0.04 | 4.276 | 5.871 | 48892/48892 | 1.000
Ch14 Mouse GSM Low | 42.2 to 43.4 | 2.50 | 2.51 | 0.17/0.04 | 2.143 | 2.943 | 48892/48892 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48892/48892 | 1.000
April 1 to 30, 2013
Ch11 Mouse GSM High | 44.4 to 46.8 | 10.00 | 7.95 | 0.20/0.05 | 6.370 | 9.872 | 48130/48130 | 1.000
Ch12 Mouse GSM Med | 44.7 to 47.3 | 5.00 | 5.02 | 0.17/0.04 | 4.113 | 5.862 | 48130/48130 | 1.000
Ch14 Mouse GSM Low | 43.4 to 46.0 | 2.50 | 2.52 | 0.16/0.04 | 2.214 | 2.995 | 48130/48130 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48130/48130 | 1.000
May 1 to 31, 2013
Ch11 Mouse GSM High | 46.8 to 47.9 | 10.00 | 7.94 | 0.19/0.04 | 5.057 | 9.940 | 48509/48510 | 1.000
Ch12 Mouse GSM Med | 47.3 to 48.7 | 5.00 | 5.01 | 0.17/0.04 | 3.264 | 7.176 | 48510/48510 | 1.000
Ch14 Mouse GSM Low | 46.0 to 47.5 | 2.50 | 2.51 | 0.17/0.04 | 1.809 | 2.957 | 48510/48510 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48510/48510 | 1.000
June 1 to 30, 2013
Ch11 Mouse GSM High | 47.9 to 49.2 | 10.00 | 7.44 | 0.17/0.04 | 6.134 | 9.224 | 47246/47248 | 1.000
Ch12 Mouse GSM Med | 48.7 to 49.9 | 5.00 | 5.01 | 0.17/0.04 | 4.185 | 5.911 | 47248/47248 | 1.000
Ch14 Mouse GSM Low | 47.5 to 49.0 | 2.50 | 2.50 | 0.16/0.04 | 1.964 | 2.923 | 47248/47248 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 47248/47248 | 1.000
July 1 to 31, 2013
Ch11 Mouse GSM High | 49.2 to 50.5 | 10.00 | 8.02 | 0.26/0.06 | 5.376 | 10.141 | 49496/49573 | 0.998
Ch12 Mouse GSM Med | 49.9 to 51.5 | 5.00 | 5.01 | 0.17/0.04 | 3.448 | 5.910 | 49573/49573 | 1.000
Ch14 Mouse GSM Low | 49.0 to 50.2 | 2.50 | 2.51 | 0.17/0.04 | 1.876 | 2.915 | 49573/49573 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 49573/49573 | 1.000
August 1 to 31, 2013
Ch11 Mouse GSM High | 50.5 to 51.3 | 10.00 | 8.33 | 0.22/0.05 | 6.666 | 10.172 | 50850/50850 | 1.000
Ch12 Mouse GSM Med | 51.5 to 52.5 | 5.00 | 4.99 | 0.18/0.04 | 4.182 | 6.536 | 50850/50850 | 1.000
Ch14 Mouse GSM Low | 50.2 to 51.3 | 2.50 | 2.50 | 0.17/0.04 | 2.065 | 3.317 | 50850/50850 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 50850/50850 | 1.000
September 1 to 30, 2013
Ch11 Mouse GSM High | 51.3 to 52.0 | 10.95 | 9.88 | 0.40/0.10 | 3.473 | 14.080 | 46959/46961 | 1.000
Ch12 Mouse GSM Med | 52.5 to 53.2 | 5.00 | 5.01 | 0.18/0.04 | 4.292 | 5.988 | 46960/46960 | 1.000
Ch14 Mouse GSM Low | 51.3 to 52.2 | 2.50 | 2.50 | 0.17/0.04 | 1.329 | 2.996 | 46956/46960 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 46960/46960 | 1.000
October 1 to 31, 2013
Ch11 Mouse GSM High | 52.0 to 53.3 | 10.95 | 10.83 | 0.22/0.05 | 6.969 | 14.792 | 50408/50408 | 1.000
Ch12 Mouse GSM Med | 53.2 to 54.0 | 5.00 | 5.01 | 0.19/0.04 | 3.215 | 5.974 | 50408/50408 | 1.000
Ch14 Mouse GSM Low | 52.2 to 53.0 | 2.50 | 2.50 | 0.16/0.04 | 1.669 | 3.009 | 50408/50408 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 50408/50408 | 1.000
November 1 to 30, 2013
Ch11 Mouse GSM High | 52.4 to 53.3 | 10.95 | 9.54 | 0.35/0.08 | 5.677 | 13.090 | 46609/46613 | 1.000
Ch12 Mouse GSM Med | 53.1 to 54.0 | 5.00 | 4.96 | 0.24/0.06 | 2.923 | 7.086 | 46612/46613 | 1.000
Ch14 Mouse GSM Low | 52.4 to 53.0 | 2.50 | 2.50 | 0.19/0.05 | 1.629 | 2.955 | 46613/46613 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 46613/46613 | 1.000
December 1 to 31, 2013
Ch11 Mouse GSM High | 51.4 to 52.4 | 10.95 | 10.22 | 0.36/0.09 | 7.156 | 13.073 | 48423/48423 | 1.000
Ch12 Mouse GSM Med | 51.9 to 53.1 | 5.00 | 4.96 | 0.21/0.05 | 3.618 | 7.513 | 48423/48423 | 1.000
Ch14 Mouse GSM Low | 51.1 to 52.4 | 2.50 | 2.50 | 0.18/0.04 | 1.475 | 4.060 | 48421/48423 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48423/48423 | 1.000
January 1 to 31, 2014
Ch11 Mouse GSM High | 51.4 to 52.1 | 10.95 | 10.08 | 0.27/0.06 | 6.308 | 13.144 | 48774/48775 | 1.000
Ch12 Mouse GSM Med | 51.9 to 52.7 | 5.00 | 5.00 | 0.20/0.05 | 3.593 | 6.330 | 48775/48775 | 1.000
Ch14 Mouse GSM Low | 51.1 to 51.6 | 2.50 | 2.50 | 0.18/0.04 | 0.472 | 3.843 | 48772/48775 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48775/48775 | 1.000
February 1 to 28, 2014
Ch11 Mouse GSM High | 52.1 to 53.2 | 10.95 | 10.92 | 0.24/0.06 | 8.258 | 15.024 | 44092/44092 | 1.000
Ch12 Mouse GSM Med | 52.7 to 53.6 | 5.00 | 4.59 | 0.41/0.10 | 2.273 | 6.443 | 43990/44092 | 0.998
Ch14 Mouse GSM Low | 51.6 to 53.1 | 2.50 | 2.50 | 0.18/0.04 | 1.622 | 3.807 | 44092/44092 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 44092/44092 | 1.000
March 1 to 31, 2014
Ch11 Mouse GSM High | 52.8 to 53.8 | 10.95 | 10.27 | 0.43/0.10 | 6.995 | 15.483 | 48571/48571 | 1.000
Ch12 Mouse GSM Med | 53.3 to 53.8 | 5.00 | 4.56 | 0.60/0.15 | 2.706 | 6.677 | 47927/48571 | 0.987
Ch14 Mouse GSM Low | 52.8 to 53.3 | 2.50 | 2.51 | 0.16/0.04 | 1.877 | 3.110 | 48571/48571 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48571/48571 | 1.000
April 1 to 30, 2014
Ch11 Mouse GSM High | 51.5 to 52.3 | 10.95 | 10.73 | 0.41/0.10 | 7.050 | 14.898 | 47274/47274 | 1.000
Ch12 Mouse GSM Med | 53.0 to 53.4 | 5.00 | 4.92 | 0.66/0.16 | 2.581 | 8.007 | 46546/47274 | 0.985
Ch14 Mouse GSM Low | 51.9 to 52.3 | 2.50 | 2.50 | 0.15/0.03 | 1.868 | 2.893 | 47274/47274 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 47274/47274 | 1.000
May 1 to 31, 2014
Ch11 Mouse GSM High | 50.5 to 51.5 | 10.95 | 10.95 | 0.22/0.05 | 6.826 | 14.016 | 48620/48622 | 1.000
Ch12 Mouse GSM Med | 51.3 to 53.0 | 5.00 | 5.00 | 0.22/0.05 | 2.622 | 7.487 | 48550/48622 | 0.999
Ch14 Mouse GSM Low | 51.2 to 51.9 | 2.50 | 2.50 | 0.15/0.03 | 2.188 | 2.921 | 48622/48622 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 48622/48622 | 1.000
June 1 to 30, 2014
Ch11 Mouse GSM High | 49.4 to 50.5 | 10.95 | 10.97 | 0.20/0.05 | 8.188 | 13.942 | 47144/47144 | 1.000
Ch12 Mouse GSM Med | 50.8 to 51.3 | 5.00 | 5.01 | 0.16/0.04 | 3.005 | 5.830 | 47142/47144 | 1.000
Ch14 Mouse GSM Low | 50.2 to 51.2 | 2.50 | 2.51 | 0.15/0.03 | 2.153 | 2.870 | 47144/47144 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 47144/47144 | 1.000
July 1 to 9, 2014
Ch11 Mouse GSM High | 49.4 to 49.4 | 10.95 | 11.08 | 0.19/0.04 | 8.839 | 13.746 | 12532/12532 | 1.000
Ch12 Mouse GSM Med | 50.8 to 50.8 | 5.00 | 5.02 | 0.15/0.04 | 4.488 | 5.844 | 12532/12532 | 1.000
Ch14 Mouse GSM Low | 50.2 to 50.2 | 2.50 | 2.51 | 0.17/0.04 | 1.995 | 3.111 | 12532/12532 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 12532/12532 | 1.000
June 18, 2012, to July 9, 2014
Ch11 Mouse GSM High | 18.9 to 53.8 | 10.95 | 9.56 | 0.44/0.11 | 3.290 | 23.576 | 1136126/ 1136221 | 1.000
Ch12 Mouse GSM Med | 18.9 to 54.0 | 5.00 | 4.97 | 0.29/0.07 | 2.105 | 11.918 | 1134656/ 1136208 | 0.999
Ch14 Mouse GSM Low | 18.8 to 53.3 | 2.50 | 2.51 | 0.17/0.04 | 0.472 | 4.060 | 1136198/ 1136208 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | 0.000 | 1136208/ 1136208 | 1.000

^a^ Ch = chamber (e.g., Ch11 = Chamber 11).

Table I-2 Summary of GSM-modulated Cell Phone RFR Exposure Data—Chamber Field^a^

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | Max [V/m] | In Range/ Total | | Ratio
June 18 to 30, 2012
Ch11 Mouse GSM High | 194.10 to 199.60 | 197.33 | 0.23/5.27 | 121.76 | 297.71 | 38944/38950 | | 1.000
Ch12 Mouse GSM Med | 137.20 to 141.20 | 139.51 | 0.21/3.45 | 88.97 | 211.67 | 38944/38950 | | 1.000
Ch14 Mouse GSM Low | 97.00 to 99.80 | 98.42 | 0.20/2.26 | 88.09 | 109.25 | 38950/38950 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 38950/38950 | | 1.000
July 1 to 31, 2012
Ch11 Mouse GSM High | 199.60 to 212.30 | 205.98 | 0.23/5.60 | 180.13 | 237.61 | 97462/97462 | | 1.000
Ch12 Mouse GSM Med | 141.20 to 150.10 | 145.84 | 0.21/3.55 | 119.12 | 174.30 | 97462/97462 | | 1.000
Ch14 Mouse GSM Low | 99.80 to 106.10 | 103.40 | 0.18/2.22 | 92.84 | 116.92 | 97462/97462 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97462/97462 | | 1.000
August 1 to 31, 2012
Ch11 Mouse GSM High | 212.30 to 222.20 | 216.19 | 0.20/5.04 | 181.61 | 257.98 | 94976/94976 | | 1.000
Ch12 Mouse GSM Med | 150.10 to 157.10 | 154.16 | 0.20/3.67 | 136.80 | 180.42 | 94976/94976 | | 1.000
Ch14 Mouse GSM Low | 106.10 to 111.10 | 108.48 | 0.18/2.26 | 95.61 | 130.19 | 94976/94976 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94976/94976 | | 1.000
September 1 to 30, 2012
Ch11 Mouse GSM High | 222.20 to 228.20 | 226.30 | 0.21/5.48 | 162.27 | 251.45 | 94372/94374 | | 1.000
Ch12 Mouse GSM Med | 157.10 to 161.40 | 160.65 | 0.19/3.49 | 115.42 | 179.26 | 94368/94370 | | 1.000
Ch14 Mouse GSM Low | 111.10 to 114.10 | 112.89 | 0.18/2.35 | 85.61 | 126.49 | 94368/94370 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94370/94370 | | 1.000
October 1 to 31, 2012
Ch11 Mouse GSM High | 228.20 to 235.60 | 232.23 | 0.20/5.31 | 135.19 | 264.78 | 97602/97602 | | 1.000
Ch12 Mouse GSM Med | 161.40 to 168.00 | 165.17 | 0.18/3.51 | 141.20 | 191.80 | 97602/97602 | | 1.000
Ch14 Mouse GSM Low | 114.10 to 117.80 | 116.22 | 0.17/2.29 | 102.50 | 129.10 | 97602/97602 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97602/97602 | | 1.000
November 1 to 30, 2012
Ch11 Mouse GSM High | 235.60 to 242.70 | 240.08 | 0.19/5.34 | 212.13 | 285.16 | 94628/94628 | | 1.000
Ch12 Mouse GSM Med | 168.00 to 171.70 | 170.49 | 0.17/3.37 | 145.05 | 192.18 | 94628/94628 | | 1.000
Ch14 Mouse GSM Low | 117.80 to 120.60 | 119.65 | 0.17/2.35 | 108.08 | 134.46 | 94628/94628 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94628/94628 | | 1.000
December 1 to 31, 2012
Ch11 Mouse GSM High | 242.70 to 247.20 | 246.27 | 0.20/5.79 | 220.75 | 280.06 | 97500/97500 | | 1.000
Ch12 Mouse GSM Med | 171.70 to 174.80 | 174.25 | 0.18/3.56 | 158.98 | 191.03 | 97496/97496 | | 1.000
Ch14 Mouse GSM Low | 120.60 to 122.90 | 122.40 | 0.17/2.38 | 111.52 | 136.85 | 97496/97496 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97496/97496 | | 1.000
January 1 to 31, 2013
Ch11 Mouse GSM High | 247.20 to 249.80 | 246.34 | 0.31/8.90 | 212.57 | 290.65 | 97378/97378 | 1.000
Ch12 Mouse GSM Med | 174.80 to 176.70 | 176.61 | 0.21/4.30 | 139.67 | 218.22 | 97362/97364 | 1.000
Ch14 Mouse GSM Low | 122.90 to 124.30 | 124.22 | 0.17/2.39 | 112.14 | 135.78 | 97364/97364 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97364/97364 | 1.000
February 1 to 28, 2013
Ch11 Mouse GSM High | 249.80 to 251.10 | 227.29 | 0.25/6.60 | 197.26 | 254.51 | 88114/88116 | 1.000
Ch12 Mouse GSM Med | 176.70 to 178.50 | 178.60 | 0.17/3.60 | 157.05 | 194.95 | 88116/88116 | 1.000
Ch14 Mouse GSM Low | 124.30 to 125.60 | 125.67 | 0.17/2.43 | 107.89 | 138.45 | 88116/88116 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 88116/88116 | 1.000
March 1 to 31, 2013
Ch11 Mouse GSM High | 251.10 to 253.60 | 229.49 | 0.26/7.11 | 207.98 | 261.00 | 97784/97784 | 1.000
Ch12 Mouse GSM Med | 178.50 to 179.30 | 179.57 | 0.17/3.62 | 165.02 | 193.99 | 97784/97784 | 1.000
Ch14 Mouse GSM Low | 125.60 to 126.20 | 126.39 | 0.17/2.55 | 116.82 | 136.92 | 97784/97784 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97784/97784 | 1.000
April 1 to 30, 2013
Ch11 Mouse GSM High | 253.60 to 256.00 | 227.10 | 0.23/5.99 | 203.37 | 253.19 | 96260/96260 | 1.000
Ch12 Mouse GSM Med | 179.30 to 181.80 | 180.58 | 0.18/3.69 | 163.42 | 195.38 | 96260/96260 | 1.000
Ch14 Mouse GSM Low | 126.20 to 127.40 | 127.12 | 0.16/2.42 | 119.14 | 138.56 | 96260/96260 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 96260/96260 | 1.000
May 1 to 31, 2013
Ch11 Mouse GSM High | 256.00 to 257.20 | 227.85 | 0.21/5.62 | 181.80 | 254.88 | 97018/97020 | 1.000
Ch12 Mouse GSM Med | 181.80 to 182.60 | 182.15 | 0.17/3.65 | 147.02 | 218.01 | 97020/97020 | 1.000
Ch14 Mouse GSM Low | 127.40 to 128.60 | 127.68 | 0.17/2.51 | 108.39 | 138.57 | 97020/97020 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97020/97020 | 1.000
June 1 to 30, 2013
Ch11 Mouse GSM High | 257.20 to 259.40 | 222.18 | 0.20/5.26 | 202.90 | 247.16 | 94490/94496 | 1.000
Ch12 Mouse GSM Med | 182.60 to 183.40 | 182.92 | 0.17/3.62 | 167.03 | 198.51 | 94496/94496 | 1.000
Ch14 Mouse GSM Low | 128.60 to 129.10 | 128.74 | 0.16/2.39 | 114.06 | 139.13 | 94496/94496 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94496/94496 | 1.000
July 1 to 31, 2013
Ch11 Mouse GSM High | 259.40 to 260.60 | 232.30 | 0.29/7.92 | 189.95 | 261.63 | 98976/99146 | 0.998
Ch12 Mouse GSM Med | 183.40 to 185.00 | 183.88 | 0.17/3.71 | 152.12 | 201.19 | 99146/99146 | 1.000
Ch14 Mouse GSM Low | 129.10 to 130.30 | 129.63 | 0.17/2.54 | 111.83 | 140.17 | 99146/99146 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 99146/99146 | 1.000
August 1 to 31, 2013
Ch11 Mouse GSM High | 260.60 to 261.60 | 238.28 | 0.24/6.76 | 212.95 | 263.95 | 101700/101700 | | 1.000
Ch12 Mouse GSM Med | 185.00 to 185.80 | 185.04 | 0.18/3.97 | 169.82 | 211.58 | 101700/101700 | | 1.000
Ch14 Mouse GSM Low | 130.30 to 130.80 | 130.56 | 0.17/2.57 | 118.52 | 150.21 | 101700/101700 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 101700/101700 | | 1.000
September 1 to 30, 2013
Ch11 Mouse GSM High | 261.60 to 273.80 | 259.49 | 0.42/12.99 | 154.24 | 310.55 | 93918/93922 | | 1.000
Ch12 Mouse GSM Med | 185.80 to 186.60 | 186.08 | 0.19/4.02 | 172.65 | 203.93 | 93920/93920 | | 1.000
Ch14 Mouse GSM Low | 130.80 to 131.40 | 131.14 | 0.17/2.55 | 95.42 | 143.74 | 93912/93920 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 93920/93920 | | 1.000
October 1 to 31, 2013
Ch11 Mouse GSM High | 273.80 to 276.10 | 273.26 | 0.23/7.32 | 219.98 | 320.51 | 100816/100816 | | 1.000
Ch12 Mouse GSM Med | 186.60 to 186.60 | 186.50 | 0.19/4.08 | 149.42 | 203.69 | 100816/100816 | | 1.000
Ch14 Mouse GSM Low | 131.40 to 131.40 | 131.40 | 0.16/2.42 | 107.28 | 144.05 | 100816/100816 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 100816/100816 | | 1.000
November 1 to 30, 2013
Ch11 Mouse GSM High | 275.00 to 276.10 | 256.54 | 0.37/11.29 | 197.87 | 301.50 | 93218/93226 | | 1.000
Ch12 Mouse GSM Med | 186.60 to 186.60 | 185.47 | 0.25/5.34 | 142.46 | 221.82 | 93224/93226 | | 1.000
Ch14 Mouse GSM Low | 131.40 to 131.40 | 131.34 | 0.20/3.01 | 106.00 | 142.76 | 93226/93226 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 93226/93226 | | 1.000
December 1 to 31, 2013
Ch11 Mouse GSM High | 273.80 to 275.00 | 264.56 | 0.38/11.98 | 222.16 | 299.75 | 96846/96846 | | 1.000
Ch12 Mouse GSM Med | 185.00 to 186.60 | 184.56 | 0.21/4.62 | 157.41 | 228.42 | 96846/96846 | | 1.000
Ch14 Mouse GSM Low | 130.80 to 131.40 | 130.98 | 0.18/2.74 | 100.51 | 166.76 | 96842/96846 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 96846/96846 | | 1.000
January 1 to 31, 2014
Ch11 Mouse GSM High | 273.80 to 275.00 | 263.34 | 0.29/8.82 | 208.57 | 301.08 | 97548/97550 | | 1.000
Ch12 Mouse GSM Med | 185.00 to 185.80 | 185.51 | 0.20/4.28 | 157.42 | 208.93 | 97550/97550 | | 1.000
Ch14 Mouse GSM Low | 130.80 to 130.80 | 130.79 | 0.18/2.80 | 56.85 | 162.24 | 97544/97550 | | 1.000
Ch13 Mouse Sham | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97550/97550 | | 1.000
February 1 to 28, 2014
Ch11 Mouse GSM High | 275.00 to 276.10 | 275.23 | 0.24/7.74 | 239.47 | 323.01 | 88184/88184 | | 1.000
Ch12 Mouse GSM Med | 185.80 to 186.60 | 178.26 | 0.45/9.39 | 125.65 | 211.52 | 87980/88184 | | 0.998
Ch14 Mouse GSM Low | 130.80 to 131.90 | 131.73 | 0.18/2.73 | 106.14 | 162.60 | 88184/88184 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 88184/88184 | | 1.000
March 1 to 31, 2014
Ch11 Mouse GSM High | 275.00 to 276.10 | 266.21 | 0.46/14.46 | 220.40 | 327.90 | 97142/97142 | | 1.000
Ch12 Mouse GSM Med | 186.60 to 186.60 | 177.33 | 0.67/14.20 | 137.09 | 215.33 | 95760/97142 | | 0.986
Ch14 Mouse GSM Low | 131.40 to 131.90 | 131.77 | 0.16/2.40 | 114.17 | 146.97 | 97142/97142 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97142/97142 | | 1.000
April 1 to 30, 2014
Ch11 Mouse GSM High | 273.80 to 275.00 | 271.16 | 0.43/13.88 | 220.51 | 319.44 | 94548/94548 | | 1.000
Ch12 Mouse GSM Med | 185.80 to 186.60 | 184.10 | 0.70/15.37 | 133.88 | 235.80 | 93074/94548 | | 0.984
Ch14 Mouse GSM Low | 130.80 to 131.40 | 131.27 | 0.15/2.29 | 113.50 | 141.25 | 94548/94548 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94548/94548 | | 1.000
May 1 to 31, 2014
Ch11 Mouse GSM High | 272.70 to 273.80 | 273.60 | 0.23/7.40 | 216.22 | 309.84 | 97240/97244 | | 1.000
Ch12 Mouse GSM Med | 185.00 to 185.80 | 185.60 | 0.24/5.11 | 134.48 | 227.23 | 97098/97244 | | 0.998
Ch14 Mouse GSM Low | 130.80 to 130.80 | 130.87 | 0.15/2.24 | 122.41 | 141.45 | 97244/97244 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97244/97244 | | 1.000
June 1 to 30, 2014
Ch11 Mouse GSM High | 271.50 to 272.70 | 272.64 | 0.20/6.44 | 236.01 | 307.96 | 94288/94288 | | 1.000
Ch12 Mouse GSM Med | 184.20 to 185.00 | 184.73 | 0.16/3.49 | 142.97 | 199.14 | 94286/94288 | | 1.000
Ch14 Mouse GSM Low | 130.30 to 130.80 | 130.94 | 0.15/2.22 | 121.45 | 140.21 | 94288/94288 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94288/94288 | | 1.000
July 1 to 9, 2014
Ch11 Mouse GSM High | 271.50 to 271.50 | 272.57 | 0.19/5.96 | 243.57 | 303.74 | 25064/25064 | | 1.000
Ch12 Mouse GSM Med | 184.20 to 184.20 | 184.80 | 0.15/3.27 | 174.73 | 199.39 | 25064/25064 | | 1.000
Ch14 Mouse GSM Low | 130.30 to 130.30 | 130.69 | 0.17/2.66 | 116.49 | 145.47 | 25064/25064 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 25064/25064 | | 1.000
June 18, 2012, to July 9, 2014
Ch11 Mouse GSM High | 194.10 to 276.10 | 244.10 | 0.48/13.78 | 121.76 | 327.90 | 2272234/ 2272442 | | 1.000
Ch12 Mouse GSM Med | 137.20 to 186.60 | 176.76 | 0.31/6.35 | 88.97 | 235.80 | 2269198/ 2272416 | | 0.999
Ch14 Mouse GSM Low | 97.00 to 131.90 | 125.14 | 0.17/2.48 | 56.85 | 166.76 | 2272396/ 2272416 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 2272416/ 2272416 | | 1.000

^a^ Ch = chamber (e.g., Ch11 = Chamber 11).

Table I-3 Summary of GSM-modulated Cell Phone RFR Exposure Data—E-Field^a^

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | Max [V/m] | In Range/ Total | Ratio
June 18 to 30, 2012
Ch11 Mouse GSM High | 194.1 to 199.6 | 220.41 | 0.36/9.20 | 134.8 | 342.3 | 38908/38950 | 0.999
Ch12 Mouse GSM Med | 137.2 to 141.2 | 148.22 | 0.31/5.41 | 93.1 | 224.6 | 38944/38950 | 1.000
Ch14 Mouse GSM Low | 97.0 to 99.8 | 93.00 | 0.25/2.72 | 82.8 | 106.6 | 38950/38950 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 38950/38950 | 1.000
July 1 to 31, 2012
Ch11 Mouse GSM High | 199.6 to 212.3 | 232.54 | 0.37/10.25 | 191.3 | 275.5 | 97310/97462 | 0.998
Ch12 Mouse GSM Med | 141.2 to 150.1 | 154.86 | 0.31/5.70 | 121.0 | 190.6 | 97460/97462 | 1.000
Ch14 Mouse GSM Low | 99.8 to 106.1 | 96.90 | 0.23/2.66 | 85.6 | 111.1 | 97462/97462 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97462/97462 | 1.000
August 1 to 31, 2012
Ch11 Mouse GSM High | 212.3 to 222.2 | 249.45 | 0.37/10.92 | 204.4 | 315.0 | 94710/94976 | 0.997
Ch12 Mouse GSM Med | 150.1 to 157.1 | 164.75 | 0.31/5.97 | 144.8 | 197.2 | 94968/94976 | 1.000
Ch14 Mouse GSM Low | 106.1 to 111.1 | 101.69 | 0.23/2.69 | 89.1 | 120.4 | 94976/94976 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94976/94976 | 1.000
September 1 to 30, 2012
Ch11 Mouse GSM High | 222.2 to 228.2 | 267.26 | 0.37/11.47 | 193.8 | 317.6 | 93216/94374 | 0.988
Ch12 Mouse GSM Med | 157.1 to 161.4 | 171.56 | 0.31/6.17 | 119.3 | 197.8 | 94366/94370 | 1.000
Ch14 Mouse GSM Low | 114.1 to 117.8 | 110.31 | 0.25/3.25 | 94.8 | 125.7 | 94962/94962 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94962/94962 | 1.000
October 1 to 31, 2012
Ch11 Mouse GSM High | 228.2 to 235.6 | 270.30 | 0.36/11.39 | 161.2 | 317.0 | 97028/97604 | 0.994
Ch12 Mouse GSM Med | 161.4 to 168.0 | 172.36 | 0.29/5.83 | 149.2 | 200.7 | 97602/97602 | 1.000
Ch14 Mouse GSM Low | 114.1 to 117.8 | 110.32 | 0.25/3.26 | 94.8 | 125.7 | 97602/97602 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97602/97602 | 1.000
November 1 to 30, 2012
Ch11 Mouse GSM High | 235.6 to 242.7 | 280.59 | 0.36/11.92 | 236.7 | 351.9 | 93952/94628 | 0.993
Ch12 Mouse GSM Med | 168.0 to 171.7 | 175.49 | 0.26/5.33 | 150.0 | 202.3 | 94628/94628 | 1.000
Ch14 Mouse GSM Low | 117.8 to 120.6 | 112.89 | 0.23/3.09 | 99.2 | 127.3 | 94628/94628 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94628/94628 | 1.000
December 1 to 31, 2012
Ch11 Mouse GSM High | 242.7 to 247.2 | 291.82 | 0.38/13.01 | 253.5 | 340.0 | 95756/97500 | 0.982
Ch12 Mouse GSM Med | 171.7 to 174.8 | 180.56 | 0.27/5.72 | 161.5 | 204.8 | 97496/97496 | 1.000
Ch14 Mouse GSM Low | 120.6 to 122.9 | 117.17 | 0.24/3.25 | 104.1 | 133.5 | 97496/97496 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97496/97496 | 1.000
January 1 to 31, 2013
Ch11 Mouse GSM High | 247.2 to 249.8 | 285.35 | 0.64/21.65 | 229.0 | 359.4 | 96120/97378 | 0.987
Ch12 Mouse GSM Med | 174.8 to 176.7 | 183.63 | 0.30/6.49 | 148.1 | 233.4 | 97362/97364 | 1.000
Ch14 Mouse GSM Low | 122.9 to 124.3 | 119.13 | 0.24/3.35 | 104.9 | 133.0 | 97364/97364 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97364/97364 | 1.000
February 1 to 28, 2013
Ch11 Mouse GSM High | 249.8 to 251.1 | 245.59 | 0.41/11.75 | 208.2 | 292.5 | 88116/88116 | 1.000
Ch12 Mouse GSM Med | 176.7 to 178.5 | 187.59 | 0.28/6.15 | 161.8 | 212.4 | 88116/88116 | 1.000
Ch14 Mouse GSM Low | 124.3 to 125.6 | 119.66 | 0.24/3.39 | 99.0 | 135.0 | 88114/88116 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 88116/88116 | 1.000
March 1 to 31, 2013
Ch11 Mouse GSM High | 251.1 to 253.6 | 248.20 | 0.40/11.68 | 213.4 | 298.3 | 97784/97784 | 1.000
Ch12 Mouse GSM Med | 178.5 to 179.3 | 187.29 | 0.30/6.68 | 163.4 | 215.1 | 97784/97784 | 1.000
Ch14 Mouse GSM Low | 125.6 to 126.2 | 121.50 | 0.25/3.56 | 109.2 | 138.8 | 97784/97784 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97784/97784 | 1.000
April 1 to 30, 2013
Ch11 Mouse GSM High | 253.6 to 256.0 | 245.75 | 0.37/10.67 | 206.0 | 283.6 | 96260/96260 | 1.000
Ch12 Mouse GSM Med | 179.3 to 181.8 | 188.33 | 0.28/6.14 | 169.2 | 215.0 | 96260/96260 | 1.000
Ch14 Mouse GSM Low | 126.2 to 127.4 | 119.94 | 0.24/3.42 | 106.9 | 134.6 | 96260/96260 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 96260/96260 | 1.000
May 1 to 31, 2013
Ch11 Mouse GSM High | 256.0 to 257.2 | 245.46 | 0.34/9.92 | 192.9 | 297.6 | 97018/97020 | 1.000
Ch12 Mouse GSM Med | 181.8 to 182.6 | 184.92 | 0.36/7.72 | 154.7 | 219.8 | 97020/97020 | 1.000
Ch14 Mouse GSM Low | 127.4 to 128.6 | 123.25 | 0.25/3.53 | 101.9 | 137.4 | 97020/97020 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97020/97020 | 1.000
June 1 to 30, 2013
Ch11 Mouse GSM High | 257.2 to 259.4 | 238.55 | 0.31/8.53 | 208.8 | 277.6 | 94496/94496 | 1.000
Ch12 Mouse GSM Med | 182.6 to 183.4 | 180.20 | 0.27/5.60 | 160.4 | 204.7 | 94496/94496 | 1.000
Ch14 Mouse GSM Low | 128.6 to 129.1 | 122.13 | 0.22/3.17 | 106.8 | 134.2 | 94496/94496 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94496/94496 | 1.000
July 1 to 31, 2013
Ch11 Mouse GSM High | 259.4 to 260.6 | 252.77 | 0.48/14.26 | 209.6 | 302.8 | 99146/99146 | 1.000
Ch12 Mouse GSM Med | 183.4 to 185.0 | 180.18 | 0.26/5.54 | 149.9 | 202.6 | 99146/99146 | 1.000
Ch14 Mouse GSM Low | 129.1 to 130.3 | 122.67 | 0.24/3.49 | 99.9 | 137.4 | 99144/99146 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 99146/99146 | 1.000
August 1 to 31, 2013
Ch11 Mouse GSM High | 260.6 to 261.6 | 238.13 | 0.36/10.20 | 205.2 | 287.5 | 101698/101700 | 1.000
Ch12 Mouse GSM Med | 185.0 to 185.8 | 180.96 | 0.29/6.22 | 160.7 | 210.2 | 101700/101700 | 1.000
Ch14 Mouse GSM Low | 130.3 to 130.8 | 124.66 | 0.25/3.62 | 109.9 | 141.5 | 101700/101700 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 101700/101700 | 1.000
September 1 to 30, 2013
Ch11 Mouse GSM High | 261.6 to 273.8 | 251.71 | 0.43/12.83 | 161.3 | 311.1 | 93890/93922 | 1.000
Ch12 Mouse GSM Med | 185.8 to 186.6 | 181.55 | 0.28/5.84 | 159.1 | 205.9 | 93920/93920 | 1.000
Ch14 Mouse GSM Low | 130.8 to 131.4 | 124.86 | 0.25/3.59 | 89.3 | 140.0 | 93912/93920 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 93920/93920 | 1.000
October 1 to 31, 2013
Ch11 Mouse GSM High | 273.8 to 276.1 | 264.68 | 0.29/9.12 | 209.0 | 306.5 | 100814/100816 | 1.000
Ch12 Mouse GSM Med | 186.6 to 186.6 | 182.15 | 0.28/5.91 | 145.4 | 205.6 | 100814/100816 | 1.000
Ch14 Mouse GSM Low | 131.4 to 131.4 | 123.98 | 0.24/3.55 | 105.9 | 138.5 | 100816/100816 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 100816/100816 | 1.000
November 1 to 30, 2013
Ch11 Mouse GSM High | 275.0 to 276.1 | 257.28 | 0.39/11.82 | 206.1 | 315.3 | 93220/93226 | 1.000
Ch12 Mouse GSM Med | 186.6 to 186.6 | 184.13 | 0.34/7.34 | 135.2 | 228.1 | 93216/93226 | 1.000
Ch14 Mouse GSM Low | 131.4 to 131.4 | 126.40 | 0.28/4.12 | 100.9 | 141.5 | 93198/93226 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 93226/93226 | 1.000
December 1 to 31, 2013
Ch11 Mouse GSM High | 273.8 to 275.0 | 265.70 | 0.39/12.26 | 214.7 | 308.3 | 96844/96846 | 1.000
Ch12 Mouse GSM Med | 185.0 to 186.6 | 179.76 | 0.29/6.11 | 155.1 | 224.0 | 96846/96846 | 1.000
Ch14 Mouse GSM Low | 130.8 to 131.4 | 122.89 | 0.25/3.62 | 95.3 | 152.2 | 96842/96846 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 96846/96846 | 1.000
January 1 to 31, 2014
Ch11 Mouse GSM High | 273.8 to 275.0 | 266.12 | 0.43/13.48 | 208.2 | 324.0 | 97548/97550 | 1.000
Ch12 Mouse GSM Med | 185.0 to 185.8 | 180.59 | 0.27/5.78 | 156.4 | 207.5 | 97550/97550 | 1.000
Ch14 Mouse GSM Low | 130.8 to 130.8 | 123.43 | 0.25/3.65 | 54.4 | 157.5 | 97538/97550 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97550/97550 | 1.000
February 1 to 28, 2014
Ch11 Mouse GSM High | 275.0 to 276.1 | 285.13 | 0.43/14.31 | 235.0 | 380.5 | 88182/88184 | 1.000
Ch12 Mouse GSM Med | 185.8 to 186.6 | 182.81 | 0.38/8.21 | 125.8 | 214.8 | 88086/88184 | 0.999
Ch14 Mouse GSM Low | 130.8 to 131.9 | 123.35 | 0.24/3.44 | 103.5 | 152.6 | 88180/88184 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 88184/88184 | 1.000
March 1 to 31, 2014
Ch11 Mouse GSM High | 275.0 to 276.1 | 261.60 | 0.57/17.65 | 199.8 | 325.6 | 96810/97142 | 0.997
Ch12 Mouse GSM Med | 186.6 to 186.6 | 178.89 | 0.67/14.44 | 138.6 | 218.0 | 96626/97142 | 0.995
Ch14 Mouse GSM Low | 131.4 to 131.9 | 124.02 | 0.24/3.40 | 105.7 | 138.7 | 97142/97142 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97142/97142 | 1.000
April 1 to 30, 2014
Ch11 Mouse GSM High | 273.8 to 275.0 | 264.65 | 0.57/18.01 | 203.2 | 327.8 | 94118/94548 | 0.995
Ch12 Mouse GSM Med | 185.8 to 186.6 | 182.58 | 0.71/15.58 | 129.0 | 246.4 | 93222/94548 | 0.986
Ch14 Mouse GSM Low | 130.8 to 131.4 | 122.29 | 0.23/3.35 | 106.3 | 141.5 | 94548/94548 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94548/94548 | 1.000
May 1 to 31, 2014
Ch11 Mouse GSM High | 272.7 to 273.8 | 268.70 | 0.37/11.81 | 201.7 | 319.0 | 97086/97244 | 0.998
Ch12 Mouse GSM Med | 185.0 to 185.8 | 184.59 | 0.34/7.30 | 131.9 | 223.2 | 97154/97244 | 0.999
Ch14 Mouse GSM Low | 130.8 to 130.8 | 122.38 | 0.23/3.30 | 108.2 | 136.7 | 97244/97244 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97244/97244 | 1.000
June 1 to 30, 2014
Ch11 Mouse GSM High | 271.5 to 272.7 | 275.38 | 0.41/13.20 | 222.4 | 327.6 | 94288/94288 | 1.000
Ch12 Mouse GSM Med | 184.2 to 185.0 | 180.65 | 0.26/5.58 | 141.8 | 202.2 | 94282/94288 | 1.000
Ch14 Mouse GSM Low | 130.3 to 130.8 | 123.72 | 0.23/3.37 | 110.5 | 137.5 | 94288/94288 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94288/94288 | 1.000
July 1 to 9, 2014
Ch11 Mouse GSM High | 271.5 to 271.5 | 281.98 | 0.27/8.95 | 242.7 | 312.4 | 25064/25064 | 1.000
Ch12 Mouse GSM Med | 184.2 to 184.2 | 185.84 | 0.22/4.78 | 169.6 | 201.3 | 25064/25064 | 1.000
Ch14 Mouse GSM Low | 130.3 to 130.3 | 125.14 | 0.23/3.34 | 113.1 | 138.1 | 25064/25064 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 25064/25064 | 1.000
June 18, 2012, to July 9, 2014
Ch11 Mouse GSM High | 194.1 to 276.1 | 259.29 | 0.88/27.75 | 134.8 | 380.5 | 2265600/ 2272442 | 0.997
Ch12 Mouse GSM Med | 137.2 to 186.6 | 179.13 | 0.47/9.94 | 93.1 | 246.4 | 2270352/ 2272416 | 0.999
Ch14 Mouse GSM Low | 97.0 to 131.9 | 118.53 | 0.26/3.55 | 54.4 | 157.5 | 2272352/ 2272416 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 2272416/ 2272416 | 1.000

^a^ Ch = chamber (e.g., Ch11 = Chamber 11).

Table I-4 Summary of GSM-modulated Cell Phone RFR Exposure Data—H-Field^a^

Chamber | Target Range [V/m] | Mean [V/m] | | | Stdev [dB]/[V/m] | Min [V/m] | | Max [V/m] | In Range/ Total | Ratio
June 18 to 30, 2012
Ch11 Mouse GSM High | 0.52 to 0.53 | 0.462 | | | 0.26/0.014 | 0.29 | | 0.67 | 38922/38950 | 0.999
Ch12 Mouse GSM Med | 0.36 to 0.38 | 0.347 | | | 0.27/0.011 | 0.23 | | 0.53 | 38944/38950 | 1.000
Ch14 Mouse GSM Low | 0.26 to 0.27 | 0.275 | | | 0.29/0.009 | 0.25 | | 0.31 | 38950/38950 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.000 | | | –/0.000 | 0.00 | | 0.00 | 38950/38950 | 1.000
July 1 to 31, 2012
Ch11 Mouse GSM High | 0.53 to 0.56 | 0.476 | | | 0.33/0.018 | 0.40 | | 0.57 | 96830/97462 | 0.994
Ch12 Mouse GSM Med | 0.38 to 0.40 | 0.363 | | | 0.25/0.011 | 0.30 | | 0.42 | 97458/97462 | 1.000
Ch14 Mouse GSM Low | 0.27 to 0.28 | 0.292 | | | 0.27/0.009 | 0.26 | | 0.33 | 97462/97462 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.000 | | | –/0.000 | 0.00 | | 0.00 | 97462/97462 | 1.000
August 1 to 31, 2012
Ch11 Mouse GSM High | 0.56 to 0.59 | 0.485 | | | 0.29/0.017 | 0.40 | | 0.56 | 93530/94976 | 0.985
Ch12 Mouse GSM Med | 0.40 to 0.42 | 0.381 | | | 0.25/0.011 | 0.33 | | 0.45 | 94976/94976 | 1.000
Ch14 Mouse GSM Low | 0.28 to 0.30 | 0.306 | | | 0.26/0.009 | 0.27 | | 0.37 | 94976/94976 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.000 | | | –/0.000 | 0.00 | | 0.00 | 94976/94976 | 1.000
September 1 to 30, 2012
Ch11 Mouse GSM High | 0.59 to 0.61 | 0.492 | | | 0.26/0.015 | 0.35 | | 0.55 | 88558/94374 | 0.938
Ch12 Mouse GSM Med | 0.42 to 0.43 | 0.397 | | | 0.25/0.012 | 0.30 | | 0.45 | 94362/94370 | 1.000
Ch14 Mouse GSM Low | 0.30 to 0.30 | 0.316 | | | 0.26/0.009 | 0.25 | | 0.36 | 94370/94370 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.000 | | | –/0.000 | 0.00 | | 0.00 | 94370/94370 | 1.000
October 1 to 31, 2012
Ch11 Mouse GSM High | 0.61 to 0.63 | 0.515 | | | 0.25/0.015 | 0.29 | | 0.58 | 95516/97604 | 0.979
Ch12 Mouse GSM Med | 0.43 to 0.45 | 0.419 | | | 0.25/0.012 | 0.34 | | 0.49 | 97602/97602 | 1.000
Ch14 Mouse GSM Low | 0.30 to 0.31 | 0.324 | | | 0.26/0.010 | 0.28 | | 0.36 | 97602/97602 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.000 | | | –/0.000 | 0.00 | | 0.00 | 97602/97602 | 1.000
November 1 to 30, 2012
Ch11 Mouse GSM High | 0.63 to 0.64 | 0.529 | | | 0.25/0.015 | 0.47 | | 0.61 | 91670/94628 | 0.969
Ch12 Mouse GSM Med | 0.45 to 0.46 | 0.439 | | | 0.24/0.012 | 0.37 | | 0.49 | 94628/94628 | 1.000
Ch14 Mouse GSM Low | 0.31 to 0.32 | 0.335 | | | 0.26/0.010 | 0.29 | | 0.38 | 94628/94628 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.000 | | | –/0.000 | 0.00 | | 0.00 | 94628/94628 | 1.000
December 1 to 31, 2012
Ch11 Mouse GSM High | 0.64 to 0.66 | 0.532 | | | 0.24/0.015 | 0.47 | | 0.60 | 90788/97500 | 0.931
Ch12 Mouse GSM Med | 0.46 to 0.46 | 0.445 | | | 0.23/0.012 | 0.40 | | 0.50 | 97496/97496 | 1.000
Ch14 Mouse GSM Low | 0.32 to 0.33 | 0.339 | | | 0.25/0.010 | 0.29 | | 0.38 | 97496/97496 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.000 | | | –/0.000 | 0.00 | | 0.00 | 97496/97496 | 1.000
January 1 to 31, 2013
Ch11 Mouse GSM High | 0.66 to 0.66 | | 0.550 | 0.32/0.021 | | | 0.46 | 0.63 | 91600/97378 | 0.941
Ch12 Mouse GSM Med | 0.46 to 0.47 | | 0.450 | 0.28/0.015 | | | 0.35 | 0.54 | 97286/97364 | 0.999
Ch14 Mouse GSM Low | 0.33 to 0.33 | | 0.343 | 0.25/0.010 | | | 0.31 | 0.39 | 97364/97364 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 97364/97364 | 1.000
February 1 to 28, 2013
Ch11 Mouse GSM High | 0.66 to 0.67 | | 0.554 | 0.23/0.015 | | | 0.49 | 0.62 | 86086/88116 | 0.977
Ch12 Mouse GSM Med | 0.47 to 0.47 | | 0.450 | 0.22/0.012 | | | 0.40 | 0.50 | 88116/88116 | 1.000
Ch14 Mouse GSM Low | 0.33 to 0.33 | | 0.349 | 0.24/0.010 | | | 0.29 | 0.39 | 88116/88116 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 88116/88116 | 1.000
March 1 to 31, 2013
Ch11 Mouse GSM High | 0.67 to 0.67 | | 0.559 | 0.25/0.016 | | | 0.49 | 0.63 | 94850/97784 | 0.970
Ch12 Mouse GSM Med | 0.47 to 0.48 | | 0.456 | 0.25/0.013 | | | 0.40 | 0.52 | 97784/97784 | 1.000
Ch14 Mouse GSM Low | 0.33 to 0.34 | | 0.348 | 0.24/0.010 | | | 0.31 | 0.39 | 97784/97784 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 97784/97784 | 1.000
April 1 to 30, 2013
Ch11 Mouse GSM High | 0.67 to 0.68 | | 0.553 | 0.21/0.014 | | | 0.49 | 0.62 | 91198/96260 | 0.947
Ch12 Mouse GSM Med | 0.48 to 0.48 | | 0.458 | 0.22/0.012 | | | 0.40 | 0.50 | 96260/96260 | 1.000
Ch14 Mouse GSM Low | 0.34 to 0.34 | | 0.356 | 0.26/0.011 | | | 0.31 | 0.39 | 96260/96260 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 96260/96260 | 1.000
May 1 to 31, 2013
Ch11 Mouse GSM High | 0.68 to 0.68 | | 0.558 | 0.22/0.014 | | | 0.45 | 0.62 | 92216/97020 | 0.950
Ch12 Mouse GSM Med | 0.48 to 0.48 | | 0.476 | 0.33/0.018 | | | 0.37 | 0.58 | 97018/97020 | 1.000
Ch14 Mouse GSM Low | 0.34 to 0.34 | | 0.350 | 0.25/0.010 | | | 0.31 | 0.39 | 97020/97020 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 97020/97020 | 1.000
June 1 to 30, 2013
Ch11 Mouse GSM High | 0.68 to 0.69 | | 0.546 | 0.23/0.015 | | | 0.48 | 0.60 | 81918/94496 | 0.867
Ch12 Mouse GSM Med | 0.48 to 0.49 | | 0.492 | 0.25/0.014 | | | 0.45 | 0.56 | 94496/94496 | 1.000
Ch14 Mouse GSM Low | 0.34 to 0.34 | | 0.359 | 0.24/0.010 | | | 0.32 | 0.39 | 94496/94496 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 94496/94496 | 1.000
July 1 to 31, 2013
Ch11 Mouse GSM High | 0.69 to 0.69 | | 0.562 | 0.25/0.016 | | | 0.45 | 0.63 | 92320/99146 | 0.931
Ch12 Mouse GSM Med | 0.49 to 0.49 | | 0.498 | 0.25/0.014 | | | 0.41 | 0.55 | 99146/99146 | 1.000
Ch14 Mouse GSM Low | 0.34 to 0.35 | | 0.362 | 0.26/0.011 | | | 0.32 | 0.40 | 99146/99146 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 99146/99146 | 1.000
August 1 to 31, 2013
Ch11 Mouse GSM High | 0.69 to 0.69 | | 0.632 | 0.45/0.034 | | | 0.51 | 0.78 | 101140/101700 | 0.994
Ch12 Mouse GSM Med | 0.49 to 0.49 | | 0.502 | 0.27/0.016 | | | 0.44 | 0.58 | 101700/101700 | 1.000
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.362 | 0.26/0.011 | | | 0.32 | 0.43 | 101700/101700 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 101700/101700 | 1.000
September 1 to 30, 2013
Ch11 Mouse GSM High | 0.69 to 0.73 | | 0.709 | 0.53/0.044 | | | 0.39 | 0.88 | 93920/93922 | 1.000
Ch12 Mouse GSM Med | 0.49 to 0.50 | | 0.506 | 0.27/0.016 | | | 0.46 | 0.58 | 93920/93920 | 1.000
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.365 | 0.25/0.011 | | | 0.27 | 0.40 | 93914/93920 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 93920/93920 | 1.000
October 1 to 31, 2013
Ch11 Mouse GSM High | 0.73 to 0.73 | | 0.748 | 0.38/0.033 | | | 0.61 | 0.89 | 100816/100816 | 1.000
Ch12 Mouse GSM Med | 0.50 to 0.50 | | 0.506 | 0.27/0.016 | | | 0.41 | 0.59 | 100816/100816 | 1.000
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.368 | 0.26/0.011 | | | 0.29 | 0.43 | 100816/100816 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 100816/100816 | 1.000
November 1 to 30, 2013
Ch11 Mouse GSM High | 0.73 to 0.73 | | 0.679 | 0.44/0.036 | | | 0.49 | 0.83 | 93208/93226 | 1.000
Ch12 Mouse GSM Med | 0.50 to 0.50 | | 0.496 | 0.29/0.017 | | | 0.40 | 0.60 | 93226/93226 | 1.000
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.361 | 0.28/0.012 | | | 0.28 | 0.41 | 93226/93226 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 93226/93226 | 1.000
December 1 to 31, 2013
Ch11 Mouse GSM High | 0.73 to 0.73 | | 0.699 | 0.48/0.040 | | | 0.56 | 0.82 | 96800/96846 | 1.000
Ch12 Mouse GSM Med | 0.49 to 0.50 | | 0.502 | 0.31/0.018 | | | 0.41 | 0.62 | 96846/96846 | 1.000
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.369 | 0.26/0.011 | | | 0.28 | 0.48 | 96844/96846 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 96846/96846 | 1.000
January 1 to 31, 2014
Ch11 Mouse GSM High | 0.73 to 0.73 | | 0.691 | 0.32/0.026 | | | 0.55 | 0.82 | 97548/97550 | 1.000
Ch12 Mouse GSM Med | 0.49 to 0.49 | | 0.505 | 0.27/0.016 | | | 0.41 | 0.58 | 97550/97550 | 1.000
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.366 | 0.26/0.011 | | | 0.16 | 0.44 | 97538/97550 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 97550/97550 | 1.000
February 1 to 28, 2014
Ch11 Mouse GSM High | 0.73 to 0.73 | | 0.704 | 0.35/0.029 | | | 0.59 | 0.82 | 88184/88184 | 1.000
Ch12 Mouse GSM Med | 0.49 to 0.50 | | 0.461 | 0.68/0.038 | | | 0.32 | 0.57 | 87662/88184 | 0.994
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.372 | 0.25/0.011 | | | 0.29 | 0.46 | 88176/88184 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 88184/88184 | 1.000
March 1 to 31, 2014
Ch11 Mouse GSM High | 0.73 to 0.73 | | 0.718 | 0.48/0.041 | | | 0.59 | 0.88 | 97142/97142 | 1.000
Ch12 Mouse GSM Med | 0.50 to 0.50 | | 0.466 | 0.74/0.041 | | | 0.33 | 0.59 | 93996/97142 | 0.968
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.370 | 0.23/0.010 | | | 0.33 | 0.41 | 97142/97142 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 97142/97142 | 1.000
April 1 to 30, 2014
Ch11 Mouse GSM High | 0.73 to 0.73 | | 0.737 | 0.46/0.040 | | | 0.60 | 0.88 | 94548/94548 | 1.000
Ch12 Mouse GSM Med | 0.49 to 0.50 | | 0.492 | 0.81/0.048 | | | 0.34 | 0.68 | 92916/94548 | 0.983
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.372 | 0.24/0.010 | | | 0.32 | 0.41 | 94548/94548 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 94548/94548 | 1.000
May 1 to 31, 2014
Ch11 Mouse GSM High | 0.72 to 0.73 | | 0.739 | 0.34/0.030 | | | 0.60 | 0.85 | 97244/97244 | 1.000
Ch12 Mouse GSM Med | 0.49 to 0.49 | | 0.495 | 0.33/0.019 | | | 0.36 | 0.61 | 97052/97244 | 0.998
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.370 | 0.22/0.010 | | | 0.34 | 0.41 | 97244/97244 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 97244/97244 | 1.000
June 1 to 30, 2014
Ch11 Mouse GSM High | 0.72 to 0.72 | | 0.716 | 0.36/0.031 | | | 0.63 | 0.84 | 94288/94288 | 1.000
Ch12 Mouse GSM Med | 0.49 to 0.49 | | 0.501 | 0.25/0.015 | | | 0.38 | 0.55 | 94284/94288 | 1.000
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.366 | 0.23/0.010 | | | 0.33 | 0.40 | 94288/94288 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 94288/94288 | 1.000
July 1 to 9, 2014
Ch11 Mouse GSM High | 0.72 to 0.72 | | 0.698 | 0.26/0.021 | | | 0.63 | 0.78 | 25064/25064 | 1.000
Ch12 Mouse GSM Med | 0.49 to 0.49 | | 0.487 | 0.23/0.013 | | | 0.45 | 0.54 | 25064/25064 | 1.000
Ch14 Mouse GSM Low | 0.35 to 0.35 | | 0.361 | 0.26/0.011 | | | 0.32 | 0.41 | 25064/25064 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 25064/25064 | 1.000
June 18, 2012, to July 9, 2014
Ch11 Mouse GSM High | 0.52 to 0.73 | | 0.607 | 0.73/0.053 | | | 0.29 | 0.89 | 2212122/ 2272442 | 0.973
Ch12 Mouse GSM Med | 0.36 to 0.50 | | 0.463 | 0.46/0.025 | | | 0.23 | 0.68 | 2266828/ 2272416 | 0.998
Ch14 Mouse GSM Low | 0.26 to 0.35 | | 0.349 | 0.26/0.011 | | | 0.16 | 0.48 | 2272388/ 2272416 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | | | 0.00 | 0.00 | 2272416/ 2272416 | 1.000

^a^ Ch = chamber (e.g., Ch11 = Chamber 11).

Table I-5 Summary of CDMA-modulated Cell Phone RFR Exposure Data—SAR^a^

Chamber | Weight Range [g] | Target [W/kg] | Mean [W/kg] | | Stdev [dB]/[W/kg] | Min [W/kg] | Max [W/kg] | In Range/ Total | Ratio
June 18 to 30, 2012
Ch01 Mouse IS95 High | 18.9 to 20.2 | 10.00 | 9.98 | | 0.13/0.03 | 5.483 | 20.437 | 19472/19475 | 1.000
Ch02 Mouse IS95 Med | 18.9 to 20.2 | 5.00 | 4.94 | | 0.17/0.04 | 3.641 | 7.729 | 19475/19475 | 1.000
Ch03 Mouse IS95 Low | 18.9 to 20.1 | 2.50 | 2.49 | | 0.11/0.03 | 2.134 | 3.273 | 19475/19475 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 19475/19475 | 1.000
July 1 to 31, 2012
Ch01 Mouse IS95 High | 20.2 to 24.6 | 10.00 | 9.98 | | 0.12/0.03 | 6.703 | 16.201 | 48730/48731 | 1.000
Ch02 Mouse IS95 Med | 20.2 to 24.6 | 5.00 | 4.96 | | 0.15/0.04 | 3.476 | 8.609 | 48730/48731 | 1.000
Ch03 Mouse IS95 Low | 20.1 to 24.7 | 2.50 | 2.49 | | 0.11/0.03 | 1.742 | 4.180 | 48730/48731 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 48731/48731 | 1.000
August 1 to 31, 2012
Ch01 Mouse IS95 High | 24.6 to 28.0 | 10.00 | 9.98 | | 0.12/0.03 | 8.349 | 13.937 | 47488/47488 | 1.000
Ch02 Mouse IS95 Med | 24.6 to 27.6 | 5.00 | 4.96 | | 0.14/0.03 | 4.115 | 9.356 | 47487/47488 | 1.000
Ch03 Mouse IS95 Low | 24.7 to 27.6 | 2.50 | 2.49 | | 0.11/0.03 | 2.031 | 3.689 | 47488/47488 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 47488/47488 | 1.000
September 1 to 30, 2012
Ch01 Mouse IS95 High | 28.0 to 30.1 | 10.00 | 9.98 | | 0.11/0.03 | 8.923 | 11.261 | 47187/47187 | 1.000
Ch02 Mouse IS95 Med | 27.6 to 29.3 | 5.00 | 4.96 | | 0.13/0.03 | 4.325 | 6.682 | 47187/47187 | 1.000
Ch03 Mouse IS95 Low | 27.6 to 29.1 | 2.50 | 2.49 | | 0.11/0.03 | 2.180 | 2.844 | 47187/47187 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 47185/47185 | 1.000
October 1 to 31, 2012
Ch01 Mouse IS95 High | 30.1 to 33.3 | 10.00 | 9.97 | | 0.11/0.03 | 8.718 | 11.420 | 48802/48802 | 1.000
Ch02 Mouse IS95 Med | 29.3 to 32.6 | 5.00 | 4.98 | | 0.13/0.03 | 4.296 | 5.798 | 48802/48802 | 1.000
Ch03 Mouse IS95 Low | 29.1 to 32.4 | 2.50 | 2.49 | | 0.10/0.02 | 2.208 | 2.766 | 48802/48802 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 48801/48801 | 1.000
November 1 to 30, 2012
Ch01 Mouse IS95 High | 33.3 to 36.7 | 10.00 | 9.98 | | 0.11/0.03 | 4.470 | 11.321 | 47313/47314 | 1.000
Ch02 Mouse IS95 Med | 32.6 to 36.1 | 5.00 | 4.98 | | 0.13/0.03 | 2.462 | 5.974 | 47313/47314 | 1.000
Ch03 Mouse IS95 Low | 32.4 to 35.5 | 2.50 | 2.49 | | 0.11/0.03 | 1.174 | 2.967 | 47313/47314 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 47314/47314 | 1.000
December 1 to 31, 2012
Ch01 Mouse IS95 High | 36.7 to 39.1 | 10.00 | 10.01 | | 0.11/0.03 | 8.925 | 11.723 | 48750/48750 | 1.000
Ch02 Mouse IS95 Med | 36.1 to 38.5 | 5.00 | 4.98 | | 0.13/0.03 | 4.364 | 6.018 | 48750/48750 | 1.000
Ch03 Mouse IS95 Low | 35.5 to 38.2 | 2.50 | 2.50 | | 0.11/0.03 | 2.227 | 2.909 | 48750/48750 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 48748/48748 | 1.000
January 1 to 31, 2013
Ch01 Mouse IS95 High | 39.1 to 41.1 | 10.00 | 9.98 | | 0.12/0.03 | 8.549 | 11.885 | 48689/48689 | 1.000
Ch02 Mouse IS95 Med | 38.5 to 40.8 | 5.00 | 4.98 | | 0.13/0.03 | 4.218 | 5.822 | 48689/48689 | 1.000
Ch03 Mouse IS95 Low | 38.2 to 40.8 | 2.50 | 2.50 | | 0.11/0.03 | 2.161 | 2.957 | 48689/48689 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 48682/48682 | 1.000
February 1 to 28, 2013
Ch01 Mouse IS95 High | 41.1 to 43.1 | 10.00 | 9.98 | | 0.12/0.03 | 8.591 | 11.811 | 44058/44058 | 1.000
Ch02 Mouse IS95 Med | 40.8 to 42.7 | 5.00 | 4.99 | | 0.14/0.03 | 3.890 | 7.124 | 44058/44058 | 1.000
Ch03 Mouse IS95 Low | 40.8 to 42.6 | 2.50 | 2.50 | | 0.11/0.03 | 2.117 | 3.036 | 44058/44058 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 44058/44058 | 1.000
March 1 to 31, 2013
Ch01 Mouse IS95 High | 43.1 to 44.9 | 10.00 | 10.01 | | 0.12/0.03 | 8.731 | 11.338 | 48892/48892 | 1.000
Ch02 Mouse IS95 Med | 42.7 to 44.3 | 5.00 | 5.00 | | 0.14/0.03 | 4.271 | 6.209 | 48892/48892 | 1.000
Ch03 Mouse IS95 Low | 42.6 to 44.0 | 2.50 | 2.50 | | 0.11/0.03 | 2.213 | 2.833 | 48892/48892 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 48892/48892 | 1.000
April 1 to 30, 2013
Ch01 Mouse IS95 High | 44.9 to 47.8 | 10.00 | 10.00 | | 0.12/0.03 | 8.512 | 12.723 | 48130/48130 | 1.000
Ch02 Mouse IS95 Med | 44.3 to 47.5 | 5.00 | 4.98 | | 0.14/0.03 | 4.329 | 5.899 | 48130/48130 | 1.000
Ch03 Mouse IS95 Low | 44.0 to 47.2 | 2.50 | 2.49 | | 0.12/0.03 | 2.196 | 2.858 | 48130/48130 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 48130/48130 | 1.000
May 1 to 31, 2013
Ch01 Mouse IS95 High | 47.8 to 49.2 | 10.00 | 9.99 | | 0.14/0.03 | 7.772 | 12.345 | 48510/48510 | 1.000
Ch02 Mouse IS95 Med | 47.5 to 49.1 | 5.00 | 4.97 | | 0.14/0.03 | 4.225 | 6.364 | 48510/48510 | 1.000
Ch03 Mouse IS95 Low | 47.2 to 48.5 | 2.50 | 2.49 | | 0.12/0.03 | 2.170 | 3.006 | 48510/48510 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 48510/48510 | 1.000
June 1 to 30, 2013
Ch01 Mouse IS95 High | 49.2 to 50.4 | 10.00 | 10.02 | | 0.15/0.03 | 7.714 | 12.935 | 47257/47257 | 1.000
Ch02 Mouse IS95 Med | 49.1 to 50.4 | 5.00 | 4.99 | | 0.14/0.03 | 4.037 | 6.047 | 47257/47257 | 1.000
Ch03 Mouse IS95 Low | 48.5 to 50.2 | 2.50 | 2.50 | | 0.25/0.06 | 1.455 | 3.737 | 47253/47257 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 47248/47248 | 1.000
July 1 to 31, 2013
Ch01 Mouse IS95 High | 50.4 to 51.6 | 10.00 | 9.99 | | 0.16/0.04 | 7.808 | 13.620 | 49573/49573 | 1.000
Ch02 Mouse IS95 Med | 50.4 to 51.7 | 5.00 | 4.97 | | 0.14/0.03 | 4.158 | 6.040 | 49573/49573 | 1.000
Ch03 Mouse IS95 Low | 50.2 to 51.4 | 2.50 | 2.50 | | 0.28/0.07 | 1.626 | 3.683 | 49573/49573 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 49573/49573 | 1.000
August 1 to 31, 2013
Ch01 Mouse IS95 High | 51.6 to 52.2 | 10.00 | | 9.99 | 0.14/0.03 | 7.168 | 12.173 | 50856/50856 | 1.000
Ch02 Mouse IS95 Med | 51.7 to 52.7 | 5.00 | | 4.99 | 0.16/0.04 | 4.279 | 6.445 | 50856/50856 | 1.000
Ch03 Mouse IS95 Low | 51.3 to 52.2 | 2.50 | | 2.50 | 0.14/0.03 | 1.851 | 3.071 | 50856/50856 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | | 0.00 | –/0.00 | 0.000 | 0.000 | 50850/50850 | 1.000
September 1 to 30, 2013
Ch01 Mouse IS95 High | 52.2 to 53.0 | 10.95 | | 10.11 | 0.14/0.03 | 8.045 | 13.922 | 46961/46961 | 1.000
Ch02 Mouse IS95 Med | 52.7 to 53.5 | 5.00 | | 5.00 | 0.15/0.03 | 4.143 | 6.336 | 46961/46961 | 1.000
Ch03 Mouse IS95 Low | 52.2 to 53.4 | 2.50 | | 2.51 | 0.35/0.08 | 1.262 | 4.130 | 46946/46961 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | | 0.00 | –/0.00 | 0.000 | 0.000 | 46960/46960 | 1.000
October 1 to 31, 2013
Ch01 Mouse IS95 High | 53.0 to 53.8 | 10.00 | | 10.03 | 0.13/0.03 | 8.027 | 12.009 | 50408/50408 | 1.000
Ch02 Mouse IS95 Med | 53.5 to 54.2 | 5.00 | | 4.99 | 0.15/0.03 | 4.224 | 6.669 | 50408/50408 | 1.000
Ch03 Mouse IS95 Low | 53.4 to 54.1 | 2.50 | | 2.50 | 0.16/0.04 | 1.718 | 3.359 | 50408/50408 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | | 0.00 | –/0.00 | 0.000 | 0.000 | 50408/50408 | 1.000
November 1 to 30, 2013
Ch01 Mouse IS95 High | 53.8 to 54.0 | 10.00 | | 10.03 | 0.15/0.04 | 4.536 | 12.268 | 46637/46639 | 1.000
Ch02 Mouse IS95 Med | 54.2 to 54.2 | 5.00 | | 4.98 | 0.16/0.04 | 2.225 | 6.187 | 46637/46639 | 1.000
Ch03 Mouse IS95 Low | 53.8 to 54.1 | 2.50 | | 2.48 | 0.27/0.06 | 0.161 | 4.469 | 46551/46639 | 0.998
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | | 0.00 | –/0.00 | 0.000 | 0.000 | 46613/46613 | 1.000
December 1 to 31, 2013
Ch01 Mouse IS95 High | 52.3 to 54.0 | 10.00 | | 10.02 | 0.14/0.03 | 7.143 | 14.712 | 48423/48423 | 1.000
Ch02 Mouse IS95 Med | 52.8 to 54.2 | 5.00 | | 4.99 | 0.16/0.04 | 3.949 | 7.068 | 48423/48423 | 1.000
Ch03 Mouse IS95 Low | 52.6 to 53.8 | 2.50 | | 2.50 | 0.14/0.03 | 1.989 | 3.035 | 48423/48423 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | | 0.00 | –/0.00 | 0.000 | 0.000 | 48423/48423 | 1.000
January 1 to 31, 2014
Ch01 Mouse IS95 High | 52.3 to 52.7 | 10.00 | | 9.99 | 0.14/0.03 | 6.121 | 14.242 | 48776/48777 | 1.000
Ch02 Mouse IS95 Med | 52.8 to 53.4 | 5.00 | | 5.00 | 0.15/0.04 | 1.378 | 6.481 | 48775/48777 | 1.000
Ch03 Mouse IS95 Low | 52.6 to 53.0 | 2.50 | | 2.51 | 0.31/0.07 | 0.429 | 4.110 | 48768/48776 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | | 0.00 | –/0.00 | 0.000 | 0.000 | 48775/48775 | 1.000
February 1 to 28, 2014
Ch01 Mouse IS95 High | 52.7 to 54.1 | 10.00 | | 9.95 | 0.13/0.03 | 6.403 | 13.519 | 44092/44092 | 1.000
Ch02 Mouse IS95 Med | 53.4 to 54.8 | 5.00 | | 4.98 | 0.16/0.04 | 2.326 | 9.889 | 44085/44092 | 1.000
Ch03 Mouse IS95 Low | 53.0 to 54.6 | 2.50 | | 2.48 | 0.35/0.08 | 1.358 | 3.784 | 44059/44092 | 0.999
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | | 0.00 | –/0.00 | 0.000 | 0.000 | 44092/44092 | 1.000
March 1 to 31, 2014
Ch01 Mouse IS95 High | 53.0 to 54.1 | 10.00 | 9.45 | | 0.48/0.12 | 0.124 | 18.080 | 48470/48590 | 0.998
Ch02 Mouse IS95 Med | 53.8 to 54.9 | 5.00 | 5.00 | | 0.16/0.04 | 2.146 | 9.590 | 48585/48590 | 1.000
Ch03 Mouse IS95 Low | 54.2 to 54.7 | 2.50 | 2.47 | | 0.35/0.08 | 0.607 | 6.319 | 48505/48590 | 0.998
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 48571/48571 | 1.000
April 1 to 30, 2014
Ch01 Mouse IS95 High | 51.8 to 52.8 | 10.00 | 9.96 | | 0.21/0.05 | 0.435 | 21.444 | 47241/47275 | 0.999
Ch02 Mouse IS95 Med | 52.9 to 53.2 | 5.00 | 5.02 | | 0.21/0.05 | 0.771 | 12.768 | 47238/47275 | 0.999
Ch03 Mouse IS95 Low | 53.3 to 53.8 | 2.50 | 2.48 | | 0.27/0.06 | 0.656 | 3.495 | 47261/47275 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 47274/47274 | 1.000
May 1 to 31, 2014
Ch01 Mouse IS95 High | 51.0 to 51.8 | 10.00 | 9.98 | | 0.14/0.03 | 8.159 | 12.373 | 48622/48622 | 1.000
Ch02 Mouse IS95 Med | 51.4 to 52.9 | 5.00 | 5.00 | | 0.14/0.03 | 3.701 | 6.542 | 48622/48622 | 1.000
Ch03 Mouse IS95 Low | 52.2 to 53.3 | 2.50 | 2.49 | | 0.27/0.06 | 1.281 | 3.566 | 48619/48622 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 48622/48622 | 1.000
June 1 to 30, 2014
Ch01 Mouse IS95 High | 50.5 to 51.2 | 10.00 | 9.97 | | 0.13/0.03 | 7.103 | 12.077 | 47144/47144 | 1.000
Ch02 Mouse IS95 Med | 51.0 to 51.4 | 5.00 | 5.00 | | 0.14/0.03 | 3.476 | 6.143 | 47144/47144 | 1.000
Ch03 Mouse IS95 Low | 50.6 to 52.2 | 2.50 | 2.49 | | 0.28/0.07 | 1.038 | 4.032 | 47132/47144 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 47144/47144 | 1.000
July 1 to 9, 2014
Ch01 Mouse IS95 High | 51.2 to 51.2 | 10.00 | 10.00 | | 0.11/0.03 | 8.426 | 11.320 | 12549/12549 | 1.000
Ch02 Mouse IS95 Med | 51.3 to 51.3 | 5.00 | 4.99 | | 0.12/0.03 | 4.148 | 5.780 | 12549/12549 | 1.000
Ch03 Mouse IS95 Low | 50.6 to 50.6 | 2.50 | 2.53 | | 0.65/0.16 | 0.633 | 4.854 | 12390/12549 | 0.987
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 12532/12532 | 1.000
June 18, 2012, to July 9, 2014
Ch01 Mouse IS95 High | 18.9 to 54.1 | 10.95 | 9.97 | | 0.17/0.04 | 0.124 | 21.444 | 1136122/ 1136284 | 1.000
Ch02 Mouse IS95 Med | 18.9 to 54.9 | 5.00 | 4.99 | | 0.15/0.03 | 0.771 | 12.768 | 1136228/ 1136284 | 1.000
Ch03 Mouse IS95 Low | 18.9 to 54.7 | 2.50 | 2.49 | | 0.21/0.05 | 0.161 | 6.319 | 1136030/ 1136283 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | 0.000 | 0.000 | 1136208/ 1136208 | 1.000

^a^ Ch = chamber (e.g., Ch11 = Chamber 11).

Table I-6 Summary of CDMA-modulated Cell Phone RFR Exposure Data—Chamber Field^a^

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | Max [V/m] | In Range/ Total | | Ratio
June 18 to 30, 2012
Ch01 Mouse IS95 High | 194.10 to 199.60 | 196.37 | 0.13/2.96 | 143.58 | 277.18 | 38944/38950 | | 1.000
Ch02 Mouse IS95 Med | 137.20 to 141.20 | 138.19 | 0.17/2.76 | 120.44 | 170.46 | 38950/38950 | | 1.000
Ch03 Mouse IS95 Low | 97.00 to 99.80 | 98.08 | 0.12/1.31 | 91.19 | 110.93 | 38950/38950 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 38950/38950 | | 1.000
July 1 to 31, 2012
Ch01 Mouse IS95 High | 199.60 to 212.30 | 205.11 | 0.12/2.82 | 173.76 | 270.15 | 97460/97462 | | 1.000
Ch02 Mouse IS95 Med | 141.20 to 150.10 | 145.03 | 0.15/2.59 | 125.14 | 196.92 | 97460/97462 | | 1.000
Ch03 Mouse IS95 Low | 99.80 to 106.10 | 103.17 | 0.11/1.37 | 88.58 | 137.22 | 97460/97462 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97462/97462 | | 1.000
August 1 to 31, 2012
Ch01 Mouse IS95 High | 212.30 to 222.20 | 217.26 | 0.12/2.98 | 199.87 | 258.23 | 94976/94976 | | 1.000
Ch02 Mouse IS95 Med | 150.10 to 157.10 | 152.68 | 0.15/2.58 | 138.34 | 208.61 | 94974/94976 | | 1.000
Ch03 Mouse IS95 Low | 106.10 to 111.10 | 108.44 | 0.11/1.37 | 98.59 | 132.85 | 94976/94976 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94976/94976 | | 1.000
September 1 to 30, 2012
Ch01 Mouse IS95 High | 222.20 to 230.90 | 227.67 | 0.11/2.97 | 212.83 | 244.74 | 94374/94374 | | 1.000
Ch02 Mouse IS95 Med | 157.10 to 161.40 | 159.33 | 0.13/2.37 | 148.22 | 184.17 | 94374/94374 | | 1.000
Ch03 Mouse IS95 Low | 111.10 to 114.10 | 112.90 | 0.11/1.46 | 104.64 | 121.19 | 94374/94374 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94370/94370 | | 1.000
October 1 to 31, 2012
Ch01 Mouse IS95 High | 230.90 to 237.60 | 233.91 | 0.11/3.07 | 215.34 | 250.45 | 97604/97604 | | 1.000
Ch02 Mouse IS95 Med | 161.40 to 166.60 | 163.67 | 0.13/2.46 | 151.48 | 176.83 | 97604/97604 | | 1.000
Ch03 Mouse IS95 Low | 114.10 to 117.80 | 115.72 | 0.11/1.42 | 108.66 | 123.97 | 97604/97604 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97602/97602 | | 1.000
November 1 to 30, 2012
Ch01 Mouse IS95 High | 237.60 to 242.70 | 240.37 | 0.11/3.13 | 158.92 | 257.10 | 94626/94628 | | 1.000
Ch02 Mouse IS95 Med | 166.60 to 171.70 | 169.18 | 0.13/2.58 | 116.96 | 185.43 | 94626/94628 | | 1.000
Ch03 Mouse IS95 Low | 117.80 to 120.60 | 119.29 | 0.12/1.60 | 80.77 | 131.35 | 94626/94628 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94628/94628 | | 1.000
December 1 to 31, 2012
Ch01 Mouse IS95 High | 242.70 to 247.20 | 245.58 | 0.11/3.21 | 231.33 | 264.34 | 97500/97500 | | 1.000
Ch02 Mouse IS95 Med | 171.70 to 173.80 | 172.59 | 0.13/2.64 | 162.14 | 190.41 | 97500/97500 | | 1.000
Ch03 Mouse IS95 Low | 120.60 to 122.90 | 121.97 | 0.11/1.55 | 113.87 | 132.39 | 97500/97500 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97496/97496 | | 1.000
January 1 to 31, 2013
Ch01 Mouse IS95 High | 247.20 to 249.80 | 249.07 | 0.12/3.50 | 230.99 | 272.55 | | 97378/97378 | 1.000
Ch02 Mouse IS95 Med | 173.80 to 175.70 | 174.88 | 0.13/2.63 | 161.36 | 189.41 | | 97378/97378 | 1.000
Ch03 Mouse IS95 Low | 122.90 to 124.30 | 123.76 | 0.11/1.65 | 115.26 | 135.11 | | 97378/97378 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 97364/97364 | 1.000
February 1 to 28, 2013
Ch01 Mouse IS95 High | 249.80 to 252.40 | 251.73 | 0.12/3.39 | 233.92 | 274.28 | | 88116/88116 | 1.000
Ch02 Mouse IS95 Med | 175.70 to 177.60 | 176.86 | 0.14/2.85 | 156.42 | 211.68 | | 88116/88116 | 1.000
Ch03 Mouse IS95 Low | 124.30 to 125.60 | 125.26 | 0.12/1.67 | 115.38 | 138.19 | | 88116/88116 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 88116/88116 | 1.000
March 1 to 31, 2013
Ch01 Mouse IS95 High | 252.40 to 253.60 | 253.18 | 0.12/3.50 | 236.57 | 269.59 | | 97784/97784 | 1.000
Ch02 Mouse IS95 Med | 177.60 to 179.30 | 178.79 | 0.14/2.88 | 165.47 | 199.50 | | 97784/97784 | 1.000
Ch03 Mouse IS95 Low | 125.60 to 126.20 | 125.98 | 0.11/1.61 | 118.72 | 133.49 | | 97784/97784 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 97784/97784 | 1.000
April 1 to 30, 2013
Ch01 Mouse IS95 High | 253.60 to 257.20 | 255.59 | 0.12/3.58 | 235.87 | 288.37 | | 96260/96260 | 1.000
Ch02 Mouse IS95 Med | 179.30 to 181.80 | 179.86 | 0.14/2.87 | 167.66 | 195.71 | | 96260/96260 | 1.000
Ch03 Mouse IS95 Low | 126.20 to 128.60 | 127.23 | 0.12/1.72 | 119.08 | 136.24 | | 96260/96260 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 96260/96260 | 1.000
May 1 to 31, 2013
Ch01 Mouse IS95 High | 257.20 to 259.40 | 257.37 | 0.14/4.29 | 226.87 | 285.93 | | 97020/97020 | 1.000
Ch02 Mouse IS95 Med | 181.80 to 183.40 | 181.64 | 0.14/2.98 | 167.27 | 205.30 | | 97020/97020 | 1.000
Ch03 Mouse IS95 Low | 128.60 to 129.10 | 128.55 | 0.12/1.77 | 119.88 | 141.09 | | 97020/97020 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 97020/97020 | 1.000
June 1 to 30, 2013
Ch01 Mouse IS95 High | 259.40 to 260.60 | 259.64 | 0.15/4.39 | 227.53 | 294.63 | | 94514/94514 | 1.000
Ch02 Mouse IS95 Med | 183.40 to 184.20 | 183.31 | 0.14/3.05 | 164.59 | 201.45 | | 94514/94514 | 1.000
Ch03 Mouse IS95 Low | 129.10 to 130.30 | 129.22 | 0.25/3.81 | 98.48 | 159.44 | | 94506/94514 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 94496/94496 | 1.000
July 1 to 31, 2013
Ch01 Mouse IS95 High | 260.60 to 261.60 | 260.92 | 0.16/4.87 | 230.46 | 304.39 | | 99146/99146 | 1.000
Ch02 Mouse IS95 Med | 184.20 to 185.00 | 184.01 | 0.14/3.03 | 168.19 | 202.70 | | 99146/99146 | 1.000
Ch03 Mouse IS95 Low | 130.30 to 130.80 | 130.53 | 0.28/4.24 | 105.17 | 158.30 | | 99146/99146 | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 99146/99146 | 1.000
August 1 to 31, 2013
Ch01 Mouse IS95 High | 261.60 to 262.80 | 261.92 | 0.14/4.30 | 222.33 | 288.89 | 101712/101712 | | 1.000
Ch02 Mouse IS95 Med | 185.00 to 185.80 | 185.08 | 0.16/3.35 | 171.22 | 210.82 | 101712/101712 | | 1.000
Ch03 Mouse IS95 Low | 130.80 to 131.40 | 130.89 | 0.14/2.08 | 113.00 | 145.03 | 101712/101712 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 101700/101700 | | 1.000
September 1 to 30, 2013
Ch01 Mouse IS95 High | 262.80 to 275.00 | 264.04 | 0.14/4.41 | 235.55 | 309.86 | 93922/93922 | | 1.000
Ch02 Mouse IS95 Med | 185.80 to 186.60 | 186.05 | 0.15/3.20 | 169.04 | 209.04 | 93922/93922 | | 1.000
Ch03 Mouse IS95 Low | 131.40 to 131.90 | 131.72 | 0.35/5.41 | 93.28 | 169.36 | 93890/93922 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 93920/93920 | | 1.000
October 1 to 31, 2013
Ch01 Mouse IS95 High | 262.80 to 263.90 | 263.44 | 0.13/4.00 | 236.10 | 288.79 | 100816/100816 | | 1.000
Ch02 Mouse IS95 Med | 186.60 to 187.40 | 186.81 | 0.15/3.17 | 171.27 | 216.71 | 100816/100816 | | 1.000
Ch03 Mouse IS95 Low | 131.90 to 132.50 | 132.12 | 0.17/2.54 | 109.99 | 152.72 | 100816/100816 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 100816/100816 | | 1.000
November 1 to 30, 2013
Ch01 Mouse IS95 High | 263.90 to 263.90 | 263.87 | 0.15/4.69 | 177.48 | 291.88 | 93274/93278 | | 1.000
Ch02 Mouse IS95 Med | 187.40 to 187.40 | 187.21 | 0.16/3.50 | 125.18 | 208.73 | 93274/93278 | | 1.000
Ch03 Mouse IS95 Low | 131.90 to 132.50 | 131.56 | 0.33/5.16 | 33.46 | 176.17 | 93098/93278 | | 0.998
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 93226/93226 | | 1.000
December 1 to 31, 2013
Ch01 Mouse IS95 High | 262.80 to 263.90 | 263.08 | 0.14/4.35 | 221.94 | 318.53 | 96846/96846 | | 1.000
Ch02 Mouse IS95 Med | 185.80 to 187.40 | 186.01 | 0.16/3.57 | 166.56 | 220.78 | 96846/96846 | | 1.000
Ch03 Mouse IS95 Low | 131.40 to 131.90 | 131.34 | 0.14/2.10 | 117.52 | 144.93 | 96846/96846 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 96846/96846 | | 1.000
January 1 to 31, 2014
Ch01 Mouse IS95 High | 262.80 to 262.80 | 262.41 | 0.14/4.18 | 205.46 | 313.40 | 97552/97554 | | 1.000
Ch02 Mouse IS95 Med | 185.80 to 186.60 | 186.14 | 0.16/3.37 | 97.83 | 212.15 | 97550/97554 | | 1.000
Ch03 Mouse IS95 Low | 131.40 to 131.40 | 131.41 | 0.31/4.82 | 54.39 | 168.36 | 97536/97552 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97550/97550 | | 1.000
February 1 to 28, 2014
Ch01 Mouse IS95 High | 262.80 to 265.00 | 264.44 | 0.13/4.06 | 212.35 | 308.55 | 88184/88184 | | 1.000
Ch02 Mouse IS95 Med | 186.60 to 187.40 | 187.06 | 0.16/3.50 | 127.99 | 263.90 | 88170/88184 | | 1.000
Ch03 Mouse IS95 Low | 131.40 to 132.50 | 131.92 | 0.36/5.64 | 97.78 | 163.25 | 88120/88184 | | 0.999
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 88184/88184 | | 1.000
March 1 to 31, 2014
Ch01 Mouse IS95 High | 262.80 to 265.00 | 255.18 | 0.64/19.48 | 22.44 | 353.11 | 96940/97180 | | 0.998
Ch02 Mouse IS95 Med | 186.60 to 187.40 | 187.10 | 0.16/3.42 | 122.08 | 258.06 | 97170/97180 | | 1.000
Ch03 Mouse IS95 Low | 132.50 to 132.50 | 131.79 | 0.38/5.91 | 65.38 | 210.94 | 97010/97180 | | 0.998
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97142/97142 | | 1.000
April 1 to 30, 2014
Ch01 Mouse IS95 High | 261.60 to 262.80 | 261.90 | 0.27/8.39 | 22.44 | 384.56 | 94478/94550 | | 0.999
Ch02 Mouse IS95 Med | 185.80 to 186.60 | 186.68 | 0.20/4.33 | 73.16 | 297.77 | 94476/94550 | | 0.999
Ch03 Mouse IS95 Low | 131.90 to 131.90 | 131.23 | 0.28/4.23 | 67.49 | 155.79 | 94522/94550 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94548/94548 | | 1.000
May 1 to 31, 2014
Ch01 Mouse IS95 High | 260.60 to 261.60 | 261.26 | 0.14/4.17 | 236.40 | 291.11 | 97244/97244 | | 1.000
Ch02 Mouse IS95 Med | 185.00 to 185.80 | 185.64 | 0.14/2.95 | 159.77 | 212.41 | 97244/97244 | | 1.000
Ch03 Mouse IS95 Low | 131.40 to 131.90 | 131.27 | 0.28/4.25 | 94.32 | 156.82 | 97238/97244 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 97244/97244 | | 1.000
June 1 to 30, 2014
Ch01 Mouse IS95 High | 260.60 to 261.60 | 260.64 | 0.13/3.91 | 219.82 | 287.61 | 94288/94288 | | 1.000
Ch02 Mouse IS95 Med | 184.20 to 185.00 | 184.79 | 0.14/2.97 | 153.76 | 204.42 | 94288/94288 | | 1.000
Ch03 Mouse IS95 Low | 130.30 to 131.40 | 130.58 | 0.28/4.32 | 84.05 | 165.61 | 94264/94288 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 94288/94288 | | 1.000
July 1 to 9, 2014
Ch01 Mouse IS95 High | 261.60 to 261.60 | 261.65 | 0.11/3.45 | 240.24 | 278.45 | 25098/25098 | | 1.000
Ch02 Mouse IS95 Med | 185.00 to 185.00 | 184.91 | 0.12/2.53 | 168.56 | 198.96 | 25098/25098 | | 1.000
Ch03 Mouse IS95 Low | 130.30 to 130.30 | 130.67 | 0.68/10.57 | 65.61 | 181.71 | 24784/25098 | | 0.987
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 25064/25064 | | 1.000
June 18, 2012, to July 9, 2014
Ch01 Mouse IS95 High | 194.10 to 275.00 | 250.68 | 0.20/5.84 | 22.44 | 384.56 | 2272240/2272568 | | 1.000
Ch02 Mouse IS95 Med | 137.20 to 187.40 | 177.23 | 0.15/3.06 | 73.16 | 297.77 | 2272456/2272568 | | 1.000
Ch03 Mouse IS95 Low | 97.00 to 132.50 | 125.25 | 0.22/3.20 | 33.46 | 210.94 | 2272056/2272566 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 2272416/2272416 | | 1.000

^a^ Ch = chamber (e.g., Ch11 = Chamber 11).

Table I-7 Summary of CDMA-modulated Cell Phone RFR Exposure Data—E-Field^a^

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | Max [V/m] | In Range/ Total | Ratio
June 18 to 30, 2012
Ch01 Mouse IS95 High | 194.1 to 199.6 | 182.96 | 0.16/3.46 | 132.6 | 264.8 | 38944/38950 | 1.000
Ch02 Mouse IS95 Med | 137.2 to 141.2 | 127.98 | 0.20/2.95 | 109.8 | 152.6 | 38926/38950 | 0.999
Ch03 Mouse IS95 Low | 97.0 to 99.8 | 94.73 | 0.17/1.82 | 86.4 | 108.0 | 38950/38950 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 38950/38950 | 1.000
July 1 to 31, 2012
Ch01 Mouse IS95 High | 199.6 to 212.3 | 191.13 | 0.18/3.93 | 161.2 | 251.6 | 97458/97462 | 1.000
Ch02 Mouse IS95 Med | 141.2 to 150.1 | 134.04 | 0.20/3.16 | 115.7 | 186.0 | 97458/97462 | 1.000
Ch03 Mouse IS95 Low | 99.8 to 106.1 | 99.09 | 0.17/1.98 | 83.9 | 131.8 | 97460/97462 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97462/97462 | 1.000
August 1 to 31, 2012
Ch01 Mouse IS95 High | 212.3 to 222.2 | 204.21 | 0.16/3.81 | 186.0 | 241.5 | 94976/94976 | 1.000
Ch02 Mouse IS95 Med | 150.1 to 157.1 | 140.96 | 0.20/3.34 | 124.8 | 194.4 | 94974/94976 | 1.000
Ch03 Mouse IS95 Low | 106.1 to 111.1 | 104.20 | 0.18/2.18 | 94.2 | 127.8 | 94976/94976 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94976/94976 | 1.000
September 1 to 30, 2012
Ch01 Mouse IS95 High | 222.2 to 230.9 | 214.97 | 0.17/4.21 | 191.7 | 239.8 | 94374/94374 | 1.000
Ch02 Mouse IS95 Med | 157.1 to 161.4 | 147.53 | 0.18/3.03 | 133.9 | 170.0 | 94374/94374 | 1.000
Ch03 Mouse IS95 Low | 111.1 to 114.1 | 107.71 | 0.17/2.09 | 98.9 | 118.0 | 94374/94374 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94370/94370 | 1.000
October 1 to 31, 2012
Ch01 Mouse IS95 High | 230.9 to 237.6 | 221.21 | 0.15/3.87 | 201.8 | 239.3 | 97604/97604 | 1.000
Ch02 Mouse IS95 Med | 161.4 to 166.6 | 149.17 | 0.17/2.99 | 134.5 | 163.2 | 97604/97604 | 1.000
Ch03 Mouse IS95 Low | 114.1 to 117.8 | 112.30 | 0.17/2.27 | 101.0 | 125.3 | 97604/97604 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97602/97602 | 1.000
November 1 to 30, 2012
Ch01 Mouse IS95 High | 237.6 to 242.7 | 227.51 | 0.17/4.54 | 151.4 | 254.3 | 94626/94628 | 1.000
Ch02 Mouse IS95 Med | 166.6 to 171.7 | 154.82 | 0.18/3.32 | 104.7 | 176.2 | 94626/94628 | 1.000
Ch03 Mouse IS95 Low | 117.8 to 120.6 | 116.59 | 0.17/2.36 | 76.7 | 128.5 | 94626/94628 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94628/94628 | 1.000
December 1 to 31, 2012
Ch01 Mouse IS95 High | 242.7 to 247.2 | 233.09 | 0.17/4.48 | 213.6 | 253.7 | 97500/97500 | 1.000
Ch02 Mouse IS95 Med | 171.7 to 173.8 | 159.76 | 0.19/3.47 | 144.1 | 176.0 | 97500/97500 | 1.000
Ch03 Mouse IS95 Low | 120.6 to 122.9 | 118.37 | 0.19/2.59 | 109.0 | 131.2 | 97500/97500 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97496/97496 | 1.000
January 1 to 31, 2013
Ch01 Mouse IS95 High | 247.2 to 249.8 | 235.20 | 0.16/4.42 | 215.1 | 260.4 | 97378/97378 | 1.000
Ch02 Mouse IS95 Med | 173.8 to 175.7 | 162.37 | 0.18/3.35 | 148.0 | 178.4 | 97378/97378 | 1.000
Ch03 Mouse IS95 Low | 122.9 to 124.3 | 118.71 | 0.18/2.51 | 108.3 | 130.2 | 97378/97378 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97364/97364 | 1.000
February 1 to 28, 2013
Ch01 Mouse IS95 High | 249.8 to 252.4 | 238.62 | 0.16/4.53 | 217.4 | 264.4 | 88116/88116 | 1.000
Ch02 Mouse IS95 Med | 175.7 to 177.6 | 162.29 | 0.19/3.61 | 141.3 | 193.5 | 88116/88116 | 1.000
Ch03 Mouse IS95 Low | 124.3 to 125.6 | 119.75 | 0.19/2.59 | 109.5 | 131.5 | 88116/88116 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 88116/88116 | 1.000
March 1 to 31, 2013
Ch01 Mouse IS95 High | 252.4 to 253.6 | 238.57 | 0.18/5.13 | 219.6 | 265.7 | 97784/97784 | 1.000
Ch02 Mouse IS95 Med | 177.6 to 179.3 | 164.78 | 0.19/3.74 | 149.7 | 187.8 | 97784/97784 | 1.000
Ch03 Mouse IS95 Low | 125.6 to 126.2 | 122.27 | 0.20/2.80 | 111.3 | 136.0 | 97784/97784 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97784/97784 | 1.000
April 1 to 30, 2013
Ch01 Mouse IS95 High | 253.6 to 257.2 | 242.43 | 0.19/5.50 | 219.5 | 273.9 | 96260/96260 | 1.000
Ch02 Mouse IS95 Med | 179.3 to 181.8 | 167.11 | 0.18/3.58 | 151.5 | 185.2 | 96260/96260 | 1.000
Ch03 Mouse IS95 Low | 126.2 to 128.6 | 123.32 | 0.18/2.59 | 113.4 | 135.4 | 96260/96260 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 96260/96260 | 1.000
May 1 to 31, 2013
Ch01 Mouse IS95 High | 257.2 to 259.4 | 244.96 | 0.20/5.75 | 215.4 | 275.7 | 97020/97020 | 1.000
Ch02 Mouse IS95 Med | 181.8 to 183.4 | 168.02 | 0.18/3.60 | 150.5 | 190.8 | 97020/97020 | 1.000
Ch03 Mouse IS95 Low | 128.6 to 129.1 | 124.68 | 0.18/2.57 | 113.0 | 137.8 | 97020/97020 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97020/97020 | 1.000
June 1 to 30, 2013
Ch01 Mouse IS95 High | 259.4 to 260.6 | 246.98 | 0.21/5.93 | 212.0 | 288.6 | 94514/94514 | 1.000
Ch02 Mouse IS95 Med | 183.4 to 184.2 | 170.19 | 0.18/3.64 | 154.4 | 190.5 | 94514/94514 | 1.000
Ch03 Mouse IS95 Low | 129.1 to 130.3 | 128.47 | 0.64/9.79 | 88.7 | 176.8 | 94186/94514 | 0.997
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94496/94496 | 1.000
July 1 to 31, 2013
Ch01 Mouse IS95 High | 260.6 to 261.6 | 249.22 | 0.21/6.06 | 220.7 | 300.9 | 99146/99146 | 1.000
Ch02 Mouse IS95 Med | 184.2 to 185.0 | 170.91 | 0.19/3.80 | 154.7 | 193.1 | 99146/99146 | 1.000
Ch03 Mouse IS95 Low | 130.3 to 130.8 | 141.91 | 0.62/10.43 | 96.1 | 177.5 | 98928/99146 | 0.998
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 99146/99146 | 1.000
August 1 to 31, 2013
Ch01 Mouse IS95 High | 261.6 to 262.8 | 249.57 | 0.20/5.69 | 215.3 | 288.2 | 101712/101712 | 1.000
Ch02 Mouse IS95 Med | 185.0 to 185.8 | 170.62 | 0.20/3.99 | 153.4 | 196.1 | 101712/101712 | 1.000
Ch03 Mouse IS95 Low | 130.8 to 131.4 | 147.36 | 0.24/4.17 | 111.4 | 161.5 | 101712/101712 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 101700/101700 | 1.000
September 1 to 30, 2013
Ch01 Mouse IS95 High | 262.8 to 275.0 | 254.31 | 0.20/6.01 | 220.4 | 300.7 | 93922/93922 | 1.000
Ch02 Mouse IS95 Med | 185.8 to 186.6 | 171.99 | 0.19/3.87 | 155.0 | 194.2 | 93922/93922 | 1.000
Ch03 Mouse IS95 Low | 131.4 to 131.9 | 136.81 | 0.82/13.59 | 85.5 | 183.6 | 93028/93922 | 0.990
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 93920/93920 | 1.000
October 1 to 31, 2013
Ch01 Mouse IS95 High | 262.8 to 263.9 | 250.46 | 0.20/5.73 | 221.9 | 282.9 | 100816/100816 | 1.000
Ch02 Mouse IS95 Med | 186.6 to 187.4 | 172.10 | 0.19/3.78 | 158.0 | 197.8 | 100816/100816 | 1.000
Ch03 Mouse IS95 Low | 131.9 to 132.5 | 140.01 | 0.32/5.24 | 95.8 | 158.3 | 100766/100816 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 100816/100816 | 1.000
November 1 to 30, 2013
Ch01 Mouse IS95 High | 263.9 to 263.9 | 254.87 | 0.21/6.33 | 172.3 | 287.3 | 93272/93278 | 1.000
Ch02 Mouse IS95 Med | 187.4 to 187.4 | 173.77 | 0.22/4.48 | 116.2 | 196.2 | 93242/93278 | 1.000
Ch03 Mouse IS95 Low | 131.9 to 132.5 | 139.81 | 0.43/7.11 | 34.8 | 193.8 | 92976/93278 | 0.997
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 93226/93226 | 1.000
December 1 to 31, 2013
Ch01 Mouse IS95 High | 262.8 to 263.9 | 264.86 | 0.26/8.09 | 222.6 | 327.2 | 96846/96846 | 1.000
Ch02 Mouse IS95 Med | 185.8 to 187.4 | 174.60 | 0.22/4.51 | 152.2 | 209.3 | 96846/96846 | 1.000
Ch03 Mouse IS95 Low | 131.4 to 131.9 | 141.81 | 0.23/3.79 | 119.4 | 161.0 | 96846/96846 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 96846/96846 | 1.000
January 1 to 31, 2014
Ch01 Mouse IS95 High | 262.8 to 262.8 | 259.88 | 0.24/7.35 | 197.0 | 322.5 | 97552/97554 | 1.000
Ch02 Mouse IS95 Med | 185.8 to 186.6 | 171.64 | 0.20/4.08 | 93.5 | 198.8 | 97550/97554 | 1.000
Ch03 Mouse IS95 Low | 131.4 to 131.4 | 138.63 | 0.57/9.33 | 56.5 | 182.3 | 96868/97552 | 0.993
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97550/97550 | 1.000
February 1 to 28, 2014
Ch01 Mouse IS95 High | 262.8 to 265.0 | 254.65 | 0.22/6.40 | 202.8 | 293.6 | 88182/88184 | 1.000
Ch02 Mouse IS95 Med | 186.6 to 187.4 | 172.87 | 0.22/4.50 | 121.5 | 251.8 | 88162/88184 | 1.000
Ch03 Mouse IS95 Low | 131.4 to 132.5 | 130.86 | 0.88/13.88 | 85.2 | 176.6 | 87104/88184 | 0.988
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 88184/88184 | 1.000
March 1 to 31, 2014
Ch01 Mouse IS95 High | 262.8 to 265.0 | 248.73 | 0.66/19.55 | 21.5 | 370.2 | 96900/97180 | 0.997
Ch02 Mouse IS95 Med | 186.6 to 187.4 | 178.11 | 0.21/4.32 | 114.7 | 249.5 | 97168/97180 | 1.000
Ch03 Mouse IS95 Low | 132.5 to 132.5 | 125.83 | 0.60/8.93 | 56.2 | 202.2 | 96866/97180 | 0.997
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97142/97142 | 1.000
April 1 to 30, 2014
Ch01 Mouse IS95 High | 261.6 to 262.8 | 251.78 | 0.30/8.89 | 20.9 | 380.7 | 94432/94550 | 0.999
Ch02 Mouse IS95 Med | 185.8 to 186.6 | 176.58 | 0.25/5.24 | 68.9 | 283.3 | 94536/94550 | 1.000
Ch03 Mouse IS95 Low | 131.9 to 131.9 | 132.52 | 0.51/7.96 | 68.5 | 160.3 | 94454/94550 | 0.999
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94548/94548 | 1.000
May 1 to 31, 2014
Ch01 Mouse IS95 High | 260.6 to 261.6 | 250.61 | 0.21/6.02 | 218.6 | 280.8 | 97244/97244 | 1.000
Ch02 Mouse IS95 Med | 185.0 to 185.8 | 174.90 | 0.18/3.74 | 145.3 | 200.0 | 97242/97244 | 1.000
Ch03 Mouse IS95 Low | 131.4 to 131.9 | 129.23 | 0.53/8.16 | 89.0 | 165.6 | 97218/97244 | 1.000
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 97244/97244 | 1.000
June 1 to 30, 2014
Ch01 Mouse IS95 High | 260.6 to 261.6 | 253.68 | 0.18/5.36 | 213.1 | 282.1 | 94288/94288 | 1.000
Ch02 Mouse IS95 Med | 184.2 to 185.0 | 177.67 | 0.23/4.76 | 153.6 | 200.6 | 94288/94288 | 1.000
Ch03 Mouse IS95 Low | 130.3 to 131.4 | 125.07 | 0.47/6.93 | 79.5 | 174.0 | 94236/94288 | 0.999
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 94288/94288 | 1.000
July 1 to 9, 2014
Ch01 Mouse IS95 High | 261.6 to 261.6 | 259.20 | 0.16/4.71 | 236.0 | 277.7 | 25098/25098 | 1.000
Ch02 Mouse IS95 Med | 185.0 to 185.0 | 184.69 | 0.16/3.33 | 168.3 | 199.6 | 25098/25098 | 1.000
Ch03 Mouse IS95 Low | 130.3 to 130.3 | 127.53 | 0.87/13.46 | 60.8 | 192.7 | 24686/25098 | 0.984
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 25064/25064 | 1.000
June 18, 2012, to July 9, 2014
Ch01 Mouse IS95 High | 194.1 to 275.0 | 239.79 | 0.28/7.76 | 20.9 | 380.7 | 2272148/ 2272568 | 1.000
Ch02 Mouse IS95 Med | 137.2 to 187.4 | 164.41 | 0.22/4.14 | 68.9 | 283.3 | 2272446/ 2272568 | 1.000
Ch03 Mouse IS95 Low | 97.0 to 132.5 | 125.83 | 0.60/9.02 | 34.8 | 202.2 | 2268550/ 2272566 | 0.998
Ch13 Mouse Sham | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 2272416/ 2272416 | 1.000

^a^ Ch = chamber (e.g., Ch11 = Chamber 11).

Table I-8 Summary of CDMA-modulated Cell Phone RFR Exposure Data—H-Field^a^

Chamber | Target Range [V/m] | | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | Max [V/m] | In Range/ Total | | Ratio
June 18 to 30, 2012
Ch01 Mouse IS95 High | 0.52 to 0.53 | | 0.556 | 0.17/0.011 | 0.41 | 0.77 | 38948/38950 | | 1.000
Ch02 Mouse IS95 Med | 0.36 to 0.38 | | 0.394 | 0.22/0.010 | 0.35 | 0.50 | 38948/38950 | | 1.000
Ch03 Mouse IS95 Low | 0.26 to 0.27 | | 0.269 | 0.17/0.005 | 0.25 | 0.30 | 38950/38950 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | 0.00 | 0.00 | 38950/38950 | | 1.000
July 1 to 31, 2012
Ch01 Mouse IS95 High | 0.53 to 0.56 | | 0.581 | 0.19/0.013 | 0.49 | 0.77 | 97460/97462 | | 1.000
Ch02 Mouse IS95 Med | 0.38 to 0.40 | | 0.414 | 0.21/0.010 | 0.36 | 0.55 | 97460/97462 | | 1.000
Ch03 Mouse IS95 Low | 0.27 to 0.28 | | 0.284 | 0.17/0.005 | 0.25 | 0.38 | 97460/97462 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | 0.00 | 0.00 | 97462/97462 | | 1.000
August 1 to 31, 2012
Ch01 Mouse IS95 High | 0.56 to 0.59 | | 0.611 | 0.17/0.012 | 0.55 | 0.73 | 94976/94976 | | 1.000
Ch02 Mouse IS95 Med | 0.40 to 0.42 | | 0.436 | 0.21/0.011 | 0.39 | 0.59 | 94974/94976 | | 1.000
Ch03 Mouse IS95 Low | 0.28 to 0.30 | | 0.299 | 0.17/0.006 | 0.27 | 0.37 | 94974/94976 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | 0.00 | 0.00 | 94976/94976 | | 1.000
September 1 to 30, 2012
Ch01 Mouse IS95 High | 0.59 to 0.61 | | 0.638 | 0.17/0.013 | 0.58 | 0.69 | 94374/94374 | | 1.000
Ch02 Mouse IS95 Med | 0.42 to 0.43 | | 0.454 | 0.19/0.010 | 0.42 | 0.53 | 94374/94374 | | 1.000
Ch03 Mouse IS95 Low | 0.30 to 0.30 | | 0.313 | 0.17/0.006 | 0.29 | 0.35 | 94374/94374 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | 0.00 | 0.00 | 94370/94370 | | 1.000
October 1 to 31, 2012
Ch01 Mouse IS95 High | 0.61 to 0.63 | | 0.654 | 0.16/0.012 | 0.59 | 0.70 | 97604/97604 | | 1.000
Ch02 Mouse IS95 Med | 0.43 to 0.44 | | 0.473 | 0.19/0.010 | 0.43 | 0.51 | 97604/97604 | | 1.000
Ch03 Mouse IS95 Low | 0.30 to 0.31 | | 0.316 | 0.17/0.006 | 0.29 | 0.34 | 97604/97604 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | 0.00 | 0.00 | 97602/97602 | | 1.000
November 1 to 30, 2012
Ch01 Mouse IS95 High | 0.63 to 0.64 | | 0.672 | 0.17/0.013 | 0.44 | 0.72 | 94626/94628 | | 1.000
Ch02 Mouse IS95 Med | 0.44 to 0.46 | | 0.487 | 0.22/0.012 | 0.34 | 0.54 | 94626/94628 | | 1.000
Ch03 Mouse IS95 Low | 0.31 to 0.32 | | 0.324 | 0.17/0.006 | 0.23 | 0.36 | 94626/94628 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | 0.00 | 0.00 | 94628/94628 | | 1.000
December 1 to 31, 2012
Ch01 Mouse IS95 High | 0.64 to 0.66 | | 0.685 | 0.17/0.013 | 0.62 | 0.74 | 97500/97500 | | 1.000
Ch02 Mouse IS95 Med | 0.46 to 0.46 | | 0.492 | 0.20/0.012 | 0.45 | 0.54 | 97500/97500 | | 1.000
Ch03 Mouse IS95 Low | 0.32 to 0.33 | | 0.333 | 0.18/0.007 | 0.30 | 0.36 | 97500/97500 | | 1.000
Ch13 Mouse Sham | 0.00 to 0.00 | | 0.000 | –/0.000 | 0.00 | 0.00 | 97496/97496 | | 1.000
January 1 to 31, 2013
Ch01 Mouse IS95 High | | 0.66 to 0.66 | 0.697 | 0.17/0.014 | 0.63 | 0.77 | 97378/97378 | | 1.000
Ch02 Mouse IS95 Med | | 0.46 to 0.47 | 0.497 | 0.19/0.011 | 0.45 | 0.55 | 97378/97378 | | 1.000
Ch03 Mouse IS95 Low | | 0.33 to 0.33 | 0.342 | 0.18/0.007 | 0.31 | 0.38 | 97378/97378 | | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 97364/97364 | | 1.000
February 1 to 28, 2013
Ch01 Mouse IS95 High | | 0.66 to 0.67 | 0.702 | 0.16/0.013 | 0.65 | 0.77 | 88116/88116 | | 1.000
Ch02 Mouse IS95 Med | | 0.47 to 0.47 | 0.508 | 0.21/0.012 | 0.46 | 0.61 | 88114/88116 | | 1.000
Ch03 Mouse IS95 Low | | 0.33 to 0.33 | 0.347 | 0.18/0.007 | 0.32 | 0.38 | 88116/88116 | | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 88116/88116 | | 1.000
March 1 to 31, 2013
Ch01 Mouse IS95 High | | 0.67 to 0.67 | 0.710 | 0.19/0.015 | 0.65 | 0.77 | 97784/97784 | | 1.000
Ch02 Mouse IS95 Med | | 0.47 to 0.48 | 0.511 | 0.22/0.013 | 0.46 | 0.56 | 97784/97784 | | 1.000
Ch03 Mouse IS95 Low | | 0.33 to 0.34 | 0.344 | 0.19/0.008 | 0.32 | 0.38 | 97784/97784 | | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 97784/97784 | | 1.000
April 1 to 30, 2013
Ch01 Mouse IS95 High | | 0.67 to 0.68 | 0.713 | 0.20/0.016 | 0.65 | 0.82 | 96260/96260 | | 1.000
Ch02 Mouse IS95 Med | | 0.48 to 0.48 | 0.511 | 0.19/0.011 | 0.47 | 0.56 | 96260/96260 | | 1.000
Ch03 Mouse IS95 Low | | 0.34 to 0.34 | 0.348 | 0.18/0.007 | 0.32 | 0.38 | 96260/96260 | | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 96260/96260 | | 1.000
May 1 to 31, 2013
Ch01 Mouse IS95 High | | 0.68 to 0.69 | 0.716 | 0.19/0.016 | 0.63 | 0.79 | 97020/97020 | | 1.000
Ch02 Mouse IS95 Med | | 0.48 to 0.49 | 0.518 | 0.21/0.013 | 0.46 | 0.59 | 97020/97020 | | 1.000
Ch03 Mouse IS95 Low | | 0.34 to 0.34 | 0.351 | 0.17/0.007 | 0.32 | 0.39 | 97020/97020 | | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 97020/97020 | | 1.000
June 1 to 30, 2013
Ch01 Mouse IS95 High | | 0.69 to 0.69 | 0.722 | 0.20/0.017 | 0.64 | 0.84 | 94514/94514 | | 1.000
Ch02 Mouse IS95 Med | | 0.49 to 0.49 | 0.521 | 0.21/0.013 | 0.46 | 0.57 | 94514/94514 | | 1.000
Ch03 Mouse IS95 Low | | 0.34 to 0.35 | 0.345 | 0.53/0.022 | 0.28 | 0.43 | 94512/94514 | | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 94496/94496 | | 1.000
July 1 to 31, 2013
Ch01 Mouse IS95 High | | 0.69 to 0.69 | 0.723 | 0.21/0.018 | 0.63 | 0.84 | 99146/99146 | | 1.000
Ch02 Mouse IS95 Med | | 0.49 to 0.49 | 0.523 | 0.21/0.013 | 0.48 | 0.58 | 99146/99146 | | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.316 | 0.45/0.017 | 0.28 | 0.41 | 99146/99146 | | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 99146/99146 | | 1.000
August 1 to 31, 2013
Ch01 Mouse IS95 High | | 0.69 to 0.70 | 0.727 | 0.19/0.016 | 0.60 | 0.81 | | 101712/101712 | 1.000
Ch02 Mouse IS95 Med | | 0.49 to 0.49 | 0.529 | 0.22/0.013 | 0.48 | 0.62 | | 101710/101712 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.303 | 0.18/0.006 | 0.28 | 0.35 | | 101712/101712 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 101700/101700 | 1.000
September 1 to 30, 2013
Ch01 Mouse IS95 High | | 0.70 to 0.73 | 0.726 | 0.19/0.016 | 0.63 | 0.85 | | 93922/93922 | 1.000
Ch02 Mouse IS95 Med | | 0.49 to 0.50 | 0.531 | 0.22/0.013 | 0.47 | 0.59 | | 93922/93922 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.336 | 0.62/0.025 | 0.22 | 0.45 | | 93914/93922 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 93920/93920 | 1.000
October 1 to 31, 2013
Ch01 Mouse IS95 High | | 0.70 to 0.70 | 0.733 | 0.19/0.016 | 0.66 | 0.82 | | 100816/100816 | 1.000
Ch02 Mouse IS95 Med | | 0.50 to 0.50 | 0.535 | 0.22/0.013 | 0.49 | 0.63 | | 100816/100816 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.330 | 0.22/0.008 | 0.29 | 0.41 | | 100816/100816 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 100816/100816 | 1.000
November 1 to 30, 2013
Ch01 Mouse IS95 High | | 0.70 to 0.70 | 0.724 | 0.20/0.017 | 0.48 | 0.81 | | 93274/93278 | 1.000
Ch02 Mouse IS95 Med | | 0.50 to 0.50 | 0.532 | 0.23/0.014 | 0.36 | 0.59 | | 93276/93278 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.327 | 0.27/0.010 | 0.19 | 0.43 | | 93096/93278 | 0.998
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 93226/93226 | 1.000
December 1 to 31, 2013
Ch01 Mouse IS95 High | | 0.70 to 0.70 | 0.693 | 0.25/0.020 | 0.59 | 0.82 | | 96846/96846 | 1.000
Ch02 Mouse IS95 Med | | 0.49 to 0.50 | 0.524 | 0.24/0.015 | 0.46 | 0.62 | | 96844/96846 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.321 | 0.19/0.007 | 0.28 | 0.36 | | 96846/96846 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 96846/96846 | 1.000
January 1 to 31, 2014
Ch01 Mouse IS95 High | | 0.70 to 0.70 | 0.703 | 0.22/0.018 | 0.57 | 0.81 | | 97554/97554 | 1.000
Ch02 Mouse IS95 Med | | 0.49 to 0.50 | 0.532 | 0.22/0.014 | 0.27 | 0.62 | | 97550/97554 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.329 | 0.39/0.015 | 0.14 | 0.41 | | 97542/97552 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 97550/97550 | 1.000
February 1 to 28, 2014
Ch01 Mouse IS95 High | | 0.70 to 0.70 | 0.727 | 0.21/0.018 | 0.59 | 0.86 | | 88184/88184 | 1.000
Ch02 Mouse IS95 Med | | 0.50 to 0.50 | 0.534 | 0.24/0.015 | 0.36 | 0.74 | | 88170/88184 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.353 | 0.70/0.029 | 0.27 | 0.41 | | 88180/88184 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 88184/88184 | 1.000
March 1 to 31, 2014
Ch01 Mouse IS95 High | | 0.70 to 0.70 | 0.694 | 0.65/0.054 | 0.10 | 0.90 | | 96954/97180 | 0.998
Ch02 Mouse IS95 Med | | 0.50 to 0.50 | 0.520 | 0.21/0.013 | 0.34 | 0.71 | | 97170/97180 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.365 | 0.43/0.019 | 0.19 | 0.58 | | 97036/97180 | 0.999
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 97142/97142 | 1.000
April 1 to 30, 2014
Ch01 Mouse IS95 High | | 0.69 to 0.70 | 0.722 | 0.31/0.026 | 0.15 | 1.03 | | 94494/94550 | 0.999
Ch02 Mouse IS95 Med | | 0.49 to 0.50 | 0.522 | 0.28/0.017 | 0.21 | 0.83 | | 94406/94550 | 0.998
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.345 | 0.38/0.015 | 0.18 | 0.42 | | 94540/94550 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 94548/94548 | 1.000
May 1 to 31, 2014
Ch01 Mouse IS95 High | | 0.69 to 0.69 | 0.721 | 0.21/0.017 | 0.64 | 0.82 | | 97244/97244 | 1.000
Ch02 Mouse IS95 Med | | 0.49 to 0.49 | 0.521 | 0.20/0.012 | 0.46 | 0.60 | | 97244/97244 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.354 | 0.37/0.016 | 0.26 | 0.42 | | 97240/97244 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 97244/97244 | 1.000
June 1 to 30, 2014
Ch01 Mouse IS95 High | | 0.69 to 0.69 | 0.710 | 0.17/0.014 | 0.60 | 0.79 | | 94288/94288 | 1.000
Ch02 Mouse IS95 Med | | 0.49 to 0.49 | 0.509 | 0.24/0.014 | 0.41 | 0.57 | | 94288/94288 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.361 | 0.27/0.011 | 0.24 | 0.43 | | 94276/94288 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 94288/94288 | 1.000
July 1 to 9, 2014
Ch01 Mouse IS95 High | | 0.69 to 0.69 | 0.701 | 0.14/0.011 | 0.65 | 0.76 | | 25098/25098 | 1.000
Ch02 Mouse IS95 Med | | 0.49 to 0.49 | 0.491 | 0.14/0.008 | 0.44 | 0.53 | | 25098/25098 | 1.000
Ch03 Mouse IS95 Low | | 0.35 to 0.35 | 0.355 | 0.68/0.029 | 0.19 | 0.49 | | 24740/25098 | 0.986
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 25064/25064 | 1.000
June 18, 2012, to July 9, 2014
Ch01 Mouse IS95 High | | 0.52 to 0.73 | 0.694 | 0.29/0.023 | 0.10 | 1.03 | | 2272276/ 2272568 | 1.000
Ch02 Mouse IS95 Med | | 0.36 to 0.50 | 0.504 | 0.23/0.013 | 0.21 | 0.83 | | 2272380/ 2272568 | 1.000
Ch03 Mouse IS95 Low | | 0.26 to 0.35 | 0.331 | 0.53/0.021 | 0.14 | 0.58 | | 2272194/ 2272566 | 1.000
Ch13 Mouse Sham | | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | 2272416/ 2272416 | 1.000

^a^ Ch = chamber (e.g., Ch11 = Chamber 11).