# Appendix H Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table H-1 Summary of Reproductive Tissue Evaluations for Male Mice at the 14-week Interim Evaluation in the Two-yearGSM-modulated Cell Phone RFR Study^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 34.8 ± 0.8 | 33.3 ± 0.8 | 34.3 ± 0.6 | 33.0 ± 0.5
L. Cauda epididymis | 0.020 ± 0.001 | 0.020 ± 0.001 | 0.021 ± 0.001 | 0.019 ± 0.001
L. Epididymis | 0.048 ± 0.002 | 0.050 ± 0.003 | 0.050 ± 0.003 | 0.047 ± 0.002
L. Testis | 0.104 ± 0.002 | 0.107 ± 0.002 | 0.101 ± 0.007 | 0.105 ± 0.002
Spermatid measurements
Spermatid heads (10^6^/testis) | 21.9 ± 1.9 | 22.2 ± 1.6 | 20.2 ± 3.0 | 22.4 ± 1.4
Spermatid heads (10^3^/mg testis) | 210.6 ± 17.0 | 208.2 ± 13.9 | 186.4 ± 26.6 | 213.0 ± 12.2
Epididymal spermatozoal measurements
Sperm motility (%) | 73.5 ± 5.7 | 66.8 ± 6.1 | 66.2 ± 7.9 | 76.8 ± 5.0
Sperm (10^6^/cauda epididymis) | 24.2 ± 4.7 | 18.0 ± 3.2 | 18.3 ± 2.2 | 15.9 ± 2.5
Sperm (10^3^/mg cauda epididymis) | 1,254.1 ± 258.5 | 921.1 ± 164.5 | 880.0 ± 122.2 | 825.1 ± 129.7

^a^ Data are presented as mean ± standard error. Differences from the sham control group are not significant by Williams’ or Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table H-2 Estrous Cycle Characterization for Female Mice at the 14-week Interim Evaluation in the Two-yearGSM-modulated Cell Phone RFR Study^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 24.4 ± 0.4 | 24.9 ± 0.5 | 25.0 ± 0.5 | 26.2 ± 0.7*
Proportion of regular cycling females^b^ | 10/10 | 10/10 | 10/10 | 10/10
Estrous cycle length (days) | 4.0 ± 0.05 | 4.0 ± 0.03 | 4.2 ± 0.22 | 4.2 ± 0.21
Estrous stages (% of cycle)
Diestrus | 33.8 | 32.5 | 33.8 | 42.0
Proestrus | 0.6 | 1.3 | 0.0 | 0.0
Estrus | 51.0 | 49.0 | 49.7 | 47.8
Metestrus | 14.6 | 15.9 | 15.9 | 9.6
Uncertain diagnoses | 0.0 | 1.3 | 0.6 | 0.6

* Significantly different (P ≤ 0.05) from the sham control group by Williams’ or Dunnett’s test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the sham control group are not significant by Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the sham control group and each exposed group indicated exposed females did not have extended estrus or diestrus.

^b^ Number of females with a regular cycle/number of females cycling.

Table H-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice at the 14-week Interim Evaluation in the Two-yearGSM-modulated Cell Phone RFR Study

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | 0.649
Overall Tests | 2.5 W/kg vs. Sham Controls | 0.999
Overall Tests | 5 W/kg vs. Sham Controls | 0.42
Overall Tests | 10 W/kg vs. Sham Controls | 0.291
Extended Estrus | Overall | 0.997
Extended Estrus | 2.5 W/kg vs. Sham Controls | 0.999
Extended Estrus | 5 W/kg vs. Sham Controls | 0.755
Extended Estrus | 10 W/kg vs. Sham Controls | 1
Extended Diestrus | Overall | 0.414
Extended Diestrus | 2.5 W/kg vs. Sham Controls | 1
Extended Diestrus | 5 W/kg vs. Sham Controls | 0.324
Extended Diestrus | 10 W/kg vs. Sham Controls | 0.147
Extended Metestrus | Overall | 1
Extended Metestrus | 2.5 W/kg vs. Sham Controls | 1
Extended Metestrus | 5 W/kg vs. Sham Controls | 1
Extended Metestrus | 10 W/kg vs. Sham Controls | 1
Extended Proestrus | Overall | 1
Extended Proestrus | 2.5 W/kg vs. Sham Controls | 1
Extended Proestrus | 5 W/kg vs. Sham Controls | 1
Extended Proestrus | 10 W/kg vs. Sham Controls | 1
Skipped Estrus | Overall | 1
Skipped Estrus | 2.5 W/kg vs. Sham Controls | 1
Skipped Estrus | 5 W/kg vs. Sham Controls | 1
Skipped Estrus | 10 W/kg vs. Sham Controls | 1
Skipped Diestrus | Overall | 1
Skipped Diestrus | 2.5 W/kg vs. Sham Controls | 1
Skipped Diestrus | 5 W/kg vs. Sham Controls | 1
Skipped Diestrus | 10 W/kg vs. Sham Controls | 1

^a^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the sham control group.

Table H-4 Summary of Reproductive Tissue Evaluations for Male Mice at the 14-week Interim Evaluation in the Two-yearCDMA-modulated Cell Phone RFR Study^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 34.8 ± 0.8 | 35.5 ± 0.4 | 33.2 ± 0.7 | 36.2 ± 0.7
L. Cauda epididymis | 0.020 ± 0.001 | 0.021 ± 0.001 | 0.020 ± 0.000 | 0.021 ± 0.000
L. Epididymis | 0.048 ± 0.002 | 0.051 ± 0.002 | 0.047 ± 0.001 | 0.051 ± 0.003
L. Testis | 0.104 ± 0.002 | 0.106 ± 0.005 | 0.105 ± 0.001 | 0.109 ± 0.002
Spermatid measurements
Spermatid heads (10^6^/testis) | 21.9 ± 1.9 | 21.2 ± 1.9 | 23.4 ± 1.6 | 22.5 ± 1.8
Spermatid heads (10^3^/mg testis) | 210.6 ± 17.0 | 196.6 ± 11.1 | 222.8 ± 15.0 | 205.4 ± 14.6
Epididymal spermatozoal measurements
Sperm motility (%) | 73.5 ± 5.7 | 66.3 ± 6.7 | 67.5 ± 5.9 | 68.1 ± 8.3
Sperm (10^6^/cauda epididymis) | 24.2 ± 4.7 | 18.5 ± 4.8 | 13.0 ± 2.1 | 18.4 ± 1.5
Sperm (10^3^/mg cauda epididymis) | 1,254.1 ± 258.5 | 851.4 ± 181.3 | 674.6 ± 118.8 | 892.2 ± 69.2

^a^ Data are presented as mean ± standard error. Differences from the sham control group are not significant by Williams’ or Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table H-5 Estrous Cycle Characterization for Female Mice at the 14-week Interim Evaluation in the Two-yearCDMA-modulated Cell Phone RFR Study^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 24.4 ± 0.4 | 25.5 ± 0.5 | 25.7 ± 0.7 | 24.5 ± 0.3
Proportion of regular cycling females^b^ | 10/10 | 10/10 | 10/10 | 10/10
Estrous cycle length (days) | 4.0 ± 0.05 | 4.8 ± 0.71 | 4.0 ± 0.07 | 4.0 ± 0.00
Estrous stages (% of cycle)
Diestrus | 33.8 | 34.8 | 42.0 | 29.9
Proestrus | 0.6 | 1.3 | 0.6 | 1.9
Estrus | 51.0 | 47.5 | 47.8 | 49.0
Metestrus | 14.6 | 15.2 | 8.9 | 19.1
Uncertain diagnoses | 0.0 | 1.3 | 0.6 | 0.0

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the sham control group are not significant by Jonckheere’s, Williams’, or Dunnett’s test (body weight) or Jonckheere’s, Shirley’s, or Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the sham control group and each exposed group indicated exposed females did not have extended estrus or diestrus.

^b^ Number of females with a regular cycle/number of females cycling.

Table H-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice at the 14-week Interim Evaluation in the Two-yearCDMA-modulated Cell Phone RFR Study

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 2.5 W/kg vs. Sham Controls | <0.001
Overall Tests | 5 W/kg vs. Sham Controls | 0.003
Overall Tests | 10 W/kg vs. Sham Controls | 0.209 | N
Extended Estrus | Overall | 0.042
Extended Estrus | 2.5 W/kg vs. Sham Controls | 0.012
Extended Estrus | 5 W/kg vs. Sham Controls | 0.333
Extended Estrus | 10 W/kg vs. Sham Controls | 0.358 | N
Extended Diestrus | Overall | 0.006
Extended Diestrus | 2.5 W/kg vs. Sham Controls | 0.113
Extended Diestrus | 5 W/kg vs. Sham Controls | 0.002
Extended Diestrus | 10 W/kg vs. Sham Controls | 0.602 | N
Extended Metestrus | Overall | 1
Extended Metestrus | 2.5 W/kg vs. Sham Controls | 1
Extended Metestrus | 5 W/kg vs. Sham Controls | 1
Extended Metestrus | 10 W/kg vs. Sham Controls | 1
Extended Proestrus | Overall | 1
Extended Proestrus | 2.5 W/kg vs. Sham Controls | 1
Extended Proestrus | 5 W/kg vs. Sham Controls | 1
Extended Proestrus | 10 W/kg vs. Sham Controls | 1
Skipped Estrus | Overall | 1
Skipped Estrus | 2.5 W/kg vs. Sham Controls | 1
Skipped Estrus | 5 W/kg vs. Sham Controls | 1
Skipped Estrus | 10 W/kg vs. Sham Controls | 1
Skipped Diestrus | Overall | 1
Skipped Diestrus | 2.5 W/kg vs. Sham Controls | 0.934
Skipped Diestrus | 5 W/kg vs. Sham Controls | 1
Skipped Diestrus | 10 W/kg vs. Sham Controls | 1
Summary of Significant Groups
Overall Tests | 2.5 W/kg vs. Sham Controls | <0.001
Overall Tests | 5 W/kg vs. Sham Controls | 0.003
Extended Estrus | 2.5 W/kg vs. Sham Controls | 0.012
Extended Diestrus | 5 W/kg vs. Sham Controls | 0.002

^a^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the sham control group.

Figure H-1

Vaginal Cytology Plots for Female Mice at the 14-week Interim Evaluation in the Two-year GSM-modulated Cell Phone RFR Study

I = Insufficient number of cells to determine stage; D = diestrus, P = proestrus, E = estrus, M = metestrusTable H3.

Figure H-2

Vaginal Cytology Plots for Female Mice at the 14-week Interim Evaluation in the Two-year CDMA-modulated Cell Phone RFR Study

I = Insufficient number of cells to determine stage; D = diestrus, P = proestrus, E = estrus, M = metestrus.