# Appendix G Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the 28-day GSM-modulated Cell Phone RFR Study^a^

| Sham Control | 5 W/kg | 10 W/kg | 15 W/kg
n | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 24.9 ± 0.4 | 25.2 ± 0.4 | 24.7 ± 0.3 | 25.0 ± 0.4
R. Adrenal gland
Absolute | 0.0032 ± 0.0006 | 0.0025 ± 0.0003 | 0.0031 ± 0.0006^b^ | 0.0030 ± 0.0003
Relative | 0.13 ± 0.02 | 0.10 ± 0.01 | 0.12 ± 0.02^b^ | 0.12 ± 0.01
Brain
Absolute | 0.47 ± 0.00 | 0.47 ± 0.00 | 0.47 ± 0.00 | 0.47 ± 0.00
Relative | 19.06 ± 0.28 | 18.63 ± 0.24 | 18.86 ± 0.25 | 18.78 ± 0.33
Heart
Absolute | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00
Relative | 5.59 ± 0.14 | 5.41 ± 0.14 | 5.50 ± 0.10 | 5.57 ± 0.15
R. Kidney
Absolute | 0.22 ± 0.01 | 0.23 ± 0.00 | 0.22 ± 0.00 | 0.22 ± 0.01
Relative | 8.80 ± 0.14 | 9.07 ± 0.14 | 8.90 ± 0.12 | 8.64 ± 0.15
Liver
Absolute | 1.29 ± 0.03 | 1.29 ± 0.03 | 1.25 ± 0.03 | 1.23 ± 0.03
Relative | 51.86 ± 0.73 | 51.24 ± 0.80 | 50.63 ± 0.94 | 49.16 ± 0.95
Lung
Absolute | 0.20 ± 0.01 | 0.19 ± 0.01^b^ | 0.20 ± 0.01 | 0.19 ± 0.01
Relative | 7.87 ± 0.35 | 7.44 ± 0.41^b^ | 8.14 ± 0.45 | 7.45 ± 0.54
R. Testis
Absolute | 0.094 ± 0.005 | 0.097 ± 0.002 | 0.093 ± 0.005 | 0.097 ± 0.002
Relative | 3.79 ± 0.21 | 3.88 ± 0.09 | 3.75 ± 0.21 | 3.87 ± 0.06
Thymus
Absolute | 0.045 ± 0.002 | 0.046 ± 0.001 | 0.046 ± 0.001 | 0.047 ± 0.002
Relative | 1.81 ± 0.06 | 1.84 ± 0.04 | 1.84 ± 0.05 | 1.89 ± 0.11
Female
Necropsy body wt. | 21.7 ± 0.3 | 21.9 ± 0.2 | 21.2 ± 0.2 | 21.0 ± 0.2*
R. Adrenal gland
Absolute | 0.0037 ± 0.0006 | 0.0031 ± 0.0006 | 0.0037 ± 0.0005 | 0.0036 ± 0.0003
Relative | 0.17 ± 0.03 | 0.14 ± 0.03 | 0.18 ± 0.02 | 0.17 ± 0.01
Brain
Absolute | 0.48 ± 0.00 | 0.49 ± 0.00 | 0.47 ± 0.00 | 0.47 ± 0.00
Relative | 22.24 ± 0.32 | 22.15 ± 0.18 | 22.21 ± 0.24 | 22.56 ± 0.27
Heart
Absolute | 0.13 ± 0.00 | 0.13 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.00*
Relative | 6.00 ± 0.19 | 5.85 ± 0.11 | 5.77 ± 0.12 | 5.62 ± 0.17
R. Kidney
Absolute | 0.17 ± 0.00 | 0.16 ± 0.00 | 0.15 ± 0.00 | 0.16 ± 0.00
Relative | 7.65 ± 0.18 | 7.44 ± 0.13 | 7.27 ± 0.18 | 7.39 ± 0.11
Liver
Absolute | 1.14 ± 0.03 | 1.18 ± 0.02 | 1.10 ± 0.02 | 1.07 ± 0.03
Relative | 52.61 ± 0.66 | 53.72 ± 0.85 | 51.77 ± 0.92 | 50.72 ± 0.95
Lung
Absolute | 0.18 ± 0.01 | 0.19 ± 0.01 | 0.17 ± 0.01 | 0.17 ± 0.00
Relative | 8.48 ± 0.45 | 8.45 ± 0.34 | 8.18 ± 0.25 | 8.06 ± 0.19
Thymus
Absolute | 0.056 ± 0.001 | 0.057 ± 0.001 | 0.054 ± 0.001 | 0.055 ± 0.002
Relative | 2.57 ± 0.07 | 2.59 ± 0.04 | 2.53 ± 0.07 | 2.62 ± 0.11

* Significantly different (P ≤ 0.05) from the sham control group by Williams’ or Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n=9.

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice at the 14-week Interim Evaluation in the Two-yearGSM-modulated Cell Phone RFR Study^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
n | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 34.8 ± 0.8 | 33.3 ± 0.8 | 34.3 ± 0.6 | 33.0 ± 0.5
Brain
Absolute | 0.48 ± 0.01 | 0.48 ± 0.00 | 0.47 ± 0.00 | 0.47 ± 0.01
Relative | 13.74 ± 0.43 | 14.44 ± 0.39 | 13.73 ± 0.28 | 14.18 ± 0.22
R. Epididymis
Absolute | 0.0504 ± 0.0024 | 0.0466 ± 0.0023 | 0.0471 ± 0.0029 | 0.0489 ± 0.0016
Relative | 1.45 ± 0.06 | 1.40 ± 0.05 | 1.37 ± 0.07 | 1.49 ± 0.05
L. Epididymis
Absolute | 0.0478 ± 0.0019 | 0.0499 ± 0.0026 | 0.0500 ± 0.0026 | 0.0468 ± 0.0023
Relative | 1.38 ± 0.06 | 1.50 ± 0.07 | 1.46 ± 0.07 | 1.43 ± 0.09
Heart
Absolute | 0.16 ± 0.00^b^ | 0.17 ± 0.01 | 0.16 ± 0.00^b^ | 0.16 ± 0.01
Relative | 4.52 ± 0.09^b^ | 5.06 ± 0.18 | 4.75 ± 0.13^b^ | 4.87 ± 0.21
R. Kidney
Absolute | 0.27 ± 0.01 | 0.26 ± 0.01 | 0.25 ± 0.00* | 0.25 ± 0.01**
Relative | 7.80 ± 0.17 | 7.89 ± 0.18 | 7.44 ± 0.14 | 7.63 ± 0.19
L. Kidney
Absolute | 0.26 ± 0.01 | 0.25 ± 0.01 | 0.25 ± 0.01 | 0.23 ± 0.00**
Relative | 7.54 ± 0.15 | 7.65 ± 0.15 | 7.20 ± 0.16 | 7.08 ± 0.16
Liver
Absolute | 1.54 ± 0.05 | 1.44 ± 0.05 | 1.38 ± 0.03*^b^ | 1.39 ± 0.03*^b^
Relative | 44.27 ± 0.73 | 43.18 ± 0.85 | 40.73 ± 0.82*^b^ | 42.31 ± 1.01^b^
Lung
Absolute | 0.28 ± 0.02 | 0.29 ± 0.02 | 0.24 ± 0.01 | 0.27 ± 0.02
Relative | 7.84 ± 0.58 | 8.62 ± 0.58 | 6.98 ± 0.34 | 8.24 ± 0.68
R. Testis
Absolute | 0.110 ± 0.002 | 0.111 ± 0.004 | 0.102 ± 0.008 | 0.109 ± 0.002
Relative | 3.16 ± 0.10 | 3.34 ± 0.11 | 2.98 ± 0.22 | 3.31 ± 0.09
L. Testis
Absolute | 0.104 ± 0.002 | 0.107 ± 0.002 | 0.101 ± 0.007 | 0.105 ± 0.002
Relative | 3.01 ± 0.12 | 3.22 ± 0.09 | 2.96 ± 0.21 | 3.20 ± 0.09
Thymus
Absolute | 0.035 ± 0.002 | 0.037 ± 0.002 | 0.037 ± 0.002 | 0.036 ± 0.002
Relative | 1.02 ± 0.07 | 1.10 ± 0.04 | 1.07 ± 0.05 | 1.10 ± 0.04
Female
Necropsy body wt. | 24.4 ± 0.4 | 24.9 ± 0.5 | 25.0 ± 0.5 | 26.2 ± 0.7*
Brain
Absolute | 0.49 ± 0.00 | 0.49 ± 0.00 | 0.49 ± 0.00 | 0.49 ± 0.01
Relative | 20.21 ± 0.32 | 19.85 ± 0.37 | 19.78 ± 0.36 | 18.86 ± 0.40*
Heart
Absolute | 0.15 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.01
Relative | 6.24 ± 0.25 | 6.34 ± 0.25 | 6.31 ± 0.22 | 6.11 ± 0.28
R. Kidney
Absolute | 0.18 ± 0.00 | 0.18 ± 0.00 | 0.17 ± 0.00 | 0.17 ± 0.01
Relative | 7.26 ± 0.13 | 7.08 ± 0.18 | 6.92 ± 0.23 | 6.65 ± 0.17*
L. Kidney
Absolute | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.15 ± 0.00 | 0.16 ± 0.01
Relative | 6.52 ± 0.16 | 6.35 ± 0.08 | 6.19 ± 0.15 | 6.20 ± 0.16
Liver
Absolute | 1.21 ± 0.03 | 1.24 ± 0.03 | 1.22 ± 0.02 | 1.28 ± 0.05
Relative | 49.60 ± 0.66 | 49.76 ± 0.59 | 48.96 ± 0.75 | 48.94 ± 1.28
Lung
Absolute | 0.31 ± 0.02 | 0.34 ± 0.02 | 0.32 ± 0.01 | 0.31 ± 0.01
Relative | 12.59 ± 0.60 | 13.45 ± 0.73 | 12.75 ± 0.39 | 11.75 ± 0.60
R. Ovary
Absolute | 0.0077 ± 0.0004 | 0.0072 ± 0.0006 | 0.0067 ± 0.0009 | 0.0070 ± 0.0006
Relative | 0.32 ± 0.02 | 0.29 ± 0.02 | 0.27 ± 0.04 | 0.27 ± 0.02
L. Ovary
Absolute | 0.0069 ± 0.0009 | 0.0058 ± 0.0006 | 0.0053 ± 0.0008 | 0.0064 ± 0.0003
Relative | 0.28 ± 0.04 | 0.23 ± 0.02 | 0.21 ± 0.03 | 0.25 ± 0.01
Thymus
Absolute | 0.041 ± 0.003 | 0.044 ± 0.001 | 0.043 ± 0.002 | 0.049 ± 0.002*
Relative | 1.66 ± 0.10 | 1.75 ± 0.04 | 1.73 ± 0.04 | 1.86 ± 0.06

* Significantly different (P ≤ 0.05) from the sham control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n=9.

Table G-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the 28-day CDMA-modulated Cell Phone RFR Study^a^

| Sham Control | 5 W/kg | 10 W/kg | 15 W/kg
n | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 24.9 ± 0.4 | 24.3 ± 0.3 | 25.2 ± 0.4 | 25.1 ± 0.3
R. Adrenal gland
Absolute | 0.0032 ± 0.0006 | 0.0025 ± 0.0002 | 0.0026 ± 0.0006 | 0.0030 ± 0.0006^b^
Relative | 0.13 ± 0.02 | 0.10 ± 0.01 | 0.10 ± 0.02 | 0.12 ± 0.02^b^
Brain
Absolute | 0.47 ± 0.00 | 0.46 ± 0.00 | 0.48 ± 0.00 | 0.47 ± 0.00
Relative | 19.06 ± 0.28 | 19.14 ± 0.13 | 19.11 ± 0.25 | 18.52 ± 0.24
Heart
Absolute | 0.14 ± 0.00 | 0.13 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00
Relative | 5.59 ± 0.14 | 5.52 ± 0.12 | 5.40 ± 0.12 | 5.58 ± 0.14
R. Kidney
Absolute | 0.22 ± 0.01 | 0.21 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.01
Relative | 8.80 ± 0.14 | 8.77 ± 0.16 | 8.86 ± 0.20 | 8.67 ± 0.20
Liver
Absolute | 1.29 ± 0.03 | 1.24 ± 0.02 | 1.29 ± 0.02 | 1.25 ± 0.02
Relative | 51.86 ± 0.73 | 51.26 ± 0.73 | 51.20 ± 0.82 | 49.85 ± 0.77
Lung
Absolute | 0.20 ± 0.01 | 0.18 ± 0.00 | 0.19 ± 0.01 | 0.18 ± 0.00
Relative | 7.87 ± 0.35 | 7.55 ± 0.16 | 7.45 ± 0.24 | 7.13 ± 0.16
R. Testis
Absolute | 0.094 ± 0.005 | 0.094 ± 0.003 | 0.099 ± 0.001 | 0.096 ± 0.003
Relative | 3.79 ± 0.21 | 3.88 ± 0.13 | 3.94 ± 0.09 | 3.81 ± 0.11
Thymus
Absolute | 0.045 ± 0.002 | 0.045 ± 0.001 | 0.046 ± 0.002 | 0.043 ± 0.001
Relative | 1.81 ± 0.06 | 1.86 ± 0.04 | 1.85 ± 0.10 | 1.71 ± 0.04
Female
Necropsy body wt. | 21.7 ± 0.3 | 21.7 ± 0.3 | 21.6 ± 0.3 | 21.2 ± 0.3
R. Adrenal gland
Absolute | 0.0037 ± 0.0006 | 0.0044 ± 0.0005 | 0.0037 ± 0.0005 | 0.0037 ± 0.0005
Relative | 0.17 ± 0.03 | 0.20 ± 0.02 | 0.17 ± 0.03 | 0.17 ± 0.02
Brain
Absolute | 0.48 ± 0.00 | 0.48 ± 0.00 | 0.48 ± 0.00 | 0.48 ± 0.00
Relative | 22.24 ± 0.32 | 22.26 ± 0.37 | 22.29 ± 0.29 | 22.48 ± 0.29
Heart
Absolute | 0.13 ± 0.00 | 0.12 ± 0.00 | 0.13 ± 0.00 | 0.12 ± 0.00
Relative | 6.00 ± 0.19 | 5.73 ± 0.17 | 5.89 ± 0.16 | 5.81 ± 0.13
R. Kidney
Absolute | 0.17 ± 0.00 | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.15 ± 0.00*
Relative | 7.65 ± 0.18 | 7.21 ± 0.14 | 7.39 ± 0.23 | 7.24 ± 0.13
Liver
Absolute | 1.14 ± 0.03 | 1.14 ± 0.02 | 1.13 ± 0.02 | 1.09 ± 0.02
Relative | 52.61 ± 0.66 | 52.79 ± 0.74 | 52.63 ± 0.68 | 51.27 ± 0.66
Lung
Absolute | 0.18 ± 0.01 | 0.20 ± 0.01 | 0.19 ± 0.01 | 0.17 ± 0.00
Relative | 8.48 ± 0.45 | 9.14 ± 0.34 | 8.78 ± 0.40 | 8.18 ± 0.22
Thymus
Absolute | 0.056 ± 0.001 | 0.055 ± 0.002 | 0.054 ± 0.002 | 0.052 ± 0.002
Relative | 2.57 ± 0.07 | 2.53 ± 0.08 | 2.52 ± 0.08 | 2.47 ± 0.08

* Significantly different (P ≤ 0.05) from the sham control group by Williams’ or Dunnett’s test

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n=9.

Table G-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice at the 14-week Interim Evaluation in the Two-yearCDMA-modulated Cell Phone RFR Study^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
n | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 34.8 ± 0.8 | 35.5 ± 0.4 | 33.2 ± 0.7 | 36.2 ± 0.7
Brain
Absolute | 0.48 ± 0.01 | 0.48 ± 0.01 | 0.47 ± 0.00 | 0.47 ± 0.00
Relative | 13.74 ± 0.43 | 13.46 ± 0.21 | 14.15 ± 0.30 | 13.09 ± 0.26
R. Epididymis
Absolute | 0.0504 ± 0.0024 | 0.0499 ± 0.0020^b^ | 0.0472 ± 0.0021^b^ | 0.0521 ± 0.0036
Relative | 1.45 ± 0.06 | 1.41 ± 0.07^b^ | 1.43 ± 0.08^b^ | 1.44 ± 0.10
L. Epididymis
Absolute | 0.0478 ± 0.0019 | 0.0510 ± 0.0020 | 0.0467 ± 0.0011 | 0.0508 ± 0.0033
Relative | 1.38 ± 0.06 | 1.44 ± 0.05 | 1.41 ± 0.03 | 1.40 ± 0.09
Heart
Absolute | 0.16 ± 0.00^b^ | 0.16 ± 0.00^b^ | 0.16 ± 0.00 | 0.16 ± 0.01
Relative | 4.52 ± 0.09^b^ | 4.65 ± 0.11^b^ | 4.70 ± 0.10 | 4.35 ± 0.09
R. Kidney
Absolute | 0.27 ± 0.01 | 0.28 ± 0.00 | 0.25 ± 0.01* | 0.25 ± 0.01
Relative | 7.80 ± 0.17 | 7.99 ± 0.16 | 7.54 ± 0.17 | 6.99 ± 0.17**
L. Kidney
Absolute | 0.26 ± 0.01 | 0.27 ± 0.01^b^ | 0.24 ± 0.00** | 0.24 ± 0.00**
Relative | 7.54 ± 0.15 | 7.57 ± 0.23^b^ | 7.10 ± 0.17 | 6.57 ± 0.12**
Liver
Absolute | 1.54 ± 0.05 | 1.58 ± 0.06 | 1.39 ± 0.04* | 1.49 ± 0.04
Relative | 44.27 ± 0.73 | 44.37 ± 1.38 | 41.76 ± 0.70 | 41.25 ± 0.85*
Lung
Absolute | 0.28 ± 0.02 | 0.28 ± 0.02 | 0.27 ± 0.02 | 0.31 ± 0.03
Relative | 7.84 ± 0.58 | 7.84 ± 0.55 | 8.13 ± 0.46 | 8.62 ± 0.80
R. Testis
Absolute | 0.110 ± 0.002 | 0.109 ± 0.005 | 0.110 ± 0.003 | 0.110 ± 0.003
Relative | 3.16 ± 0.10 | 3.09 ± 0.14 | 3.31 ± 0.10 | 3.04 ± 0.09
L. Testis
Absolute | 0.104 ± 0.002 | 0.106 ± 0.005 | 0.105 ± 0.001 | 0.109 ± 0.002
Relative | 3.01 ± 0.12 | 2.99 ± 0.14 | 3.18 ± 0.07 | 3.01 ± 0.07
Thymus
Absolute | 0.035 ± 0.002 | 0.035 ± 0.002 | 0.033 ± 0.001 | 0.043 ± 0.002*
Relative | 1.02 ± 0.07 | 1.00 ± 0.06 | 1.00 ± 0.03 | 1.18 ± 0.05
Female
Necropsy body wt. | 24.4 ± 0.4 | 25.5 ± 0.5 | 25.7 ± 0.7 | 24.5 ± 0.3
Brain
Absolute | 0.49 ± 0.00 | 0.50 ± 0.01 | 0.49 ± 0.01 | 0.49 ± 0.00
Relative | 20.21 ± 0.32 | 19.64 ± 0.50 | 19.28 ± 0.42 | 20.04 ± 0.27
Heart
Absolute | 0.15 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.01 | 0.15 ± 0.00
Relative | 6.24 ± 0.25 | 6.50 ± 0.15 | 6.30 ± 0.28 | 6.11 ± 0.16
R. Kidney
Absolute | 0.18 ± 0.00 | 0.18 ± 0.01 | 0.18 ± 0.00 | 0.16 ± 0.00
Relative | 7.26 ± 0.13 | 7.16 ± 0.17 | 7.13 ± 0.22 | 6.68 ± 0.17
L. Kidney
Absolute | 0.16 ± 0.00 | 0.17 ± 0.00 | 0.17 ± 0.00 | 0.15 ± 0.00
Relative | 6.52 ± 0.16 | 6.54 ± 0.11 | 6.47 ± 0.20 | 6.20 ± 0.16
Liver
Absolute | 1.21 ± 0.03 | 1.26 ± 0.03 | 1.25 ± 0.02 | 1.17 ± 0.04
Relative | 49.60 ± 0.66 | 49.38 ± 0.72 | 48.97 ± 0.89 | 47.65 ± 1.15
Lung
Absolute | 0.31 ± 0.02 | 0.33 ± 0.02 | 0.33 ± 0.01 | 0.31 ± 0.01
Relative | 12.59 ± 0.60 | 13.03 ± 0.48 | 12.87 ± 0.40 | 12.67 ± 0.52
R. Ovary
Absolute | 0.0077 ± 0.0004 | 0.0080 ± 0.0007 | 0.0071 ± 0.0007 | 0.0068 ± 0.0005
Relative | 0.32 ± 0.02 | 0.32 ± 0.03 | 0.28 ± 0.03 | 0.28 ± 0.02
L. Ovary
Absolute | 0.0069 ± 0.0009 | 0.0068 ± 0.0005 | 0.0060 ± 0.0006 | 0.0055 ± 0.0005
Relative | 0.28 ± 0.04 | 0.27 ± 0.02 | 0.23 ± 0.03 | 0.22 ± 0.02
Thymus
Absolute | 0.041 ± 0.003 | 0.043 ± 0.002 | 0.044 ± 0.002 | 0.045 ± 0.001
Relative | 1.66 ± 0.10 | 1.70 ± 0.04 | 1.71 ± 0.05 | 1.83 ± 0.05

* Significantly different (P ≤ 0.05) from the sham control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n=9.