# Appendix F Hematology Results

Table F-1 Hematology Data for Mice at the 14-week Interim Evaluation in the Two-year GSM-modulated Cell Phone RFR Study^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
n | 10 | 10 | 10 | 10
Male
Hematocrit (%) | 54.8 ± 0.5 | 54.1 ± 0.9 | 54.2 ± 0.3 | 53.5 ± 0.5
Manual hematocrit (%) | 50 ± 0 | 49 ± 1^b^ | 49 ± 0 | 49 ± 0
Hemoglobin (g/dL) | 16.1 ± 0.1 | 16.0 ± 0.2 | 16.0 ± 0.1 | 15.9 ± 0.2
Erythrocytes (106/µL) | 10.87 ± 0.09 | 10.66 ± 0.15 | 10.76 ± 0.06 | 10.61 ± 0.10
Reticulocytes (103/µL) | 386.3 ± 8.2 | 363.6 ± 9.3 | 358.5 ± 7.5 | 357.9 ± 7.9
Nucleated erythrocytes (/100 leukocytes) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 50.4 ± 0.1 | 50.8 ± 0.2 | 50.4 ± 0.2 | 50.4 ± 0.2
Mean cell hemoglobin (pg) | 14.8 ± 0.0 | 15.0 ± 0.1 | 14.9 ± 0.1 | 15.0 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 29.4 ± 0.1 | 29.5 ± 0.1 | 29.5 ± 0.1 | 29.7 ± 0.1
Platelets (103/µL) | 1,115 ± 31 | 1,065 ± 30 | 1,111 ± 35 | 1,116 ± 32
Leukocytes (103/µL) | 5.80 ± 0.50 | 5.11 ± 0.53 | 5.52 ± 0.43 | 6.30 ± 0.47
Segmented neutrophils (103/µL) | 0.68 ± 0.06 | 0.58 ± 0.07 | 0.62 ± 0.04 | 0.67 ± 0.05
Lymphocytes (103/µL) | 4.82 ± 0.41 | 4.28 ± 0.44 | 4.63 ± 0.37 | 5.29 ± 0.40
Monocytes (103/µL) | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.11 ± 0.01
Basophils (103/µL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01
Eosinophils (103/µL) | 0.09 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.01 | 0.10 ± 0.01
Large unstained cells (103/µL) | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01
Female
Hematocrit (%) | 54.9 ± 2.0 | 55.7 ± 0.9 | 55.6 ± 0.5 | 55.2 ± 0.4
Manual hematocrit (%) | 50 ± 2 | 52 ± 1 | 52 ± 1 | 51 ± 0
Hemoglobin (g/dL) | 16.4 ± 0.5 | 16.8 ± 0.3 | 16.8 ± 0.2 | 16.5 ± 0.1
Erythrocytes (106/µL) | 10.77 ± 0.34 | 10.88 ± 0.16 | 10.90 ± 0.11 | 10.75 ± 0.07
Reticulocytes (103/µL) | 346.8 ± 17.4 | 365.5 ± 20.0 | 328.6 ± 13.5 | 378.6 ± 15.5
Nucleated erythrocytes (/100 leukocytes) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 50.9 ± 0.3 | 51.2 ± 0.2 | 51.1 ± 0.2 | 51.4 ± 0.2
Mean cell hemoglobin (pg) | 15.2 ± 0.1 | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 29.9 ± 0.3 | 30.1 ± 0.1 | 30.2 ± 0.1 | 29.8 ± 0.1
Platelets (103/µL) | 758 ± 65 | 714 ± 37 | 717 ± 52 | 782 ± 29
Leukocytes (103/µL) | 5.15 ± 0.57 | 5.06 ± 0.60 | 5.07 ± 0.57 | 4.88 ± 0.58
Segmented neutrophils (103/µL) | 0.60 ± 0.08 | 0.53 ± 0.07 | 0.44 ± 0.07 | 0.58 ± 0.06
Lymphocytes (103/µL) | 4.35 ± 0.49 | 4.30 ± 0.51 | 4.41 ± 0.49 | 4.09 ± 0.52
Monocytes (103/µL) | 0.07 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01
Basophils (103/µL) | 0.03 ± 0.01 | 0.04 ± 0.00 | 0.04 ± 0.01 | 0.03 ± 0.00
Eosinophils (103/µL) | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01
Large unstained cells (103/µL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.00

^a^ Data are presented as mean ± standard error. Jonckheere’s test for trend and Shirley’s and Dunn’s tests were performed on unrounded data.

^b^ n=9.

Table F-2 Hematology Data for Mice at the 14-week Interim Evaluation in the Two-year CDMA-modulated Cell Phone RFR Study^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
n | 10 | 10 | 10 | 10
Male
Hematocrit (%) | 54.8 ± 0.5 | 54.6 ± 0.6 | 54.0 ± 0.6 | 54.5 ± 0.6
Manual hematocrit (%) | 50 ± 0 | 50 ± 1 | 49 ± 1 | 50 ± 1
Hemoglobin (g/dL) | 16.1 ± 0.1 | 16.0 ± 0.2 | 16.0 ± 0.2 | 16.1 ± 0.2
Erythrocytes (10^6^/µL) | 10.87 ± 0.09 | 10.77 ± 0.09 | 10.68 ± 0.12 | 10.76 ± 0.11
Reticulocytes (10^3^/µL) | 386.3 ± 8.2 | 367.1 ± 9.0 | 360.3 ± 8.8 | 374.6 ± 6.3
Nucleated erythrocytes (/100 leukocytes) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 50.4 ± 0.1 | 50.7 ± 0.2 | 50.6 ± 0.1 | 50.7 ± 0.2
Mean cell hemoglobin (pg) | 14.8 ± 0.0 | 14.9 ± 0.1 | 14.9 ± 0.1 | 15.0 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 29.4 ± 0.1 | 29.3 ± 0.1 | 29.5 ± 0.1 | 29.6 ± 0.1
Platelets (10^3^/µL) | 1,115 ± 31 | 1,087 ± 36 | 1,128 ± 30 | 1,104 ± 40
Leukocytes (10^3^/µL) | 5.80 ± 0.50 | 5.41 ± 0.35 | 5.57 ± 0.43 | 5.45 ± 0.44
Segmented neutrophils (10^3^/µL) | 0.68 ± 0.06 | 0.59 ± 0.04 | 0.62 ± 0.05 | 0.58 ± 0.05
Lymphocytes (10^3^/µL) | 4.82 ± 0.41 | 4.57 ± 0.31 | 4.67 ± 0.38 | 4.57 ± 0.36
Monocytes (10^3^/µL) | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01
Basophils (10^3^/µL) | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01
Eosinophils (10^3^/µL) | 0.09 ± 0.01 | 0.07 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.02
Large unstained cells (10^3^/µL) | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01
Female
Hematocrit (%) | 54.9 ± 2.0 | 55.2 ± 0.8 | 56.4 ± 0.6 | 56.1 ± 0.4
Manual hematocrit (%) | 50 ± 2 | 52 ± 1 | 52 ± 1 | 52 ± 0
Hemoglobin (g/dL) | 16.4 ± 0.5 | 16.6 ± 0.2 | 17.0 ± 0.2 | 16.8 ± 0.2
Erythrocytes (10^6^/µL) | 10.77 ± 0.34 | 10.78 ± 0.14 | 11.10 ± 0.11 | 10.96 ± 0.06
Reticulocytes (10^3^/µL) | 346.8 ± 17.4 | 371.2 ± 14.4 | 366.7 ± 20.6 | 374.7 ± 13.8
Nucleated erythrocytes (/100 leukocytes) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 50.9 ± 0.3 | 51.2 ± 0.2 | 50.8 ± 0.2 | 51.2 ± 0.1
Mean cell hemoglobin (pg) | 15.2 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.1 | 15.3 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 29.9 ± 0.3 | 30.1 ± 0.1 | 30.1 ± 0.1 | 29.9 ± 0.2
Platelets (10^3^/µL) | 758 ± 65 | 736 ± 53 | 668 ± 38 | 685 ± 41
Leukocytes (10^3^/µL) | 5.15 ± 0.57 | 5.24 ± 0.45 | 4.66 ± 0.55 | 4.53 ± 0.34
Segmented neutrophils (10^3^/µL) | 0.60 ± 0.08 | 0.52 ± 0.04 | 0.51 ± 0.08 | 0.42 ± 0.05
Lymphocytes (10^3^/µL) | 4.35 ± 0.49 | 4.52 ± 0.40 | 3.95 ± 0.46 | 3.92 ± 0.31
Monocytes (10^3^/µL) | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01
Basophils (10^3^/µL) | 0.03 ± 0.01 | 0.04 ± 0.00 | 0.03 ± 0.01 | 0.03 ± 0.01
Eosinophils (10^3^/µL) | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01
Large unstained cells (10^3^/µL) | 0.04 ± 0.01 | 0.04 ± 0.00 | 0.04 ± 0.01 | 0.04 ± 0.00

^a^ Data are presented as mean ± standard error. Jonckheere’s test for trend and Shirley’s and Dunn’s tests were performed on unrounded data.