# Appendix E Genetic Toxicology

## E.1 Collection of Tissue Samples for Genotoxicity Testing

Exposures ceased at 7 a.m. on the day of necropsy at 14 weeks. Thirty-five male mice (five sham controls, 15 that were exposed to CDMA, and 15 that were exposed to GSM) were necropsied approximately 2 to 4 hours after cessation of exposure and 35 female mice (five sham controls, 15 that were exposed to CDMA, and 15 that were exposed to GSM) were necropsied approximately 5 to 7 hours after cessation of exposure. Animals were necropsied in the following order: one animal from each exposure group starting with the sham control group, moving through each of the exposed groups for each of the radio frequency modulations in turn, then rotating back to the sham control group; animals were necropsied in numerical order within each exposure group. Five different tissues (cerebrum, frontal cortex, hippocampus, liver, and blood leukocytes) were collected from each animal for the comet assay. Because blood was examined in both the micronucleus and the comet assays, a single tube of blood was collected per animal by retroorbital bleeding, and the sample was divided into two aliquots, one that was processed for the comet assay and the other for the micronucleus assay.

## E.2 Comet Assay

For preparation of samples for the comet assay, a 50 µL sample of blood was transferred to a tube containing 1 mL of freshly prepared cold mincing buffer [Mg^+2^, Ca^+2^, and phenol free Hank’s Balanced Salt Solution (Life Technologies, Carlsbad, CA) with 20 mM ethylenediaminetetraacetic acid (EDTA) pH 7.3 to 7.5 and 10% v/v fresh dimethyl sulfoxide (DMSO)]. The liver and the hippocampus, cerebellum, and frontal cortex sections of the brain were rinsed with cold mincing buffer to remove residual blood and held on ice briefly (≤5 minutes) until processed. Small portions (3 to 4 mm) of the left lobe of the liver and each brain section were placed in tubes containing cold mincing solution and rapidly minced until finely dispersed. All samples prepared for the comet assay were immediately flash frozen in liquid nitrogen^195^ and subsequently transferred to a –80° C freezer for storage until shipment by overnight courier on dry ice to the analytical laboratory. Upon receipt, all samples were immediately placed in a –80° C freezer for storage until further processing.

Blood and tissue samples were thawed on ice and maintained on ice during slide preparation. Just prior to use, each cell suspension was shaken gently to mix the cells and placed back on ice for 15 to 30 seconds to allow clumps to settle. A portion of the supernatant was empirically diluted with 0.5% low melting point agarose (Lonza, Walkersville, MD) dissolved in Dulbecco’s phosphate buffer (Ca^+2^, Mg^+2^, and phenol free) at 37° C and layered onto each well of a 2-well CometSlide^™^ (Trevigen, Gaithersburg, MD). Slides were immersed in cold lysing solution [2.5 M NaCl, 100 mM Na_2_EDTA, 10 mM tris(hydroxymethyl)aminomethane (Tris), pH 10, containing freshly added 10% DMSO (Fisher Scientific, Pittsburgh, PA) and 1% Triton X-100] overnight in a refrigerator, protected from light. The following day, the slides were rinsed in 0.4 M Trizma base (pH 7.5), randomly placed onto the platform of a horizontal electrophoresis unit and treated with cold alkali solution (300 mM NaOH, 1 mM Na_2_EDTA, pH>13) for 20 minutes to allow DNA unwinding, then electrophoresed at 4º to 9º C for 20 minutes at 25 V (0.7 V/cm), with a current of approximately 300 mA. Following electrophoresis, slides were neutralized with 0.4 M Trizma base (pH 7.5) for 5 minutes and then dehydrated by immersion in absolute ethanol (Pharmco-AAPER, Shelbyville, KY) for at least 5 minutes and allowed to air dry. Slides were prepared in a laboratory with a relative humidity no more than 60% and stored at room temperature in a desiccator with a relative humidity of no more than 60% until stained and scored; stained slides were stored in a desiccator. NaCl, Na_2_EDTA, Triton X-100, and Trizma base were purchased from Sigma-Aldrich (St. Louis, MO); NaOH was purchased from Fisher Scientific (Pittsburgh, PA).

After staining with SYBR^®^ Gold (Molecular Probes, Life Technologies, Grand Island, NY), slides, independently coded to mask treatment, were scored using Comet Assay IV Imaging Software, Version 4.3.1 (Perceptive Instruments, Ltd., Suffolk, UK) validated for GLP Part 11 compliance. In the alkaline (pH>13) comet assay, when damaged nuclear DNA fragments, it undergoes unidirectional migration through the agarose gel within an electrical field, forming an image that resembles a comet, and the greater the amount of fragmentation, the greater the amount of DNA migration that will occur. The image analysis software partitions the intensity of the fluorescent signal of the DNA in the entire comet image into the percent that is attributable to the comet head and the percent attributable to the tail. Manual adjustment of the automated detection of head and tail features is sometimes required. To evaluate DNA damage levels, the extent of DNA migration was characterized for 100 scorable comet figures per animal/tissue as percent tail DNA (intensity of all tail pixels divided by the total intensity of all pixels in the comet, expressed as a percentage).

Comet figures are classified during the scoring process as scorable (evaluated for percent tail DNA), non-scorable (due to inability to evaluate percent tail DNA, e.g. if comets overlapped), and “hedgehog.” Hedgehogs either have no defined head, i.e., all DNA appears to be in the tail, or the head and tail appear to be separated. Hedgehogs may represent cells that have sustained high levels of DNA damage and are apoptotic, although certain data suggest they may represent cells with high levels of repairable DNA damage^196; 197^. The frequency of hedgehogs (%HH) was determined by tabulating the number observed in a separate group of 100 cells per animal/tissue.

In Technical Report 595^198^, in which the comet assay results in rats exposed to cell phone radio frequency radiation (RFR) are reported, it was noted that a marked interanimal variation in percent tail DNA and high %HH values were observed in some tissues, yet the range of percent tail DNA values appeared to be truncated at approximately 65%. To better understand these observations, rat slides were reanalyzed by scoring 150 cells/tissue per animal, as recommended by the OECD guideline^180^. In this rescoring of the rat samples, all scorable cells were included in the sample of 150 analyzed cells, regardless of the apparent level of DNA damage estimated by the scorer prior to software analysis of the images; highly damaged cells that were unscorable using the software (true HH) were not included. For the 150-cell scoring method, the %HH was not independently determined due to limitations at the time in the comet assay software arising from the added number of cells scored. Therefore, %HH was estimated by dividing the number of comets having greater than or equal to 90% tail DNA by 150.

Although far less interanimal variation was observed in mouse tissues compared to rat tissues, in an effort to maintain consistency in analyses across species, the mouse tissues that showed a clear response or a suggestion of a treatment-related effect were reevaluated using the same 150-cell approach that was used to reevaluate all of the rat tissues. These tissues included male mouse frontal cortex and female mouse liver and peripheral blood exposed to the CDMA and GSM modulations.

Although there was no concurrent positive control group in these cell phone RFR studies, slides were made with human TK6 cells treated with ethyl methanesulfonate (standard positive control compound for the comet assay) and were included in each electrophoresis run with each slide set as an internal technical positive control.

## E.3 Micronucleus Assay

For the micronucleus assay, sampling schedules were as described for the comet assay. At 14 weeks, blood samples (approximately 200 μL) obtained by retroorbital bleeding (one sample per mouse) were placed into EDTA tubes and immediately refrigerated. The samples were sent on the day of collection to the analytical laboratory well insulated on cold packs via overnight delivery. Upon arrival, blood samples were diluted in anticoagulant (heparin) and fixed in ice cold methanol (Sigma-Aldrich; St. Louis, MO) according to instructions provided with the MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY). Fixed blood samples were stored in a –80° C freezer for at least 3 days prior to analysis by flow cytometry.

Flow cytometric analysis of red blood cell samples was performed using MicroFlowPLUS Kit reagents and a FACSCalibur™ dual-laser bench top system (Becton Dickinson Biosciences, San Jose, CA) as described by Witt et al.^199^. Both mature [normochromatic erythrocytes (NCEs)] and immature [reticulocytes; polychromatic erythrocytes (PCEs)] erythrocytes were analyzed for the presence of micronuclei. Immature erythrocytes are distinguished by the presence of an active transferrin receptor (CD-71) on the cell surface. For each sample, 20,000 (± 2,000) immature CD71-positive erythrocytes were analyzed by flow cytometry to determine the frequency of micronucleated reticulocytes. Aggregates were excluded on the basis of forward and side scatter, platelets were excluded based on staining with an anti-CD61 antibody, and nucleated leukocytes were excluded on the basis of intense propidium iodide staining. Typically, more than one million NCEs (CD-71 negative) were enumerated concurrently during PCE analysis, allowing for calculation of the percentage of PCEs among total erythrocytes as a measure of bone marrow toxicity.

## E.4 Data Analysis for the Comet and Micronucleus Assays

Data from both the comet and the micronucleus assays were analyzed using the same statistical methods^200^. Mean percent tail DNA was calculated for each cell type for each animal; likewise, mean micronucleated PCEs/1,000 PCEs and micronucleated NCEs/1,000 NCEs, as well as % PCEs, were calculated for each animal. These data are summarized in the tables as mean ± standard error of the mean. Levene’s test was used to determine if variances among treatment groups were equal at P = 0.05. When variances were equal, linear regression analysis was used to test for linear trend and Williams’ test was used to evaluate pairwise differences of each exposed group with the sham control group. When variances were unequal, nonparametric methods were used to analyze the data; Jonckheere’s test was used to evaluate linear trend and Dunn’s test was used to assess the significance of pairwise differences of each exposed group with the sham control group. To maintain the overall significance level at 0.05, the trend as well as the pairwise differences from the sham control group were declared statistically significant if P<0.025. A result was considered positive if the trend test was significant and if at least one exposed group was significantly elevated over the sham control group, or if two or more exposed groups were significantly increased over the corresponding sham control group. A response was considered equivocal if only the trend test was significant or if only a single exposed group was significantly increased over the sham control.

## E.5 Results

Twenty sets of tissues obtained from animals at the 14-week interim evaluation in the 2-year study were evaluated for DNA damage using the comet assay (two sexes, five tissues, two cell phone RFR modulations). Results are reported based on the 100-cell scoring approach that was the standard method in use at the time of the study. Data for some tissues obtained using a second, 150-cell scoring approach recommended by a recently adopted international guideline for the in vivo comet assay, are noted for comparison. Significant increases in DNA damage were observed in cells of the frontal cortex of male mice exposed to both modulations, CDMA and GSM (Table E-1, Table E-2). Positive results were also obtained for male mouse frontal cortex (CDMA and GSM) (Table E-3) using the 150-cell approach. Of note is the low percent tail DNA value in the frontal cortex of sham control mice. There is no appropriate historical control database to provide context for this response, but bonafide changes in DNA damage levels in a treatment group should remain constant relative to the control value. No technical aspects of the study that may have influenced this control value independently of the treated group values (e.g., % agarose gel, duration of electrophoresis, electromagnetic field strength, slide position in the electrophoresis tank) were identified. Technical factors that influence control levels have not been shown to alter sensitivity to detect effects in treated groups^193^. No other tissues showed evidence of a treatment-related effect in male mice. In female mice exposed to the CDMA modulation, significant increases in DNA damage were seen in blood leukocytes using both scoring approaches (Table E-4, Table E-6). In female mouse liver samples exposed to either modulation, the mean percent tail DNA was elevated above the sham control for all exposures when evaluated using either scoring approach. Results of the 100-cell scoring approach were judged to be negative (Table E-4, Table E-5); scoring 150 cells resulted in a negative call for GSM-exposed female mice (Table E-6) but in CDMA-exposed female mouse liver, significant increases (P = 0.009) in percent tail DNA were seen in the 5 and 10 W/kg groups, resulting in a positive call for this dataset.

In the micronucleus assay for male mice exposed to CDMA (Table E-7), although a significant trend was observed for micronucleated PCEs (P = 0.013), the absolute increase was quite small and fell within the laboratory’s historical control range. In addition, no corresponding increase in micronucleated NCEs was observed; the mature erythrocyte population ought to be in steady state equilibrium after continuous 14 weeks of exposure, such as occurred in this study. Thus, the overall result in the micronucleus assay for male mice exposed to CDMA was judged to be negative. No other significant effects on either micronucleus frequency or % PCEs were seen in male or female mice exposed to either modulation of cell phone RFR.

Table E-1 DNA Damage in Male Mice Exposed to CDMA-modulated Cell Phone RFR for 14 Weeks (100-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b^
Frontal Cortex
Sham Control^d^ | 0 | 0.63 ± 0.08 | | 0.40 ± 0.24
CDMA | 2.5 | 3.46 ± 0.65 | 0.014 | 0.60 ± 0.40
| 5 | 5.88 ± 1.06 | 0.001 | 0.60 ± 0.24
| 10 | 8.85 ± 1.09 | 0.001 | 4.40 ± 1.69
| | P = 0.001e
Hippocampus
Sham Control | 0 | 7.69 ± 2.00 | | 1.20 ± 0.58
CDMA | 2.5 | 9.59 ± 4.33 | 0.521 | 5.40 ± 2.11
| 5 | 6.44 ± 1.21 | 0.606 | 2.80 ± 0.97
| 10 | 6.38 ± 0.93 | 0.641 | 4.40 ± 2.27
| | P = 0.740
Cerebellum
Sham Control | 0 | 5.48 ± 1.30 | | 1.80 ± 0.80
CDMA | 2.5 | 7.35 ± 2.47 | 0.339 | 4.40 ± 2.06
| 5 | 7.87 ± 2.80 | 0.404 | 4.60 ± 2.34
| 10 | 5.43 ± 2.43 | 0.431 | 1.60 ± 0.93
| | P = 0.554
Liver
Sham Control | 0 | 16.30 ± 2.21 | | 6.80 ± 2.82
CDMA | 2.5 | 20.27 ± 5.53 | 1.000 | 21.60 ± 16.88
| 5 | 16.15 ± 1.15 | 1.000 | 11.00 ± 3.77
| 10 | 16.43 ± 0.83 | 1.000 | 7.20 ± 1.11
| | P = 0.368
Peripheral Blood
Sham Control | 0 | 1.60 ± 0.68 | | 0.40 ± 0.24
CDMA | 2.5 | 2.10 ± 0.50 | 0.449 | 1.20 ± 0.58
| 5 | 1.30 ± 0.28 | 0.527 | 0.40 ± 0.24
| 10 | 2.86 ± 0.26 | 0.046 | 1.40 ± 0.87
| | P = 0.057

^a^ Study was performed at ILS, Inc. The detailed protocol (100 cell) is presented by Recio et al.^195^. Groups of five mice per exposure group were 5 to 6 weeks old when exposure began.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ No exposure to CDMA-modulated cell phone RFR.

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E-2 DNA Damage in Male Mice Exposed to GSM-modulated Cell Phone RFR for 14 Weeks (100-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b^
Frontal Cortex
Sham Controld | 0 | 0.63 ± 0.08 | | 0.40 ± 0.24
GSM | 2.5 | 1.71 ± 0.46 | 0.081 | 1.80 ± 0.97
| 5 | 1.39 ± 0.15 | 0.081 | 1.60 ± 0.81
| 10 | 3.73 ± 0.65 | 0.001 | 1.00 ± 0.45
| | P = 0.001e
Hippocampus
Sham Control | 0 | 7.69 ± 2.00 | | 1.20 ± 0.58
GSM | 2.5 | 8.74 ± 1.93 | 0.514 | 5.40 ± 2.11
| 5 | 7.17 ± 1.08 | 0.598 | 2.20 ± 0.97
| 10 | 6.90 ± 1.19 | 0.633 | 5.40 ± 2.54
| | P = 0.720
Cerebellum
Sham Control | 0 | 5.48 ± 1.30 | | 1.80 ± 0.80
GSM | 2.5 | 3.66 ± 0.30 | 0.831 | 3.00 ± 1.38
| 5 | 3.90 ± 0.59 | 0.896 | 1.80 ± 0.92
| 10 | 3.85 ± 1.08 | 0.919 | 3.40 ± 1.50
| | P = 0.838
Liver
Sham Control | 0 | 16.30 ± 2.21 | | 6.80 ± 2.82
GSM | 2.5 | 17.66 ± 1.89 | 0.469 | 8.20 ± 3.84
| 5 | 15.40 ± 1.20 | 0.549 | 6.60 ± 1.96
| 10 | 18.94 ± 2.00 | 0.213 | 12.80 ± 4.40
| | P = 0.198
Peripheral Blood
Sham Control | 0 | 1.60 ± 0.68 | | 0.40 ± 0.24
GSM | 2.5 | 1.85 ± 0.96 | 0.416 | 1.20 ± 1.20
| 5 | 1.75 ± 0.37 | 0.491 | 1.00 ± 0.55
| 10 | 1.85 ± 0.24 | 0.494 | 0.80 ± 0.58
| | P = 0.408

^a^ Study was performed at ILS, Inc. The detailed protocol (100 cell) is presented by Recio et al.^195^. Groups of five mice per exposure group were 5 to 6 weeks old when exposure began.

^b^ Mean ±standard error

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ No exposure to GSM-modulated cell phone RFR

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E-3 DNA Damage in the Frontal Cortex of Male Mice Exposed to CDMA- or GSM-modulated Cell Phone RFR for 14 Weeks (150-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b,d^
Sham Control^e^ | 0 | 1.32 ± 0.21 | | 0
CDMA | 2.5 | 4.52 ± 0.57 | 0.131 | 0
| 5 | 6.06 ± 0.96 | 0.018 | 0
| 10 | 10.04 ± 2.08 | 0.001 | 0.53 ± 0.39
| | P = 0.001^f^
GSM | 2.5 | 4.25 ± 1.20 | 0.063 | 0.13 ± 0.13
| 5 | 3.69 ± 0.53 | 0.063 | 0
| 10 | 5.60 ± 1.28 | 0.006 | 0.13 ± 0.13
| | P = 0.004

^a^ Study was performed at ILS, Inc. The detailed protocol (150 cell) is presented by OECD^180^. Groups of five mice per exposure group were 5 to 6 weeks old when exposure began.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ Percent hedgehogs=estimated as the number of comets with ≥90% tail DNA/150.

^e^ No exposure to CDMA- or GSM-modulated cell phone RFR.

^f^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E-4 DNA Damage in Female Mice Exposed to CDMA-modulated Cell Phone RFR for 14 Weeks (100-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b^
Frontal Cortex
Sham Control^d^ | 0 | 8.11 ± 2.13 | | 3.40 ± 1.47
CDMA | 2.5 | 4.88 ± 0.55 | 0.911 | 0.80 ± 0.49
| 5 | 4.89 ± 0.57 | 0.955 | 1.20 ± 0.49
| 10 | 4.80 ± 0.90 | 0.968 | 0.80 ± 0.58
| | P = 0.935^e^
Hippocampus
Sham Control | 0 | 8.15 ± 1.65 | | 2.60 ± 1.69
CDMA | 2.5 | 5.76 ± 1.00 | 0.839 | 1.80 ± 0.80
| 5 | 5.22 ± 1.02 | 0.903 | 1.20 ± 0.58
| 10 | 5.34 ± 1.82 | 0.925 | 2.20 ± 0.97
| | P = 0.892
Cerebellum
Sham Control | 0 | 5.88 ± 0.85 | | 0.20 ± 0.20
CDMA | 2.5 | 6.78 ± 1.67 | 0.296 | 1.75 ± 1.03
| 5 | 8.39 ± 1.13 | 0.194 | 0.20 ± 0.20
| 10 | 6.73 ± 0.77 | 0.207 | 0.40 ± 0.40
| | P = 0.298
Liver
Sham Control | 0 | 5.48 ± 0.60 | | 0.60 ± 0.40
CDMA | 2.5 | 7.54 ± 0.90 | 0.034 | 1.00 ± 0.45
| 5 | 7.36 ± 0.72 | 0.041 | 4.40 ± 2.11
| 10 | 7.63 ± 0.59 | 0.030 | 2.00 ± 0.77
| | P = 0.050
Peripheral Blood
Sham Control | 0 | 1.03 ± 0.13 | | 0.20 ± 0.20
CDMA | 2.5 | 2.52 ± 0.54 | 0.020 | 2.00 ± 1.14
| 5 | 1.71 ± 0.37 | 0.024 | 0
| 10 | 2.20 ± 0.19 | 0.018 | 0.20 ± 0.20
| | P = 0.085

^a^ Study was performed at ILS, Inc. The detailed protocol (100 cell) is presented by Recio et al.^195^. Groups of five mice per exposure group were 5 to 6 weeks old when exposure began.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ No exposure to CDMA-modulated cell phone RFR.

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E-5 Damage in Female Mice Exposed to GSM-modulated Cell Phone RFR for 14 Weeks (100-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b^
Frontal Cortex
Sham Control^d^ | 0 | 8.11 ± 2.13 | | 3.40 ± 1.47
GSM | 2.5 | 7.33 ± 0.90 | 0.657 | 1.00 ± 0.45
| 5 | 7.69 ± 1.98 | 0.744 | 2.00 ± 0.84
| 10 | 5.74 ± 0.62 | 0.779 | 1.00 ± 0.32
| | P = 0.861^e^
Hippocampus
Sham Control | 0 | 8.15 ± 1.65 | | 2.60 ± 1.69
GSM | 2.5 | 6.23 ± 1.00 | 0.866 | 0.80 ± 0.58
| 5 | 4.54 ± 1.29 | 0.923 | 1.20 ± 0.58
| 10 | 5.22 ± 1.23 | 0.942 | 1.60 ± 1.36
| | P = 0.933
Cerebellum
Sham Control | 0 | 5.88 ± 0.85 | | 0.20 ± 0.20
GSM | 2.5 | 6.56 ± 1.22 | 1.000 | 1.20 ± 0.73
| 5 | 5.26 ± 0.59 | 1.000 | 0.60 ± 0.40
| 10 | 6.54 ± 1.71 | 1.000 | 1.80 ± 0.73
| | P = 0.606
Liver
Sham Control | 0 | 5.48 ± 0.60 | | 0.60 ± 0.40
GSM | 2.5 | 7.06 ± 0.61 | 0.096 | 3.40 ± 1.17
| 5 | 6.36 ± 0.25 | 0.117 | 1.20 ± 0.37
| 10 | 6.47 ± 0.79 | 0.124 | 2.60 ± 1.33
| | P = 0.249
Peripheral Blood
Sham Control | 0 | 1.03 ± 0.13 | | 0.20 ± 0.20
GSM | 2.5 | 1.25 ± 0.44 | 0.335 | 0.20 ± 0.20
| 5 | 1.17 ± 0.08 | 0.400 | 0
| 10 | 1.32 ± 0.34 | 0.316 | 0
| | P = 0.266

^a^ Study was performed at ILS, Inc. The detailed protocol (100 cell) is presented by Recio et al.^195^. Groups of five mice per exposure group were 5 to 6 weeks old when exposure began.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ No exposure to GSM-modulated cell phone RFR.

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E-6 DNA Damage in Female Mice Exposed to CDMA- or GSM-modulated Cell Phone RFR for 14 Weeks (150-Cell Method)^a^

| Dose (W/kg) | Percent Tail DNA^b^ | P Value^c^ | Percent Hedgehogs^b,d^
Liver
Sham Control^e^ | 0 | 4.34 ± 0.60 | | 0
CDMA | 2.5 | 6.20 ± 0.99 | 0.050 | 0
| 5 | 8.30 ± 0.92 | 0.009 | 0
| 10 | 6.14 ± 0.26 | 0.009 | 0
| | P = 0.100^f^
GSM | 2.5 | 7.44 ± 0.48 | 0.027 | 0
| 5 | 5.45 ± 0.96 | 0.032 | 0
| 10 | 6.52 ± 0.75 | 0.030 | 0
| | P = 0.133
Peripheral Blood
Sham Control | 0 | 2.15 ± 0.08 | | 0
CDMA | 2.5 | 3.62 ± 0.66 | 0.011 | 0
| 5 | 3.39 ± 0.45 | 0.015 | 0.13 ± 0.13
| 10 | 2.45 ± 0.24 | 0.428 | 0
| | P = 0.173
GSM | 2.5 | 2.58 ± 0.35 | 0.504 | 0
| 5 | 2.23 ± 0.19 | 1.000 | 0
| 10 | 2.28 ± 0.51 | 1.000 | 0
| | P = 0.657

^a^ Study was performed at ILS, Inc. The detailed protocol (150 cell) is presented by OECD.^180^. Groups of five mice per exposure group were 5 to 6 weeks old when exposure began.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ Percent hedgehogs = estimated as the number of comets with ≥90% tail DNA/150.

^e^ No exposure to CDMA- or GSM-modulated cell phone RFR.

^f^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.

Table E-7 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Exposure to CDMA- or GSM-modulated Cell Phone RFR for 14 Weeks^a^

| Dose (W/kg) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Sham Control^d^ | 0 | 5 | 2.55 ± 0.11 | | 1.50 ± 0.04 | | 1.43 ± 0.04
CDMA | 2.5 | 5 | 2.44 ± 0.13 | 0.611 | 1.45 ± 0.03 | 0.748 | 1.45 ± 0.04 | 0.765
| 5 | 5 | 2.77 ± 0.13 | 0.168 | 1.46 ± 0.04 | 0.827 | 1.48 ± 0.04 | 0.736
| 10 | 5 | 2.93 ± 0.18 | 0.044 | 1.49 ± 0.02 | 0.736 | 1.45 ± 0.04 | 0.778
| | | P = 0.013^e^ | | P = 0.497 | | P = 0.803
GSM | 2.5 | 5 | 2.84 ± 0.14 | 0.384 | 1.49 ± 0.04 | 0.695 | 1.39 ± 0.04 | 0.667
| 5 | 5 | 2.47 ± 0.19 | 0.455 | 1.45 ± 0.02 | 0.781 | 1.38 ± 0.04 | 0.787
| 10 | 5 | 2.53 ± 0.13 | 0.484 | 1.50 ± 0.02 | 0.675 | 1.45 ± 0.07 | 0.830
| | | P = 0.733 | | P = 0.561 | | P = 0.809
Female
Sham Control | 0 | 5 | 2.72 ± 0.27 | | 1.18 ± 0.02 | | 1.31 ± 0.11
CDMA | 2.5 | 5 | 2.16 ± 0.15 | 0.846 | 1.06 ± 0.04 | 0.956 | 1.31 ± 0.12 | 1.000
| 5 | 5 | 2.32 ± 0.22 | 0.908 | 1.09 ± 0.03 | 0.982 | 1.43 ± 0.11 | 0.930
| 10 | 5 | 2.48 ± 0.20 | 0.883 | 1.14 ± 0.02 | 0.929 | 1.26 ± 0.09 | 0.935
| | | P = 0.629 | | P = 0.585 | | P = 0.843
GSM | 2.5 | 5 | 2.50 ± 0.40 | 0.774 | 1.14 ± 0.05 | 0.827 | 1.18 ± 0.08 | 0.671
| 5 | 5 | 2.35 ± 0.15 | 0.850 | 1.09 ± 0.02 | 0.893 | 1.16 ± 0.06 | 0.791
| 10 | 5 | 2.16 ± 0.15 | 0.878 | 1.12 ± 0.04 | 0.916 | 1.43 ± 0.08 | 0.438
| | | P = 0.937 | | P = 0.891 | | P = 0.245

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^199^. Mice were 5 to 6 weeks old when exposure began. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the sham control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ No exposure to CDMA- or GSM-modulated cell phone RFR.

^e^ Dose-related trend derived from one-tailed linear regression or Jonckheere’s test; the trend is significant when P ≤ 0.025.