# Appendix D Summary of Lesions in Female Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

Table D-1 Summary of the Incidence of Neoplasms in Female Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Disposition Summary
Animals initially in study | 105 | 104 | 105 | 105
14-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Moribund | 9 | 5 | 4 | 4
Natural deaths | 14 | 9 | 16 | 14
Survivors
Died last week of study | 1 | 3 | 1 | 1
Terminal euthanasia | 66 | 72 | 69 | 71
Animals examined microscopically | 100 | 99 | 100 | 100
Systems Examined at 14 Weeks with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (87) | (88) | (87) | (87)
Gallbladder | (79) | (75) | (72) | (73)
Intestine large, cecum | (84) | (82) | (80) | (81)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Intestine large, colon | (84) | (85) | (85) | (86)
Intestine large, rectum | (88) | (86) | (84) | (88)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Osteosarcoma, metastatic, skin | 1 (1%) | – | – | –
Intestine small, duodenum | (82) | (81) | (80) | (77)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Intestine small, ileum | (83) | (82) | (76) | (81)
Intestine small, jejunum | (84) | (81) | (80) | (77)
Liver | (89) | (88) | (90) | (90)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Hemangiosarcoma | – | 1 (1%) | – | –
Hepatoblastoma | 1 (1%) | – | – | –
Hepatocellular adenoma | 14 (16%) | 20 (23%) | 17 (19%) | 13 (14%)
Hepatocellular adenoma, multiple | 5 (6%) | 4 (5%) | 5 (6%) | 7 (8%)
Hepatocellular carcinoma | 6 (7%) | 5 (6%) | 3 (3%) | 5 (6%)
Hepatocellular carcinoma, multiple | 2 (2%) | – | 2 (2%) | –
Hepatocholangiocarcinoma | – | – | 1 (1%) | –
Osteosarcoma, metastatic, bone | 1 (1%) | – | – | 1 (1%)
Osteosarcoma, metastatic, brain | – | 1 (1%) | – | –
Osteosarcoma, metastatic, skin | 1 (1%) | – | – | –
Sarcoma, metastatic, skeletal muscle | – | 1 (1%) | – | –
Mesentery | (29) | (24) | (34) | (24)
Fibrosarcoma, metastatic, skin | 1 (3%) | – | – | –
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (4%)
Renal mesenchymal tumor, metastatic, kidney | 1 (3%) | – | – | –
Sarcoma, metastatic, skeletal muscle | – | 1 (4%) | – | –
Fat, hemangioma | 1 (3%) | – | – | –
Fat, lipoma | – | 2 (8%) | 1(3%) | –
Pancreas | (87) | (86) | (85) | (84)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (1%)
Renal mesenchymal tumor, metastatic, kidney | 1 (1%) | – | – | –
Acinus, adenoma | – | – | 1 (1%) | –
Salivary glands | (89) | (88) | (87) | (89)
Stomach, forestomach | (86) | (88) | (87) | (87)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (1%)
Squamous cell papilloma | 1 (1%) | 1 (1%) | – | 1 (1%)
Stomach, glandular | (85) | (88) | (85) | (83)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Cardiovascular System
Aorta | (84) | (87) | (89) | (90)
Heart | (90) | (89) | (90) | (90)
Osteosarcoma, metastatic, bone | – | – | 1 (1%) | 1 (1%)
Osteosarcoma, metastatic, skin | 1 (1%) | – | – | –
Sarcoma, metastatic, skeletal muscle | – | 1 (1%) | – | –
Endocrine System
Adrenal cortex | (84) | (88) | (87) | (88)
Adenoma | 1 (1%) | – | – | –
Adrenal medulla | (83) | (87) | (84) | (84)
Pheochromocytoma benign | – | – | – | 1 (1%)
Pheochromocytoma malignant | 2 (2%) | – | – | –
Bilateral, pheochromocytoma benign | – | – | 1(1%) | –
Islets, pancreatic | (87) | (88) | (89) | (87)
Adenoma | – | – | – | 1 (1%)
Carcinoma | 1 (1%) | – | – | –
Parathyroid gland | (60) | (59) | (65) | (68)
Pituitary gland | (80) | (79) | (88) | (86)
Pars distalis, adenoma | 6 (8%) | 8 (10%) | 8 (9%) | 1 (1%)
Pars distalis, carcinoma | – | – | – | 1 (1%)
Pars distalis, fibrosarcoma, metastatic, skin | – | – | – | 1 (1%)
Thyroid gland | (86) | (87) | (88) | (88)
C-cell carcinoma | 1(1%) | – | – | –
Follicular cell, adenoma | – | 2(2%) | 1(1%) | 1(1%)
General Body System
Tissue NOS | (1) | (1) | (1) | (0)
Hemangiosarcoma | – | 1 (100%) | – | –
Abdominal, osteosarcoma, metastatic, skin | 1 (100%) | – | – | –
Genital System
Clitoral gland | (82) | (82) | (81) | (82)
Ovary | (75) | (84) | (84) | (83)
Adenocarcinoma, metastatic, uterus | – | 2 (2%) | – | –
Cystadenoma | 2 (3%) | 2 (2%) | 6 (7%) | 6 (7%)
Granulosa cell tumor benign | 1 (1%) | – | – | –
Hemangioma | 2 (3%) | – | – | 1 (1%)
Luteoma | – | – | 2 (2%) | 1 (1%)
Teratoma benign | – | – | 1 (1%) | –
Thecoma malignant | 1 (1%) | – | – | –
Tubulostromal adenoma | – | – | 1 (1%) | –
Uterus | (89) | (89) | (88) | (90)
Adenocarcinoma | – | 2 (2%) | – | 1 (1%)
Adenoma | – | – | 1(1%) | –
Fibroma | 1 (1%) | – | – | –
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Granular cell tumor malignant | – | 1 (1%) | – | –
Hemangiosarcoma | – | 1 (1%) | – | 1 (1%)
Leiomyoma | 1 (1%) | – | –
Leiomyosarcoma | – | 1 (1%) | 1 (1%) | 2 (2%)
Polyp stromal | – | – | – | 1 (1%)
Hematopoietic System
Bone marrow | (90) | (89) | (89) | (89)
Hemangiosarcoma | – | – | 1 (1%) | –
Lymph node | (18) | (21) | (18) | (18)
Bronchial, adenocarcinoma, metastatic, uterus | – | 1 (5%) | – | –
Bronchial, alveolar/bronchiolar carcinoma metastatic, lung | 1 (6%) | – | – | –
Bronchial, fibrosarcoma, metastatic, skin | 1 (6%) | – | – | –
Iliac, hemangiosarcoma | – | 1 (5%) | – | –
Lumbar, leiomyosarcoma, metastatic, uterus | – | – | – | 1 (6%)
Pancreatic, adenocarcinoma, metastatic, uterus | – | 1 (5%) | – | –
Lymph node, mandibular | (76) | (79) | (76) | (73)
Lymph node, mesenteric | (71) | (86) | (75) | (81)
Adenocarcinoma, metastatic, uterus | – | 1 (1%) | – | –
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Hemangiosarcoma | – | 1 (1%)
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (1%)
Renal mesenchymal tumor, metastatic, kidney | 1 (1%) | – | – | –
Sarcoma, metastatic, skeletal muscle | – | 1 (1%) | – | –
Spleen | (86) | (87) | (86) | (88)
Hemangiosarcoma | – | 3 (3%) | 2 (2%) | 1 (1%)
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (1%)
Thymus | (85) | (83) | (82) | (82)
Osteosarcoma, metastatic, bone | – | – | 1 (1%) | –
Integumentary System
Mammary gland | (85) | (87) | (90) | (88)
Adenocarcinoma | – | – | – | 2 (2%)
Adenoma | – | 1 (1%) | 2 (2%) | –
Skin | (90) | (89) | (90) | (90)
Squamous cell carcinoma | – | – | – | 1 (1%)
Subcutaneous tissue, fibroma | 1 (1%) | – | – | –
Subcutaneous tissue, fibroma, multiple | – | – | – | 1(1%)
Subcutaneous tissue, fibrosarcoma | 3 (3%) | 1 (1%) | 3 (3%) | 2 (2%)
Subcutaneous tissue, fibrosarcoma, multiple | – | – | – | 1 (1%)
Subcutaneous tissue, hemangioma | – | 1 (1%) | – | –
Subcutaneous tissue, hemangiosarcoma | 2 (2%) | – | – | 1 (1%)
Subcutaneous tissue, lipoma | 1 (1%) | – | – | –
Subcutaneous tissue, malignant fibrous histiocytoma | – | 1 (1%) | 1 (1%) | –
Subcutaneous tissue, osteosarcoma | 1 (1%) | – | – | –
Subcutaneous tissue, sarcoma | 2 (2%) | – | – | –
Musculoskeletal System
Bone | (90) | (89) | (90) | (89)
Hemangioma | 1 (1%) | – | – | –
Osteosarcoma | 1 (1%) | 2 (2%) | 1 (1%) | 2 (2%)
Skeletal muscle | (89) | (89) | (90) | (90)
Adenocarcinoma, metastatic, uterus | – | 1 (1%) | – | –
Hemangiosarcoma | – | 2 (2%) | – | –
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (1%)
Osteosarcoma | 1 (1%) | – | – | –
Sarcoma | – | 1 (1%) | – | –
Nervous System
Brain | (87) | (88) | (90) | (90)
Carcinoma, metastatic, pituitary gland | – | – | – | 1 (1%)
Fibrosarcoma, metastatic, skin | – | – | – | 1 (1%)
Osteosarcoma, metastatic, skeletal muscle | 1 (1%) | – | – | –
Osteosarcoma, metastatic, uncertain primary site | – | 1 (1%) | – | –
Brain trigeminal ganglion | (75) | (82) | (75) | (74)
Nerve trigeminal | (56) | (30) | (52) | (51)
Peripheral nerve, sciatic | (88) | (88) | (89) | (88)
Spinal cord | (90) | (89) | (90) | (90)
Osteosarcoma, metastatic, bone | – | – | – | 1 (1%)
Respiratory System
Lung | (90) | (89) | (90) | (90)
Alveolar/bronchiolar adenoma | 3 (3%) | 6 (7%) | 4 (4%) | 1 (1%)
Alveolar/bronchiolar adenoma, multiple | – | – | – | 1 (1%)
Alveolar/bronchiolar carcinoma | 3 (3%) | 3 (3%) | 3 (3%) | 5 (6%)
Carcinoma, metastatic, thyroid gland | 1 (1%) | – | – | –
Fibrosarcoma, metastatic, skin | 1 (1%) | – | 1 (1%) | –
Granular cell tumor malignant, metastatic, uterus | – | 1(1%) | – | –
Hepatocellular carcinoma, metastatic, liver | 2 (2%) | – | 1 (1%) | –
Osteosarcoma, metastatic, bone | 1 (1%) | 1 (1%) | 1 (1%) | 2 (2%)
Osteosarcoma, metastatic, brain | – | 1 (1%) | – | –
Osteosarcoma, metastatic, skeletal muscle | 1 (1%) | – | – | –
Osteosarcoma, metastatic, skin | 1 (1%) | – | – | –
Sarcoma, metastatic, skeletal muscle | – | 1 (1%) | – | –
Squamous cell carcinoma, metastatic, skin | – | – | – | 1 (1%)
Mediastinum | (2) | (0) | (0) | (0)
Hepatocellular carcinoma, metastatic, liver | 1 (50%) | – | – | –
Nose | (89) | (89) | (90) | (90)
Respiratory epithelium, adenoma | – | – | – | 1 (1%)
Trachea | (90) | (87) | (89) | (88)
Special Senses System
Eye | (89) | (89) | (90) | (89)
Harderian gland | (89) | (88) | (89) | (89)
Adenocarcinoma | – | 1 (1%) | 1 (1%) | 2 (2%)
Adenoma | 4 (4%) | 8 (9%) | 8 (9%) | 4 (4%)
Urinary System
Kidney | (89) | (89) | (88) | (87)
Adenocarcinoma, metastatic, uterus | – | 1 (1%) | – | –
Renal mesenchymal tumor | 1 (1%) | – | – | –
Renal tubule, adenoma | 2 (2%) | – | – | –
Urinary bladder | (86) | (86) | (83) | (85)
Systemic Lesions
Multiple organs^b^ | (90) | (89) | (90) | (90)
Histiocytic sarcoma | 8 (9%) | 3 (3%) | 2 (2%) | 7 (8%)
Leukemia erythrocytic | – | 1 (1%) | – | –
Leukemia granulocytic | – | – | 2 (2%) | –
Lymphoma malignant | 2 (2%) | 9 (10%) | 6 (7%) | 7 (8%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 59 | 62 | 56 | 56
Total primary neoplasms
Two-year study | 85 | 96 | 88 | 83
Total animals with benign neoplasms
Two-year study | 36 | 42 | 43 | 32
Total benign neoplasms
Two-year study | 47 | 55 | 59 | 42
Total animals with malignant neoplasms
Two-year study | 33 | 32 | 26 | 36
Total malignant neoplasms
Two-year study | 38 | 41 | 29 | 41
Total animals with metastatic neoplasms
Two-year study | 9 | 6 | 3 | 6
Total metastatic neoplasms
Two-year study | 29 | 17 | 5 | 16
Total animals with malignant neoplasms of uncertain primary site
Two-year study | – | 1 | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Harderian Gland: Adenoma
Overall rate^a^ | 4/90 (4%) | 8/89 (9%) | 8/90 (9%) | 4/90 (4%)
Adjusted rate^b^ | 5.0% | 9.5% | 9.6% | 4.8%
Terminal rate^c^ | 4/67 (6%) | 8/74 (11%) | 7/69 (10%) | 4/71 (6%)
First incidence (days) | 739 (T) | 739 (T) | 704 | 739 (T)
Poly-3 test^d^ | P = 0.415N | P = 0.208 | P = 0.208 | P = 0.621N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 4/90 (4%) | 9/89 (10%) | 9/90 (10%) | 6/90 (7%)
Adjusted rate | 5.0% | 10.7% | 10.7% | 7.2%
Terminal rate | 4/67 (6%) | 9/74 (12%) | 8/69 (12%) | 5/71 (7%)
First incidence (days) | 739 (T) | 739 (T) | 704 | 653
Poly-3 test | P = 0.482 | P = 0.143 | P = 0.143 | P = 0.397
Liver: Hepatocellular Adenoma
Overall rate | 19/89 (21%)^e^ | 24/88 (27%) | 22/90 (24%) | 20/90 (22%)
Adjusted rate | 23.6% | 28.8% | 26.0% | 24.1%
Terminal rate | 17/67 (25%) | 22/73 (30%) | 17/69 (25%) | 18/71 (25%)
First incidence (days) | 511 | 579 | 644 | 679
Poly-3 test | P = 0.466N | P = 0.282 | P = 0.429 | P = 0.543
Liver: Hepatocellular Carcinoma
Overall rate | 8/89 (9%) | 5/88 (6%) | 5/90 (6%) | 5/90 (6%)
Adjusted rate | 10.0% | 6.0% | 6.0% | 6.0%
Terminal rate | 7/67 (10%) | 3/73 (4%) | 3/69 (4%) | 5/71 (7%)
First incidence (days) | 656 | 639 | 692 | 739 (T)
Poly-3 test | P = 0.255N | P = 0.255N | P = 0.251N | P = 0.259N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 25/89 (28%) | 29/88 (33%) | 26/90 (29%) | 22/90 (24%)
Adjusted rate | 30.9% | 34.5% | 30.6% | 26.5%
Terminal rate | 22/67 (33%) | 25/73 (34%) | 19/69 (28%) | 20/71 (28%)
First incidence (days) | 511 | 579 | 644 | 679
Poly-3 test | P = 0.217N | P = 0.371 | P = 0.552N | P = 0.325N
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 9/89 (10%) | 5/88 (6%) | 5/90 (6%) | 5/90 (6%)
Adjusted rate | 11.3% | 6.0% | 6.0% | 6.0%
Terminal rate | 8/67 (12%) | 3/73 (4%) | 3/69 (4%) | 5/71 (7%)
First incidence (days) | 656 | 639 | 692 | 739 (T)
Poly-3 test | P = 0.186N | P = 0.178N | P = 0.174N | P = 0.181N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 3/90 (3%) | 6/89 (7%) | 4/90 (4%) | 2/90 (2%)
Adjusted rate | 3.8% | 7.2% | 4.8% | 2.4%
Terminal rate | 3/67 (5%) | 5/74 (7%) | 4/69 (6%) | 2/71 (3%)
First incidence (days) | 739 (T) | 738 | 739 (T) | 739 (T)
Poly-3 test | P = 0.262N | P = 0.271 | P = 0.525 | P = 0.484N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 3/90 (3%) | 3/89 (3%) | 3/90 (3%) | 5/90 (6%)
Adjusted rate | 3.7% | 3.6% | 3.6% | 6.0%
Terminal rate | 2/67 (3%) | 3/74 (4%) | 1/69 (1%) | 4/71 (6%)
First incidence (days) | 607 | 739 (T) | 511 | 684
Poly-3 test | P = 0.270 | P = 0.641N | P = 0.638N | P = 0.377
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 6/90 (7%) | 9/89 (10%) | 7/90 (8%) | 6/90 (7%)
Adjusted rate | 7.5% | 10.7% | 8.3% | 7.2%
Terminal rate | 5/67 (8%) | 8/74 (11%) | 5/69 (7%) | 5/71 (7%)
First incidence (days) | 607 | 738 | 511 | 684
Poly-3 test | P = 0.423N | P = 0.325 | P = 0.536 | P = 0.595N
Ovary: Cystadenoma
Overall rate | 2/75 (3%) | 2/84 (2%) | 6/84 (7%) | 6/83 (7%)
Adjusted rate | 3.0% | 2.5% | 7.6% | 7.9%
Terminal rate | 2/56 (4%) | 2/70 (3%) | 6/66 (9%) | 5/65 (8%)
First incidence (days) | 739 (T) | 739 (T) | 739 (T) | 597
Poly-3 test | P = 0.077 | P = 0.627N | P = 0.202 | P = 0.189
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 6/80 (8%) | 8/79 (10%) | 8/88 (9%) | 1/86 (1%)
Adjusted rate | 8.4% | 10.7% | 9.8% | 1.3%
Terminal rate | 5/60 (8%) | 8/67 (12%) | 6/68 (9%) | 1/68 (2%)
First incidence (days) | 703 | 739 (T) | 704 | 739 (T)
Poly-3 test | P = 0.029N | P = 0.430 | P = 0.499 | P = 0.043N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 6/80 (8%) | 8/79 (10%) | 8/88 (9%) | 2/86 (2%)
Adjusted rate | 8.4% | 10.7% | 9.8% | 2.5%
Terminal rate | 5/60 (8%) | 8/67 (12%) | 6/68 (9%) | 2/68 (3%)
First incidence (days) | 703 | 739 (T) | 704 | 739 (T)
Poly-3 test | P = 0.063N | P = 0.430 | P = 0.499 | P = 0.104N
Skin (Subcutaneous Tissue): Fibrosarcoma or Sarcoma
Overall rate | 5/90 (6%) | 1/89 (1%) | 3/90 (3%) | 3/90 (3%)
Adjusted rate | 6.2% | 1.2% | 3.6% | 3.6%
Terminal rate | 1/67 (2%) | 0/74 (0%) | 1/69 (1%) | 2/71 (3%)
First incidence (days) | 607 | 715 | 669 | 731
Poly-3 test | P = 0.422N | P = 0.097N | P = 0.338N | P = 0.346N
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, or Sarcoma
Overall rate | 6/90 (7%) | 1/89 (1%) | 3/90 (3%) | 3/90 (3%)
Adjusted rate | 7.4% | 1.2% | 3.6% | 3.6%
Terminal rate | 2/67 (3%) | 0/74 (0%) | 1/69 (1%) | 2/71 (3%)
First incidence (days) | 607 | 715 | 669 | 731
Poly-3 test | P = 0.301N | P = 0.054N | P = 0.228N | P = 0.235N
All Organs: Hemangiosarcoma
Overall rate | 2/90 (2%) | 7/89 (8%) | 2/90 (2%) | 3/90 (3%)
Adjusted rate | 2.5% | 8.3% | 2.4% | 3.6%
Terminal rate | 1/67 (2%) | 4/74 (5%) | 0/69 (0%) | 2/71 (3%)
First incidence (days) | 703 | 626 | 644 | 653
Poly-3 test | P = 0.436N | P = 0.098 | P = 0.674N | P = 0.517
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 6/90 (7%) | 8/89 (9%) | 2/90 (2%) | 4/90 (4%)
Adjusted rate | 7.5% | 9.5% | 2.4% | 4.8%
Terminal rate | 5/67 (8%) | 5/74 (7%) | 0/69 (0%) | 3/71 (4%)
First incidence (days) | 703 | 626 | 644 | 653
Poly-3 test | P = 0.161N | P = 0.431 | P = 0.122N | P = 0.349N
All Organs: Histiocytic Sarcoma
Overall rate | 8/90 (9%) | 3/89 (3%) | 2/90 (2%) | 7/90 (8%)
Adjusted rate | 9.7% | 3.5% | 2.4% | 8.4%
Terminal rate | 2/67 (3%) | 1/74 (1%) | 0/69 (0%) | 5/71 (7%)
First incidence (days) | 562 | 493 | 725 | 675
Poly-3 test | P = 0.558 | P = 0.098N | P = 0.048N | P = 0.494N
All Organs: Malignant Lymphoma
Overall rate | 2/90 (2%) | 9/89 (10%) | 6/90 (7%) | 7/90 (8%)
Adjusted rate | 2.5% | 10.7% | 7.2% | 8.4%
Terminal rate | 1/67 (2%) | 8/74 (11%) | 4/69 (6%) | 4/71 (6%)
First incidence (days) | 604 | 689 | 716 | 635
Poly-3 test | P = 0.220 | P = 0.035 | P = 0.152 | P = 0.094
All Organs: Benign Neoplasms
Overall rate | 36/90 (40%) | 42/89 (47%) | 43/90 (48%) | 32/90 (36%)
Adjusted rate | 44.1% | 49.7% | 50.7% | 38.3%
Terminal rate | 32/67 (48%) | 38/74 (51%) | 34/69 (49%) | 29/71 (41%)
First incidence (days) | 511 | 579 | 644 | 597
Poly-3 test | P = 0.180N | P = 0.283 | P = 0.240 | P = 0.274N
All Organs: Malignant Neoplasms
Overall rate | 33/90 (37%) | 33/89 (37%) | 26/90 (29%) | 36/90 (40%)
Adjusted rate | 38.1% | 37.9% | 29.8% | 41.6%
Terminal rate | 17/67 (25%) | 21/74 (28%) | 12/69 (17%) | 25/71 (35%)
First incidence (days) | 448 | 493 | 499 | 484
Poly-3 test | P = 0.382 | P = 0.552N | P = 0.160N | P = 0.379
All Organs: Benign or Malignant Neoplasms
Overall rate | 59/90 (66%) | 62/89 (70%) | 56/90 (62%) | 56/90 (62%)
Adjusted rate | 67.6% | 71.3% | 64.1% | 64.1%
Terminal rate | 42/67 (63%) | 50/74 (68%) | 40/69 (58%) | 43/71 (61%)
First incidence (days) | 448 | 493 | 499 | 484
Poly-3 test | P = 0.242N | P = 0.360 | P = 0.366N | P = 0.371N

T = terminal euthanasia

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, ovary, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ A single incidence of hepatoblastoma occurred in an animal that also had an adenoma.

Table D-3 Historical Incidence of Malignant Lymphoma in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: All Studies
Antimony trioxide (October 2008) | 7/50
2,3-Butanedione (August 2009) | 9/50
Green tea extract (July 2007) | 7/50
2-Hydroxy-4-methoxybenzophenone (July 2010) | 5/50
Indole-3-carbinol (April 2007) | 6/50
CIMSTAR 3800 (May 2008) | 18/50
Trim VX (August 2009) | 10/50
p-Chloro-á,á,á-trifluorotoluene (January 2011) | 9/50
Pentabromodiphenyl ether mixture [DE-71 (technical grade)] (February 2008) | 7/50
Radiofrequency radiation (June 2012) | 2/90
Tetrabromobisphenol A (August 2007) | 9/50
Overall Historical Incidence
Total (%) | 89/590 (15.1%)
Mean ± standard deviation | 16.0% ± 8.3%
Range | 2%-36%

^a^ Data as of August 2017; includes data for histiocytic, lymphocytic, mixed, unspecified, or undifferentiated cell types.

Table D-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Disposition Summary
Animals initially in study | 105 | 104 | 105 | 105
14-week Interim Evaluation | 15 | 15 | 15 | 15
Early deaths
Moribund | 9 | 5 | 4 | 4
Natural deaths | 14 | 9 | 16 | 14
Survivors
Died last week of study | 1 | 3 | 1 | 1
Terminal euthanasia | 66 | 72 | 69 | 71
Animals examined microscopically | 100 | 99 | 100 | 100
14-week Interim Evaluation
Alimentary System
Liver | (10) | (10) | (10) | (10)
Inflammation, focal | 1 (10%) | – | 3 (30%) | 2 (20%)
Necrosis, focal | – | – | 1 (10%) | –
Endocrine System
Thyroid gland | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | 1 (10%) | – | – | –
Hematopoietic System
Lymph node, mandibular | (8) | (8) | (9) | (10)
Hemorrhage | – | – | 1 (11%) | –
Thymus | (10) | (10) | (10) | (10)
Hemorrhage | – | – | 1 (10%) | 2 (20%)
Nervous System
Spinal cord | (10) | (10) | (10) | (10)
Cyst, squamous | – | 1 (10%) | – | –
Respiratory System
Lung | (10) | (10) | (10) | (10)
Hemorrhage | – | – | 1 (10%) | –
Special Senses System
Eye | (10) | (10) | (10) | (10)
Retina, dysplasia | – | 1 (10%) | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10)
Nephropathy, chronic progressive | – | 1 (10%) | – | –
Interstitium, infiltration cellular, lymphocyte | – | 1 (10%) | 1 (10%) | 5 (50%)
Urinary bladder | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | – | – | 1 (10%) | 2 (20%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Genital System
Integumentary System
Musculoskeletal System
Two-year Study
Alimentary System
Esophagus | (87) | (88) | (87) | (87)
Gallbladder | (79) | (75) | (72) | (73)
Cyst | – | – | 1 (1%) | –
Infiltration cellular, lymphocyte | 2 (3%) | 4 (5%) | 2 (3%) | 3 (4%)
Epithelium, hyperplasia, diffuse | – | – | 1 (1%) | –
Intestine large, cecum | (84) | (82) | (80) | (81)
Intestine large, colon | (84) | (85) | (85) | (86)
Intestine large, rectum | (88) | (86) | (84) | (88)
Intestine small, duodenum | (82) | (81) | (80) | (77)
Inflammation, acute | 1 (1%) | – | – | –
Intestine small, ileum | (83) | (82) | (76) | (81)
Inflammation, suppurative | – | 1 (1%) | – | –
Peyer’s patch, hyperplasia, lymphoid | – | 2 (2%) | – | –
Intestine small, jejunum | (84) | (81) | (80) | (77)
Peyer’s patch, hyperplasia, lymphoid | 1 (1%) | 2 (2%) | – | –
Liver | (89) | (88) | (90) | (90)
Angiectasis | – | – | – | 1 (1%)
Basophilic focus | 4 (4%) | 4 (5%) | 3 (3%) | 1 (1%)
Clear cell focus | 1 (1%) | – | – | –
Eosinophilic focus | 2 (2%) | – | 2 (2%) | 2 (2%)
Extramedullary hematopoiesis | 1 (1%) | 2 (2%) | – | 2 (2%)
Fatty change | 7 (8%) | 1 (1%) | 2 (2%) | 9 (10%)
Hemorrhage | 1 (1%) | – | 1 (1%) | 1 (1%)
Infiltration cellular, lymphocyte | 33 (37%) | 22 (25%) | 26 (29%) | 24 (27%)
Infiltration cellular, mononuclear cell | 1 (1%) | – | – | –
Inflammation, focal | 4 (4%) | 2 (2%) | – | –
Inflammation, chronic active | 1 (1%) | – | – | 2 (2%)
Mixed cell focus | 5 (6%) | – | – | –
Necrosis | 6 (7%) | 2 (2%) | 3 (3%) | 4 (4%)
Centrilobular, necrosis | – | – | – | 1 (1%)
Hepatocyte, fatty change, focal | 3 (3%) | – | 1 (1%) | –
Hepatocyte, hypertrophy | – | – | 1 (1%) | –
Kupffer cell, hyperplasia | 1 (1%) | – | – | –
Oval cell, hyperplasia | – | – | 1 (1%) | –
Mesentery | (29) | (24) | (34) | (24)
Artery, inflammation, chronic | – | – | 1 (3%) | –
Fat, infiltration cellular, lymphocyte | 2 (7%) | – | 1 (3%) | 1 (4%)
Fat, inflammation, chronic | – | – | – | 2 (8%)
Fat, inflammation, chronic active | 1 (3%) | – | – | 2 (8%)
Fat, mineral | – | 1 (4%) | 2 (6%) | –
Fat, necrosis | 25 (86%) | 22 (92%) | 30 (88%) | 19 (79%)
Pancreas | (87) | (86) | (85) | (84)
Infiltration cellular, lymphocyte | 27 (31%) | 23 (27%) | 21 (25%) | 19 (23%)
Inflammation, chronic active | 1 (1%) | – | – | –
Necrosis | – | 1 (1%) | – | 2 (2%)
Acinus, atrophy | – | – | 1 (1%) | 2 (2%)
Duct, cyst | 1 (1%) | – | 3 (4%) | 1 (1%)
Salivary glands | (89) | (88) | (87) | (89)
Atrophy | 1 (1%) | – | – | –
Infiltration cellular, lymphocyte | 59 (66%) | 61 (69%) | 54 (62%) | 60 (67%)
Stomach, forestomach | (86) | (88) | (87) | (87)
Cyst | – | – | 1 (1%) | –
Epithelium, hyperplasia, focal | – | – | 1 (1%) | 1 (1%)
Stomach, glandular | (85) | (88) | (85) | (83)
Cyst | 3 (4%) | 2 (2%) | – | –
Infiltration cellular, lymphocyte | – | – | 2 (2%) | –
Cardiovascular System
Aorta | (84) | (87) | (89) | (90)
Degeneration | – | – | 1 (1%) | –
Inflammation, acute | – | – | 1 (1%) | –
Inflammation, chronic active | 1 (1%) | – | – | –
Thrombus | – | – | – | 1 (1%)
Heart | (90) | (89) | (90) | (90)
Bacteria | 1 (1%) | – | 1 (1%) | 2 (2%)
Cardiomyopathy | 3 (3%) | 4 (4%) | 4 (4%) | 6 (7%)
Thrombus | 3 (3%) | – | – | 2 (2%)
Artery, inflammation, chronic active | – | 2 (2%) | 1 (1%) | –
Endothelium, hyperplasia | – | 1 (1%) | – | –
Epicardium, infiltration cellular, mixed cell | 1 (1%) | – | – | –
Epicardium, infiltration cellular, mononuclear cell | 1 (1%) | – | – | –
Myocardium, fibrosis | 1 (1%) | – | – | 1 (1%)
Myocardium, hemorrhage | – | 1 (1%) | – | –
Myocardium, inflammation, acute | – | – | – | 2 (2%)
Myocardium, inflammation, chronic active | 1 (1%) | 1 (1%) | 2 (2%)
Myocardium, mineral | 4 (4%) | – | 1 (1%) | 2 (2%)
Myocardium, necrosis | – | – | 1 (1%) | –
Valve, hemorrhage | 1 (1%) | – | – | –
Valve, infiltration cellular, lymphocyte | 1 (1%) | – | – | –
Valve, thrombus | 1 (1%) | – | 1 (1%) | –
Endocrine System
Adrenal cortex | (84) | (88) | (87) | (88)
Accessory adrenal cortical nodule | – | – | 2 (2%) | 3 (3%)
Angiectasis | 1 (1%) | – | – | –
Hemorrhage | 1 (1%) | – | 1 (1%) | 1 (1%)
Hyperplasia, focal | – | 1 (1%) | – | –
Infiltration cellular, mixed cell | – | – | 1 (1%) | –
Mineral | 1 (1%) | – | – | –
Vacuolization cytoplasmic | – | 1 (1%) | – | –
Vacuolization cytoplasmic, focal | – | – | – | 1 (1%)
Bilateral, extramedullary hematopoiesis | 1 (1%) | – | – | –
Bilateral, infiltration cellular, mixed cell | – | – | 1 (1%) | –
Bilateral, vacuolization cytoplasmic | – | 1 (1%) | – | 2 (2%)
Subcapsular, hyperplasia | 81 (96%) | 84 (95%) | 84 (97%) | 86 (98%)
Adrenal medulla | (83) | (87) | (84) | (84)
Hemorrhage | 2 (2%) | – | – | –
Hyperplasia | – | 2 (2%) | 1 (1%) | –
Mineral | 1 (1%) | – | – | –
Islets, pancreatic | (87) | (88) | (89) | (87)
Hyperplasia | 1 (1%) | – | 1 (1%) | 2 (2%)
Infiltration cellular, lymphocyte | 3 (3%) | 3 (3%) | 5 (6%) | 1 (1%)
Parathyroid gland | (60) | (59) | (65) | (68)
Cyst | 1 (2%) | – | – | –
Infiltration cellular, lymphocyte | – | 1 (2%) | – | 1 (1%)
Pituitary gland | (80) | (79) | (88) | (86)
Pars distalis, angiectasis | 2 (3%) | 9 (11%) | 4 (5%) | 2 (2%)
Pars distalis, cyst | 1 (1%) | 1 (1%) | 1 (1%) | 2 (2%)
Pars distalis, hyperplasia, focal | 2 (3%) | 2 (3%) | 4 (5%) | 6 (7%)
Thyroid gland | (86) | (87) | (88) | (88)
Infiltration cellular, lymphocyte | 1 (1%) | 1 (1%) | 7 (8%) | 5 (6%)
Inflammation, chronic active | – | 1 (1%) | – | –
Follicle, cyst | 1 (1%) | – | 2 (2%) | 3 (3%)
General Body System
Tissue NOS | (1) | (1) | (1) | (0)
Genital System
Clitoral gland | (82) | (82) | (81) | (82)
Infiltration cellular, lymphocyte | 3 (4%) | – | – | 1 (1%)
Inflammation, granulomatous | – | – | – | 1 (1%)
Duct, cyst | 1 (1%) | 1 (1%) | – | –
Ovary | (75) | (84) | (84) | (83)
Angiectasis | – | 3 (4%) | – | –
Cyst | 9 (12%) | 11 (13%) | 7 (8%) | 4 (5%)
Hemorrhage | 1 (1%) | 1 (1%) | – | –
Infiltration cellular, histiocyte | – | – | 1 (1%) | –
Inflammation, granulomatous | – | – | – | 1 (1%)
Mineral | 1 (1%) | – | 1 (1%) | –
Follicle, cyst | 9 (12%) | 7 (8%) | 6 (7%) | 8 (10%)
Granulosa cell, hyperplasia | – | – | – | 1 (1%)
Paraovarian tissue, cyst | – | 2 (2%) | – | –
Uterus | (89) | (89) | (88) | (90)
Adenomyosis | – | – | 1 (1%) | –
Angiectasis | 1 (1%) | 3 (3%) | 3 (3%) | 4 (4%)
Dilation | 35 (39%) | 21 (24%) | 44 (50%) | 37 (41%)
Hemorrhage | 1 (1%) | – | – | –
Infiltration cellular, lymphocyte | – | – | – | 1 (1%)
Inflammation, chronic active | – | – | 1 (1%) | –
Mineral | – | – | 1 (1%) | –
Necrosis | – | – | 1 (1%) | –
Thrombus | 1 (1%) | – | 3 (3%) | 1 (1%)
Arteriole, degeneration | – | – | 1 (1%) | –
Endometrium, cyst | 3 (3%) | – | – | 2 (2%)
Endometrium, hyperplasia, cystic | 68 (76%) | 75 (84%) | 67 (76%) | 68 (76%)
Endometrium, metaplasia, squamous | 1 (1%) | – | – | –
Hematopoietic System
Bone marrow | (90) | (89) | (89) | (89)
Hypercellularity | 7 (8%) | 8 (9%) | 3 (3%) | 4 (4%)
Hypocellularity | 1 (1%) | – | 1 (1%) | –
Myeloid cell, hypercellularity | 1 (1%) | 1 (1%) | – | –
Lymph node | (18) | (21) | (18) | (18)
Hemorrhage | – | – | 1 (6%) | –
Hyperplasia, lymphoid | 1 (6%) | – | – | –
Infiltration cellular, mixed cell | – | – | – | 1 (6%)
Axillary, infiltration cellular, mixed cell | 1 (6%) | – | – | –
Axillary, pigment | 1 (6%) | – | – | –
Bronchial, hemorrhage | – | – | 1 (6%) | –
Bronchial, hyperplasia, lymphoid | 2 (11%) | 2 (10%) | – | 1 (6%)
Bronchial, infiltration cellular, histiocyte | – | 1 (5%) | – | –
Bronchial, infiltration cellular, mixed cell | – | 1 (5%) | – | –
Iliac, hemorrhage | 1 (6%) | – | 3 (17%) | 1 (6%)
Iliac, hyperplasia, lymphoid | 4 (22%) | 4 (19%) | 9 (50%) | 4 (22%)
Iliac, infiltration cellular, histiocyte | – | 1 (5%) | 1 (6%) | –
Iliac, infiltration cellular, mixed cell | 1 (6%) | 1 (5%) | 1 (6%) | 1 (6%)
Iliac, infiltration cellular, plasma cell | – | – | 1 (6%) | –
Iliac, pigment | – | 1 (5%) | 2 (11%) | –
Lumbar, hemorrhage | – | 1 (5%) | – | –
Lumbar, hyperplasia, lymphoid | – | 2 (10%) | 1 (6%) | –
Lumbar, infiltration cellular, mixed cell | 1 (6%) | – | – | –
Mediastinal, hyperplasia, lymphoid | 1 (6%) | 4 (19%) | 1 (6%) | 3 (17%)
Mediastinal, infiltration cellular, histiocyte | – | – | – | 1 (6%)
Pancreatic, hyperplasia, lymphoid | 1 (6%) | – | – | 1 (6%)
Renal, ectasia | – | 1 (5%) | – | –
Renal, hemorrhage | 1 (6%) | – | – | –
Renal, hyperplasia, lymphoid | 3 (17%) | – | 2 (11%) | 2 (11%)
Renal, infiltration cellular, mixed cell | – | 1 (5%) | – | –
Lymph node, mandibular | (76) | (79) | (76) | (73)
Hemorrhage | 3 (4%) | 1 (1%) | 1 (1%) | 2 (3%)
Hyperplasia, lymphoid | 1 (1%) | 1 (1%) | 1 (1%) | 2 (3%)
Infiltration cellular, histiocyte | – | 1 (1%) | 1 (1%) | –
Infiltration cellular, mixed cell | 1 (1%) | – | – | –
Lymph node, mesenteric | (71) | (86) | (75) | (81)
Ectasia | – | – | – | 1 (1%)
Erythrophagocytosis | 1 (1%) | – | – | –
Hemorrhage | 1 (1%) | 3 (3%) | 6 (8%) | 3 (4%)
Hyperplasia, lymphoid | 1 (1%) | 5 (6%) | 4 (5%) | 4 (5%)
Infiltration cellular, histiocyte | 3 (4%) | 4 (5%) | 2 (3%) | 4 (5%)
Infiltration cellular, plasma cell | – | – | 1 (1%) | –
Spleen | (86) | (87) | (86) | (88)
Atrophy | 1 (1%) | – | – | –
Extramedullary hematopoiesis | 20 (23%) | 18 (21%) | 12 (14%) | 16 (18%)
Hemorrhage | – | 1 (1%) | – | –
Hyperplasia, lymphoid | 11 (13%) | 10 (11%) | 12 (14%) | 14 (16%)
Capsule, fibrosis | 1 (1%) | – | 1 (1%) | –
Thymus | (85) | (83) | (82) | (82)
Atrophy | 5 (6%) | 3 (4%) | 4 (5%) | 2 (2%)
Cyst | 2 (2%) | 4 (5%) | 4 (5%) | 6 (7%)
Hemorrhage | – | 2 (2%) | 1 (1%) | 2 (2%)
Hyperplasia, lymphoid | 1 (1%) | – | 2 (2%) | –
Integumentary System
Mammary gland | (85) | (87) | (90) | (88)
Hyperplasia, focal | 1 (1%) | – | 1 (1%) | –
Hyperplasia, diffuse | 1 (1%) | 1 (1%) | – | –
Infiltration cellular, lymphocyte | – | 1 (1%) | – | –
Duct, dilation | 1 (1%) | 2 (2%) | 2 (2%) | 2 (2%)
Skin | (90) | (89) | (90) | (90)
Ulcer | 2 (2%) | 3 (3%) | 1 (1%) | 1 (1%)
Epidermis, hyperplasia, focal | – | 1 (1%) | – | 1 (1%)
Hair follicle, atrophy | 2 (2%) | 2 (2%) | – | 5 (6%)
Subcutaneous tissue, fibrosis | – | – | – | 1 (1%)
Musculoskeletal System
Bone | (90) | (89) | (90) | (89)
Fibro-osseous lesion | 11 (12%) | – | 1 (1%) | 2 (2%)
Increased bone | – | 1 (1%) | 1 (1%) | –
Skeletal muscle | (89) | (89) | (90) | (90)
Degeneration | – | 1 (1%) | – | 1 (1%)
Infiltration cellular, lymphocyte | 16 (18%) | 7 (8%) | 11 (12%) | 9 (10%)
Mineral | 1 (1%) | – | – | –
Nervous System
Brain | (87) | (88) | (90) | (90)
Hemorrhage | 2 (2%) | – | – | 2 (2%)
Hydrocephalus | 1 (1%) | – | – | –
Inflammation, acute | 1 (1%) | – | – | –
Mineral | 80 (92%) | 81 (92%) | 78 (87%) | 74 (82%)
Necrosis | 1 (1%) | – | 1 (1%) | –
Artery, meninges, inflammation, chronic active | – | 3 (3%) | 1 (1%) | 1 (1%)
Brain trigeminal ganglion | (75) | (82) | (75) | (74)
Nerve trigeminal | (56) | (30) | (52) | (51)
Peripheral nerve, sciatic | (88) | (88) | (89) | (88)
Axon, degeneration | 12 (14%) | 4 (5%) | 8 (9%) | 11 (13%)
Spinal cord | (90) | (89) | (90) | (90)
Cyst, squamous, multiple | – | – | 1 (1%) | 1 (1%)
Degeneration | – | 1 (1%) | – | –
Demyelination | – | 1 (1%) | – | –
Metaplasia, osseous | – | 1 (1%) | – | –
Necrosis | – | 2 (2%) | – | –
Respiratory System
Lung | (90) | (89) | (90) | (90)
Congestion | – | – | 2 (2%) | 4 (4%)
Hemorrhage | 4 (4%) | 7 (8%) | 4 (4%) | 4 (4%)
Infiltration cellular, histiocyte | 1 (1%) | 2 (2%) | 1 (1%) | 2 (2%)
Infiltration cellular, lymphocyte | 3 (3%) | 2 (2%) | 4 (4%) | –
Infiltration cellular, mixed cell | – | 1 (1%) | – | –
Infiltration cellular, mononuclear cell | – | 1 (1%) | – | –
Inflammation, granulomatous | – | 1 (1%) | – | –
Inflammation, acute | 1 (1%) | – | – | –
Inflammation, chronic | 1 (1%) | – | – | –
Inflammation, chronic active | – | – | – | 1 (1%)
Alveolar epithelium, hyperplasia, focal | 1 (1%) | 3 (3%) | 3 (3%) | 3 (3%)
Mediastinum | (2) | (0) | (0) | (0)
Nose | (89) | (89) | (90) | (90)
Inflammation, acute | 1 (1%) | – | – | –
Respiratoryepithelium, accumulation, hyaline droplet | – | – | 1 (1%) | –
Trachea | (90) | (87) | (89) | (88)
Special Senses System
Eye | (89) | (89) | (90) | (89)
Phthisis bulbi | – | – | – | 1 (1%)
Anterior chamber, inflammation, acute | – | – | – | 1 (1%)
Harderian gland | (89) | (88) | (89) | (89)
Hyperplasia, focal | – | 1 (1%) | – | –
Infiltration cellular, lymphocyte | 58 (65%) | 66 (75%) | 61 (69%) | 64 (72%)
Urinary System
Kidney | (89) | (89) | (88) | (87)
Cyst | 1 (1%) | – | – | –
Infarct | 14 (16%) | 26 (29%) | 23 (26%) | 17 (20%)
Metaplasia, osseous | 2 (2%) | 1 (1%) | 2 (2%) | 2 (2%)
Nephropathy, chronic progressive | 8 (9%) | 12 (13%) | 7 (8%) | 7 (8%)
Bilateral, infarct | 1 (1%) | – | – | –
Interstitium, infiltration cellular, lymphocyte | 63 (71%) | 65 (73%) | 50 (57%) | 50 (57%)
Medulla, mineral | – | – | – | 1 (1%)
Papilla, mineral | – | – | 2 (2%) | –
Papilla, necrosis | – | 1 (1%) | – | –
Pelvis, dilation | 1 (1%) | – | – | –
Renal tubule, cyst | – | – | – | 1 (1%)
Renal tubule, dilation | 1 (1%) | – | 1 (1%) | 1 (1%)
Renal tubule, mineral | 1 (1%) | – | – | –
Renal tubule, vacuolization cytoplasmic | – | – | 1 (1%) | –
Urinary bladder | (86) | (86) | (83) | (85)
Angiectasis | – | – | 6 (7%) | 2 (2%)
Infiltration cellular, lymphocyte | 62 (72%) | 64 (74%) | 70 (84%) | 65 (76%)
Transitional epithelium, hyperplasia, diffuse | – | – | 1 (1%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.