# Appendix C Summary of Lesions in Male Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

Table C-1 Summary of the Incidence of Neoplasms in Male Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Disposition Summary
Animals initially in study | 105 | 106 | 105 | 105
14-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | – | – | 1 | –
Moribund | 8 | 2 | 5 | 3
Natural deaths | 16 | 6 | 13 | 16
Survivors
Terminal euthanasia | 66 | 83 | 71 | 71
Animals examined microscopically | 100 | 101 | 100 | 100
Systems Examined at 14 Weeks with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (88) | (91) | (89) | (88)
Gallbladder | (73) | (80) | (75) | (76)
Intestine large, cecum | (81) | (87) | (81) | (80)
Adenoma | – | – | 1(1%) | –
Intestine large, colon | (84) | (88) | (84) | (81)
Adenocarcinoma | – | – | 1(1%) | –
Intestine large, rectum | (84) | (89) | (85) | (85)
Intestine small, duodenum | (77) | (86) | (81) | (80)
Adenocarcinoma | 1(1%) | – | – | –
Intestine small, ileum | (81) | (88) | (83) | (81)
Adenoma | – | – | – | 1(1%)
Intestine small, jejunum | (79) | (87) | (81) | (82)
Adenocarcinoma | 2(3%) | – | 1(1%) | 2(2%)
Adenoma | – | – | – | 1(1%)
Hepatocellular carcinoma, metastatic, liver | 1(1%) | – | – | –
Liver | (90) | (89) | (90) | (90)
Hemangiosarcoma | 1(1%) | 4(4%) | 2(2%) | 1(1%)
Hepatoblastoma | 6(7%) | 6(7%) | 15(17%) | 7(8%)
Hepatoblastoma, multiple | – | – | 1(1%) | –
Hepatocellular adenoma | 25(28%) | 23(26%) | 22(24%) | 36(40%)
Hepatocellular adenoma, multiple | 27(30%) | 43(48%) | 33(37%) | 26(29%)
Hepatocellular carcinoma | 26(29%) | 13(15%) | 18(20%) | 24(27%)
Hepatocellular carcinoma, multiple | 2(2%) | 5(6%) | 7(8%) | 7(8%)
Hepatocholangiocarcinoma | 1(1%) | – | – | 2(2%)
Malignant fibrous histiocytoma, metastatic, skin | 1(1%) | – | – | –
Sarcoma, metastatic, skeletal muscle | – | – | – | 1(1%)
Mesentery | (12) | (9) | (18) | (16)
Hemangiosarcoma | 1(8%) | – | – | –
Hepatoblastoma, metastatic, liver | | – | 1(6%) | –
Malignant fibrous histiocytoma, metastatic,skin | 1(8%) | – | – | –
Fat, hepatocholangiocarcinoma, metastatic, liver | 1(8%) | – | – | –
Fat, lipoma | 1(8%) | – | 2(11%) | –
Pancreas | (87) | (88) | (88) | (88)
Hepatocholangiocarcinoma, metastatic, liver | 1(1%) | – | – | –
Salivary glands | (90) | (90) | (89) | (90)
Stomach, forestomach | (88) | (89) | (86) | (87)
Squamous cell papilloma | – | – | 1(1%) | –
Stomach, glandular | (87) | (88) | (87) | (87)
Malignant fibrous histiocytoma, metastatic, skin | 1(1%) | – | – | –
Tooth | (27) | (15) | (17) | (23)
Cardiovascular System
Aorta | (89) | (88) | (90) | (89)
Alveolar/bronchiolar carcinoma, metastatic lung | 1(1%) | – | – | –
Blood vessel | (1) | (1) | (0) | (0)
Heart | (90) | (91) | (90) | (90)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1(1%) | 1(1%) | – | –
Hemangioma | – | 1(1%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1(1%) | – | – | 1(1%)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1(1%)
Endocrine System
Adrenal cortex | (90) | (89) | (90) | (89)
Bilateral, malignant fibrous histiocytoma, metastatic, skin | 1(1%) | – | – | –
Bilateral, subcapsular, adenoma | – | 1(1%) | 1(1%) | –
Subcapsular, adenoma | – | 1(1%) | 3(3%) | 4(4%)
Subcapsular, carcinoma | – | – | 1(1%) | –
Adrenal medulla | (90) | (89) | (88) | (89)
Pheochromocytoma benign | – | – | – | 1(1%)
Islets, pancreatic | (88) | (90) | (89) | (89)
Adenoma | – | 1(1%) | – | –
Carcinoma | – | 1(1%) | – | –
Parathyroid gland | (68) | (57) | (66) | (65)
Pituitary gland | (86) | (84) | (89) | (83)
Pars distalis, adenoma | – | – | 2(2%) | –
Pars distalis, carcinoma | – | – | 1(1%) | –
Thyroid gland | (89) | (89) | (88) | (87)
Follicular cell, adenoma | – | 1(1%) | 1(1%) | 1(1%)
General Body System
Peritoneum | (1) | (0) | (0) | (0)
Hepatocholangiocarcinoma, metastatic, liver | 1(100%) | – | – | –
Tissue NOS | (0) | (1) | (0) | (0)
Fat, hemangiosarcoma | – | 1(100%) | – | –
Genital System
Coagulating gland | (2) | (3) | (0) | (1)
Epididymis | (90) | (91) | (90) | (90)
Preputial gland | (89) | (89) | (89) | (89)
Prostate | (90) | (86) | (90) | (88)
Seminal vesicle | (90) | (90) | (90) | (90)
Fibroma | 1(1%) | – | – | –
Malignant fibrous histiocytoma, metastatic, skin | 1(1%) | – | – | –
Testis | (90) | (91) | (88) | (90)
Interstitial cell, adenoma | 2(2%) | 2(2%) | – | –
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Hemangiosarcoma | – | – | 1(1%) | –
Lymph node | (6) | (6) | (11) | (10)
Axillary, hepatocholangiocarcinoma metastatic, liver | 1(17%) | – | – | –
Axillary, squamous cell carcinoma, metastatic, skin | – | – | 1(9%) | –
Bronchial, sarcoma, metastatic, skeletal muscle | – | – | – | 1(10%)
Lumbar, squamous cell carcinoma, metastatic, skin | – | – | 1(9%) | –
Pancreatic, hepatoblastoma, metastatic, liver | – | – | 1(9%) | –
Lymph node, mandibular | (72) | (70) | (63) | (64)
Lymph node, mesenteric | (85) | (88) | (86) | (85)
Hemangioma | 1(1%) | – | – | –
Hepatoblastoma, metastatic, liver | – | – | 1(1%) | –
Malignant fibrous histiocytoma, metastatic, skin | 1(1%) | – | – | –
Spleen | (87) | (89) | (87) | (86)
Hemangiosarcoma | – | 2(2%) | 1(1%) | 2(2%)
Thymus | (75) | (76) | (80) | (81)
Integumentary System
Mammary gland | (2) | (1) | (0) | (3)
Skin | (90) | (91) | (90) | (90)
Lipoma | – | – | – | 1(1%)
Pilomatrixoma | 1(1%) | – | – | –
Squamous cell carcinoma | – | – | 1(1%) | –
Squamous cell papilloma | – | – | – | 1(1%)
Subcutaneous tissue, hemangiosarcoma | 1(1%) | – | – | –
Subcutaneous tissue, lipoma | 1(1%) | – | 1(1%) | –
Subcutaneous tissue, malignant fibrous histiocytoma | 1(1%) | 1(1%) | 2(2%) | –
Musculoskeletal System
Bone | (90) | (91) | (90) | (90)
Skeletal muscle | (90) | (91) | (90) | (90)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1(1%) | 1(1%) | –
Hepatoblastoma, metastatic, liver | – | – | 1(1%) | –
Hepatocellular carcinoma, metastatic, liver | 1(1%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1(1%) | – | – | 1(1%)
Malignant fibrous histiocytoma, metastatic, skin | 1(1%) | – | – | –
Sarcoma | 1(1%) | – | – | 1(1%)
Squamous cell carcinoma, metastatic, skin | – | – | 1(1%) | –
Nervous System
Brain | (90) | (91) | (90) | (90)
Carcinoma, metastatic, pituitary gland | – | – | 1(1%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1(1%) | – | – | –
Brain trigeminal ganglion | (69) | (79) | (80) | (80)
Nerve trigeminal | (67) | (57) | (43) | (55)
Peripheral nerve, sciatic | (89) | (91) | (87) | (88)
Spinal cord | (90) | (91) | (90) | (90)
Respiratory System
Lung | (90) | (91) | (90) | (90)
Alveolar/bronchiolar adenoma | 11(12%) | 8(9%) | 14(16%) | 12(13%)
Alveolar/bronchiolar adenoma, multiple | 2(2%) | – | 2(2%) | –
Alveolar/bronchiolar carcinoma | 11(12%) | 13(14%) | 11(12%) | 11(12%)
Alveolar/bronchiolar carcinoma, multiple | 2(2%) | – | – | –
Hepatoblastoma, metastatic, liver | 1(1%) | – | 2(2%) | –
Hepatocellular carcinoma, metastatic, liver | 11(12%) | 4(4%) | 9(10%) | 11(12%)
Hepatocholangiocarcinoma, metastatic, liver | 1(1%) | – | – | 1(1%)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1(1%)
Squamous cell carcinoma, metastatic, skin | – | – | 1(1%) | –
Nose | (90) | (91) | (90) | (90)
Trachea | (90) | (90) | (90) | (89)
Special Senses System
Eye | (90) | (91) | (89) | (90)
Harderian gland | (88) | (91) | (90) | (88)
Adenocarcinoma | 3(3%) | 3(3%) | 1(1%) | 2(2%)
Adenoma | 6(7%) | 4(4%) | 4(4%) | 4(5%)
Urinary System
Kidney | (90) | (89) | (90) | (90)
Hepatocellular carcinoma, metastatic, liver | 1(1%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1(1%) | – | – | –
Malignant fibrous histiocytoma, metastatic, skin | 1(1%) | – | – | –
Sarcoma, metastatic, skeletal muscle | – | – | – | 1(1%)
Renal tubule, adenoma | – | – | – | 1(1%)
Ureter | (0) | (0) | (1) | (0)
Urinary bladder | (87) | (90) | (90) | (89)
Systemic Lesions
Multiple organs^b^ | (90) | (91) | (90) | (90)
Histiocytic sarcoma | – | 2(2%) | 1(1%) | 2(2%)
Leukemia granulocytic | – | – | – | 1(1%)
Lymphoma malignant | 6(7%) | 3(3%) | 5(6%) | 4(4%)
Mast cell tumor | 1(1%) | – | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 79 | 80 | 82 | 94
Total primary neoplasms
Two-year study | 144 | 139 | 157 | 155
Total animals with benign neoplasms
Two-year study | 61 | 70 | 63 | 70
Total benign neoplasms
Two-year study | 77 | 85 | 87 | 89
Total animals with malignant neoplasms
Two-year study | 49 | 42 | 58 | 50
Total malignant neoplasms
Two-year study | 66 | 54 | 70 | 66
Total animals with metastatic neoplasms
Two-year study | 14 | 6 | 14 | 13
Total metastatic neoplasms
Two-year study | 34 | 6 | 21 | 19
Total animals with uncertain neoplasms- benign or malignant
Two-year study | 1 | – | – | –
Total uncertain neoplasms
Two-year study | 1 | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Harderian Gland: Adenoma
Overall rate^a^ | 6/90 (7%) | 4/91 (4%) | 4/90 (4%) | 4/90 (4%)
Adjusted rate^b^ | 7.5% | 4.6% | 4.7% | 4.8%
Terminal rate^c^ | 6/66 (9%) | 4/83 (5%) | 4/71 (6%) | 3/71 (4%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 707
Poly-3 test^d^ | P = 0.342N | P = 0.322N | P = 0.342N | P = 0.353N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 9/90 (10%) | 7/91 (8%) | 5/90 (6%) | 6/90 (7%)
Adjusted rate | 11.2% | 8.0% | 5.9% | 7.2%
Terminal rate | 8/66 (12%) | 7/83 (8%) | 5/71 (7%) | 5/71 (7%)
First incidence (days) | 690 | 729 (T) | 729 (T) | 707
Poly-3 test | P = 0.237N | P = 0.331N | P = 0.176N | P = 0.273N
Liver: Hepatocellular Adenoma
Overall rate | 52/90 (58%) | 66/89 (74%) | 55/90 (61%) | 62/90 (69%)
Adjusted rate | 62.3% | 75.4% | 64.9% | 72.7%
Terminal rate | 45/66 (68%) | 64/83 (77%) | 51/71 (72%) | 54/71 (76%)
First incidence (days) | 393 | 625 | 656 | 478
Poly-3 test | P = 0.199 | P = 0.043 | P = 0.428 | P = 0.096
Liver: Hepatocellular Carcinoma
Overall rate | 28/90 (31%) | 18/89 (20%) | 25/90 (28%) | 31/90 (34%)
Adjusted rate | 34.2% | 20.6% | 29.0% | 36.2%
Terminal rate | 18/66 (27%) | 16/83 (19%) | 18/71 (25%) | 22/71 (31%)
First incidence (days) | 608 | 629 | 559 | 461
Poly-3 test | P = 0.177 | P = 0.033N | P = 0.287N | P = 0.459
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 67/90 (74%) | 70/89 (79%) | 66/90 (73%) | 73/90 (81%)
Adjusted rate | 79.1% | 79.6% | 76.6% | 83.3%
Terminal rate | 51/66 (77%) | 67/83 (81%) | 58/71 (82%) | 59/71 (83%)
First incidence (days) | 393 | 625 | 559 | 461
Poly-3 test | P = 0.278 | P = 0.543 | P = 0.412N | P = 0.302
Liver: Hepatoblastoma
Overall rate | 6/90 (7%) | 6/89 (7%) | 16/90 (18%) | 7/90 (8%)
Adjusted rate | 7.5% | 6.9% | 18.9% | 8.5%
Terminal rate | 5/66 (8%) | 6/83 (7%) | 14/71 (20%) | 7/71 (10%)
First incidence (days) | 711 | 729 (T) | 679 | 729 (T)
Poly-3 test | P = 0.328 | P = 0.562N | P = 0.026 | P = 0.523
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 32/90 (36%) | 22/89 (25%) | 37/90 (41%) | 35/90 (39%)
Adjusted rate | 39.1% | 25.1% | 42.8% | 40.9%
Terminal rate | 22/66 (33%) | 20/83 (24%) | 28/71 (39%) | 26/71 (37%)
First incidence (days) | 608 | 629 | 559 | 461
Poly-3 test | P = 0.159 | P = 0.036N | P = 0.370 | P = 0.472
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 68/90 (76%) | 70/89 (79%) | 69/90 (77%) | 75/90 (83%)
Adjusted rate | 80.3% | 79.6% | 79.8% | 85.6%
Terminal rate | 52/66 (79%) | 67/83 (81%) | 59/71 (83%) | 61/71 (86%)
First incidence (days) | 393 | 625 | 559 | 461
Poly-3 test | P = 0.175 | P = 0.532N | P = 0.548N | P = 0.230
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 13/90 (14%) | 8/91 (9%) | 16/90 (18%) | 12/90 (13%)
Adjusted rate | 16.0% | 9.1% | 19.0% | 14.4%
Terminal rate | 9/66 (14%) | 7/83 (8%) | 15/71 (21%) | 11/71 (16%)
First incidence (days) | 488 | 594 | 727 | 585
Poly-3 test | P = 0.441 | P = 0.131N | P = 0.382 | P = 0.474N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 13/90 (14%) | 13/91 (14%) | 11/90 (12%) | 11/90 (12%)
Adjusted rate | 16.1% | 14.7% | 12.9% | 13.1%
Terminal rate | 12/66 (18%) | 10/83 (12%) | 9/71 (13%) | 8/71 (11%)
First incidence (days) | 568 | 625 | 588 | 518
Poly-3 test | P = 0.326N | P = 0.486N | P = 0.360N | P = 0.375N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 23/90 (26%) | 21/91 (23%) | 25/90 (28%) | 21/90 (23%)
Adjusted rate | 28.1% | 23.7% | 29.4% | 24.9%
Terminal rate | 18/66 (27%) | 17/83 (21%) | 22/71 (31%) | 17/71 (24%)
First incidence (days) | 488 | 594 | 588 | 518
Poly-3 test | P = 0.444N | P = 0.312N | P = 0.496 | P = 0.385N
All Organs: Hemangiosarcoma
Overall rate | 2/90 (2%) | 7/91 (8%) | 4/90 (4%) | 3/90 (3%)
Adjusted rate | 2.5% | 8.0% | 4.7% | 3.6%
Terminal rate | 0/66 (0%) | 7/83 (8%) | 4/71 (6%) | 3/71 (4%)
First incidence (days) | 702 | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.483N | P = 0.107 | P = 0.362 | P = 0.513
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/90 (3%) | 8/91 (9%) | 4/90 (4%) | 3/90 (3%)
Adjusted rate | 3.7% | 9.2% | 4.7% | 3.6%
Terminal rate | 1/66 (2%) | 8/83 (10%) | 4/71 (6%) | 3/71 (4%)
First incidence (days) | 702 | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.325N | P = 0.135 | P = 0.526 | P = 0.647N
All Organs: Malignant Lymphoma
Overall rate | 6/90 (7%) | 3/91 (3%) | 5/90 (6%) | 4/90 (4%)
Adjusted rate | 7.3% | 3.4% | 5.9% | 4.8%
Terminal rate | 4/66 (6%) | 3/83 (4%) | 3/71 (4%) | 4/71 (6%)
First incidence (days) | 263 | 729 (T) | 674 | 729 (T)
Poly-3 test | P = 0.413N | P = 0.217N | P = 0.478N | P = 0.366N
All Organs: Benign Neoplasms
Overall rate | 61/90 (68%) | 70/91 (77%) | 63/90 (70%) | 70/90 (78%)
Adjusted rate | 72.4% | 79.2% | 73.8% | 81.6%
Terminal rate | 51/66 (77%) | 67/83 (81%) | 57/71 (80%) | 61/71 (86%)
First incidence (days) | 393 | 594 | 571 | 478
Poly-3 test | P = 0.134 | P = 0.192 | P = 0.487 | P = 0.099
All Organs: Malignant Neoplasms
Overall rate | 49/90 (54%) | 42/91 (46%) | 58/90 (64%) | 50/90 (56%)
Adjusted rate | 57.6% | 47.5% | 66.4% | 56.9%
Terminal rate | 33/66 (50%) | 38/83 (46%) | 45/71 (63%) | 36/71 (51%)
First incidence (days) | 263 | 625 | 549 | 416
Poly-3 test | P = 0.320 | P = 0.117N | P = 0.148 | P = 0.524N
All Organs: Benign or Malignant Neoplasms
Overall rate | 79/90 (88%) | 80/91 (88%) | 82/90 (91%) | 84/90 (93%)
Adjusted rate | 90.2% | 90.0% | 93.3% | 94.0%
Terminal rate | 59/66 (89%) | 75/83 (90%) | 67/71 (94%) | 67/71 (94%)
First incidence (days) | 263 | 594 | 549 | 416
Poly-3 test | P = 0.159 | P = 0.586N | P = 0.309 | P = 0.251

T = terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver and lung; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

Table C-3 Historical Incidence of Liver Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatoblastoma | Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Historical Incidence: All Studies
Antimony trioxide (October 2008) | 30/50 | 15/50 | 2/50 | 39/50
2,3-Butanedione (August 2009) | 17/50 | 17/50 | 1/50 | 32/50
Green tea extract (July 2007) | 35/50 | 15/50 | 2/50 | 40/50
2-Hydroxy-4-methoxybenzophenone (July 2010) | 21/49 | 8/49 | 1/49 | 26/49
Indole-3-carbinol (April 2007) | 26/50 | 12/50 | 3/50 | 36/50
CIMSTAR 3800 (May 2008) | 24/50 | 11/50 | 0/50 | 32/50
Trim VX (August 2009) | 23/50 | 21/50 | 0/50 | 34/50
p-Chloro-á,á,á-trifluorotoluene (January 2011) | 25/50 | 8/50 | 1/50 | 31/50
Pentabromodiphenyl ether mixture [DE-71 (technical grade)] (February 2008) | 23/50 | 18/50 | 1/50 | 31/50
Radiofrequency radiation (June 2012) | 52/90 | 28/90 | 6/90 | 68/90
Tetrabromobisphenol A (August 2007) | 32/50 | 11/50 | 2/50 | 39/50
Overall Historical Incidence
Total (%) | 308/589 (52.3%) | 164/589 (27.8%) | 19/589 (3.2%) | 408/589 (69.3%)
Mean ± standard deviation | 51.9% ± 10.3% | 27.6% ± 8.3% | 3.0% ± 2.2% | 68.8% ± 8.6%
Range | 34% - 70% | 16% - 42% | 0% - 7% | 53% - 80%

^a^ Data as of August 2017.

Table C-4 Summary of the Incidence of Non-neoplastic Lesions in Male MiceExposed to CDMA-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Disposition Summary
Animals initially in study | 105 | 106 | 105 | 105
14-week Interim Evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | – | – | 1 | –
Moribund | 8 | 2 | 5 | 3
Natural deaths | 16 | 6 | 13 | 16
Survivors
Terminal euthanasia | 66 | 83 | 71 | 71
Animals examined microscopically | 100 | 101 | 100 | 100
14-week Interim Evaluation
Alimentary System
Liver | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | – | – | 1 (10%) | –
Infiltration cellular, mixed cell, multifocal | – | – | 2 (20%) | –
Infiltration cellular, mixed cell | – | 1 (10%) | – | –
Inflammation, focal | – | – | – | 1 (10%)
Salivary glands | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | – | 1 (10%) | – | –
Endocrine System
Thyroid gland | (10) | (9) | (10) | (10)
Infiltration cellular, lymphocyte | – | – | – | 1 (10%)
Hematopoietic System
Lymph node, mandibular | (5) | (8) | (9) | (10)
Hemorrhage | – | – | 1 (11%) | 2 (20%)
Nervous System
Brain | (10) | (10) | (10) | (10)
Hemorrhage | 1 (10%) | – | – | –
Respiratory System
Lung | (10) | (10) | (10) | (10)
Congestion | 1 (10%) | – | – | –
Hemorrhage | 2 (20%) | – | – | –
Infiltration cellular, mixed cell | – | – | 1 (10%) | –
Urinary System
Kidney | (10) | (10) | (10) | (10)
Nephropathy, chronic progressive | 1 (10%) | – | 1 (10%) | 1 (10%)
Interstitium, infiltration cellular, lymphocyte | 2 (20%) | 2 (20%) | 3 (30%) | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Genital System
Integumentary System
Musculoskeletal System
Special Senses System
Two-year Study
Alimentary System
Esophagus | (88) | (91) | (89) | (88)
Infiltration cellular, lymphocyte | – | 1 (1%) | – | –
Gallbladder | (73) | (80) | (75) | (76)
Cyst | – | – | 1 (1%) | –
Intestine large, cecum | (81) | (87) | (81) | (80)
Intestine large, colon | (84) | (88) | (84) | (81)
Intestine large, rectum | (84) | (89) | (85) | (85)
Intestine small, duodenum | (77) | (86) | (81) | (80)
Peyer’s patch, hyperplasia, lymphoid | – | – | – | 1 (1%)
Intestine small, ileum | (81) | (88) | (83) | (81)
Peyer’s patch, hyperplasia, lymphoid | 1 (1%) | 1 (1%) | 1 (1%) | 3 (4%)
Peyer’s patch, infiltration cellular, plasma cell | 1 (1%) | – | – | –
Intestine small, jejunum | (79) | (87) | (81) | (82)
Inflammation, granulomatous | 1 (1%) | – | – | –
Epithelium, cyst | 1 (1%) | – | – | –
Peyer’s patch, hyperplasia, lymphoid | – | 1 (1%) | 2 (2%) | 3 (4%)
Peyer’s patch, infiltration, cellular, polymorphonuclear | – | 1 (1%) | – | –
Serosa, inflammation, granulomatous | – | – | 1 (1%) | –
Liver | (90) | (89) | (90) | (90)
Angiectasis | – | – | 1 (1%) | –
Basophilic focus | 1 (1%) | 2 (2%) | 3 (3%) | 2 (2%)
Clear cell focus | 28 (31%) | 49 (55%) | 35 (39%) | 31 (34%)
Congestion, chronic | – | 1 (1%) | – | –
Eosinophilic focus | 4 (4%) | 5 (6%) | 2 (2%) | 5 (6%)
Extramedullary hematopoiesis | 2 (2%) | – | 1 (1%) | 2 (2%)
Fatty change | 37 (41%) | 51 (57%) | 26 (29%) | 33 (37%)
Fibrosis | 1 (1%) | – | – | –
Hemorrhage | 1 (1%) | – | – | –
Infiltration cellular, lymphocyte | 2 (2%) | – | 1 (1%) | 3 (3%)
Infiltration cellular, mixed cell | 1 (1%) | 1 (1%) | – | –
Infiltration cellular, polymorphonuclear | – | – | – | 1 (1%)
Inflammation, focal | 1 (1%) | 1 (1%) | – | 1 (1%)
Inflammation, chronic active | 2 (2%) | – | 1 (1%) | –
Metaplasia | – | – | – | 1 (1%)
Mineral | – | – | – | 1 (1%)
Mixed cell focus | 2 (2%) | 2 (2%) | 3 (3%) | 1 (1%)
Necrosis | 6 (7%) | 2 (2%) | 9 (10%) | 10 (11%)
Bile duct, cyst | – | – | – | 1 (1%)
Capsule, fibrosis | – | 1 (1%) | – | 1 (1%)
Hepatocyte, degeneration | – | – | 1 (1%) | –
Vein, inflammation, chronic active | – | 1 (1%) | – | –
Mesentery | (12) | (9) | (18) | (16)
Artery, inflammation, chronic active | – | 1 (11%) | – | 1 (6%)
Artery, thrombus | – | – | – | 1 (6%)
Fat, inflammation, granulomatous | – | – | 1 (6%) | 1 (6%)
Fat, necrosis | 8 (67%) | 8 (89%) | 14 (78%) | 12 (75%)
Pancreas | (87) | (88) | (88) | (88)
Hemorrhage | 1 (1%) | – | – | –
Infiltration cellular, lymphocyte | 3 (3%) | 2 (2%) | 2 (2%) | 4 (5%)
Inflammation, granulomatous | 1 (1%) | – | – | –
Artery, inflammation, chronic | – | 1 (1%) | – | –
Duct, cyst | 1 (1%) | – | – | 1 (1%)
Duct, fibrosis | 1 (1%) | – | –
Salivary glands | (90) | (90) | (89) | (90)
Infiltration cellular, lymphocyte | 58 (64%) | 67 (74%) | 68 (76%) | 61 (68%)
Stomach, forestomach | (88) | (89) | (86) | (87)
Cyst, squamous | – | 1 (1%) | – | 3 (3%)
Inflammation, acute | – | – | 1 (1%) | –
Ulcer | – | – | – | 1 (1%)
Epithelium, hyperplasia, focal | 3 (3%) | – | 3 (3%) | –
Epithelium, hyperplasia, diffuse | – | – | – | 1 (1%)
Stomach, glandular | (87) | (88) | (87) | (87)
Hemorrhage | 1 (1%) | – | – | –
Mineral | – | – | 2 (2%) | –
Epithelium, hyperplasia, focal | 1 (1%) | – | – | –
Tooth | (27) | (15) | (17) | (23)
Dysplasia | 26 (96%) | 15 (100%) | 16 (94%) | 22 (96%)
Inflammation, suppurative | 2 (7%) | 1 (7%) | – | –
Inflammation, chronic active | – | – | 1 (6%) | 2 (9%)
Cardiovascular System
Aorta | (89) | (88) | (90) | (89)
Inflammation, chronic | – | 1 (1%) | – | –
Blood vessel | (1) | (1) | (0) | (0)
Inflammation, chronic | 1 (100%) | 1 (100%) | – | –
Heart | (90) | (91) | (90) | (90)
Bacteria | 1 (1%) | – | 1 (1%) | –
Cardiomyopathy | 1 (11%) | 6 (7%) | 6 (7%) | 10 (11%)
Inflammation, acute | 1 (1%) | – | 1 (1%) | 1 (1%)
Inflammation, chronic active | 2 (2%) | – | 1 (1%) | –
Mineral | – | – | – | 1 (1%)
Thrombus | 1 (1%) | 1 (1%) | 1 (1%) | –
Artery, inflammation, chronic active | 1 (1%) | 3 (3%) | 1 (1%) | –
Endocardium, mineral | 1 (1%) | – | – | –
Endothelium, hyperplasia | – | 2 (2%) | – | 1 (1%)
Epicardium, inflammation, chronic | 1 (1%) | – | – | –
Epicardium, mineral | 1 (1%) | – | – | –
Intima, vein, hyperplasia | – | 2 (2%) | – | –
Myocardium, infiltration cellular, lymphocyte | – | 2 (2%) | – | 2 (2%)
Myocarcium, inflammation, chronic active | – | 1 (1%) | – | –
Myocardium, mineral | 2 (2%) | 2 (2%) | – | 1 (1%)
Myocardium, necrosis | 1 (1%) | – | 1 (1%) | –
Valve, inflammation, chronic active | – | 1 (1%) | – | –
Vein, inflammation, chronic active | – | 1 (1%) | – | –
Endocrine System
Adrenal cortex | (90) | (89) | (90) | (89)
Accessory adrenal cortical nodule | 1 (1%) | – | – | –
Angiectasis | 1 (1%) | – | – | –
Hemorrhage | – | 1 (1%) | – | –
Hyperplasia, focal | 3 (3%) | 3 (3%) | 3 (3%) | 1 (1%)
Hypertrophy, focal | 2 (2%) | 8 (9%) | – | 3 (3%)
Vacuolization cytoplasmic, focal | – | 1 (1%) | – | –
Bilateral, hyperplasia, focal | – | – | 1 (1%) | –
Bilateral, hypertrophy, focal | 1 (1%) | 1 (1%) | – | 1 (1%)
Subcapsular, hyperplasia | 69 (77%) | 73 (82%) | 74 (82%) | 66 (74%)
Adrenal medulla | (90) | (89) | (88) | (89)
Hyperplasia | – | 1 (1%) | – | –
Islets, pancreatic | (88) | (90) | (89) | (89)
Hyperplasia | 18 (20%) | 13 (14%) | 14 (16%) | 11 (12%)
Infiltration cellular, lymphocyte | 2 (2%) | 1 (1%) | – | 4 (4%)
Parathyroid gland | (68) | (57) | (66) | (65)
Cyst | – | 1 (2%) | – | 1 (2%)
Pituitary gland | (86) | (84) | (89) | (83)
Pars distalis, angiectasis | 1 (1%) | – | – | –
Pars distalis, cyst | 3 (3%) | 1 (1%) | 1 (1%) | 2 (2%)
Pars distalis, hyperplasia, focal | 1 (1%) | – | – | –
Thyroid gland | (89) | (89) | (88) | (87)
Infiltration cellular, lymphocyte | – | 1 (1%) | 1 (1%) | –
Arteriole, inflammation, chronic active | – | 1 (1%) | – | –
Epithelium, follicle, hyperplasia, focal | – | 1 (1%) | – | –
General Body System
Peritoneum | (1) | (0) | (0) | (0)
Tissues NOS | (0) | (1) | (0) | (0)
Genital System
Coagulating gland | (2) | (3) | (0) | (1)
Cyst | 2 (100%) | 3 (100%) | – | 1 (100%)
Infiltration cellular, lymphocyte | – | 1 (33%) | – | –
Inflammation, chronic | – | 1 (33%) | – | –
Epididymis | (90) | (91) | (90) | (90)
Granuloma sperm | 1 (1%) | – | 2 (2%) | –
Infiltration cellular, lymphocyte | 29 (32%) | 26 (29%) | 26 (29%) | 32 (36%)
Infiltration cellular, mononuclear cell | – | 1 (1%) | – | –
Artery, inflammation, chronic | – | 1 (1%) | 1 (1%) | –
Preputial gland | (89) | (89) | (89) | (89)
Atrophy | – | 1 (1%) | – | –
Infiltration cellular, lymphocyte | 43 (48%) | 40 (45%) | 39 (44%) | 38 (43%)
Inflammation, suppurative | 1 (1%) | – | – | –
Inflammation, chronic active | 1 (1%) | 3 (3%) | 3 (3%) | 1 (1%)
Bilateral, inflammation, chronic active | – | – | – | 1 (1%)
Bilateral, duct, dilation | 6 (7%) | 4 (4%) | 5 (6%) | 3 (3%)
Duct, dilation | 10 (11%) | 10 (11%) | 5 (6%) | 5 (6%)
Duct, inflammation, chronic active | – | – | – | 1 (1%)
Duct, necrosis | 1 (1%) | – | – | –
Prostate | (90) | (86) | (90) | (88)
Infiltration cellular, lymphocyte | 4 (4%) | 8 (9%) | 10 (11%) | 9 (10%)
Inflammation, acute | – | – | 1 (1%) | –
Inflammation, chronic active | 1 (1%) | – | – | –
Arteriole, inflammation, chronic | – | 1 (1%) | – | –
Seminal vesicle | (90) | (90) | (90) | (90)
Dilation | 4 (4%) | 9 (10%) | 4 (4%) | 2 (2%)
Inflammation, chronic active | 1 (1%) | – | – | 1 (1%)
Bilateral, dilation | 27 (30%) | 19 (21%) | 26 (29%) | 14 (16%)
Testis | (90) | (91) | (88) | (90)
Bilateral, germinal epithelium, atrophy | – | – | 1 (1%) | –
Germ cell, degeneration | 2 (2%) | 2 (2%) | 4 (5%) | 7 (8%)
Seminiferous tubule, necrosis | – | – | – | 1 (1%)
Hematopoietic System
Bone marrow | (90) | (90) | (90) | (90)
Hypercellularity | 3 (3%) | – | 2 (2%) | 3 (3%)
Myeloid cell, hypercellularity | – | – | 1 (1%) | –
Lymph node | (6) | (6) | (11) | (10)
Bronchial, hyperplasia, lymphoid | – | – | – | 2 (20%)
Iliac, erythrophagocytosis | – | 1 (17%) | – | –
Iliac, hemorrhage | – | – | 1 (9%) | –
Iliac, hyperplasia, lymphoid | – | 2 (33%) | 4 (36%) | –
Iliac, infiltration cellular, histiocyte | – | – | – | 1 (10%)
Iliac, pigment | – | – | 2 (18%) | 1 (10%)
Inguinal, hyperplasia, lymphoid | – | – | – | 2 (20%)
Mediastinal, hyperplasia, lymphoid | – | 2 (33%) | 1 (9%) | 2 (20%)
Renal, hemorrhage | 1 (17%) | – | – | –
Renal, pigment | – | – | 1 (9%) | –
Lymph node, mandibular | (72) | (70) | (63) | (64)
Hemorrhage | – | – | 1 (2%) | 1 (2%)
Hyperplasia, lymphoid | 2 (3%) | – | 1 (2%) | 2 (3%)
Infiltration cellular, histiocyte | 1 (1%) | 1 (1%) | 1 (2%) | 2 (3%)
Infiltration cellular, plasma cell | – | 1 (1%) | – | –
Lymph node, mesenteric | (85) | (88) | (86) | (85)
Erythrophagocytosis | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Hemorrhage | 10 (12%) | 21 (24%) | 16 (19%) | 14 (16%)
Hyperplasia, lymphoid | 4 (5%) | 3 (3%) | 5 (6%) | 6 (7%)
Infiltration cellular, histiocyte | 8 (9%) | 7 (8%) | 5 (6%) | 5 (6%)
Infiltration cellular, mixed cell | – | – | 1 (1%) | –
Infiltration cellular, plasma cell | 1 (1%) | – | 1 (1%) | –
Spleen | (87) | (89) | (87) | (86)
Extramedullary hematopoiesis | 15 (17%) | 7 (8%) | 21 (24%) | 16 (19%)
Hyperplasia, lymphoid | 5 (6%) | 4 (4%) | 3 (3%) | 9 (10%)
Thymus | (75) | (76) | (80) | (81)
Atrophy | 11 (15%) | 3 (4%) | 8 (10%) | 5 (6%)
Cyst | 11 (15%) | 17 (22%) | 19 (24%) | 19 (23%)
Hemorrhage | 1 (1%) | – | – | 1 (1%)
Hyperplasia, lymphoid | – | 2 (3%) | – | –
Mammary gland | (2) | (1) | (0) | (3)
Skin | (90) | (91) | (90) | (90)
Infiltration cellular, mixed cell | 1 (1%) | – | – | –
Inflammation, chronic | – | – | – | 1 (1%)
Ulcer | 2 (2%) | 1 (1%) | 2 (2%) | 4 (4%)
Epidermis, hyperplasia, focal | – | – | 1 (1%) | 2 (2%)
Musculoskeletal System
Bone | (90) | (91) | (90) | (90)
Fibro-osseous lesion | – | – | 1 (1%) | –
Increased bone | – | – | – | 1 (1%)
Skeletal muscle | (90) | (91) | (90) | (90)
Degeneration | 1 (1%) | 1 (1%) | – | –
Infiltration cellular, lymphocyte | 3 (3%) | 1 (1%) | 1 (1%) | 4 (4%)
Inflammation, granulomatous | – | – | – | 1 (1%)
Inflammation, acute | – | – | 1 (1%) | –
Nervous System
Brain | (90) | (91) | (90) | (90)
Hemorrhage | 2 (2%) | – | – | –
Infiltration cellular, lymphocyte | 1 (1%) | – | – | –
Mineral | 79 (88%) | 80 (88%) | 77 (86%) | 77 (86%)
Necrosis | – | 1 (1%) | – | –
Artery, meninges, inflammation, chronic active | 1 (1%) | 2 (2%) | 3 (3%) | 1 (1%)
Meninges, inflammation, chronic | – | – | 1 (1%) | –
Brain trigeminal ganglion | (69) | (79) | (80) | (80)
Nerve trigeminal | (67) | (57) | (43) | (55)
Peripheral nerve, sciatic | (89) | (91) | (87) | (88)
Inflammation, chronic active | – | – | – | 1 (1%)
Axon, degeneration | 9 (10%) | 5 (5%) | 4 (5%) | 11 (13%)
Spinal cord | (90) | (91) | (90) | (90)
Degeneration | – | 1 (1%) | – | –
Necrosis | 1 (1%) | 1 (1%) | 1 (1%) | –
Squamous cyst | – | – | – | 2 (2%)
Artery, meninges, inflammation, chronic active | 1 (1%) | 2 (2%) | 4 (4%) | 1 (1%)
Respiratory System
Lung | (90) | (91) | (90) | (90)
Congestion | 2 (2%) | – | 3 (3%) | 2 (2%)
Hemorrhage | 3 (3%) | 2 (2%) | 4 (4%) | 1 (1%)
Infiltration cellular, histiocyte | 6 (7%) | 5 (5%) | 3 (3%) | 5 (6%)
Infiltration cellular, lymphocyte | 1 (1%) | 1 (1%) | 3 (3%) | –
Infiltration, mononuclear cell | – | – | 1 (1%) | 3 (3%)
Inflammation, granulomatous | – | – | – | 1 (1%)
Alveolar epithelium, hyperplasia, focal | 6 (7%) | 7 (8%) | 8 (9%) | 5 (6%)
Bronchiole, foreign body | 1 (1%) | – | – | –
Bronchiole, inflammation, suppurative | 1 (1%) | – | – | –
Nose | (90) | (91) | (90) | (90)
Infiltration cellular, lymphocyte | – | – | 1 (1%) | –
Inflammation, acute | 1 (1%) | – | – | –
Respiratory epithelium, accumulation, hyaline droplet | 1 (1%) | – | – | 1 (1%)
Respiratory epithelium, hyperplasia | 5 (6%) | 1 (1%) | – | –
Vomeronasal organ, fibrosis | 1 (1%) | – | – | –
Trachea | (90) | (90) | (90) | (89)
Special Senses System
Eye | (90) | (91) | (89) | (90)
Atrophy | – | – | 1 (1%) | 1 (1%)
Bilateral, cornea, inflammation, chronic active | – | – | – | 1 (1%)
Bilateral, iris, synechia | – | – | – | 1 (1%)
Cornea, edema | – | 1 (1%) | – | –
Cornea, fibrosis | 1 (1%) | – | – | –
Cornea, hyperplasia, squamous, diffuse | – | 1 (1%) | – | –
Sclera, inflammation, acute | – | – | 1 (1%) | –
Harderian gland | (88) | (91) | (90) | (88)
Hemorrhage | 1 (1%) | – | – | –
Hyperplasia, focal | 2 (2%) | 3 (3%) | 1 (1%) | –
Infiltration cellular, lymphocyte | 36 (41%) | 41 (45%) | 40 (44%) | 38 (43%)
Mineral | – | 1 (1%) | – | –
Urinary System
Kidney | (90) | (89) | (90) | (90)
Infarct | 7 (8%) | 6 (7%) | 11 (12%) | 7 (8%)
Inflammation, suppurative | 1 (1%) | – | – | –
Inflammation, granulomatous | 1 (1%) | – | – | –
Metaplasia, osseous | 3 (3%) | 8 (9%) | 3 (3%) | 5 (6%)
Mineral | – | 3 (3%) | 1 (1%) | 1 (1%)
Nephropathy, chronic progressive | 74 (82%) | 84 (94%) | 81 (90%) | 77 (86%)
Artery, inflammation, chronic active | – | 1 (1%) | – | –
Bilateral, bacteria | – | – | 1 (1%) | –
Bilateral, infarct | – | 1 (1%) | – | 2 (2%)
Bilateral, inflammation, acute | – | – | 1 (1%) | –
Bilateral, renal tubule, pigment | – | – | – | 1 (1%)
Glomerulus, cyst | 1 (1%) | 2 (2%) | – | 1 (1%)
Interstitium, infiltration cellular, lymphocyte | 41 (46%) | 55 (62%) | 57 (63%) | 40 (44%)
Interstitium, inflammation, acute | – | – | – | 1 (1%)
Papilla, bacteria | – | – | 1 (1%) | –
Papilla, inflammation, acute | – | – | 1 (1%) | –
Pelvis, dilation | 1 (1%) | – | – | 2 (2%)
Pelvis, inflammation, acute | – | – | – | 1 (1%)
Renal tubule, cyst | 8 (9%) | 11 (12%) | 7 (8%) | 10 (11%)
Renal tubule, hyperplasia, focal | – | 1 (1%) | – | –
Renal tubule, mineral | 1 (1%) | 4 (4%) | 4 (4%) | 5 (6%)
Urothelium, inflammation, chronic active | 1 (1%) | – | – | –
Ureter | (0) | (0) | (1) | (0)
Inflammation, chronic active | – | – | 1 (100%) | –
Urinary bladder | (87) | (90) | (90) | (89)
Hemorrhage | 3 (3%) | – | – | –
Infiltration cellular, lymphocyte | 26 (30%) | 33 (37%) | 39 (43%) | 41 (46%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.