# Appendix B Summary of Lesions in Female Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

Table B-1 Summary of the Incidence of Neoplasms in Female Mice Exposed to GSM-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
14-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Moribund | 9 | 9 | 9 | 6
Natural deaths | 14 | 7 | 11 | 11
Survivors
Died last week of study | 1 | 4 | 2 | 1
Terminal euthanasia | 66 | 70 | 68 | 72
Animals examined microscopically | 100 | 100 | 100 | 100
Systems Examined at 14 Weeks with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (87) | (90) | (87) | (90)
Gallbladder | (79) | (75) | (74) | (72)
Intestine large, cecum | (84) | (82) | (83) | (82)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Leiomyosarcoma | – | – | – | 1 (1%)
Intestine large, colon | (84) | (84) | (86) | (85)
Intestine large, rectum | (88) | (86) | (88) | (86)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Osteosarcoma, metastatic, skin | 1 (1%) | – | – | –
Intestine small, duodenum | (82) | (83) | (84) | (81)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Intestine small, ileum | (83) | (82) | (82) | (80)
Intestine small, jejunum | (84) | (81) | (81) | (80)
Adenoma | – | 1 (1%) | – | –
Liver | (89) | (90) | (90) | (89)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Hemangiosarcoma | – | 1 (1%) | – | 1 (1%)
Hepatoblastoma | 1 (1%) | – | – | –
Hepatocellular adenoma | 14 (16%) | 16 (18%) | 11 (12%) | 8 (9%)
Hepatocellular adenoma, multiple | 5 (6%) | 2 (2%) | 2 (2%) | 2 (2%)
Hepatocellular carcinoma | 6 (7%) | 6 (7%) | 5 (6%) | 5 (6%)
Hepatocellular carcinoma, multiple | 2 (2%) | – | 1 (1%) | 1 (1%)
Hepatocholangiocarcinoma | – | – | 1 (1%) | –
Osteosarcoma, metastatic, bone | 1 (1%) | – | – | –
Osteosarcoma, metastatic, skin | 1 (1%) | – | – | –
Mesentery | (29) | (24) | (32) | (30)
Fibrosarcoma, metastatic, skin | 1 (3%) | – | – | –
Renal mesenchymal tumor, metastatic, kidney | 1 (3%) | – | – | –
Fat, hemangioma | 1 (3%) | – | – | –
Fat, lipoma | – | 1 (4%) | – | 1 (3%)
Oral mucosa | (0) | (0) | (2) | (0)
Pancreas | (87) | (88) | (89) | (86)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Hemangioma | – | – | – | 1 (1%)
Hepatocellular carcinoma, metastatic, liver | – | – | 1 (1%) | –
Renal mesenchymal tumor, metastatic, kidney | 1 (1%) | – | – | –
Acinus, carcinoma | – | – | 1 (1%) | –
Salivary glands | (89) | (89) | (90) | (90)
Adenocarcinoma, metastatic, Harderian gland | – | 1 (1%) | – | –
Stomach, forestomach | (86) | (89) | (90) | (85)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Squamous cell papilloma | 1 (1%) | – | – | –
Stomach, glandular | (85) | (87) | (85) | (85)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Tongue | (0) | (0) | (1) | (0)
Tooth | (0) | (0) | (1) | (0)
Cardiovascular System
Aorta | (84) | (88) | (90) | (89)
Blood vessel | (0) | (0) | (2) | (0)
Heart | (90) | (90) | (90) | (90)
Adenocarcinoma, metastatic, Harderian gland | – | 1 (1%) | – | –
Hemangioma | – | – | 1 (1%) | –
Osteosarcoma, metastatic, skin | 1 (1%) | – | – | –
Endocrine System
Adrenal cortex | (84) | (88) | (90) | (90)
Adenoma | 1 (1%) | – | – | –
Adrenal medulla | (83) | (84) | (86) | (87)
Pheochromocytoma benign | – | – | 1 (1%) | –
Pheochromocytoma malignant | 2 (2%) | – | – | –
Islets, pancreatic | (87) | (88) | (90) | (86)
Adenoma | – | – | 1 (1%) | 1 (1%)
Carcinoma | 1 (1%) | 1 (1%) | – | –
Parathyroid gland | (60) | (57) | (64) | (62)
Pituitary gland | (80) | (80) | (84) | (84)
Pars distalis, adenoma | 6 (8%) | 5 (6%) | 7 (8%) | 5 (6%)
Pars distalis, carcinoma | – | – | 2 (2%) | 1 (1%)
Thyroid gland | (86) | (89) | (86) | (86)
C-cell, carcinoma | 1 (1%) | – | – | –
Follicular cell, carcinoma | – | – | 1 (1%) | –
General Body System
Peritoneum | (0) | (0) | (1) | (0)
Tissue NOS | (1) | (1) | (1) | (2)
Hemangiosarcoma | – | – | – | 1 (50%)
Abdominal, osteosarcoma, metastatic, skin | 1 (100%) | – | – | –
Genital System
Clitoral gland | (82) | (84) | (80) | (86)
Ovary | (75) | (86) | (82) | (80)
Cystadenoma | 2 (3%) | 2 (2%) | 3 (4%) | 6 (8%)
Granulosa cell tumor benign | 1 (1%) | – | 1 (1%) | 1 (1%)
Hemangioma | 2 (3%) | 2 (2%) | – | –
Hemangiosarcoma | – | 1 (1%) | – | –
Luteoma | – | 1 (1%) | – | –
Teratoma benign | – | – | 2 (2%) | 1 (1%)
Thecoma malignant | 1 (1%) | – | – | –
Oviduct | (0) | (0) | (1) | (0)
Uterus | (89) | (90) | (90) | (89)
Adenocarcinoma | – | – | – | 1 (1%)
Fibroma | 1 (1%) | – | – | –
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Hemangiosarcoma | – | – | 1 (1%) | –
Leiomyoma | 1 (1%) | – | – | –
Polyp stromal | – | 3 (3%) | 2 (2%) | 2 (2%)
Vagina | (0) | (0) | (1) | (0)
Hematopoietic System
Bone marrow | (90) | (89) | (89) | (90)
Hemangiosarcoma | – | – | 2 (2%) | 1 (1%)
Lymph node | (18) | (20) | (16) | (14)
Bronchial, alveolar/bronchiolar carcinoma, metastatic, lung | 1 (6%) | – | – | –
Bronchial, fibrosarcoma, metastatic, skin | 1 (6%) | – | – | –
Lymph node, mandibular | (76) | (77) | (81) | (83)
Lymph node, mesenteric | (71) | (84) | (80) | (83)
Fibrosarcoma, metastatic, skin | 1 (1%) | – | – | –
Hemangiosarcoma | – | – | – | 1 (1%)
Renal mesenchymal tumor, metastatic, kidney | 1 (1%) | – | – | –
Spleen | (86) | (87) | (89) | (87)
Hemangiosarcoma | – | 2 (2%) | 2 (2%) | –
Thymus | (85) | (80) | (84) | (86)
Integumentary System
Mammary gland | (85) | (88) | (88) | (84)
Adenocarcinoma | – | – | 1 (1%) | 1 (1%)
Skin | (90) | (90) | (90) | (90)
Sebaceous gland, adenoma | – | 1 (1%) | – | –
Subcutaneous tissue, fibroma | 1 (1%) | – | – | –
Subcutaneous tissue, fibrosarcoma | 3 (3%) | – | 3 (3%) | –
Subcutaneous tissue, hemangiosarcoma | 2 (2%) | – | – | –
Subcutaneous tissue, lipoma | 1 (1%) | – | – | –
Subcutaneous tissue, malignant fibrous histiocytoma | – | 1 (1%) | 3 (3%) | –
Subcutaneous tissue, osteosarcoma | 1 (1%) | – | – | –
Subcutaneous tissue, sarcoma | 2 (2%) | – | 1 (1%) | 1 (1%)
Musculoskeletal System
Bone | (90) | (90) | (89) | (90)
Hemangioma | 1 (1%) | – | – | –
Hemangiosarcoma | – | 1 (1%) | – | –
Osteosarcoma | 1 (1%) | – | – | –
Skeletal muscle | (89) | (90) | (90) | (90)
Adenocarcinoma, metastatic, Harderian gland | – | 1 (1%) | – | –
Osteosarcoma | 1 (1%) | – | – | 1 (1%)
Rhabdomyosarcoma | – | – | – | 1 (1%)
Sarcoma, metastatic, skin | – | – | 1 (1%) | –
Nervous System
Brain | (87) | (90) | (90) | (90)
Carcinoma, metastatic, pituitary gland | – | – | 2 (2%) | 1 (1%)
Meningioma benign | – | 1 (1%) | – | –
Osteosarcoma, metastatic, skeletal muscle | 1 (1%) | – | – | –
Brain trigeminal ganglion | (75) | (74) | (80) | (79)
Nerve trigeminal | (56) | (58) | (53) | (35)
Carcinoma, metastatic, pituitary gland | – | – | – | 1 (3%)
Peripheral nerve | (0) | (0) | (1) | (0)
Peripheral nerve, sciatic | (88) | (87) | (88) | (88)
Spinal cord | (90) | (90) | (90) | (90)
Respiratory System
Larynx | (0) | (0) | (2) | (0)
Lung | (90) | (90) | (90) | (90)
Adenocarcinoma, metastatic, Harderian gland | – | 1 (1%) | – | –
Alveolar/bronchiolar adenoma | 3 (3%) | 5 (6%) | 7 (8%) | 1 (1%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (1%) | – | –
Alveolar/bronchiolar carcinoma | 3 (3%) | 1 (1%) | – | 1 (1%)
Carcinoma, metastatic, pancreas | – | – | 1 (1%) | –
Carcinoma, metastatic, thyroid gland | 1 (1%) | – | – | –
Fibrosarcoma, metastatic, skin | 1 (1%) | – | 2 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 2 (2%) | – | 2 (2%) | 1 (1%)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (1%) | –
Osteosarcoma, metastatic, bone | 1 (1%) | – | – | –
Osteosarcoma, metastatic, skeletal muscle | 1 (1%) | – | – | –
Osteosarcoma, metastatic, skin | 1 (1%) | – | – | –
Sarcoma, metastatic, skin | – | – | 1 (1%) | –
Mediastinum | (2) | (0) | (0) | (0)
Hepatocellular carcinoma, metastatic, liver | 1 (50%) | – | – | –
Nose | (89) | (90) | (90) | (90)
Adenocarcinoma, metastatic, Harderian gland | – | 1 (1%) | – | –
Pleura | (0) | (0) | (1) | (0)
Trachea | (90) | (89) | (90) | (90)
Special Senses System
Ear | (0) | (0) | (1) | (0)
Eye | (89) | (88) | (90) | (90)
Harderian gland | (89) | (90) | (90) | (87)
Adenocarcinoma | – | 1 (1%) | 1 (1%) | –
Adenoma | 4 (4%) | 7 (8%) | 5 (6%) | 6 (7%)
Lacrimal gland | (0) | (1) | (2) | (0)
Zymbal’s gland | (0) | (0) | (1) | (0)
Urinary System
Kidney | (89) | (87) | (89) | (88)
Renal mesenchymal tumor | 1 (1%) | – | – | –
Renal tubule, adenoma | 2 (2%) | – | – | –
Ureter | (0) | (0) | (1) | (0)
Urethra | (0) | (0) | (1) | (0)
Urinary bladder | (86) | (87) | (86) | (86)
Systemic Lesions
Multiple organs^b^ | (90) | (90) | (90) | (90)
Histiocytic sarcoma | 8 (9%) | 2 (2%) | 8 (9%) | 5 (6%)
Leukemia erythrocytic | – | 1 (1%) | – | –
Lymphoma malignant | 2 (2%) | 13 (14%) | 9 (10%) | 6 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Two-year study | 59 | 55 | 57 | 44
Total primary neoplasms
Two-year study | 85 | 79 | 85 | 64
Total animals with benign neoplasms
Two-year study | 36 | 37 | 35 | 29
Total benign neoplasms
Two-year study | 47 | 48 | 43 | 35
Total animals with malignant neoplasms
Two-year study | 33 | 27 | 35 | 24
Total malignant neoplasms
Two-year study | 38 | 31 | 42 | 29
Total animals with metastatic neoplasms
Two-year study | 9 | 1 | 9 | 2
Total metastatic neoplasms
Two-year study | 29 | 5 | 11 | 3

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Harderian Gland: Adenoma
Overall rate^a^ | 4/90 (4%) | 7/90 (8%) | 5/90 (6%) | 6/90 (7%)
Adjusted rate^b^ | 5.0% | 8.3% | 6.0% | 7.2%
Terminal rate^c^ | 4/67 (6%) | 4/72 (6%) | 5/69 (7%) | 6/72 (8%)
First incidence (days) | 739 (T) | 562 | 739 (T) | 739 (T)
Poly-3 test^d^ | P = 0.436 | P = 0.299 | P = 0.524 | P = 0.398
Harderian Gland: Adenoma or Carcinoma
Overall rate | 4/90 (4%) | 8/90 (9%) | 6/90 (7%) | 6/90 (7%)
Adjusted rate | 5.0% | 9.4% | 7.2% | 7.2%
Terminal rate | 4/67 (6%) | 4/72 (6%) | 6/69 (9%) | 6/72 (8%)
First incidence (days) | 739 (T) | 562 | 739 (T) | 739 (T)
Poly-3 test | P = 0.471 | P = 0.214 | P = 0.397 | P = 0.398
Liver: Hepatocellular Adenoma
Overall rate | 19/89 (21%)^e^ | 18/90 (20%) | 13/90 (14%) | 10/89 (11%)
Adjusted rate | 23.6% | 21.5% | 15.6% | 12.0%
Terminal rate | 17/67 (25%) | 17/72 (24%) | 11/69 (16%) | 9/72 (13%)
First incidence (days) | 511 | 638 | 674 | 700
Poly-3 test | P = 0.022N | P = 0.448N | P = 0.134N | P = 0.041N
Liver: Hepatocellular Carcinoma
Overall rate | 8/89 (9%) | 6/90 (7%) | 6/90 (7%) | 6/89 (7%)
Adjusted rate | 10.0% | 7.2% | 7.2% | 7.2%
Terminal rate | 7/67 (10%) | 4/72 (6%) | 5/69 (7%) | 4/72 (6%)
First incidence (days) | 656 | 650 | 701 | 720
Poly-3 test | P = 0.348N | P = 0.354N | P = 0.358N | P = 0.361N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 25/89 (28%) | 24/90 (27%) | 17/90 (19%) | 15/89 (17%)
Adjusted rate | 30.9% | 28.5% | 20.3% | 18.0%
Terminal rate | 22/67 (33%) | 21.72 (29%) | 14/69 (20%) | 12/72 (17%)
First incidence (days) | 511 | 638 | 674 | 700
Poly-3 test | P = 0.020N | P = 0.436N | P = 0.082N | P = 0.040N
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 9/89 (10%) | 6/90 (7%) | 6/90 (7%) | 6/89 (7%)
Adjusted rate | 11.3% | 7.2% | 7.2% | 7.2%
Terminal rate | 8/67 (12%) | 4/72 (6%) | 5/69 (7%) | 4/72 (6%)
First incidence (days) | 656 | 650 | 701 | 720
Poly-3 test | P = 0.268N | P = 0.261N | P = 0.265N | P = 0.267N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 3/90 (3%) | 6/90 (7%) | 7/90 (8%) | 1/90 (1%)
Adjusted rate | 3.8% | 7.2% | 8.4% | 1.2%
Terminal rate | 3/67 (5%) | 6/72 (8%) | 7/69 (10%) | 1/72 (1%)
First incidence (days) | 739 (T) | 739 (T) | 739 (T) | 739 (T)
Poly-3 test | P = 0.190N | P = 0.268 | P = 0.180 | P = 0.292N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 6/90 (7%) | 6/90 (7%) | 7/90 (8%) | 2/90 (2%)
Adjusted rate | 7.5% | 7.2% | 8.4% | 2.4%
Terminal rate | 5/67 (8%) | 6/72 (8%) | 7/69 (10%) | 2/72 (3%)
First incidence (days) | 607 | 739 (T) | 739 (T) | 739 (T)
Poly-3 test | P = 0.108N | P = 0.592N | P = 0.526 | P = 0.127N
Ovary: Cystadenoma
Overall rate | 2/75 (3%) | 2/86 (2%) | 3/82 (4%) | 6/80 (8%)
Adjusted rate | 3.0% | 2.5% | 3.9% | 7.9%
Terminal rate | 2/56 (4%) | 2/69 (3%) | 3/65 (5%) | 6/67 (9%)
First incidence (days) | 739 (T) | 739 (T) | 739 (T) | 739 (T)
Poly-3 test | P = 0.067 | P = 0.623N | P = 0.564 | P = 0.186
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 6/80 (8%) | 5/80 (6%) | 7/84 (8%) | 5/84 (6%)
Adjusted rate | 8.4% | 6.8% | 9.0% | 6.4%
Terminal rate | 5/60 (8%) | 5/65 (8%) | 4/64 (6%) | 5/68 (7%)
First incidence (days) | 703 | 739 (T) | 712 | 739 (T)
Poly-3 test | P = 0.417N | P = 0.475N | P = 0.563 | P = 0.435N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 6/80 (8%) | 5/80 (6%) | 9/84 (11%) | 6/84 (7%)
Adjusted rate | 8.4% | 6.8% | 11.5% | 7.6%
Terminal rate | 5/60 (8%) | 5/65 (8%) | 4/64 (6%) | 5/68 (7%)
First incidence (days) | 703 | 739 (T) | 606 | 676
Poly-3 test | P = 0.553 | P = 0.475N | P = 0.362 | P = 0.549N
Skin (Subcutaneous Tissue): Fibrosarcoma or Sarcoma
Overall rate | 5/90 (6%) | 0/90 (0%) | 4/90 (4%) | 1/90 (1%)
Adjusted rate | 6.2% | 0.0% | 4.8% | 1.2%
Terminal rate | 1/67 (2%) | 0/72 (0%) | 1/69 (1%) | 0/72 (0%)
First incidence (days) | 607 | –^f^ | 646 | 607
Poly-3 test | P = 0.159N | P = 0.031N | P = 0.478N | P = 0.098N
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, or Sarcoma
Overall rate | 6/90 (7%) | 0/90 (0%) | 4/90 (4%) | 1/90 (1%)
Adjusted rate | 7.4% | 0.0% | 4.8% | 1.2%
Terminal rate | 2/67 (3%) | 0/72 (0%) | 1/69 (1%) | 0/72 (0%)
First incidence (days) | 607 | – | 646 | 607
Poly-3 test | P = 0.094N | P = 0.016N | P = 0.351N | P = 0.055N
Skin (Subcutaneous Tissue): Fibrosarcoma, Sarcoma, or Malignant Fibrous Histiocytoma
Overall rate | 5/90 (6%) | 1/90 (1%) | 7/90 (8%) | 1/90 (1%)
Adjusted rate | 6.2% | 1.2% | 8.4% | 1.2%
Terminal rate | 1/67 (2%) | 0/72 (0%) | 3/69 (4%) | 0/72 (0%)
First incidence (days) | 607 | 562 | 646 | 607
Poly-3 test | P = 0.193N | P = 0.097N | P = 0.407 | P = 0.098N
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, Sarcoma, or Malignant Fibrous Histiocytoma
Overall rate | 6/90 (7%) | 1/90 (1%) | 7/90 (8%) | 1/90 (1%)
Adjusted rate | 7.4% | 1.2% | 8.4% | 1.2%
Terminal rate | 2/67 (3%) | 0/72 (0%) | 3/69 (4%) | 0/72 (0%)
First incidence (days) | 607 | 562 | 646 | 607
Poly-3 test | P = 0.125N | P = 0.054N | P = 0.527 | P = 0.055N
All Organs: Hemangiosarcoma
Overall rate | 2/90 (2%) | 5/90 (6%) | 3/90 (3%) | 3/90 (3%)
Adjusted rate | 2.5% | 6.0% | 3.6% | 3.6%
Terminal rate | 1/67 (2%) | 4/72 (6%) | 1/69 (1%) | 2/72 (3%)
First incidence (days) | 703 | 638 | 629 | 720
Poly-3 test | P = 0.572N | P = 0.238 | P = 0.521 | P = 0.518
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 6/90 (7%) | 7/90 (8%) | 4/90 (4%) | 4/90 (4%)
Adjusted rate | 7.5% | 8.4% | 4.8% | 4.8%
Terminal rate | 5/97 (8%) | 6/72 (8%) | 1/69 (1%) | 3/72 (4%)
First incidence (days) | 703 | 638 | 629 | 720
Poly-3 test | P = 0.218N | P = 0.533 | P = 0.343N | P = 0.348N
All Organs: Histiocytic Sarcoma
Overall rate | 8/90 (9%) | 2/90 (2%) | 8/90 (9%) | 5/90 (6%)
Adjusted rate | 9.7% | 2.4% | 9.5% | 5.9%
Terminal rate | 2/67 (3%) | 1/72 (1%) | 3/69 (4%) | 1/72 (1%)
First incidence (days) | 562 | 458 | 629 | 660
Poly-3 test | P = 0.419N | P = 0.048N | P = 0.587N | P = 0.270N
All Organs: Malignant Lymphoma
Overall rate | 2/90 (2%) | 13/90 (14%) | 9/90 (10%) | 6/90 (7%)
Adjusted rate | 2.5% | 15.6% | 10.7% | 7.1%
Terminal rate | 1/67 (1%) | 12/72 (17%) | 5/69 (7%) | 3/72 (4%)
First incidence (days) | 604 | 731 | 516 | 590
Poly-3 test | P = 0.474 | P = 0.004 | P = 0.035 | P = 0.153
All Organs: Benign Neoplasms
Overall rate | 36/90 (40%) | 37/90 (41%) | 35/90 (39%) | 29/90 (32%)
Adjusted rate | 44.1% | 43.2% | 41.7% | 34.3%
Terminal rate | 32/67 (48%) | 31/72 (43%) | 29/69 (42%) | 26/72 (36%)
First incidence (days) | 511 | 403 | 674 | 390
Poly-3 test | P = 0.094N | P = 0.515N | P = 0.439N | P = 0.127N
All Organs: Malignant Neoplasms
Overall rate | 33/90 (37%) | 27/90 (30%) | 35/90 (39%) | 24/90 (27%)
Adjusted rate | 38.1% | 31.4% | 39.8% | 27.9%
Terminal rate | 17/67 (25%) | 19/72 (26%) | 17/69 (25%) | 12/72 (17%)
First incidence (days) | 448 | 458 | 516 | 590
Poly-3 test | P = 0.139N | P = 0.220N | P = 0.469 | P = 0.101N
All Organs: Benign or Malignant Neoplasms
Overall rate | 59/90 (66%) | 55/90 (61%) | 57/90 (63%) | 44/90 (49%)
Adjusted rate | 67.6% | 62.8% | 64.7% | 50.6%
Terminal rate | 42/67 (63%) | 43/72 (60%) | 38/69 (55%) | 31/72 (43%)
First incidence (days) | 448 | 403 | 516 | 390
Poly-3 test | P = 0.012N | P = 0.303N | P = 0.401N | P = 0.015N

(T) = terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, ovary, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ A single incidence of hepatoblastoma occurred in an animal that also had an adenoma.

^f^ Not applicable; no neoplasms in animal group.

Table B-3 Historical Incidence of Malignant Lymphoma in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: All Studies
Antimony trioxide (October 2008) | 7/50
2,3-Butanedione (August 2009) | 9/50
Green tea extract (July 2007) | 7/50
2-Hydroxy-4-methoxybenzophenone (July 2010) | 5/50
Indole-3-carbinol (April 2007) | 6/50
CIMSTAR 3800 (May 2008) | 18/50
Trim VX (August 2009) | 10/50
p-Chloro-á,á,á-trifluorotoluene (January 2011) | 9/50
Pentabromodiphenyl ether mixture [DE-71 (technical grade)] (February 2008) | 7/50
Radiofrequency radiation (June 2012) | 2/90
Tetrabromobisphenol A (August 2007) | 9/50
Overall Historical Incidence
Total (%) | 89/590 (15.1%)
Mean ± standard deviation | 16.0% ± 8.3%
Range | 2%–36%

^a^ Data as of August 2017; includes data for histiocytic, lymphocytic, mixed, unspecified, or undifferentiated cell types.

Table B-4 Summary of the Incidence of Non-neoplastic Lesions in Female Mice Exposed to GSM-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
14-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Moribund | 9 | 9 | 9 | 6
Natural deaths | 14 | 7 | 11 | 11
Survivors
Died last week of study | 1 | 4 | 2 | 1
Terminal euthanasia | 66 | 70 | 68 | 72
Animals examined microscopically | 100 | 100 | 100 | 100
14-week Interim Evaluation
Alimentary System
Liver | (10) | (10) | (10) | (9)
Inflammation, focal | 1 (10%) | 2 (20%) | 4 (40%) | 3 (33%)
Necrosis | – | 1 (10%) | – | –
Salivary glands | (10) | (10) | (10) | (9)
Infiltration cellular, lymphocyte | – | – | 3 (30%) | –
Stomach, glandular | (10) | (10) | (10) | (9)
Infiltration cellular, mixed cell | – | 1 (10)% | – | –
Endocrine System
Thyroid gland | (10) | (10) | (10) | (9)
Infiltration cellular, lymphocyte | 1 (10%) | – | – | –
Hematopoietic System
Thymus | (10) | (10) | (10) | (9)
Hemorrhage | – | 2 (20%) | 3 (30%) | –
Integumentary System
Skin | (10) | (10) | (10) | (9)
Hair follicle, inflammation, chronic active | – | – | – | 1 (11%)
Nervous System
Spinal cord | (10) | (10) | (10) | (10)
Cyst, squamous, multiple | – | – | – | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (9)
Hemorrhage | – | 1 (10%) | – | –
Special Senses System
Harderian gland | (10) | (10) | (10) | (9)
Infiltration cellular, lymphocyte | – | – | – | 1 (11%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Nephropathy, chronic progressive | – | 1 (10%) | – | –
Interstitium, infiltration cellular, lymphocyte | – | – | 3 (30%) | –
Urinary bladder | (10) | (10) | (10) | (9)
Infiltration cellular, lymphocyte | – | – | – | 1 (11%)
Systems Examined with No Lesions Observed
Cardiovascular System
General Body System
Genital System
Musculoskeletal System
Two-year Study
Alimentary System
Esophagus | (87) | (90) | (87) | (90)
Gallbladder | (79) | (75) | (74) | (72)
Cyst | – | 1 (1%) | 1 (1%) | –
Infiltration cellular, lymphocyte | 2 (3%) | 5 (7%) | 2 (3%) | 4 (6%)
Intestine large, cecum | (84) | (82) | (83) | (82)
Intestine large, colon | (84) | (84) | (86) | (85)
Intestine large, rectum | (88) | (86) | (88) | (86)
Intestine small, duodenum | (82) | (83) | (84) | (81)
Inflammation, acute | 1 (1%) | – | – | –
Intestine small, ileum | (83) | (82) | (82) | (80)
Peyer’s patch, hyperplasia, lymphoid | – | – | 1 (1%) | –
Intestine small, jejunum | (84) | (81) | (81) | (80)
Peyer’s patch, hyperplasia, lymphoid | 1 (1%) | 1 (1%) | – | –
Liver | (89) | (90) | (90) | (89)
Basophilic focus | 4 (4%) | 2 (2%) | 5 (6%) | 5 (6%)
Clear cell focus | 1 (1%) | – | – | –
Eosinophilic focus | 2 (2%) | 1 (1%) | 1 (1%) | –
Extramedullary hematopoiesis | 1 (1%) | – | 1 (1%) | –
Fatty change | 7 (8%) | 1 (1%) | – | 2 (2%)
Hemorrhage | 1 (1%) | 1 (1%) | 1 (1%) | –
Infiltration cellular, lymphocyte | 33 (37%) | 25 (28%) | 21 (23%) | 32 (36%)
Infiltration cellular, mononuclear cell | 1 (1%) | 2 (2%) | 1 (1%) | –
Infiltration cellular, polymorphonuclear | – | 1 (1%) | – | –
Inflammation, focal | 4 (4%) | 2 (2%) | – | –
Inflammation, acute | – | – | 1 (1%) | –
Inflammation, chronic active | 1 (1%) | – | – | –
Mixed cell focus | 5 (6%) | 1 (1%) | – | 1 (1%)
Necrosis | 6 (7%) | 5 (6%) | 6 (7%) | 3 (3%)
Artery, inflammation, chronic | – | – | 1 (1%) | –
Bile duct, cyst | – | 1 (1%) | 1 (1%) | –
Centrilobular, hepatocyte, hypertrophy | – | – | – | 1 (1%)
Hepatocyte, fatty change, focal | 3 (3%) | – | 1 (1%) | –
Hepatocyte, hyperplasia | – | – | 1 (1%) | –
Hepatocyte, hypertrophy | – | – | 1 (1%) | –
Hepatocyte, inclusion body intracytoplasmic | – | – | – | 1 (1%)
Hepatocyte, vacuolization cytoplasmic | – | – | 4 (4%) | 1 (1%)
Kupffer cell, hyperplasia | 1 (1%) | – | – | –
Mesentery | (29) | (24) | (32) | (30)
Artery, inflammation, chronic | – | 2 (8%) | – | –
Fat, infiltration cellular, lymphocyte | 2 (7%) | 1 (4%) | – | –
Fat, inflammation, granulomatous | – | 1 (4%) | – | –
Fat, inflammation, chronic active | 1 (3%) | – | – | –
Fat, mineral | – | 1 (4%) | 1 (3%) | –
Fat, necrosis | 25 (86%) | 19 (79%) | 27 (84%) | 27 (90%)
Oral mucosa | (0) | (0) | (2) | (0)
Pancreas | (87) | (88) | (89) | (86)
Degeneration | – | – | – | 1 (1%)
Infiltration cellular, lipocyte | – | 1 (1%) | – | 1 (1%)
Infiltration cellular, histiocyte | – | – | 1 (1%) | –
Infiltration cellular, lymphocyte | 27 (31%) | 26 (30%) | 30 (34%) | 24 (28%)
Inflammation, suppurative | – | – | – | 1 (1%)
Inflammation, chronic active | 1 (1%) | – | – | –
Necrosis | – | – | – | 1 (1%)
Acinus, atrophy | – | – | 2 (2%) | 1 (1%)
Duct, cyst | 1 (1%) | 1 (1%) | 2 (2%) | 3 (3%)
Duct, inflammation, chronic active | – | – | – | 1 (1%)
Salivary glands | (89) | (89) | (90) | (90)
Atrophy | 1 (1%) | – | – | –
Infiltration cellular, lymphocyte | 59 (66%) | 54 (61%) | 55 (61%) | 62 (69%)
Inflammation, acute | – | 1 (1%) | – | –
Mineral | – | – | 1 (1%) | –
Arteriole, inflammation, chronic | – | 1 (1%) | – | –
Stomach, forestomach | (86) | (89) | (90) | (85)
Cyst | – | – | 1 (1%) | –
Hyperkeratosis | – | – | 1 (1%) | –
Ulcer | – | 1 (1%) | – | –
Epithelium, hyperplasia, focal | – | – | 2 (2%) | –
Stomach, glandular | (85) | (87) | (85) | (85)
Cyst | 3 (4%) | 3 (3%) | 4 (5%) | –
Infiltration cellular, lymphocyte | – | – | 1 (1%) | 2 (2%)
Ulcer | – | – | 1 (1%) | –
Tongue | (0) | (0) | (1) | (0)
Tooth | (0) | (0) | (1) | (0)
Cardiovascular System
Aorta | (84) | (88) | (90) | (89)
Degeneration | – | – | – | 1 (1%)
Inflammation, chronic active | 1 (1%) | – | – | –
Blood vessel | (0) | (0) | (2) | (0)
Heart | (90) | (90) | (90) | (90)
Bacteria | 1 (1%) | 1 (1%) | 2 (2%) | –
Cardiomyopathy | 3 (3%) | 1 (1%) | 3 (3%) | 3 (3%)
Thrombus | 3 (3%) | 1 (1%) | 2 (2%) | –
Artery, inflammation, chronic active | – | 4 (4%) | – | 1 (1%)
Endocardium, hyperplasia | – | – | 1 (1%) | –
Epicardium, infiltration cellular, mixed cell | 1 (1%) | – | – | –
Epicardium, infiltration cellular, mononuclear cell | 1 (1%) | – | – | –
Myocardium, fibrosis | 1 (1%) | – | – | –
Myocardium, infiltration cellular, lymphocyte | – | – | 1 (1%) | 2 (2%)
Myocardium, inflammation, acute | – | 1 (1%) | 2 (2%) | –
Myocardium, inflammation, chronic active | 1 (1%) | – | – | –
Myocardium, mineral | 4 (4%) | – | – | 1 (1%)
Valve, hemorrhage | 1 (1%) | – | – | –
Valve, infiltration cellular, lymphocyte | 1 (1%) | – | – | –
Valve, inflammation, chronic | – | – | 1 (1%) | –
Valve, thrombus | 1 (1%) | – | – | –
Endocrine System
Adrenal cortex | (84) | (88) | (90) | (90)
Accessory adrenal cortical nodule | – | 1 (1%) | 1 (1%) | 1 (1%)
Angiectasis | 1 (1%) | – | – | –
Hemorrhage | 1 (1%) | – | 3 (3%) | –
Mineral | 1 (1%) | – | – | –
Vacuolization cytoplasmic | – | 2 (2%) | – | –
Bilateral, extramedullary hematopoiesis | 1 (1%) | – | – | –
Bilateral, hyperplasia, focal | – | 1 (1%) | – | –
Bilateral, vacuolization cytoplasmic | – | 3 (3%) | 1 (1%) | 1 (1%)
Subcapsular, hyperplasia | 81 (96%) | 85 (97%) | 88 (98%) | 86 (96%)
Adrenal medulla | (83) | (84) | (86) | (87)
Hemorrhage | 2 (2%) | – | 1 (1%) | –
Hyperplasia | – | – | 2 (2%) | –
Mineral | 1 (1%) | – | – | –
Islets, pancreatic | (87) | (88) | (90) | (86)
Hyperplasia | 1 (1%) | 3 (3%) | 1 (1%) | –
Infiltration cellular, lymphocyte | 3 (3%) | 2 (2%) | 2 (2%) | 3 (3%)
Parathyroid gland | (60) | (57) | (64) | (62)
Cyst | 1 (2%) | – | – | –
Infiltration cellular, lymphocyte | – | – | 1 (2%) | 1 (2%)
Pituitary gland | (80) | (80) | (84) | (84)
Pars distalis, angiectasis | 2 (3%) | 7 (9%) | 6 (7%) | 5 (6%)
Pars distalis, cyst | 1 (1%) | 3 (4%) | – | 1 (1%)
Pars distalis, cytoplasmic alteration | – | – | – | 1 (1%)
Pars distalis, hyperplasia, focal | 2 (3%) | 4 (5%) | 5 (6%) | 4 (5%)
Thyroid gland | (86) | (89) | (86) | (86)
Infiltration cellular, lymphocyte | 1 (1%) | 6 (7%) | 6 (7%) | 3 (3%)
Ultimobranchial cyst | – | – | 2 (2%) | –
Follicle, cyst | 1 (1%) | 1 (1%) | – | –
Follicular cell, hyperplasia, focal | – | 4 (4%) | – | –
General Body System
Peritoneum | (0) | (0) | (1) | (0)
Tissue NOS | (1) | (1) | (1) | (2)
Genital System
Clitoral gland | (82) | (84) | (80) | (86)
Infiltration cellular, lymphocyte | 3 (4%) | – | – | 1 (1%)
Duct, cyst | 1 (1%) | – | 1 (1%) | –
Ovary | (75) | (86) | (82) | (80)
Angiectasis | – | 1 (1%) | 1 (1%) | 2 (3%)
Cyst | 9 (12%) | 13 (15%) | 8 (10%) | 7 (9%)
Cyst, squamous | – | – | 1 (1%) | –
Hemorrhage | 1 (1%) | 2 (2%) | 1 (1%) | –
Hyperplasia, cystic, papillary | – | 1 (1%) | 1 (1%) | –
Hyperplasia, tubulostromal | – | – | – | 1 (1%)
Infiltration cellular, lymphocyte | – | – | – | 1 (1%)
Mineral | 1 (1%) | – | – | –
Thrombus | – | – | 1 (1%) | 1 (1%)
Bursa, cyst | – | – | – | 1 (1%)
Follicle, cyst | 9 (12%) | 11 (13%) | 6 (7%) | 7 (9%)
Granulosa cell, hyperplasia | – | 2 (2%) | – | –
Paraovarian tissue, cyst | – | – | – | 1 (1%)
Oviduct | (0) | (0) | (1) | (0)
Uterus | (89) | (90) | (90) | (89)
Angiectasis | 1 (1%) | 6 (7%) | 5 (6%) | 3 (3%)
Congestion | – | 1 (1%) | – | –
Dilation | 35 (39%) | 29 (32%) | 30 (33%) | 26 (29%)
Hemorrhage | 1 (1%) | 1 (1%) | 1 (1%) | –
Infiltration cellular, lymphocyte | – | – | 1 (1%) | –
Inflammation, acute | – | 1 (1%) | – | –
Thrombus | 1 (1%) | – | – | –
Endometrium, cyst | 3 (3%) | – | – | 1 (1%)
Endometrium, hyperplasia | – | 1 (1%) | – | 1 (1%)
Endometrium, hyperplasia, cystic | 68 (76%) | 75 (83%) | 72 (80%) | 68 (76%)
Endometrium, metaplasia, squamous | 1 (1%) | – | – | –
Vagina | (0) | (0) | (1) | (0)
Hematopoietic System
Bone marrow | (90) | (89) | (89) | (90)
Hypercellularity | 7 (8%) | 8 (9%) | 4 (4%) | 4 (4%)
Hypocellularity | 1 (1%) | 1 (1%) | – | –
Myeloid cell, hypercellularity | 1 (1%) | – | – | –
Lymph node | (18) | (20) | (16) | (14)
Hemorrhage | – | – | 1 (6%) | 1 (7%)
Hyperplasia, lymphoid | 1 (6%) | – | – | –
Axillary, infiltration cellular, mixed cell | 1 (6%) | – | – | –
Axillary, pigment | 1 (6%) | – | – | –
Bronchial, hyperplasia, lymphoid | 2 (11%) | – | – | 4 (29%)
Iliac, erythrophagocytosis | – | 1 (5%) | – | –
Iliac, hemorrhage | 1 (6%) | – | 2 (13%) | –
Iliac, hyperplasia, lymphoid | 4 (22%) | 2 (10%) | 6 (38%) | 2 (14%)
Iliac, infiltration cellular, histiocyte | – | 1 (5%) | 1 (6%) | –
Iliac, infiltration cellular, mixed cell | 1 (6%) | 1 (5%) | 4 (25%) | –
Iliac, pigment | – | – | 4 (25%) | –
Lumbar, hyperplasia, lymphoid | – | 1 (5%) | – | –
Lumbar, infiltration cellular, mixed cell | 1 (6%) | – | – | –
Mediastinal, hyperplasia, lymphoid | 1 (6%) | 2 (10%) | – | –
Mediastinal, infiltration cellular, plasma cell | – | 1 (5%) | – | –
Pancreatic, hyperplasia, lymphoid | 1 (6%) | – | – | –
Renal, erythrophagocytosis | – | – | 1 (6%) | –
Renal, hemorrhage | 1 (6%) | – | – | –
Renal, hyperplasia, lymphoid | 3 (17%) | 2 (10%) | 1 (6%) | –
Lymph node, mandibular | (76) | (77) | (81) | (83)
Hemorrhage | 3 (4%) | 2 (3%) | 1 (1%) | 1 (1%)
Hyperplasia, lymphoid | 1 (1%) | 1 (1%) | 1 (1%) | 4 (5%)
Infiltration cellular, histiocyte | – | – | 2 (2%) | –
Infiltration cellular, mixed cell | 1 (1%) | – | – | –
Lymph node, mesenteric | (71) | (84) | (80) | (83)
Angiectasis | – | 1 (1%) | – | –
Erythrophagocytosis | 1 (1%) | – | 1 (1%) | –
Hemorrhage | 1 (1%) | 4 (5%) | 2 (3%) | 1 (1%)
Hyperplasia, lymphoid | 1 (1%) | 10 (12%) | 3 (4%) | 3 (4%)
Infiltration cellular, histiocyte | 3 (4%) | 8 (10%) | 6 (8%) | 4 (5%)
Infiltration cellular, plasma cell | – | 2 (2%) | – | –
Spleen | (86) | (87) | (89) | (87)
Atrophy | 1 (1%) | – | – | –
Extramedullary hematopoiesis | 20 (23%) | 15 (17%) | 19 (21%) | 11 (13%)
Hyperplasia, lymphoid | 11 (13%) | 7 (8%) | 13 (15%) | 10 (11%)
Capsule, fibrosis | 1 (1%) | – | – | –
Capsule, inflammation, chronic active | – | – | 1 (1%) | –
Thymus | (85) | (80) | (84) | (86)
Atrophy | 5 (6%) | 3 (4%) | 8 (10%) | 1 (1%)
Cyst | 2 (2%) | 2 (3%) | 7 (8%) | 2 (2%)
Hemorrhage | – | – | 1 (1%) | 1 (1%)
Hyperplasia, lymphoid | 1 (1%) | – | 2 (2%) | 2 (2%)
Infiltration cellular, histiocyte | – | 1 (1%) | – | –
Integumentary System
Mammary gland | (85) | (88) | (88) | (84)
Hyperplasia, focal | 1 (1%) | – | 1 (1%) | –
Hyperplasia, diffuse | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Duct, dilation | 1 (1%) | 1 (1%) | 2 (2%) | 1 (1%)
Skin | (90) | (90) | (90) | (90)
Inflammation, chronic | – | 1 (1%) | – | –
Ulcer | 2 (2%) | 2 (2%) | 2 (2%) | 2 (2%)
Epidermis, hyperplasia, multifocal | – | – | – | 1 (1%)
Hair follicle, atrophy | 2 (2%) | 1 (1%) | 4 (4%) | 8 (9%)
Subcutaneous tissue, inflammation, chronic | – | – | 1 (1%) | –
Musculoskeletal System
Bone | (90) | (90) | (89) | (90)
Decreased bone | – | 1 (1%) | – | –
Fibro-osseous lesion | 11 (12%) | 6 (7%) | 4 (4%) | 3 (3%)
Increased bone | – | 1 (1%) | – | 1 (1%)
Periosteum, vertebra, inflammation, granulomatous | – | 1 (1%) | – | –
Skeletal muscle | (89) | (90) | (90) | (90)
Degeneration | – | – | 2 (2%) | 1 (1%)
Infiltration cellular, lymphocyte | 16 (18%) | 5 (6%) | 10 (11%) | 16 (18%)
Inflammation, chronic active | – | – | – | 1 (1%)
Mineral | 1 (1%) | – | – | –
Arteriole, inflammation, chronic | – | 2 (2%) | – | –
Nervous System
Brain | (87) | (90) | (90) | (90)
Cyst, squamous | – | – | 2 (2%) | –
Hemorrhage | 2 (2%) | – | 3 (3%) | –
Hydrocephalus | 1 (1%) | – | – | –
Inflammation, acute | 1 (1%) | – | – | –
Inflammation, chronic | – | 1 (1%) | – | –
Mineral | 80 (92%) | 78 (87%) | 77 (86%) | 78 (87%)
Necrosis | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Artery, meninges, inflammation, chronic active | – | 5 (6%) | 3 (3%) | 2 (2%)
Brain trigeminal ganglion | (75) | (74) | (80) | (79)
Nerve trigeminal | (56) | (58) | (53) | (35)
Peripheral nerve | (0) | (0) | (1) | (0)
Peripheral nerve, sciatic | (88) | (87) | (88) | (88)
Axon, degeneration | 12 (14%) | 6 (7%) | 7 (8%) | 6 (7%)
Spinal cord | (90) | (90) | (90) | (90)
Cyst, squamous | – | 1 (1%) | – | –
Necrosis | – | 3 (3%) | – | –
Artery, meninges, inflammation, chronic active | – | 5 (6%) | 1 (1%) | 2 (2%)
Respiratory System
Larynx | (0) | (0) | (2) | (0)
Lung | (90) | (90) | (90) | (90)
Congestion | – | 2 (2%) | 2 (2%) | 1 (1%)
Hemorrhage | 4 (4%) | 1 (1%) | 3 (3%) | 3 (3%)
Hyperplasia, lymphoid | – | 1 (1%) | 1 (1%) | –
Infiltration cellular, histiocyte | 1 (1%) | 2 (2%) | – | –
Infiltration cellular, lymphocyte | 3 (3%) | 1 (1%) | 2 (2%) | 3 (3%)
Infiltration cellular, mononuclear cell | – | 1 (1%) | – | –
Inflammation, acute | 1 (1%) | – | – | –
Inflammation, chronic | 1 (1%) | – | – | –
Inflammation, chronic active | – | – | – | 1 (1%)
Alveolar epithelium, hyperplasia, focal | 1 (1%) | 1 (1%) | 1 (1%) | 3 (3%)
Serosa, inflammation, chronic | – | 1 (1%) | – | –
Mediastinum | (2) | (0) | (0) | (0)
Nose | (89) | (90) | (90) | (90)
Inflammation, acute | 1 (1%) | – | – | –
Respiratory epithelium, accumulation, hyaline droplet | – | 1 (1%) | – | –
Respiratory epithelium, hyperplasia | – | – | 1 (1%) | –
Vomeronasal organ, cyst | – | – | – | 1 (1%)
Pleura | (0) | (0) | (1) | (0)
Trachea | (90) | (89) | (90) | (90)
Special Senses System
Ear | (0) | (0) | (1) | (0)
Eye | (89) | (88) | (90) | (90)
Phthisis bulbi | – | – | 1 (1%) | –
Anterior chamber, inflammation, acute | – | – | – | 1 (1%)
Bilateral, retina, hemorrhage | – | – | 1 (1%) | –
Cornea, inflammation, acute | – | – | 1 (1%) | 1 (1%)
Cornea, inflammation, chronic | – | – | 2 (2%) | –
Cornea, inflammation, chronic active | – | 1 (1%) | – | –
Cornea, necrosis | – | 1 (1%) | 1 (1%) | –
Harderian gland | (89) | (90) | (90) | (87)
Hyperplasia, focal | – | – | 1 (1%) | –
Infiltration cellular, lymphocyte | 58 (65%) | 68 (76%) | 69 (77%) | 63 (72%)
Inflammation, chronic active | – | – | – | 1 (1%)
Lacrimal gland | (0) | (1) | (2) | (0)
Zymbal’s gland | (0) | (0) | (1) | (0)
Urinary System
Kidney | (89) | (87) | (89) | (88)
Cyst | 1 (1%) | – | – | –
Glomerulopathy, hyaline | – | 2 (2%) | – | –
Hemorrhage | – | – | – | 1 (1%)
Infarct | 14 (16%) | 19 (22%) | 20 (22%) | 14 (16%)
Inflammation, acute | – | – | 1 (1%) | –
Metaplasia, osseous | 2 (2%) | 2 (2%) | 2 (2%) | 2 (2%)
Nephropathy, chronic progressive | 8 (9%) | 15 (17%) | 19 (21%) | 14 (16%)
Bilateral, infarct | 1 (1%) | – | – | –
Interstitium, infiltration cellular, lymphocyte | 63 (71%) | 60 (69%) | 65 (73%) | 56 (64%)
Papilla, mineral | – | 2 (2%) | 1 (1%) | 1 (1%)
Pelvis, dilatation | 1 (1%) | – | – | –
Pelvis, mineral | – | – | – | 1 (1%)
Pelvis, necrosis | – | – | 1 (1%) | –
Renal tubule, dilation | 1 (1%) | – | 1 (1%) | 1 (1%)
Renal tubule, hyaline droplet | – | 1 (1%) | – | –
Renal tubule, mineral | 1 (1%) | – | 1 (1%) | –
Renal tubule, vacuolization cytoplasmic | – | 1 (1%) | – | –
Ureter | (0) | (0) | (1) | (0)
Urethra | (0) | (0) | (1) | (0)
Urinary bladder | (86) | (87) | (86) | (86)
Angiectasis | – | – | – | 2 (2%)
Infiltration cellular, lymphocyte | 62 (72%) | 67 (77%) | 65 (76%) | 68 (79%)
Inflammation, acute | – | – | 1 (1%) | –
Arteriole, inflammation, chronic | – | 1 (1%) | – | –
Urothelium, hyperplasia | – | – | 1 (1%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.