# Appendix A Summary of Lesions in Male Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

Table A-1 Summary of the Incidence of Neoplasms in Male Mice Exposed to GSM-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
14-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | – | 1 | – | –
Moribund | 8 | 6 | 2 | 6
Natural deaths | 16 | 19 | 8 | 12
Survivors
Died last week of study | – | – | 1 | 4
Terminal euthanasia | 66 | 63 | 79 | 68
Missing | – | 1 | – | –
Animals examined microscopically | 100 | 100 | 100 | 100
14-week Interim Evaluation
Nervous System
Brain | (10) | (10) | (10) | (10)
Hamartoma, lipomatous | – | – | – | 1 (10%)
Systems Examined with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (88) | (87) | (88) | (90)
Gallbladder | (73) | (66) | (74) | (79)
Intestine large, cecum | (81) | (77) | (84) | (78)
Leiomyoma | – | – | 1 (1%) | –
Intestine large, colon | (84) | (83) | (85) | (84)
Intestine large, rectum | (84) | (85) | (86) | (84)
Intestine small, duodenum | (77) | (77) | (83) | (79)
Adenocarcinoma | 1 (1%) | 1 (1%) | – | –
Adenoma | – | – | 1 (1%) | –
Intestine small, ileum | (81) | (79) | (85) | (80)
Intestine small, jejunum | (79) | (79) | (82) | (79)
Adenocarcinoma | 2 (3%) | – | – | 1 (1%)
Hepatocellular carcinoma, metastatic, liver | 1 (1%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (1%) | – | –
Liver | (90) | (89) | (90) | (90)
Adenocarcinoma, metastatic, harderian gland | – | 1 (1%) | – | –
Carcinoma, metastatic, islets, pancreatic | – | – | – | 1 (1%)
Hemangioma | – | – | 1 (1%) | –
Hemangiosarcoma | 1 (1%) | 3 (3%) | 2 (2%) | 2 (2%)
Hepatoblastoma | 6 (7%) | 3 (3%) | 8 (9%) | 1 (1%)
Hepatoblastoma, multiple | – | – | 1 (1%) | –
Hepatocellular adenoma | 25 (28%) | 28 (31%) | 20 (22%) | 26 (29%)
Hepatocellular adenoma, multiple | 27 (30%) | 33 (37%) | 46 (51%) | 29 (32%)
Hepatocellular carcinoma | 26 (29%) | 23 (26%) | 28 (31%) | 19 (21%)
Hepatocellular carcinoma, multiple | 2 (2%) | 2 (2%) | 2 (2%) | 3 (3%)
Hepatocholangiocarcinoma | 1 (1%) | 4 (4%) | – | –
Malignant fibrous histiocytoma, metastatic, skin | 1 (1%) | – | – | –
Mesentery | (12) | (14) | (13) | (17)
Hemangiosarcoma | 1 (8%) | – | 1 (8%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (7%) | – | –
Malignant fibrous histiocytoma, metastatic, skin | 1 (8%) | – | – | –
Fat, hepatocholangiocarcinoma, metastatic, liver | 1 (8%) | 1 (7%) | – | –
Fat, lipoma | 1 (8%) | – | – | –
Pancreas | (87) | (88) | (88) | (86)
Hepatocholangiocarcinoma, metastatic, liver | 1 (1%) | 2 (2%) | – | –
Salivary glands | (90) | (89) | (89) | (89)
Stomach, forestomach | (88) | (87) | (89) | (87)
Squamous cell papilloma | – | 1 (1%) | 2 (2%)
Stomach, glandular | (87) | (86) | (88) | (85)
Malignant fibrous histiocytoma, metastatic, skin | 1 (1%) | – | – | –
Tooth | (27) | (26) | (16) | (20)
Cardiovascular System
Aorta | (89) | (89) | (89) | (87)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (1%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (1%) | – | –
Blood vessel | (1) | (0) | (0) | (0)
Heart | (90) | (89) | (90) | (90)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (1%) | 1 (1%) | – | 2 (2%)
Hemangiosarcoma | – | 1 (1%) | – | 1 (1%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (1%) | 2 (2%) | – | –
Endocrine System
Adrenal cortex | (90) | (89) | (89) | (88)
Bilateral, malignant fibrous histiocytoma, metastatic, skin | 1 (1%) | – | – | –
Subcapsular, adenoma | – | 3 (3%) | 3 (3%) | –
Adrenal medulla | (90) | (88) | (88) | (86)
Islets, pancreatic | (88) | (88) | (90) | (89)
Adenoma | – | – | – | 2 (2%)
Adenoma, multiple | – | 1 (1%) | – | –
Carcinoma | – | – | 1 (1%) | 1 (1%)
Parathyroid gland | (68) | (68) | (67) | (66)
Pituitary gland | (86) | (85) | (87) | (85)
Thyroid gland | (89) | (88) | (88) | (88)
General Body System
Peritoneum | (1) | (0) | (0) | (0)
Hepatocholangiocarcinoma, metastatic, liver | 1 (100%) | – | – | –
Tissue NOS | (0) | (0) | (0) | (1)
Genital System
Coagulating gland | (2) | (2) | (0) | (4)
Epididymis | (90) | (89) | (90) | (90)
Hemangioma | – | 1 (1%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (1%) | – | –
Preputial gland | (89) | (88) | (90) | (89)
Prostate | (90) | (87) | (90) | (87)
Seminal vesicle | (90) | (88) | (90) | (90)
Fibroma | 1 (1%) | – | – | –
Malignant fibrous histiocytoma, metastatic, skin | 1 (1%) | – | – | –
Testis | (90) | (88) | (90) | (90)
Hemangioma | – | 1 (1%) | – | –
Interstitial cell, adenoma | 2 (2%) | – | – | –
Hematopoietic System
Bone marrow | (90) | (88) | (90) | (90)
Hemangiosarcoma | – | – | 1 (1%) | 1 (1%)
Lymph node | (6) | (8) | (7) | (9)
Sarcoma, metastatic, skin | – | 1 (13%) | – | –
Axillary, hepatocholangiocarcinoma, metastatic, liver | 1 (17%) | – | – | –
Lymph node, mandibular | (72) | (61) | (63) | (60)
Lymph node, mesenteric | (85) | (82) | (88) | (83)
Hemangioma | 1 (1%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (1%) | – | –
Malignant fibrous histiocytoma, metastatic, skin | 1 (1%) | – | – | –
Spleen | (87) | (88) | (89) | (88)
Hemangiosarcoma | – | 4 (5%) | 1 (1%) | 1 (1%)
Thymus | (75) | (83) | (81) | (72)
Hepatocellular carcinoma, metastatic, liver | – | 1 (1%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 3 (4%) | – | –
Thymoma benign | – | – | 1 (1%) | –
Integumentary System
Mammary gland | (2) | (5) | (2) | (8)
Skin | (90) | (89) | (90) | (90)
Keratoacanthoma | – | – | 1 (1%) | –
Pilomatrixoma | 1 (1%) | – | – | –
Sebaceous gland, adenoma | – | – | 1 (1%) | –
Subcutaneous tissue, fibrosarcoma | – | – | – | 1 (1%)
Subcutaneous tissue, hemangioma | – | – | – | 1 (1%)
Subcutaneous tissue, hemangiosarcoma | 1 (1%) | – | 2 (2%) | –
Subcutaneous tissue, lipoma | 1 (1%) | – | – | –
Subcutaneous tissue, liposarcoma | | 1 (1%) | – | –
Subcutaneous tissue, malignant fibrous histiocytoma | 1 (1%) | – | 4 (4%) | 3 (3%)
Subcutaneous tissue, malignant fibrous histiocytoma, multiple | – | – | 1 (1%) | –
Subcutaneous tissue, sarcoma | – | 1 (1%) | – | –
Musculoskeletal System
Bone | (90) | (88) | (90) | (90)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (1%) | – | –
Skeletal muscle | (90) | (89) | (90) | (90)
Hepatocellular carcinoma, metastatic, liver | 1 (1%) | – | 1 (1%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (1%) | 2 (2%) | – | –
Malignant fibrous histiocytoma, metastatic, skin | 1 (1%) | – | – | –
Sarcoma | 1 (1%) | – | – | –
Nervous System
Brain | (90) | (89) | (90) | (90)
Hepatocholangiocarcinoma, metastatic, liver | 1 (1%) | – | – | –
Brain trigeminal ganglion | (69) | (79) | (72) | (79)
Nerve trigeminal | (67) | (53) | (66) | (63)
Peripheral nerve, sciatic | (89) | (89) | (90) | (89)
Spinal cord | (90) | (89) | (90) | (90)
Respiratory System
Lung | (90) | (89) | (90) | (90)
Adenocarcinoma, metastatic, Harderian gland | – | 1 (1%) | – | –
Alveolar/bronchiolar adenoma | 11 (12%) | 13 (15%) | 16 (18%) | 15 (17%)
Alveolar/bronchiolar adenoma, multiple | 2 (2%) | – | 2 (2%) | 1 (1%)
Alveolar/bronchiolar carcinoma | 11 (12%) | 12 (13%) | 15 (17%) | 17 (19%)
Alveolar/bronchiolar carcinoma, multiple | 2 (2%) | – | 1 (1%) | 1 (1%)
Carcinoma, metastatic, islets, pancreatic | – | – | – | 1 (1%)
Hepatoblastoma, metastatic, liver | 1 (1%) | 1 (1%) | – | 1 (1%)
Hepatocellular carcinoma, metastatic, liver | 11 (12%) | 8 (9%) | 6 (7%) | 5 (6%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (1%) | 3 (3%) | – | –
Sarcoma, metastatic, skin | – | 1 (1%) | – | –
Mediastinum | (0) | (0) | (2) | (1)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (100%)
Hibernoma | – | – | 2 (100%) | –
Nose | (90) | (89) | (90) | (89)
Trachea | (90) | (89) | (89) | (90)
Special Senses System
Eye | (90) | (89) | (90) | (90)
Adenocarcinoma, metastatic, Harderian gland | – | 1 (1%) | – | –
Harderian gland | (88) | (89) | (90) | (90)
Adenocarcinoma | 3 (3%) | 2 (2%) | 1 (1%) | –
Adenoma | 6 (7%) | 7 (8%) | 11 (12%) | 5 (6%)
Urinary System
Kidney | (90) | (89) | (90) | (89)
Alveolar/bronchiolar carcinoma, metastatic, lung | | – | – | 1 (1%)
Hepatocellular carcinoma, metastatic, liver | 1 (1%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (1%) | 2 (2%) | – | –
Malignant fibrous histiocytoma, metastatic, skin | 1 (1%) | – | – | –
Renal tubule, adenoma | – | 1 (1%) | 1 (1%) | –
Urinary bladder | (87) | (88) | (90) | (89)
Hemangioma | – | 2 (2%) | – | –
Urothelium, papilloma | – | – | – | 2 (2%)
Systemic Lesions
Multiple organs^b^ | (90) | (89) | (90) | (90)
Histiocytic sarcoma | – | – | 1 (1%) | 2 (2%)
Leukemia granulocytic | – | – | – | 1 (1%)
Lymphoma malignant | 6 (7%) | 4 (4%) | 3 (3%) | 4 (4%)
Mast cell tumor | 1 (1%) | – | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^
14-week interim evaluation | – | – | – | 1
Two-year study | 79 | 82 | 82 | 77
Total primary neoplasms
14-week interim evaluation | – | – | – | 1
Two-year study | 144 | 152 | 182 | 140
Total animals with benign neoplasms
14-week interim evaluation | – | – | – | 1
Two-year study | 61 | 67 | 77 | 61
Total benign neoplasms
14-week interim evaluation | – | – | – | 1
Two-year study | 77 | 91 | 109 | 81
Total animals with malignant neoplasms
Two-year study | 49 | 47 | 53 | 45
Total malignant neoplasms
Two-year study | 66 | 61 | 73 | 59
Total animals with metastatic neoplasms
Two-year study | 14 | 15 | 6 | 10
Total metastatic neoplasms
Two-year study | 34 | 37 | 7 | 12
Total animals with uncertain neoplasms-benign or malignant
Two-year study | 1 | – | – | –
Total uncertain neoplasms
Two-year study | 1 | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Mice Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Harderian Gland: Adenoma
Overall rate^a^ | 6/90 (7%) | 7/89 (8%) | 11/90 (12%) | 5/90 (6%)
Adjusted rate^b^ | 7.5% | 8.7% | 12.7% | 6.0%
Terminal rate^c^ | 6/66 (9%) | 5/63 (8%) | 11/80 (14%) | 4/72 (6%)
First incidence (days) | 729 (T) | 672 | 729 (T) | 689
Poly-3 test^d^ | P = 0.415N | P = 0.506 | P = 0.194 | P = 0.470N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 9/90 (10%) | 9/89 (10%) | 12/90 (13%) | 5/90 (6%)
Adjusted rate | 11.2% | 11.1% | 13.9% | 6.0%
Terminal rate | 8/66 (12%) | 5/63 (8%) | 12/80 (15%) | 4/72 (6%)
First incidence (days) | 690 | 651 | 729 (T) | 689
Poly-3 test | P = 0.160N | P = 0.588N | P = 0.386 | P = 0.179N
Liver: Hepatocellular Adenoma
Overall rate | 52/90 (58%) | 61/89 (69%) | 66/90 (73%) | 55/90 (61%)
Adjusted rate | 62.3% | 73.8% | 75.3% | 64.7%
Terminal rate | 45/66 (68%) | 52/63 (83%) | 61/80 (76%) | 49/72 (68%)
First incidence (days) | 393 | 533 | 605 | 614
Poly-3 test | P = 0.526N | P = 0.072 | P = 0.044 | P = 0.437
Liver: Hepatocellular Carcinoma
Overall rate | 28/90 (31%) | 25/89 (28%) | 30/90 (33%) | 22/90 (24%)
Adjusted rate | 34.2% | 30.0% | 34.1% | 25.9%
Terminal rate | 18/66 (27%) | 15/63 (24%) | 25/80 (31%) | 17/72 (24%)
First incidence (days) | 608 | 547 | 604 | 538
Poly-3 test | P = 0.169N | P = 0.340N | P = 0.556N | P = 0.157N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 67/90 (74%) | 68/89 (76%) | 74/90 (82%) | 64/90 (71%)
Adjusted rate | 79.1% | 79.9% | 83.4% | 74.3%
Terminal rate | 51/66 (77%) | 52/63 (83%) | 66/80 (83%) | 54/72 (75%)
First incidence (days) | 393 | 533 | 604 | 538
Poly-3 test | P = 0.232N | P = 0.526 | P = 0.296 | P = 0.281N
Liver: Hepatoblastoma
Overall rate | 6/90 (7%) | 3/89 (3%) | 9/90 (10%) | 1/90 (1%)
Adjusted rate | 7.5% | 3.7% | 10.4% | 1.2%
Terminal rate | 5/66 (8%) | 3/63 (5%) | 8/80 (10%) | 1/72 (1%)
First incidence (days) | 711 | 729 (T) | 667 | 729 (T)
Poly-3 test | P = 0.105N | P = 0.244N | P = 0.350 | P = 0.054N
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 32/90 (36%) | 27/89 (30%) | 35/90 (39%) | 23/90 (26%)
Adjusted rate | 39.1% | 32.4% | 39.7% | 27.1%
Terminal rate | 22/66 (33%) | 17/63 (27%) | 29/80 (36%) | 18/72 (25%)
First incidence (days) | 608 | 547 | 604 | 538
Poly-3 test | P = 0.089N | P = 0.230N | P = 0.534 | P = 0.067N
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 68/90 (76%) | 68/89 (76%) | 74/90 (82%) | 65/90 (72%)
Adjusted rate | 80.3% | 79.9% | 83.4% | 75.4%
Terminal rate | 52/66 (79%) | 52/63 (83%) | 66/80 (83%) | 55/72 (76%)
First incidence (days) | 393 | 533 | 604 | 538
Poly-3 test | P = 0.243N | P = 0.553N | P = 0.367 | P = 0.276N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 13/90 (14%) | 13/89 (15%) | 18/90 (20%) | 16/90 (18%)
Adjusted rate | 16.0% | 16.0% | 20.7% | 19.0%
Terminal rate | 9/66 (14%) | 10/63 (16%) | 16/80 (20%) | 14/72 (19%)
First incidence (days) | 488 | 663 | 604 | 658
Poly-3 test | P = 0.297 | P = 0.583 | P = 0.279 | P = 0.380
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 13/90 (14%) | 12/89 (13%) | 16/90 (18%) | 18/90 (20%)
Adjusted rate | 16.1% | 14.7% | 18.5% | 21.2%
Terminal rate | 12/66 (18%) | 8/63 (13%) | 16/80 (20%) | 14/72 (19%)
First incidence (days) | 568 | 594 | 729 (T) | 614
Poly-3 test | P = 0.165 | P = 0.488N | P = 0.418 | P = 0.259
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 23/90 (26%) | 24/89 (27%) | 32/90 (36%) | 34/90 (38%)
Adjusted rate | 28.1% | 29.2% | 36.8% | 39.9%
Terminal rate | 18/66 (27%) | 17/63 (27%) | 30/80 (38%) | 28/72 (39%)
First incidence (days) | 488 | 594 | 604 | 614
Poly-3 test | P = 0.040 | P = 0.506 | P = 0.149 | P = 0.074
Skin (Subcutaneous Tissue): Malignant Fibrous Histiocytoma
Overall rate | 1/90 (1%) | 0/89 (0%) | 5/90 (6%) | 3/90 (3%)
Adjusted rate | 1.2% | 0.0% | 5.8% | 3.6%
Terminal rate | 0/66 (0%) | 0/63 (0%) | 4/80 (5%) | 3/72 (4%)
First incidence (days) | 674 | –^e^ | 654 | 729 (T)
Poly-3 test | P = 0.127 | P = 0.499N | P = 0.124 | P = 0.321
Skin (Subcutaneous Tissue): Fibrosarcoma, Sarcoma, or Malignant Fibrous Histiocytoma
Overall rate | 1/90 (1%) | 1/89 (1%) | 5/90 (6%) | 4/90 (4%)
Adjusted rate | 1.2% | 1.2% | 5.8% | 4.7%
Terminal rate | 0/66 (0%) | 0/63 (0%) | 4/80 (5%) | 3/72 (4%)
First incidence (days) | 674 | 523 | 654 | 488
Poly-3 test | P = 0.093 | P = 0.758N | P = 0.124 | P = 0.197
Spleen: Hemangiosarcoma
Overall rate | 0/87 (0%) | 4/88 (5%) | 1/89 (1%) | 1/88 (1%)
Adjusted rate | 0.0% | 5.0% | 1.2% | 1.2%
Terminal rate | 0/66 (0%) | 3/63 (5%) | 1/80 (1%) | 0/72 (0%)
First incidence (days) | – | 672 | 729 (T) | 681
Poly-3 test | P = 0.538N | P = 0.065 | P = 0.515 | P = 0.507
All Organs: Hemangiosarcoma
Overall rate | 2/90 (2%) | 6/89 (7%) | 6/90 (7%) | 2/90 (2%)
Adjusted rate | 2.5% | 7.4% | 6.9% | 2.4%
Terminal rate | 0/66 (0%) | 4/63 (6%) | 6/80 (8%) | 1/72 (1%)
First incidence (days) | 702 | 667 | 729 (T) | 681
Poly-3 test | P = 0.394N | P = 0.141 | P = 0.163 | P = 0.677N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/90 (3%) | 10/89 (11%) | 7/90 (8%) | 3/90 (3%)
Adjusted rate | 3.7% | 12.3% | 8.1% | 3.6%
Terminal rate | 1/66 (2%) | 8/63 (13%) | 7/80 (9%) | 2/72 (3%)
First incidence (days) | 702 | 667 | 729 (T) | 681
Poly-3 test | P = 0.277N | P = 0.042 | P = 0.195 | P = 0.641N
All Organs: Malignant Lymphoma
Overall rate | 6/90 (7%) | 4/89 (4%) | 3/90 (3%) | 4/90 (4%)
Adjusted rate | 7.3% | 4.9% | 3.5% | 4.8%
Terminal rate | 4/66 (6%) | 1/63 (2%) | 3/80 (4%) | 3/72 (4%)
First incidence (days) | 263 | 609 | 729 (T) | 690
Poly-3 test | P = 0.307N | P = 0.375N | P = 0.222N | P = 0.359N
All Organs: Benign Neoplasms
Overall rate | 61/90 (68%) | 67/89 (75%) | 77/90 (86%) | 61/90 (68%)
Adjusted rate | 72.4% | 80.8% | 87.4% | 71.4%
Terminal rate | 51/66 (77%) | 53/63 (89%) | 71/80 (89%) | 53/72 (74%)
First incidence (days) | 393 | 533 | 604 | 614
Poly-3 test | P = 0.386N | P = 0.126 | P = 0.009 | P = 0.510N
All Organs: Malignant Neoplasms
Overall rate | 49/90 (54%) | 47/89 (53%) | 53/90 (59%) | 45/90 (50%)
Adjusted rate | 57.6% | 54.1% | 59.8% | 51.8%
Terminal rate | 33/66 (50%) | 27/63 (43%) | 46/80 (58%) | 34/72 (47%)
First incidence (days) | 263 | 523 | 604 | 488
Poly-3 test | P = 0.291N | P = 0.379N | P = 0.443 | P = 0.269N
All Organs: Benign or Malignant Neoplasms
Overall rate | 79/90 (88%) | 82/89 (92%) | 82/90 (91%) | 77/90 (86%)
Adjusted rate | 90.2% | 93.7% | 92.4% | 87.7%
Terminal rate | 59/66 (89%) | 59/63 (94%) | 74/80 (93%) | 62/72 (86%)
First incidence (days) | 263 | 523 | 604 | 488
Poly-3 test | P = 0.231N | P = 0.275 | P = 0.398 | P = 0.389N

T = terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, and spleen; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table A-3 Historical Incidence of Skin Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Malignant Fibrous Histiocytoma | Fibrosarcoma, Sarcoma, or Malignant Fibrous Histiocytoma
Historical Incidence: All Studies
Antimony trioxide (October 2008) | 0/50 | 0/50
2,3-Butanedione (August 2009) | 0/50 | 0/50
Green tea extract (July 2007) | 0/50 | 0/50
2-Hydroxy-4-methoxybenzophenone (July 2010) | 0/49 | 0/49
Indole-3-carbinol (April 2007) | 0/50 | 1/50
CIMSTAR 3800 (May 2008) | 0/50 | 0/50
Trim VX (August 2009) | 0/50 | 1/50
p-Chloro-á,á,á-trifluorotoluene (January 2011) | 1/50 | 1/50
Pentabromodiphenyl ether mixture [DE-71 (technical grade)] (February 2008) | 0/50 | 0/50
Radiofrequency radiation (June 2012) | 1/90 | 1/90
Tetrabromobisphenol A (August 2007) | 0/50 | 1/50
Overall Historical Incidence
Total (%) | 2/589 (0.3%) | 5/589 (0.9%)
Mean ± standard deviation | 0.3% ± 0.7% | 0.8% ± 1.0%
Range | 0%–2% | 0%–2%

^a^ Data as of August 2017.

Table A-4 Historical Incidence of Alveolar/bronchiolar Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: All Studies
Antimony trioxide (October 2008) | 10/50 | 4/50 | 13/50
2,3-Butanedione (August 2009) | 5/50 | 5/50 | 9/50
Green tea extract (July 2007) | 12/50 | 2/50 | 14/50
2-Hydroxy-4-methoxybenzophenone (July 2010) | 7/49 | 5/49 | 11/49
Indole-3-carbinol (April 2007) | 4/50 | 4/50 | 8/50
CIMSTAR 3800 (May 2008) | 5/50 | 8/50 | 13/50
Trim VX (August 2009) | 6/50 | 10/50 | 14/50
p-Chloro-á,á,á-trifluorotoluene (January 2011) | 11/50 | 6/50 | 17/50
Pentabromodiphenyl ether mixture [DE-71 (technical grade)] (February 2008) | 5/50 | 5/50 | 10/50
Radiofrequency radiation (June 2012) | 13/90 | 13/90 | 23/90
Tetrabromobisphenol A (August 2007) | 6/50 | 4/50 | 10/50
Overall Historical Incidence
Total (%) | 84/589 (14.3%) | 66/589 (11.2%) | 142/589 (24.1%)
Mean ± standard deviation | 14.3% ± 5.4% | 11.0% ± 4.4% | 24.0% ± 5.3%
Range | 8%–24% | 4%–20% | 16%–34%

^a^ Data as of August 2017.

Table A-5 Summary of the Incidence of Non-neoplastic Lesions in Male Mice Exposed to GSM-modulated Cell Phone RFR for Two Years^a^

| Sham Control | 2.5 W/kg | 5 W/kg | 10 W/kg
Disposition Summary
Animals initially in study | 105 | 105 | 105 | 105
14-week interim evaluation | 15 | 15 | 15 | 15
Early deaths
Accidental death | – | 1 | – | –
Moribund | 8 | 6 | 2 | 6
Natural deaths | 16 | 19 | 8 | 12
Survivors
Died last week of study | – | – | 1 | 4
Terminal euthanasia | 66 | 63 | 79 | 68
Missing | – | 1 | – | –
Animals examined microscopically | 100 | 100 | 100 | 100
14-week Interim Evaluation
Alimentary System
Liver | (10) | (10) | (10) | (10)
Inflammation, focal | – | 2 (20%) | 4 (40%) | –
Pancreas | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | – | 1 (10%) | – | –
Inflammation, chronic | – | 1 (10%) | – | –
Genital System
Prostate | (10) | (10) | (10) | (10)
Infiltration cellular, lymphocyte | – | – | 2 (20%) | 1 (10%)
Hematopoietic System
Lymph node, mandibular | (5) | (7) | (10) | (8)
Hemorrhage | – | – | 2 (20%) | –
Nervous System
Brain | (10) | (10) | (10) | (10)
Hemorrhage | 1 (10%) | 1 (10%) | – | –
Respiratory System
Lung | (10) | (10) | (10) | (10)
Congestion | 1 (10%) | – | – | 1 (10%)
Hemorrhage | 2 (20%) | 3 (30%) | 2 (20%) | 2 (20%)
Nose | (10) | (10) | (10) | (10)
Respiratory epithelium, hyperplasia | – | 2 (20%) | 1 (10%) | –
Urinary System
Kidney | (10) | (10) | (10) | (10)
Nephropathy, chronic progressive | 1 (10%) | 2 (20%) | 1 (10%) | –
Interstitium, infiltration cellular, lymphocyte | 2 (20%) | 1 (10%) | 1 (10%) | 1 (10%)
Systems Examined with No Lesions Observed
Cardiovascular System
Endocrine System
General Body System
Integumentary System
Musculoskeletal System
Special Senses System
Two-year Study
Alimentary System
Esophagus | (88) | (87) | (88) | (90)
Gallbladder | (73) | (66) | (74) | (79)
Inflammation, acute | – | 1 (2%) | – | –
Intestine large, cecum | (81) | (77) | (84) | (78)
Intestine large, colon | (84) | (83) | (85) | (84)
Intestine large, rectum | (84) | (85) | (86) | (84)
Intestine small, duodenum | (77) | (77) | (83) | (79)
Intestine small, ileum | (81) | (79) | (85) | (80)
Peyer’s patch, hyperplasia, lymphoid | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Peyer’s patch, infiltration cellular, plasma cell | 1 (1%) | – | – | –
Intestine small, jejunum | (79) | (79) | (82) | (79)
Inflammation, granulomatous | 1 (1%) | – | – | –
Epithelium, cyst | 1 (1%) | – | – | –
Peyer’s patch, hyperplasia, lymphoid | – | – | 1 (1%) | 1 (1%)
Liver | (90) | (89) | (90) | (90)
Angiectasis | – | – | 2 (2%) | –
Basophilic focus | 1 (1%) | 2 (2%) | 4 (4%) | 3 (3%)
Clear cell focus | 28 (31%) | 34 (38%) | 41 (46%) | 31 (34%)
Eosinophilic focus | 4 (4%) | 4 (4%) | 8 (9%) | 1 (1%)
Extramedullary hematopoiesis | 2 (2%) | 2 (2%) | 2 (2%) | –
Fatty change | 37 (41%) | 31 (35%) | 35 (39%) | 35 (39%)
Fibrosis | 1 (1%) | – | – | –
Hemorrhage | 1 (1%) | – | – | –
Infiltration cellular, lymphocyte | 2 (2%) | – | – | 2 (2%)
Infiltration cellular, mixed cell | 1 (1%) | – | – | –
Inflammation, focal | 1 (1%) | 1 (1%) | 3 (3%) | –
Inflammation, chronic | – | – | – | 2 (2%)
Inflammation, chronic active | 2 (2%) | – | 1 (1%) | 1 (1%)
Mixed cell focus | 2 (2%) | 3 (3%) | 7 (8%) | 4 (4%)
Necrosis | 6 (7%) | 6 (7%) | 4 (4%) | 3 (3%)
Bile duct, cyst | – | 2 (2%) | 1 (1%) | –
Hepatocyte, fatty change, focal | – | 1 (1%) | – | 2 (2%)
Mesentery | (12) | (14) | (13) | (17)
Artery, inflammation, chronic active | – | 1 (7%) | – | 2 (12%)
Fat, hemorrhage | – | 1 (7%) | – | –
Fat, inflammation, granulomatous | – | – | – | 1 (6%)
Fat, mineral | – | – | 1 (8%) | –
Fat, necrosis | 8 (67%) | 11 (79%) | 12 (92%) | 13 (76%)
Pancreas | (87) | (88) | (88) | (86)
Hemorrhage | 1 (1%) | – | – | –
Infiltration cellular, lymphocyte | 3 (3%) | 5 (6%) | 3 (3%) | 1 (1%)
Infiltration cellular, mixed cell | – | – | – | 1 (1%)
Inflammation, granulomatous | 1 (1%) | – | – | –
Inflammation, acute | – | – | – | 1 (1%)
Inflammation, chronic active | – | – | – | 1 (1%)
Acinus, atrophy | – | 1 (1%) | – | –
Duct, cyst | 1 (1%) | 2 (2%) | – | –
Duct, fibrosis | 1 (1%) | – | – | –
Salivary glands | (90) | (89) | (89) | (89)
Infiltration cellular, lymphocyte | 58 (64%) | 59 (66%) | 65 (73%) | 65 (73%)
Stomach, forestomach | (88) | (87) | (89) | (87)
Cyst, squamous | – | – | 1 (1%) | 3 (3%)
Hyperkeratosis | – | 1 (1%) | – | 2 (2%)
Infiltration cellular, lymphocyte | – | – | 1 (1%) | –
Inflammation, chronic | – | – | 1 (1%) | –
Epithelium, hyperplasia, focal | 3 (3%) | 2 (2%) | 2 (2%) | –
Epithelium, hyperplasia, diffuse | – | 1 (1%) | – | 1 (1%)
Stomach, glandular | (87) | (86) | (88) | (85)
Accumulation, hyaline droplet | – | 2 (2%) | – | –
Cyst | – | – | – | 1 (1%)
Hemorrhage | 1 (1%) | – | – | –
Ulcer | – | – | – | 1 (1%)
Epithelium, hyperplasia, focal | 1 (1%) | – | – | –
Tooth | (27) | (26) | (16) | (20)
Dysplasia | 26 (96%) | 26 (100%) | 14 (88%) | 20 (100%)
Inflammation, suppurative | 2 (7%) | – | 2 (13%) | –
Inflammation, chronic active | – | – | – | 1 (5%)
Cardiovascular System
Aorta | (89) | (89) | (89) | (87)
Blood vessel | (1) | (0) | (0) | (0)
Inflammation, chronic | 1 (100%) | – | – | –
Heart | (90) | (89) | (90) | (90)
Bacteria | 1 (1%) | 2 (2%) | – | –
Cardiomyopathy | 10 (11%) | 2 (2%) | 1 (1%) | 2 (2%)
Inflammation, acute | 1 (1%) | – | – | –
Inflammation, chronic active | 2 (2%) | 2 (2%) | – | 1 (1%)
Thrombus | 1 (1%) | 2 (2%) | – | 1 (1%)
Artery, inflammation, chronic active | 1 (1%) | 2 (2%) | – | 3 (3%)
Endocardium, mineral | 1 (1%) | – | – | –
Endothelium, hyperplasia | – | 1 (1%) | – | 1 (1%)
Epicardium, inflammation, chronic | 1 (1%) | – | – | –
Epicardium, mineral | 1 (1%) | – | – | –
Myocardium, hemorrhage | – | 1 (1%) | – | –
Myocardium, mineral | 2 (2%) | 2 (2%) | 1 (1%) | 1 (1%)
Myocardium, necrosis | 1 (1%) | 2 (2%) | – | –
Endocrine System
Adrenal cortex | (90) | (89) | (89) | (88)
Accessory adrenal cortical nodule | 1 (1%) | – | – | –
Angiectasis | 1 (1%) | – | – | –
Hyperplasia, focal | 3 (3%) | 1 (1%) | 6 (7%) | 6 (7%)
Hypertrophy, focal | 2 (2%) | 8 (9%) | 9 (10%) | 1 (1%)
Infiltration cellular, mononuclear cell | – | – | – | 1 (1%)
Bilateral, hyperplasia, focal | – | – | 1 (1%) | –
Bilateral, hypertrophy, focal | 1 (1%) | 5 (6%) | 4 (4%) | 1 (1%)
Subcapsular, hyperplasia | 69 (77%) | 72 (81%) | 80 (90%) | 72 (82%)
Adrenal medulla | (90) | (88) | (88) | (86)
Islets, pancreatic | (88) | (88) | (90) | (89)
Atrophy | – | – | – | 1 (1%)
Hyperplasia | 18 (20%) | 20 (23%) | 16 (18%) | 10 (11%)
Infiltration cellular, lymphocyte | 2 (2%) | 1 (1%) | 2 (2%) | –
Parathyroid gland | (68) | (68) | (67) | (66)
Cyst | – | 2 (3%) | 4 (6%) | 1 (2%)
Pituitary gland | (86) | (85) | (87) | (85)
Pars distalis, angiectasis | 1 (1%) | – | – | –
Pars distalis, cyst | 3 (3%) | 4 (5%) | 3 (3%) | 4 (5%)
Pars distalis, hyperplasia, focal | 1 (1%) | 2 (2%) | 1 (1%) | –
Thyroid gland | (89) | (88) | (88) | (88)
Infiltration cellular, lymphocyte | – | – | 1 (1%) | 1 (1%)
General Body System
Peritoneum | (1) | (0) | (0) | (0)
Tissues NOS | (0) | (0) | (0) | (1)
Genital System
Coagulating gland | (2) | (2) | (0) | (4)
Cyst | 2 (100%) | 1 (50%) | – | 3 (75%)
Bilateral, inflammation, chronic active | – | 1 (50%) | – | –
Epididymis | (90) | (89) | (90) | (90)
Granuloma sperm | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Infiltration cellular, lymphocyte | 29 (32%) | 17 (19%) | 22 (24%) | 28 (31%)
Spermatocele | – | – | – | 1 (1%)
Bilateral, duct, atrophy | – | – | – | 1 (1%)
Preputial gland | (89) | (88) | (90) | (89)
Infiltration cellular, lymphocyte | 43 (48%) | 32 (36%) | 38 (42%) | 33 (37%)
Inflammation, suppurative | 1 (1%) | – | – | –
Inflammation, chronic active | 1 (1%) | – | 1 (1%) | –
Bilateral, hyperplasia | – | – | 1 (1%) | –
Bilateral, duct, dilation | 6 (7%) | 2 (2%) | 9 (10%) | 2 (2%)
Duct, dilation | 10 (11%) | 6 (7%) | 11 (12%) | 4 (4%)
Duct, inflammation, chronic active | – | – | 1 (1%) | –
Duct, necrosis | 1 (1%) | – | – | –
Prostate | (90) | (87) | (90) | (87)
Hyperplasia, focal | – | – | – | 1 (1%)
Infiltration cellular, lymphocyte | 4 (4%) | 3 (3%) | 6 (7%) | 9 (10%)
Inflammation, acute | – | 1 (1%) | – | 5 (6%)
Inflammation, chronic active | 1 (1%) | – | 1 (1%) | –
Seminal vesicle | (90) | (88) | (90) | (90)
Dilation | 4 (4%) | 4 (5%) | 5 (6%) | 4 (4%)
Hyperplasia | – | – | – | 1 (1%)
Inflammation, chronic active | 1 (1%) | 1 (1%) | – | –
Bilateral, atrophy | – | – | – | 1 (1%)
Bilateral, dilation | 27 (30%) | 26 (30%) | 23 (26%) | 29 (32%)
Bilateral, fibrosis | – | – | – | 1 (1%)
Bilateral, inflammation, acute | – | – | – | 1 (1%)
Bilateral, inflammation, chronic | – | 1 (1%) | 1 (1%) | –
Bilateral, inflammation, chronic active | – | – | – | 1 (1%)
Testis | (90) | (88) | (90) | (90)
Bilateral, germ cell, degeneration | – | – | – | 1 (1%)
Germ cell, degeneration | 2 (2%) | 1 (1%) | 1 (1%) | –
Hematopoietic System
Bone marrow | (90) | (88) | (90) | (90)
Hypercellularity | 3 (3%) | – | 2 (2%) | 3 (3%)
Lymph node | (6) | (8) | (7) | (9)
Bronchial, infiltration cellular, mixed cell | – | – | – | 1 (11%)
Iliac, erythrophagocytosis | – | 1 (13%) | – | –
Iliac, hemorrhage | – | 1 (13%) | – | –
Iliac, hyperplasia, lymphoid | – | 1 (13%) | – | 2 (22%)
Iliac, infiltration cellular, histiocyte | – | 2 (25%) | 2 (29%) | –
Iliac, infiltration cellular, plasma cell | – | – | – | 1 (11%)
Iliac, pigment | – | – | 2 (29%) | –
Lumbar, hemorrhage | – | – | – | 1 (11%)
Mediastinal, hyperplasia, lymphoid | – | – | – | 1 (11%)
Mediastinal, infiltration cellular, plasma cell | – | 1 (13%) | – | –
Pancreatic, hyperplasia, lymphoid | – | – | 2 (29%) | –
Renal, hemorrhage | 1 (17%) | – | 1 (14%) | –
Renal, hyperplasia, lymphoid | – | – | 1 (14%) | –
Renal, infiltration cellular, mixed cell | – | – | – | 1 (11%)
Lymph node, mandibular | (72) | (61) | (63) | (60)
Hemorrhage | – | 1 (2%) | – | –
Hyperplasia, lymphoid | 2 (3%) | – | – | –
Infiltration cellular, histiocyte | 1 (1%) | – | – | 1 (2%)
Lymph node, mesenteric | (85) | (82) | (88) | (83)
Erythrophagocytosis | 1 (1%) | 5 (6%) | 4 (5%) | 1 (1%)
Hemorrhage | 10 (12%) | 11 (13%) | 7 (8%) | 13 (16%)
Hyperplasia, lymphoid | 4 (5%) | 2 (2%) | 2 (2%) | 5 (6%)
Infiltration cellular, histiocyte | 8 (9%) | 7 (9%) | 5 (6%) | 4 (5%)
Infiltration cellular, mixed cell | – | 2 (2%) | – | –
Infiltration cellular, plasma cell | 1 (1%) | 1 (1%) | 1 (1%) | 1 (1%)
Spleen | (87) | (88) | (89) | (88)
Extramedullary hematopoiesis | 15 (17%) | 15 (17%) | 13 (15%) | 12 (14%)
Hyperplasia, lymphoid | 5 (6%) | 2 (2%) | 5 (6%) | 3 (3%)
White pulp, atrophy | – | – | 1 (1%) | –
Thymus | (75) | (83) | (81) | (72)
Atrophy | 11 (15%) | 16 (19%) | 4 (5%) | 14 (19%)
Cyst | 11 (15%) | 16 (19%) | 26 (32%) | 15 (21%)
Hemorrhage | 1 (1%) | 1 (1%) | 1 (1%) | –
Infiltration cellular, histiocyte | – | – | – | 1 (1%)
Integumentary System
Mammary gland | (2) | (5) | (2) | (8)
Skin | (90) | (89) | (90) | (90)
Cyst, squamous | – | – | – | 1 (1%)
Hyperkeratosis | – | 1 (1%) | – | –
Infiltration cellular, mixed cell | 1 (1%) | – | – | –
Inflammation, chronic | – | 1 (1%) | – | –
Ulcer | 2 (2%) | 2 (2%) | 2 (2%) | 1 (1%)
Epidermis, hyperplasia, focal | – | 1 (1%) | – | –
Hair follicle, atrophy | – | – | – | 2 (2%)
Subcutaneous tissue, inflammation, granulomatous | – | – | 1 (1%) | –
Musculoskeletal System
Bone | (90) | (88) | (90) | (90)
Callus | – | – | – | 1 (1%)
Increased bone | – | – | 1 (1%) | –
Skeletal muscle | (90) | (89) | (90) | (90)
Degeneration | 1 (1%) | – | – | 1 (1%)
Infiltration cellular, lymphocyte | 3 (3%) | – | 5 (6%) | 5 (6%)
Inflammation, acute | – | 1 (1%) | – | 1 (1%)
Inflammation, chronic active | – | – | – | 1 (1%)
Necrosis | – | 1 (1%) | – | –
Nervous System
Brain | (90) | (89) | (90) | (90)
Hemorrhage | 2 (2%) | 2 (2%) | – | –
Infiltration cellular, lymphocyte | 1 (1%) | – | – | –
Inflammation, acute | – | 1 (1%) | – | –
Mineral | 79 (88%) | 81 (91%) | 80 (89%) | 76 (84%)
Squamous cyst | – | – | 1 (1%) | –
Artery, meninges, inflammation, chronic active | 1 (1%) | – | – | 1 (1%)
Brain trigeminal ganglion | (69) | (79) | (72) | (79)
Nerve trigeminal | (67) | (53) | (66) | (63)
Peripheral nerve, sciatic | (89) | (89) | (90) | (89)
Axon, degeneration | 9 (10%) | 9 (10%) | 9 (10) | 4 (4%)
Spinal cord | (90) | (89) | (90) | (90)
Cyst, squamous | – | – | 1 (1%) | –
Degeneration | – | 1 (1%) | – | –
Hemorrhage | – | 1 (1%) | – | –
Necrosis | 1 (1%) | 1 (1%) | – | 1 (1%)
Artery, meninges, inflammation, chronic active | 1 (1%) | – | 2 (2%) | 1 (1%)
Respiratory System
Lung | (90) | (89) | (90) | (90)
Congestion | 2 (2%) | 2 (2%) | 3 (3%) | 3 (3%)
Hemorrhage | 3 (3%) | 5 (6%) | 4 (4%) | 3 (3%)
Infiltration cellular, histiocyte | 6 (7%) | 1 (1%) | 1 (1%) | 2 (2%)
Infiltration cellular, lymphocyte | 1 (1%) | – | 1 (1%) | –
Infiltration, chronic active | – | 1 (1%) | – | –
Alveolar epithelium, hyperplasia, focal | 6 (7%) | 8 (9%) | 8 (9%) | 7 (8%)
Bronchiole, foreign body | 1 (1%) | – | – | –
Bronchiole, inflammation, suppurative | 1 (1%) | – | – | –
Mediastinum | (0) | (0) | (2) | (1)
Nose | (90) | (89) | (90) | (89)
Inflammation, acute | 1 (1%) | – | – | –
Respiratory epithelium, accumulation, hyaline droplet | 1 (1%) | – | – | –
Respiratory epithelium, hyperplasia | 5 (6%) | – | – | –
Vomeronasal organ, fibrosis | 1 (1%) | – | – | –
Trachea | (90) | (89) | (89) | (90)
Special Senses System
Eye | (90) | (89) | (90) | (90)
Phthisis bulbi | – | 1 (1%) | 3 (3%) | 1 (1%)
Cornea, fibrosis | 1 (1%) | – | – | –
Cornea, inflammation, chronic active | – | – | – | 1 (1%)
Optic nerve, degeneration | – | – | 1 (1%) | –
Retina, atrophy | – | – | – | 1 (1%)
Retina, degeneration | – | – | 1 (1%) | –
Harderian gland | (88) | (89) | (90) | (90)
Hemorrhage | 1 (1%) | – | – | –
Hyperplasia, focal | 2 (2%) | 1 (1%) | 2 (2%) | 1 (1%)
Infiltration cellular, lymphocyte | 36 (41%) | 36 (40%) | 32 (36%) | 40 (44%)
Urinary System
Kidney | (90) | (89) | (90) | (89)
Bacteria | – | 1 (1%) | – | –
Infarct | 7 (8%) | 4 (4%) | 4 (4%) | 8 (9%)
Infiltration cellular, histiocyte | – | 1 (1%) | – | –
Infiltration cellular, mixed cell | – | 1 (1%) | – | –
Inflammation, suppurative | 1 (1%) | – | – | –
Inflammation, granulomatous | 1 (1%) | – | – | –
Inflammation, acute | – | 1 (1%) | – | –
Metaplasia, osseous | 3 (3%) | 6 (7%) | 5 (6%) | 1 (1%)
Mineral | – | 2 (2%) | – | –
Nephropathy, chronic progressive | 74 (82%) | 66 (74%) | 76 (84%) | 74 (83%)
Bilateral, bacteria | – | 1 (1%) | – | –
Bilateral, inflammation, acute | – | 1 (1%) | – | 1 (1%)
Bilateral, renal tubule, bacteria | – | – | – | 1 (1%)
Bilateral, renal tubule, pigment | – | 1 (1%) | – | 1 (1%)
Glomerulus, cyst | 1 (1%) | – | – | 1 (1%)
Interstitium, infiltration cellular, lymphocyte | 41 (46%) | 50 (56%) | 56 (62%) | 44 (49%)
Pelvis, dilation | 1 (1%) | – | – | 1 (1%)
Renal tubule, accumulation, hyaline droplet | – | – | – | 1 (1%)
Renal tubule, bacteria | – | 1 (1%) | – | –
Renal tubule, cyst | 8 (9%) | 3 (3%) | 4 (4%) | 5 (6%)
Renal tubule, dilation | – | – | – | 1 (1%)
Renal tubule, mineral | 1 (1%) | – | – | 4 (4%)
Urothelium, inflammation, chronic active | 1 (1%) | – | – | –
Urinary bladder | (87) | (88) | (90) | (89)
Hemorrhage | 3 (3%) | – | – | –
Infiltration cellular, lymphocyte | 26 (30%) | 20 (23%) | 24 (27%) | 21 (24%)
Inflammation, acute | – | 1 (1%) | – | –
Inflammation, chronic active | – | 1 (1%) | – | –
Transitional epithelium, hyperplasia, diffuse | – | 1 (1%) | – | –
Transitional epithelium, hyperplasia, multifocal | – | 2 (2%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.