# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-DATA-TR595

Report Series: NTP Technical Report Series

Report Series Number: 595

Official citation: National Toxicology Program (NTP). 2018. Technical report on the toxicology and carcinogenesis studies in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats exposed to whole-body radio frequency radiation at a frequency (900 Mhz) and modulations (GSM and CDMA) used by cell phones. Research Triangle Park, NC: National Toxicology Program. NTP Technical Report 595.