# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats Exposed to Whole-body Radio Frequency Radiation at a Frequency (900 Mhz) and Modulations (GSM and CDMA) Used by Cell Phones on March 26–28, 2018, are listed below. Panel members served as independent scientists, not as representatives of any institution, company, or governmental agency. The panel was divided into two groups. Panel 1 provided consultation on the reverberation chamber technology and Panel 2 provided recommendations on the study findings and NTP’s draft conclusions. In this capacity, reviewers were charged to:

Panel 1:

- Assess the reverberation chamber technology for evaluating the effects of cell phone radiofrequency radiation exposure in rats.

Panel 2:

- Review and evaluate the scientific and technical elements of the study and its presentation.
- Determine whether the study’s experimental design, conduct, and findings support NTP’s conclusions regarding the carcinogenic activity and toxicity of the test agent.

## Peer Reviewers

- David L. Eaton, Ph.D., Chair
  University of Washington
  Seattle, Washington, USA

## Peer Review Panel 1

- Frank S. Barnes, Ph.D.
  University of Colorado (retired)
  Boulder, Colorado, USA
- Asimina Kiourti, Ph.D.
  The Ohio State University (present for Days 1 and 2)
  Columbus, Ohio, USA
- James Lin, Ph.D.
  University of Illinois at Chicago (retired)
  Chicago, Illinois, USA

## Peer Review Panel 2

- Rick Adler, D.V.M., Ph.D.
  GlaxoSmithKline
  King of Prussia, Pennsylvania, USA
- Lydia Andrews-Jones, D.V.M., Ph.D.
  Allergan, Inc.
  Irvine, California, USA
- J. Mark Cline, D.V.M., Ph.D.
  Wake Forest School of Medicine
  Winston-Salem, North Carolina, USA
- George B. Corcoran, Ph.D.
  Wayne State University
  Detroit, Michigan, USA
- Susan P. Felter, Ph.D.
  Procter & Gamble
  Cincinnati, Ohio, USA
- Jack R. Harkema, D.V.M., Ph.D.
  Michigan State University
  East Lansing, Michigan, USA
- Wolfgang Kaufmann, D.V.M., Ph.D.
  Merck Group (retired)
  Bad Dürkheim, Germany
- Tyler Malys, Ph.D.
  Data Management Services
  Frederick, Maryland, USA
- Kamala Pant, M.S.
  BioReliance
  Washington, District of Columbia, USA
- Matthias Rinke, D.V.M., Ph.D.
  Bayer Pharma AG (retired)
  Wülfrath, Germany
- Laurence Whiteley, D.V.M., Ph.D.
  Pfizer
  Boston, Massachusetts, USA