# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M.E. Wyde, Ph.D., Study Scientist
  M.F. Cesta, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, Ph.D.
  J.R. Bucher, Ph.D.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  G.K. Roberts, Ph.D.
  K.R. Shockley, Ph.D.
  R.C. Sills, D.V.M., Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Management of peer review of draft document
  M.S. Wolfe, Ph.D.
- Oversight for data management
  J.M. Fostel, Ph.D.
- Coordinated Pathology Peer Reviews and Pathology Working Groups (January 29, February 11, 12, and 25, March 3 and 23, and April 11, 2016, and April 26 and 27, 2017)
  M.F. Cesta, D.V.M., Ph.D.
- IIT Research Institute, Chicago, Illinois, USA
  Conducted studies
  D.L. McCormick, Ph.D., Principal Investigator
  T.L. Horn, Ph.D., Study Director
  J.R. Gauger, B.S., Engineer
- IT’IS Foundation, Zurich, Switzerland
  Constructed and maintained exposure system
  N. Kuster, Ph.D.
  M. Capstick, Ph.D.
- National Institute of Standards and Technology, Boulder, Colorado, USA
  Conducted independent validation of the exposure system
  P.F. Wilson, Ph.D., Principle Investigator
  G. Koepke, M.S.
  J.M. Ladbury, M.S.
- Pathology Associates International, A Charles River Company, Research Triangle Park, North Carolina, USA
  Evaluated pathology findings
  J.S. Hoane, D.V.M., Ph.D., Principal Investigator
  J.M. Pletcher, D.V.M., M.P.H., Principal Investigator
  L. Brennecke, D.V.M.
  C. Detrisac, D.V.M., Ph.D.
- Evaluated sperm motility
  F.T. Les, M.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.E. Brix, D.V.M., Ph.D.
- Conducted pathology review
  T.A. Crabbs, D.V.M.
  M.M. Gruebbel, D.V.M., Ph.D.
  J.F. Hardisty, D.V.M.
  R.R. Maronpot, D.V.M., M.S., M.P.H.
  R.A. Miller, D.V.M., Ph.D.
  C.C. Shackelford, D.V.M., Ph.D.
- Coordinated Pathology Peer Reviews and Pathology Working Groups (January 29, February 11, 12, and 25, March 3 and 23, and April 11, 2016, and April 26 and 27, 2017)
  T.A. Crabbs, D.V.M.
  M.M. Gruebbel, D.V.M., Ph.D.
  G.A. Willson, D.V.M.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Peer Review (October 13, 2016)
  M.P. Jokinen, D.V.M.
- Conducted comet and micronucleus assays for male and female mice exposed to GSM- or CDMA-modulated cell phone RFR for 14 weeks
  L. Recio, Ph.D., Principle Investigator
  C.A. Hobbs, Ph.D., Laboratory Director
  A.S. Green, B.S.
  P.V. Garibaldi, B.S.
  C.A. Lentz, B.S.
  K.G. Shepard, B.S.
  J.W. Winters, B.S.
- RTI International, Research Triangle Park, North Carolina, USA
  Provided SMVCE analysis
  R.W. Tyl, Ph.D., Principal Investigator
  M.C. Marr, B.A.
  C.S. Sloan, M.S.