# References

1 Office of Engineering and Technology (OET). Questions and answers about biological effects and potential hazards of radiofrequency electromagnetic fields. Washington, DC: Federal Communications Commission; 1999. OET Bulletin 56, 4th ed. https://transition.fcc.gov/Bureaus/Engineering_Technology/Documents/bulletins/oet56/oet56e4.pdf
2 Buddhikot MM Kennedy I Mullany F Viswanathan H Ultra‐broadband femtocells via opportunistic reuse of multi‐operator and multi‐service spectrum. Bell Labs Tech J. 2009;13(4):129–143. 10.1002/bltj.20340
3 National Toxicology Program (NTP). Peer review of the draft NTP technical reports on cell phone radiofrequency radiation – March 26-28, 2018. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2018. https://ntp.niehs.nih.gov/about/org/sep/trpanel/meetings/docs/2018/march/videos/capstick-ladbury/index.html
4 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of carcinogenic risks to humans. Non-ionizing radiation, part 2: Radiofrequency electromagnetic fields. Vol. 102. Lyon, France: IARC; 2013.
5 Pew Research Center Survey. Mobile fact sheet: Internet and technology. Washington, DC: Pew Research Center; 2017. http://www.pewinternet.org/fact-sheet/mobile
6 Cellular Telecommunications Industry Association (CTIA). Annual wireless industry survey. 2017.
7 United States Code (USC). 42:§4321 et seq.
8 Code of Federal Regulations (CFR). 47:§1.1310.
9 Adair RK Biophysical limits on athermal effects of RF and microwave radiation. Bioelectromagnetics. 2003;24(1):39–48. 10.1002/bem.10061 12483664
10 Prohofsky EW RF absorption involving biological macromolecules. Bioelectromagnetics. 2004;25(6):441–451. 10.1002/bem.20013 15300730
11 Sheppard AR Swicord ML Balzano Q Quantitative evaluations of mechanisms of radiofrequency interactions with biological molecules and processes. Health Phys. 2008;95(4):365–396. 10.1097/01.HP.0000319903.20660.37 18784511
12 Manna D Ghosh R Effect of radiofrequency radiation in cultured mammalian cells: A review. Electromagn Biol Med. 2016;35(3):265–301. 10.3109/15368378.2015.1092158 27053138
13 Smialowicz RJ Rogers RR Garner RJ Riddle MM Luebke RW Rowe DG Microwaves (2,450 MHz) suppress murine natural killer cell activity. Bioelectromagnetics. 1983;4(4):371–381. 10.1002/bem.2250040408 6651889
14 Guy AW Chou C-K Kunz LL Crowley J Krupp J Summary. Vol. 9. Seattle (WA): University of Washington, School of Medicine, Department of Rehabilitation Medicine, Bioelectromagnetics Research Laboratory; 1985. (Effects of long-term low-level radio-frequency radiation exposure on rats.). http://www.dtic.mil/docs/citations/ADA159512.
15 Veyret B Bouthet C Deschaux P De Seze R Geffard M Joussot‐Dubien J Le Diraison M Moreau JM Caristan A Antibody responses of mice exposed to low‐power microwaves under combined, pulse‐and‐amplitude modulation. Bioelectromagnetics. 1991;12(1):47–56. 10.1002/bem.2250120107 2012621
16 Novoselova EG Fesenko EE Makar VR Sadovnikov VB Microwaves and cellular immunity: II. Immunostimulating effects of microwaves and naturally occurring antioxidant nutrients. Bioelectrochem Bioenerg. 1999;49(1):37–41. 10.1016/S0302-4598(99)00059-8 10619446
17 Lushnikov KV Gapeev AB Sadovnikov VB Cheremis NK Effect of extremely high frequency electromagnetic radiation of low intensity on parameters of humoral immunity in healthy mice [In Russian]. Biofizika. 2001;46(4):753–760. 11558390
18 Kolomytseva MP Gapeev AB Sadovnikov VB Chemeris NK Suppression of nonspecific resistance of the body under the effect of extremely high frequency electromagnetic radiation of low intensity [In Russian]. Biofizika. 2002;47(1):71–77. 11855293
19 Elekes E Thuróczy G Szabó LD Effect on the immune system of mice exposed chronically to 50 Hz amplitude‐modulated 2.45 GHz microwaves. Bioelectromagnetics. 1996; 17(3):246-248. 10.1002/(SICI)1521-186X(1996)17:3%3C246::AID-BEM11%3E3.0.CO;2-O
20 Chagnaud JL Veyret B In vivo exposure of rats to GSM-modulated microwaves: flow cytometry analysis of lymphocyte subpopulations and of mitogen stimulation. Int J Radiat Biol. 1999;75(1):111–113. 10.1080/095530099140861 9972797
21 Gatta L Pinto R Ubaldi V Pace L Galloni P Lovisolo GA Marino C Pioli C Effects of in vivo exposure to GSM-modulated 900 MHz radiation on mouse peripheral lymphocytes. Radiat Res. 2003;160(5):600–605. 10.1667/RR3078 14565821
22 Nasta F Prisco MG Pinto R Lovisolo GA Marino C Pioli C Effects of GSM-modu-lated radiofrequency electromagnetic fields on B cell peripheral differentiation and antibody production. Radiat Res. 2006;165(6):664–670. 10.1667/RR3555.1 16802866
23 Ohtani S Ushiyama A Maeda M Ogasawara Y Wang J Kunugita N Ishii K The effects of radio-frequency electromagnetic fields on T cell function during development. J Radiat Res (Tokyo). 2015;56(3):467–474. 10.1093/jrr/rru126 25835473
24 Fritze K Wiessner C Kuster N Sommer C Gass P Hermann DM Kiessling M Hossmann KA Effect of global system for mobile communication microwave exposure on the genomic response of the rat brain. Neuroscience. 1997;81(3):627–639. 10.1016/S0306-4522(97)00228-5 9316016
25 Belyaev IY Koch CB Terenius O Roxström‐Lindquist K Malmgren LOG H Sommer W Salford LG Persson BR H. Sommer W, Salford LG, Persson BRR. Exposure of rat brain to 915 MHz GSM microwaves induces changes in gene expression but not double stranded DNA breaks or effects on chromatin conformation. Bioelectromagnetics. 2006;27(4):295–306. 10.1002/bem.20216 16511873
26 Nittby H Widegren B Krogh M Grafström G Berlin H Rehn G Eberhardt JL Malmgren L Persson BRR Salford LG Exposure to radiation from global system for mobile communications at 1,800 MHz significantly changes gene expression in rat hippocampus and cortex. Environmentalist. 2008;28(4):458–465. 10.1007/s10669-008-9170-8
27 Stagg RB Hawel LH 3rd Pastorian K Cain C Adey WR Byus CV Effect of immobilization and concurrent exposure to a pulse-modulated microwave field on core body temperature, plasma ACTH and corticosteroid, and brain ornithine decarboxylase, Fos and Jun mRNA. Radiat Res. 2001;155(4):584–592. 10.1667/0033-7587(2001)155[0584:EOIACE]2.0.CO;2 11260660
28 Paparini A Rossi P Gianfranceschi G Brugaletta V Falsaperla R De Luca P Romano Spica V No evidence of major transcriptional changes in the brain of mice exposed to 1800 MHz GSM signal. Bioelectromagnetics. 2008;29(4):312–323. 10.1002/bem.20399 18175331
29 McNamee JP Bellier PV Konkle ATM Thomas R Wasoontarajaroen S Lemay E Gajda GB Analysis of gene expression in mouse brain regions after exposure to 1.9 GHz radiofrequency fields. Int J Radiat Biol. 2016;92(6):338–350. 10.3109/09553002.2016.1159353 27028625
30 Ammari M Lecomte A Sakly M Abdelmelek H de-Seze R Exposure to GSM 900 MHz electromagnetic fields affects cerebral cytochrome c oxidase activity. Toxicology. 2008;250(1):70–74. 10.1016/j.tox.2008.05.019 18585429
31 Ammari M Gamez C Lecomte A Sakly M Abdelmelek H De Seze R GFAP expression in the rat brain following sub-chronic exposure to a 900 MHz electromagnetic field signal. Int J Radiat Biol. 2010;86(5):367–375. 10.3109/09553000903567946 20397841
32 Dasdag S Akdag MZ Ulukaya E Uzunlar AK Ocak AR Effect of mobile phone exposure on apoptotic glial cells and status of oxidative stress in rat brain. Electromagn Biol Med. 2009;28(4):342–354. 10.3109/15368370903206556 20017625
33 Lee HJ Pack JK Kim TH Kim N Choi SY Lee JS Kim SH Lee YS The lack of histological changes of CDMA cellular phone‐based radio frequency on rat testis. Bioelectromagnetics. 2010;31(7):528–534. 10.1002/bem.20589 20607737
34 Masuda H Sanchez S Dulou PE Haro E Anane R Billaudel B Lévêque P Veyret B Effect of GSM-900 and -1800 signals on the skin of hairless rats. I: 2-hour acute exposures. Int J Radiat Biol. 2006;82(9):669–674. 10.1080/09553000600930079 17050479
35 Sanchez S Masuda H Billaudel B Haro E Anane R Lévêque P Ruffie G Lagroye I Veyret B Effect of GSM-900 and-1800 signals on the skin of hairless rats. II: 12-week chronic exposures. Int J Radiat Biol. 2006;82(9):675–680. 10.1080/09553000600930087 17050480
36 Sanchez S Masuda H Ruffie G De Gannes FP Billaudel B Haro E Lévêque P Lagroye I Veyret B Effect of GSM-900 and-1800 signals on the skin of hairless rats. III: expression of heat shock proteins. Int J Radiat Biol. 2008;84(1):61–68. 10.1080/09553000701616098 17852563
37 Liu Q Si T Xu X Liang F Wang L Pan S Electromagnetic radiation at 900 MHz induces sperm apoptosis through bcl-2, bax and caspase-3 signaling pathways in rats. Reprod Health. 2015;12(1):65. 10.1186/s12978-015-0062-3 26239320
38 Pyrpasopoulou A Kotoula V Cheva A Hytiroglou P Nikolakaki E Magras IN Xenos TD Tsiboukis TD Karkavelas G Bone morphogenetic protein expression in newborn rat kidneys after prenatal exposure to radiofrequency radiation. Bioelectromagnetics. 2004;25(3):216–227. 10.1002/bem.10185 15042631
39 Eşmekaya MA Seyhan N Ömeroğlu S Pulse modulated 900 MHz radiation induces hypothyroidism and apoptosis in thyroid cells: A light, electron microscopy and immunohistochemical study. Int J Radiat Biol. 2010;86(12):1106–1116. 10.3109/09553002.2010.502960 20807179
40 Ohtani S Ushiyama A Maeda M Hattori K Kunugita N Wang J Ishii K Exposure time-dependent thermal effects of radiofrequency electromagnetic field exposure on the whole body of rats. J Toxicol Sci. 2016;41(5):655–666. 10.2131/jts.41.655 27665775
41 Ilhan A Gurel A Armutcu F Kamisli S Iraz M Akyol O Ozen S Ginkgo biloba prevents mobile phone-induced oxidative stress in rat brain. Clin Chim Acta. 2004;340(1-2):153–162. 10.1016/j.cccn.2003.10.012 14734207
42 Meral I Mert H Mert N Deger Y Yoruk I Yetkin A Keskin S Effects of 900-MHz electromagnetic field emitted from cellular phone on brain oxidative stress and some vitamin levels of guinea pigs. Brain Res. 2007;1169:120–124. 10.1016/j.brainres.2007.07.015 17674954
43 Sokolovic D Djindjic B Nikolic J Bjelakovic G Pavlovic D Kocic G Krstic D Cvetkovic T Pavlovic V Melatonin reduces oxidative stress induced by chronic exposure of microwave radiation from mobile phones in rat brain. J Radiat Res (Tokyo). 2008;49(6):579–586. 10.1269/jrr.07077 18827438
44 İmge EB KiliçoĞlu B, Devrim E, Çetin R, Durak I. Effects of mobile phone use on brain tissue from the rat and a possible protective role of vitamin C–a preliminary study. Int J Radiat Biol. 2010;86(12):1044–1049. 10.3109/09553002.2010.501838 20698742
45 Ozguner F Altinbas A Ozaydin M Dogan A Vural H Kisioglu AN Cesur G Yildirim NG Mobile phone-induced myocardial oxidative stress: protection by a novel antioxidant agent caffeic acid phenethyl ester. Toxicol Ind Health. 2005;21(7-8):223–230. 10.1191/0748233705th228oa 16342473
46 Oktem F Ozguner F Mollaoglu H Koyu A Uz E Oxidative damage in the kidney induced by 900-MHz-emitted mobile phone: protection by melatonin. Arch Med Res. 2005;36(4):350–355. 10.1016/j.arcmed.2005.03.021 15950073
47 Ozguner F Oktem F Armagan A Yilmaz R Koyu A Demirel R Vural H Uz E Comparative analysis of the protective effects of melatonin and caffeic acid phenethyl ester (CAPE) on mobile phone-induced renal impairment in rat. Mol Cell Biochem. 2005;276(1-2):31–37. 10.1007/s11010-005-2734-8 16132682
48 Ozguner F Bardak Y Comlekci S Protective effects of melatonin and caffeic acid phenethyl ester against retinal oxidative stress in long-term use of mobile phone: A comparative study. Mol Cell Biochem. 2006;282(1-2):83–88. 10.1007/s11010-006-1267-0 16317515
49 Ozgur E Güler G Seyhan N Mobile phone radiation-induced free radical damage in the liver is inhibited by the antioxidants N-acetyl cysteine and epigallocatechin-gallate. Int J Radiat Biol. 2010;86(11):935–945. 10.3109/09553002.2010.496029 20807176
50 Tomruk A Guler G Dincel AS The influence of 1800 MHz GSM-like signals on hepatic oxidative DNA and lipid damage in nonpregnant, pregnant, and newly born rabbits. Cell Biochem Biophys. 2010;56(1):39–47. 10.1007/s12013-009-9068-1 19851891
51 Oral B Guney M Ozguner F Karahan N Mungan T Comlekci S Cesur G Endometrial apoptosis induced by a 900-MHz mobile phone: preventive effects of vitamins E and C. Adv Ther. 2006;23(6):957–973. 10.1007/BF02850217 17276964
52 Guney M Ozguner F Oral B Karahan N Mungan T 900 MHz radiofrequency-induced histopathologic changes and oxidative stress in rat endometrium: Protection by vitamins E and C. Toxicol Ind Health. 2007;23(7):411–420. 10.1177/0748233707080906 18536493
53 Mailankot M Kunnath AP Jayalekshmi H Koduru B Valsalan R Radio frequency electromagnetic radiation (RF-EMR) from GSM (0.9/1.8 GHz) mobile phones induces oxidative stress and reduces sperm motility in rats. Clinics (São Paulo). 2009;64(6):561–565. 10.1590/S1807-59322009000600011 19578660
54 Yakymenko I Tsybulin O Sidorik E Henshel D Kyrylenko O Kyrylenko S Oxidative mechanisms of biological activity of low-intensity radiofrequency radiation. Electromagn Biol Med. 2016;35(2):186–202. 10.3109/15368378.2015.1043557 26151230
55 Sonmez OF Odaci E Bas O Kaplan S Purkinje cell number decreases in the adult female rat cerebellum following exposure to 900 MHz electromagnetic field. Brain Res. 2010;1356:95–101. 10.1016/j.brainres.2010.07.103 20691167
56 Eberhardt JL Persson BRR Brun AE Salford LG Malmgren LOG Blood-brain barrier permeability and nerve cell damage in rat brain 14 and 28 days after exposure to microwaves from GSM mobile phones. Electromagn Biol Med. 2008;27(3):215–229. 10.1080/15368370802344037 18821198
57 Nittby H Brun A Eberhardt J Malmgren L Persson BRR Salford LG Increased blood–brain barrier permeability in mammalian brain 7 days after exposure to the radiation from a GSM-900 mobile phone. Pathophysiology. 2009;16(2-3):103–112. 19345073
58 Nittby H Brun A Strömblad S Moghadam MK Sun W Malmgren L Eberhardt J Persson BR Salford LG Nonthermal GSM RF and ELF EMF effects upon rat BBB permeability. Environmentalist. 2011;31(2):140–148. 10.1007/s10669-011-9307-z
59 Grafström G Nittby H Brun A Malmgren L Persson BRR Salford LG Eberhardt J Histopathological examinations of rat brains after long-term exposure to GSM-900 mobile phone radiation. Brain Res Bull. 2008;77(5):257–263. 10.1016/j.brainresbull.2008.08.004 18782606
60 de Gannes FP Billaudel B Taxile M Haro E Ruffié G Lévêque P Veyret B Lagroye I Effects of head-only exposure of rats to GSM-900 on blood-brain barrier permeability and neuronal degeneration. Radiat Res. 2009;172(3):359–367. 10.1667/RR1578.1 19708785
61 McQuade JMS Merritt JH Miller SA Scholin T Cook MC Salazar A Rahimi OB Murphy MR Mason PA Radiofrequency-radiation exposure does not induce detectable leakage of albumin across the blood-brain barrier. Radiat Res. 2009;171(5):615–621. 10.1667/RR1507.1 19580497
62 Masuda H Ushiyama A Takahashi M Wang J Fujiwara O Hikage T Nojima T Fujita K Kudo M Ohkubo C Effects of 915 MHz electromagnetic-field radiation in TEM cell on the blood-brain barrier and neurons in the rat brain. Radiat Res. 2009;172(1):66–73. 10.1667/RR1542.1 19580508
63 Frey AH Headaches from cellular telephones: are they real and what are the implications? Environ Health Perspect. 1998;106(3):101–103. 10.1289/ehp.98106101 9441959
64 Chia S-E Chia H-P Tan J-S Prevalence of headache among handheld cellular telephone users in Singapore: A community study. Environ Health Perspect. 2000;108(11):1059–1062. 10.1289/ehp.001081059 11102297
65 Hocking B Westerman R Neurological abnormalities associated with mobile phone use. Occup Med. 2000;50(5):366–368. 10.1093/occmed/50.5.366 10975136
66 Sandström M Wilen J Hansson Mild K Oftedal G Mobile phone use and subjective symptoms. Comparison of symptoms experienced by users of analogue and digital mobile phones. Occup Med. 2001;51(1):25–35. 10.1093/occmed/51.1.25 11235824
67 Santini R Santini P Danze JM Le Ruz P Seigne M Investigation on the health of people living near mobile telephone relay stations: I/Incidence according to distance and sex [In French]. Pathol Biol (Paris). 2002;50(6):369–373. 10.1016/S0369-8114(02)00311-5 12168254
68 Santini R Seigne M Bonhomme-Faivre L Bouffet S Defrasne E Sage M Symptoms experienced by users of digital cellular phones: A study of a French engineering school. Electromagn Biol Med. 2002;21(1):81–88. 10.1081/JBC-120003113
69 Kwon MS Hämäläinen H Effects of mobile phone electromagnetic fields: critical evaluation of behavioral and neurophysiological studies. Bioelectromagnetics. 2011;32(4):253–272. 10.1002/bem.20635 21452356
70 Mann K Röschke J Effects of pulsed high-frequency electromagnetic fields on human sleep. Neuropsychobiology. 1996;33(1):41–47. 10.1159/000119247 8821374
71 Wagner P Röschke J Mann K Hiller W Frank C Human sleep under the influence of pulsed radiofrequency electromagnetic fields: A polysomnographic study using standardized conditions. Bioelectromagnetics. 1998; 19(3):199-202. 10.1002/(SICI)1521-186X(1998)19:3<199::AID-BEM8>3.0.CO;2-X
72 Borbély AA Huber R Graf T Fuchs B Gallmann E Achermann P Pulsed high-frequency electromagnetic field affects human sleep and sleep electroencephalogram. Neurosci Lett. 1999;275(3):207–210. 10.1016/S0304-3940(99)00770-3 10580711
73 Huber R Graf T Cote KA Wittmann L Gallmann E Matter D Schuderer J Kuster N Borbély AA Achermann P Exposure to pulsed high-frequency electromagnetic field during waking affects human sleep EEG. Neuroreport. 2000;11(15):3321–3325. 10.1097/00001756-200010200-00012 11059895
74 Huber R Treyer V Borbély AA Schuderer J Gottselig JM Landolt HP Werth E Berthold T Kuster N Buck A Electromagnetic fields, such as those from mobile phones, alter regional cerebral blood flow and sleep and waking EEG. J Sleep Res. 2002;11(4):289–295. 10.1046/j.1365-2869.2002.00314.x 12464096
75 Huber R Schuderer J Graf T Jütz K Borbély AA Kuster N Achermann P Radio frequency electromagnetic field exposure in humans: estimation of SAR distribution in the brain, effects on sleep and heart rate. Bioelectromagnetics. 2003;24(4):262–276. 10.1002/bem.10103 12696086
76 Loughran SP Wood AW Barton JM Croft RJ Thompson B Stough C The effect of electromagnetic fields emitted by mobile phones on human sleep. Neuroreport. 2005;16(17):1973–1976. 10.1097/01.wnr.0000186593.79705.3c 16272890
77 Hung C-S Anderson C Horne JA McEvoy P Mobile phone ‘talk-mode’ signal delays EEG-determined sleep onset. Neurosci Lett. 2007;421(1):82–86. 10.1016/j.neulet.2007.05.027 17548154
78 Regel SJ Tinguely G Schuderer J Adam M Kuster N Landolt HP Achermann P Pulsed radio‐frequency electromagnetic fields: dose‐dependent effects on sleep, the sleep EEG and cognitive performance. J Sleep Res. 2007;16(3):253–258. 10.1111/j.1365-2869.2007.00603.x 17716273
79 Lowden A Åkerstedt T Ingre M Wiholm C Hillert L Kuster N Nilsson JP Arnetz B Sleep after mobile phone exposure in subjects with mobile phone‐related symptoms. Bioelectromagnetics. 2011;32(1):4–14. 10.1002/bem.20609 20857453
80 Wagner P Röschke J Mann K Fell J Hiller W Frank C Grözinger M Human sleep EEG under the influence of pulsed radio frequency electromagnetic fields. Neuropsychobiology. 2000;42(4):207–212. 10.1159/000026695 11096337
81 Volkow ND Tomasi D Wang G-J Vaska P Fowler JS Telang F Alexoff D Logan J Wong C Effects of cell phone radiofrequency signal exposure on brain glucose metabolism. JAMA. 2011;305(8):808–813. 10.1001/jama.2011.186 21343580
82 Lin JC Cancer occurrences in laboratory rats from exposure to RF and microwave radiation. IEEE J Electromagn RF Microw Med Biol. 2017;1(1):2–13. 10.1109/JERM.2017.2721427 30215027
83 Repacholi MH Lerchl A Röösli M Sienkiewicz Z Auvinen A Breckenkamp J d’Inzeo G Elliott P Frei P Heinrich S Systematic review of wireless phone use and brain cancer and other head tumors. Bioelectromagnetics. 2012;33(3):187–206. 10.1002/bem.20716 22021071
84 Yang M Guo W Yang C Tang J Huang Q Feng S Jiang A Xu X Jiang G Mobile phone use and glioma risk: A systematic review and meta-analysis. PLoS One. 2017;12(5):e0175136. 10.1371/journal.pone.0175136 28472042
85 Tillmann T Ernst H Ebert S Kuster N Behnke W Rittinghausen S Dasenbrock C Carcinogenicity study of GSM and DCS wireless communication signals in B6C3F1 mice. Bioelectromagnetics. 2007;28(3):173–187. 10.1002/bem.20283 17019729
86 La Regina M Moros EG Pickard WF Straube WL Baty J Roti Roti JL The effect of chronic exposure to 835.62 MHz FDMA or 847.74 MHz CDMA radiofrequency radiation on the incidence of spontaneous tumors in rats. Radiat Res. 2003;160(2):143–151. 10.1667/RR3028 12859224
87 Smith P Kuster N Ebert S Chevalier H-J GSM and DCS wireless communication signals: combined chronic toxicity/carcinogenicity study in the Wistar rat. Radiat Res. 2007;168(4):480–492. 10.1667/RR0680.1 17903030
88 Utteridge TD Gebski V Finnie JW Vernon-Roberts B Kuchel TR Long-term exposure of Eμ-Pim1 transgenic mice to 898.4 MHz microwaves does not increase lymphoma incidence. Radiat Res. 2002;158(3):357–364. 10.1667/0033-7587(2002)158[0357:LTEOEP]2.0.CO;2 12175314
89 Sommer AM Streckert J Bitz AK Hansen VW Lerchl A No effects of GSM-modulated 900 MHz electromagnetic fields on survival rate and spontaneous development of lymphoma in female AKR/J mice. BMC Cancer. 2004;4(1):77. 10.1186/1471-2407-4-77 15538947
90 Sommer AM Bitz AK Streckert J Hansen VW Lerchl A Lymphoma development in mice chronically exposed to UMTS-modulated radiofrequency electromagnetic fields. Radiat Res. 2007;168(1):72–80. 10.1667/RR0857.1 17723000
91 Oberto G Rolfo K Yu P Carbonatto M Peano S Kuster N Ebert S Tofani S Carcinogenicity study of 217 Hz pulsed 900 MHz electromagnetic fields in Pim1 transgenic mice. Radiat Res. 2007;168(3):316–326. 10.1667/rr0425.1 17705642
92 Lee HJ Jin YB Lee JS Choi SY Kim TH Pack JK Choi HD Kim N Lee YS Lymphoma development of simultaneously combined exposure to two radiofrequency signals in AKR/J mice. Bioelectromagnetics. 2011;32(6):485–492. 10.1002/bem.20655 21437920
93 International Agency for Research on Cancer (IARC). IARC report to the Union for International Cancer Control (UICC) on the interphone study. Lyon, France: IARC; 2011. http://interphone.iarc.fr/UICC_Report_Final_03102011.pdf
94 Cardis E Richardson L Deltour I Armstrong B Feychting M Johansen C Kilkenny M McKinney P Modan B Sadetzki S The INTERPHONE study: Design, epidemiological methods, and description of the study population. Eur J Epidemiol. 2007;22(9):647–664. 10.1007/s10654-007-9152-z 17636416
95 INTERPHONE Study Group. Brain tumour risk in relation to mobile telephone use: results of the INTERPHONE international case–control study. Int J Epidemiol. 2010;39(3):675–694. 10.1093/ije/dyq079 20483835
96 INTERPHONE Study Group. Acoustic neuroma risk in relation to mobile telephone use: results of the INTERPHONE international case–control study. Cancer Epidemiol. 2011;35(5):453–464. 10.1016/j.canep.2011.05.012 21862434
97 Saika K Katanoda K Comparison of time trends in brain and central nervous system cancer mortality (1990–2006) between countries based on the WHO mortality database. Jap J Clin Oncol. 2011; 41(2):304-305. 10.1093/jjco/hyr004
98 Lönn S Klaeboe L Hall P Mathiesen T Auvinen A Christensen HC Johansen C Salminen T Tynes T Feychting M Incidence trends of adult primary intracerebral tumors in four Nordic countries. Int J Cancer. 2004;108(3):450–455. 10.1002/ijc.11578 14648713
99 Nelson PD Toledano MB McConville J Quinn MJ Cooper N Elliott P Trends in acoustic neuroma and cellular phones: is there a link? Neurology. 2006;66(2):284–285. 10.1212/01.wnl.0000194218.79519.ea 16434678
100 Röösli M Michel G Kuehni CE Spoerri A Cellular telephone use and time trends in brain tumour mortality in Switzerland from 1969 to 2002. Eur J Cancer Prev. 2007;16(1):77–82. 10.1097/01.cej.0000203618.61936.cd 17220708
101 Deltour I Johansen C Auvinen A Feychting M Klaeboe L Schüz J Time trends in brain tumor incidence rates in Denmark, Finland, Norway, and Sweden, 1974–2003. J Natl Cancer Inst. 2009;101(24):1721–1724. 10.1093/jnci/djp415 19959779
102 de Vocht F Burstyn I Cherrie JW Time trends (1998–2007) in brain cancer incidence rates in relation to mobile phone use in England. Bioelectromagnetics. 2011;32(5):334–339. 10.1002/bem.20648 21280060
103 Muscat JE Hinsvark M Malkin M Mobile telephones and rates of brain cancer. Neuroepidemiology. 2006;27(1):55–56. 10.1159/000094381 16825795
104 Propp JM McCarthy BJ Davis FG Preston-Martin S Descriptive epidemiology of vestibular schwannomas. Neuro-oncol. 2006;8(1):1–11. 10.1215/S1522851704001097 16443943
105 Inskip PD Hoover RN Devesa SS Brain cancer incidence trends in relation to cellular telephone use in the United States. Neuro-oncol. 2010;12(11):1147–1151. 10.1093/neuonc/noq077 20639214
106 Nomura E Ioka A Tsukuma H Trends in the incidence of primary intracranial tumors in Osaka, Japan. Jap J Clin Oncol. 2011; 41(2):291-294. 10.1093/jjco/hyq204
107 Cook A Woodward A Pearce N Marshall C Cellular telephone use and time trends for brain, head and neck tumours. N Z Med J. 2003;116(1175):U457. 12838353
108 Czerninski R Zini A Sgan-Cohen HD Risk of parotid malignant tumors in Israel (1970–2006). Epidemiology. 2011;22(1):130–131. 10.1097/EDE.0b013e3181feb9f0 21150362
109 Johansen C Boice JD Jr McLaughlin JK Olsen JH Cellular telephones and cancer—a nationwide cohort study in Denmark. J Natl Cancer Inst. 2001;93(3):203–207. 10.1093/jnci/93.3.203 11158188
110 Schüz J Jacobsen R Olsen JH Boice JD Jr McLaughlin JK Johansen C Cellular telephone use and cancer risk: update of a nationwide Danish cohort. J Natl Cancer Inst. 2006;98(23):1707–1713. 10.1093/jnci/djj464 17148772
111 Schüz J Elliott P Auvinen A Kromhout H Poulsen AH Johansen C Olsen JH Hillert L Feychting M Fremling K An international prospective cohort study of mobile phone users and health (Cosmos): design considerations and enrolment. Cancer Epidemiol. 2011;35(1):37–43. 10.1016/j.canep.2010.08.001 20810339
112 Takebayashi T Varsier N Kikuchi Y Wake K Taki M Watanabe S Akiba S Yamaguchi N Mobile phone use, exposure to radiofrequency electromagnetic field, and brain tumour: A case–control study. Br J Cancer. 2008;98(3):652–659. 10.1038/sj.bjc.6604214 18256587
113 Schoemaker MJ Swerdlow AJ Risk of pituitary tumors in cellular phone users: A case-control study. Epidemiology. 2009;20(3):348–354. 10.1097/EDE.0b013e31819c7ba8 19279493
114 Hardell L Carlberg M Ohlson CG Westberg H Eriksson M Hansson Mild K Use of cellular and cordless telephones and risk of testicular cancer. Int J Androl. 2007;30(2):115–122. 10.1111/j.1365-2605.2006.00721.x 17209885
115 Hardell L Hallquist A Mild KH Carlberg M Gertzen H Schildt E-B Dahlqvist Å No association between the use of cellular or cordless telephones and salivary gland tumours. Occup Environ Med. 2004;61(8):675–679. 10.1136/oem.2003.011262 15258273
116 Lönn S Ahlbom A Christensen HC Johansen C Schüz J Edström S Henriksson G Lundgren J Wennerberg J Feychting M Mobile phone use and risk of parotid gland tumor. Am J Epidemiol. 2006;164(7):637–643. 10.1093/aje/kwj242 16818464
117 Stang A Schmidt-Pokrzywniak A Lash TL Lommatzsch PK Taubert G Bornfeld N Jöckel K-H Mobile phone use and risk of uveal melanoma: results of the risk factors for uveal melanoma case-control study. J Natl Cancer Inst. 2009;101(2):120–123. 10.1093/jnci/djn441 19141780
118 Hardell L Carlberg M Mild KH Eriksson M Case-control study on the use of mobile and cordless phones and the risk for malignant melanoma in the head and neck region. Pathophysiology. 2011;18(4):325–333. 10.1016/j.pathophys.2011.06.001 21764571
119 Hardell L Eriksson M Carlberg M Sundström C Mild KH Use of cellular or cordless telephones and the risk for non-Hodgkin’s lymphoma. Int Arch Occup Environ Health. 2005;78(8):625–632. 10.1007/s00420-005-0003-5 16001209
120 Linet MS Taggart T Severson RK Cerhan JR Cozen W Hartge P Colt J Cellular telephones and non‐Hodgkin lymphoma. Int J Cancer. 2006;119(10):2382–2388. 10.1002/ijc.22151 16894556
121 Kaufman DW Anderson TE Issaragrisil S Risk factors for leukemia in Thailand. Ann Hematol. 2009;88(11):1079–1088. 10.1007/s00277-009-0731-9 19294385
122 Aydin D Feychting M Schüz J Tynes T Andersen TV Schmidt LS Poulsen AH Johansen C Prochazka M Lannering B Mobile phone use and brain tumors in children and adolescents: A multicenter case–control study. J Natl Cancer Inst. 2011;103(16):1264–1276. 10.1093/jnci/djr244 21795665
123 Hardell L Carlberg M Mild KH Use of mobile phones and cordless phones is associated with increased risk for glioma and acoustic neuroma. Pathophysiology. 2013;20(2):85–110. 23261330
124 Hardell L Carlberg M Söderqvist F Mild KH Pooled analysis of case-control studies on acoustic neuroma diagnosed 1997-2003 and 2007-2009 and use of mobile and cordless phones. Int J Oncol. 2013;43(4):1036–1044. 10.3892/ijo.2013.2025 23877578
125 Hardell L Carlberg M Using the Hill viewpoints from 1965 for evaluating strengths of evidence of the risk for brain tumors associated with use of mobile and cordless phones1. Rev Environ Health. 2013;28(2-3):97–106. 10.1515/reveh-2013-0006 24192496
126 Hardell L Carlberg M Mobile phone and cordless phone use and the risk for glioma–Analysis of pooled case-control studies in Sweden, 1997–2003 and 2007–2009. Pathophysiology. 2015;22(1):1–13. 25466607
127 Carlberg M Hardell L Pooled analysis of Swedish case-control studies during 1997‑2003 and 2007-2009 on meningioma risk associated with the use of mobile and cordless phones. Oncol Rep. 2015;33(6):3093–3098. 10.3892/or.2015.3930 25963528
128 Coureau G Bouvier G Lebailly P Fabbro-Peray P Gruber A Leffondre K Guillamo J-S Loiseau H Mathoulin-Pélissier S Salamon R Mobile phone use and brain tumours in the CERENAT case-control study. Occup Environ Med. 2014;71(7):514–522. 10.1136/oemed-2013-101754 24816517
129 Yoon S Choi J-W Lee E An H Choi HD Kim N Mobile phone use and risk of glioma: A case-control study in Korea for 2002-2007. Environ Health Toxicol. 2015;30:e2015015. 10.5620/eht.e2015015 26726040
130 Pettersson D Mathiesen T Prochazka M Bergenheim T Florentzson R Harder H Nyberg G Siesjö P Feychting M Long-term mobile phone use and acoustic neuroma risk. Epidemiology. 2014;25(2):233–241. 10.1097/EDE.0000000000000058 24434752
131 Benson VS Pirie K Schüz J Reeves GK Beral V Green J Collaborators MWS Million Women Study Collaborators Mobile phone use and risk of brain neoplasms and other cancers: prospective study. Int J Epidemiol. 2013;42(3):792–802. 10.1093/ije/dyt072 23657200
132 Benson VS Pirie K Schüz J Reeves GK Beral V Green J Authors’ response to: The case of acoustic neuroma: Comment on mobile phone use and risk of brain neoplasms and other cancers. Int J Epidemiol. 2013;43(1):275. 10.1093/ije/dyt186 24078152
133 Prasad M Kathuria P Nair P Kumar A Prasad K Mobile phone use and risk of brain tumours: A systematic review of association between study quality, source of funding, and research outcomes. Neurol Sci. 2017;38(5):797–810. 10.1007/s10072-017-2850-8 28213724
134 Lagorio S Röösli M Mobile phone use and risk of intracranial tumors: A consistency analysis. Bioelectromagnetics. 2014;35(2):79–90. 10.1002/bem.21829 24375548
135 Ioannidis JPA Meta-analyses in environmental and occupational health. Occup Environ Med. 2018;75(6):443–445. 10.1136/oemed-2016-104128 29574405
136 Brusick D Albertini R McRee D Peterson D Williams G Hanawalt P Preston J Genotoxicity of radiofrequency radiation. Environ Mol Mutag. 1998; 32(1):1-16. 10.1002/(SICI)1098-2280(1998)32:1%3C1::AID-EM1%3E3.0.CO;2-Q
137 Verschaeve L Juutilainen J Lagroye I Miyakoshi J Saunders R De Seze R Tenforde T Van Rongen E Veyret B Xu Z In vitro and in vivo genotoxicity of radiofrequency fields. Mutat Res Rev Mutat Res. 2010;705(3):252–268. 10.1016/j.mrrev.2010.10.001 20955816
138 Vijayalaxmi, Prihoda TJ. Genetic damage in human cells exposed to non-ionizing radiofrequency fields: A meta-analysis of the data from 88 publications (1990–2011). Mutat Res Genet Toxicol Environ Mutagen. 2012;749(1-2):1–16. 10.1016/j.mrgentox.2012.09.007
139 Speit G Schütz P Hoffmann H Genotoxic effects of exposure to radiofrequency electromagnetic fields (RF-EMF) in cultured mammalian cells are not independently reproducible. Mutat Res Genet Toxicol Environ Mutagen. 2007;626(1-2):42–47. 10.1016/j.mrgentox.2006.08.003 16997616
140 Speit G Gminski R Tauber R Genotoxic effects of exposure to radiofrequency electromagnetic fields (RF-EMF) in HL-60 cells are not reproducible. Mutat Res Genet Toxicol Environ Mutagen. 2013;755(2):163–166. 10.1016/j.mrgentox.2013.06.014 23817106
141 Asanami S Shimono K High body temperature induces micronuclei in mouse bone marrow. Mutat Res Genet Toxicol Environ Mutagen. 1997;390(1-2):79–83. 10.1016/S0165-1218(97)00002-5 9150755
142 Komae N Hibino Y Sugano N Analysis of micronuclei induced under hyperthermic conditions in human lymphocyte culture by fluorescence in situ hybridization (FISH) and spectral karyotyping (SKY) methods [In Japanese]. Yakugaku Zasshi. 1999;119(10):763–772. 10.1248/yakushi1947.119.10_763 10518460
143 Speit G Schütz P Hyperthermia-induced genotoxic effects in human A549 cells. Mutat Res/Fund Mol Mech Mutag. 2013; 747-748:1-5. 10.1016/j.mrfmmm.2013.04.008
144 Kampinga HH Dikomey E Hyperthermic radiosensitization: mode of action and clinical relevance. Int J Radiat Biol. 2001;77(4):399–408. 10.1080/09553000010024687 11304434
145 Hunt CR Pandita RK Laszlo A Higashikubo R Agarwal M Kitamura T Gupta A Rief N Horikoshi N Baskaran R Hyperthermia activates a subset of ataxia-telangiectasia mutated effectors independent of DNA strand breaks and heat shock protein 70 status. Cancer Res. 2007;67(7):3010–3017. 10.1158/0008-5472.CAN-06-4328 17409407
146 Wyde ME, Horn TL, Capstick MH, Ladbury JM, Koepke G, Wilson PF, Kissling GE, Stout MD, Kuster N, Melnick RL et al. Pilot studies of the National Toxicology Program’s cell phone radiofrequency radiation reverberation chamber exposure system (publication pending). 2018.
147 Gong Y Capstick MH Kuehn S Wilson PF Ladbury JM Koepke G McCormick DL Melnick RL Kuster N Life-time dosimetric assessment for mice and rats exposed in reverberation chambers for the two-year NTP cancer bioassay study on cell phone radiation. IEEE Trans Electromagn Compat. 2017;59(6):1798–1808. 10.1109/TEMC.2017.2665039 29217849
148 Capstick MH Kuehn S Berdinas-Torres V Gong Y Wilson PF Ladbury JM Koepke G McCormick DL Gauger J Melnick RL A radio frequency radiation exposure system for rodents based on reverberation chambers. IEEE Trans Electromagn Compat. 2017;59(4):1041–1052. 10.1109/TEMC.2017.2649885 29217848
149 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
150 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
151 Weinberger MA How valuable is blind evaluation in histopathologic examinations in conjunction with animal toxicity studies? Toxicol Pathol. 1979;7(2):14–17. 10.1177/019262337900700204
152 Prasse K Hildebrandt P Dodd D Letter to the editor. Toxicol Pathol. 1986;14(2):274–275. 10.1177/019262338601400218 3764324
153 Society of Toxicologic Pathology. Editorial: society of Toxicologic Pathologists’ position paper on blinded slide reading. Toxicol Pathol. 1986;14(4):493–494. 10.1177/019262338601400419 3809899
154 Iatropoulos MJ Society of Toxicologic Pathologists position paper: “Blinded” microscopic examination of tissues from toxicologic or oncogenic studies In: Grice HC, Ciminera JL, editors. Carcinogenicity. Heidelberg, Germany: Springer; 1988. 10.1007/978-3-642-61364-7_16
155 Crissman JW Goodman DG Hildebrandt PK Maronpot RR Prater DA Riley JH Seaman WJ Thake DC Best practices guideline: toxicologic histopathology. Toxicol Pathol. 2004;32(1):126–131. 10.1080/01926230490268756 14713558
156 Neef N Nikula KJ Francke-Carroll S Boone L Regulatory forum opinion piece: blind reading of histopathology slides in general toxicology studies. Toxicol Pathol. 2012;40(4):697–699. 10.1177/0192623312438737 22407309
157 Brix AE Hardisty JF McConnell EE Combining neoplasms for evaluation of rodent carcinogenesis studies. In: Hsu CH Stedeford Teditors. Cancer Risk Assessment: Chemical Carcinogenesis, Hazard Evaluation, and Risk Quantification. Hoboken (NJ): John Wiley & Sons, Inc; 2010. p. 699–715. 10.1002/9780470622728.ch28
158 Wyde M Cesta M Blystone C Elmore S Foster P Hooth M Kissling G Malarkey D Stills R Stout MReport of partial findings from the National Toxicology Program carcinogenesis studies of cell phone radiofrequency radiation in Hsd: Sprague Dawley® SD rats (whole body exposures). 2016. 10.1101/055699
159 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53(282):457–481. 10.1080/01621459.1958.10501452
160 Cox DR Regression models and life‐tables. J R Stat Soc B. 1972;34(2):187–202.
161 Tarone RE Tests for trend in life table analysis. Biometrika. 1975;62(3):679–690. 10.1093/biomet/62.3.679
162 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. 10.2307/2531856 3390507
163 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989;12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
164 Piegorsch WW, Bailer AJ. Statistics for Environmental Biology and Toxicology, Section 6.3.2. London, UK: Chapman & Hall; 1997.
165 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986;46(9):4372–4378. 3731095
166 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. 10.2307/2532200 8241374
167 Nam JM A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987;43(3):701–705. 10.2307/2532006 3663825
168 Rao JNK Scott AJ A simple method for the analysis of clustered binary data. Biometrics. 1992;48(2):577–585. 10.2307/2532311 1637980
169 Fung KY Krewski D Rao JNK Scott AJ Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994;14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
170 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
171 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. 10.1080/01621459.1955.10501294
172 Hsu JC The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992;1(2):151–168.
173 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
174 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
175 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
176 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
177 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252. 10.1080/00401706.1964.10490181
178 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1/2):133–145. 10.2307/2333011
179 Dixon WJ Massey FJ Jr Introduction to statistical analysis. 2nd ed. New York (NY): McGraw-Hill Book Company, Inc; 1957. p. 276–278, 412.
180 Tukey JW Easy summaries – Numerical and graphical. Exploratory Data Analysis. Reading (MA): Addison-Wesley; 1977. p. 43–44.
181 Code of Federal Regulations (CFR). 21:Part 58.
182 Schmid W The micronucleus test. Mutat Res. 1975;31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
183 Heddle JA Hite M Kirkhart B Mavournin K MacGregor JT Newell GW Salamone MF The induction of micronuclei as a measure of genotoxicity: A report of the US Environmental Protection Agency Gene-Tox Program. Mutat Res Rev Mutat Res. 1983;123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
184 Organisation for Economic Cooperation and Development (OECD). OECD guideline for the testing of chemicals: In vivo mammalian alkaline comet assay. Paris, France: OECD Publishing; 2014. Testing Guideline 489.
185 Tice RR Agurell E Anderson D Burlinson B Hartmann A Kobayashi H Miyamae Y Rojas E Ryu JC Sasaki YF Single cell gel/comet assay: Guidelines for in vitro and in vivo genetic toxicology testing. Environ Mol Mutag. 2000; 35(3):206-221. 10.1002/(SICI)1098-2280(2000)35:3<206::AID-EM8>3.0.CO;2-J
186 Collins AR The comet assay for DNA damage and repair: Principles, applications, and limitations. Mol Biotechnol. 2004;26(3):249–261. 10.1385/MB:26:3:249 15004294
187 Brendler-Schwaab S Hartmann A Pfuhler S Speit G The in vivo comet assay: use and status in genotoxicity testing. Mutagenesis. 2005;20(4):245–254. 10.1093/mutage/gei033 15899933
188 Burlinson B Tice RR Speit G Agurell E Brendler-Schwaab SY Collins AR Escobar P Honma M Kumaravel TS Nakajima MIn Vivo Comet Assay Workgroup, part of the Fourth International Workgroup on Genotoxicity Testing Fourth International Workgroup on Genotoxicity testing: results of the in vivo Comet assay workgroup. Mutat Res Genet Toxicol Environ Mutagen. 2007;627(1):31–35. 10.1016/j.mrgentox.2006.08.011 17118697
189 Pfuhler S Wolf HU Detection of DNA‐crosslinking agents with the alkaline comet assay. Environ Mol Mutag. 1996; 27(3):196-201. 10.1002/(SICI)1098-2280(1996)27:3%3C196::AID-EM4%3E3.0.CO;2-D
190 Hartmann A Agurell E Beevers C Brendler-Schwaab S Burlinson B Clay P Collins A Smith A Speit G Thybaud V4th International Comet Assay Workshop Recommendations for conducting the in vivo alkaline Comet assay. Mutagenesis. 2003;18(1):45–51. 10.1093/mutage/18.1.45 12473734
191 Miller JA Miller EC Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH Watson JD Winsten JAeditors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
192 Straus DS Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67(2):233–241. 7021938
193 Crawford BD Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA Flamm WG Lorentzen RJeditors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co., Inc; 1985. p. 13–59.
194 Witt KL Knapton A Wehr CM Hook GJ Mirsalis J Shelby MD MacGregor JT Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short‐term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutag. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
195 Sasaki YF Sekihashi K Izumiyama F Nishidate E Saga A Ishida K Tsuda S The comet assay with multiple mouse organs: comparison of comet assay results and carcinogenicity with 208 chemicals selected from the IARC monographs and US NTP Carcinogenicity Database. Crit Rev Toxicol. 2000;30(6):629–799. 10.1080/10408440008951123 11145306
196 National Toxicology Program (NTP). Historical controls. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2018. https://ntp.niehs.nih.gov/results/dbsearch/historical/index.html [Accessed: January 24, 2018]
197 National Toxicology Program (NTP). Toxicology and carcinogenesis studies in B6C3F1/N mice exposed to whole-body radio frequency radiation at a frequency (1,900 MHz) and modulations (GSM and CDMA) used by cell phones. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2018. Technical Report Series No. 596.
198 International Comission on Non-Ionizing Radiation Protection (ICNIRP). Guidelines for limiting exposure to time-varying electric, magnetic, and electromagnetic fields (up to 300 GHz). Health Phys. 1998;74(4):494–522. 9525427
199 Barthold SW Griffey SM Percy DH Pathology of laboratory rodents and rabbits. 4th ed. Hoboken (NJ): John Wiley & Sons, Inc; 2016. p. 156. 10.1002/9781118924051
200 Hauet-Broere F Wieten L Guichelaar T Berlo S Van der Zee R Van Eden W Heat shock proteins induce T cell regulation of chronic inflammation. Ann Rheum Dis. 2006;65 Suppl 3:65–68. 10.1136/ard.2006.058495 17038477
201 Rao GN Diet and kidney diseases in rats. Toxicol Pathol. 2002;30(6):651–656. 10.1080/01926230290166733 12512864
202 Taberski K Klose M Grote K El Ouardi A Streckert J Hansen VW Lerchl A Noninvasive assessment of metabolic effects of exposure to 900 MHz electromagnetic fields on Djungarian Hamsters (Phodopus sungorus). Radiat Res. 2014;181(6):617–622. 10.1667/RR13646.1 24844649
203 MacKenzie WF Alison R Heart. In: Boorman GA Eustis SL Elwell MR Montgomery CA Jr MacKenzie WFeditors. Pathology of the Fischer Rat Reference and Atlas. San Diego (CA): Academic Press, Inc; 1990. p. 461.
204 Berridge BR Mowat V Nagai H Nyska A Okazaki Y Clements PJ Rinke M Snyder PW Boyle MC Wells MY CleMents PJ, Rinke M, Snyder PW, Boyle MC, Wells MY. Non-proliferative and proliferative lesions of the cardiovascular system of the rat and mouse. J Toxicol Pathol. 2016;29(3) Suppl:1S–47S. 10.1293/tox.29.3S-1 27621537
205 Falcioni L Bua L Tibaldi E Lauriola M De Angelis L Gnudi F Mandrioli D Manservigi M Manservisi F Manzoli I Report of final results regarding brain and heart tumors in Sprague-Dawley rats exposed from prenatal life until natural death to mobile phone radiofrequency field representative of a 1.8 GHz GSM base station environmental emission. Environ Res. 2018;165:496–503. 10.1016/j.envres.2018.01.037 29530389
206 Ruediger HW Genotoxic effects of radiofrequency electromagnetic fields. Pathophysiology. 2009;16(2-3):89–102. 19285841
207 Lönn S Ahlbom A Hall P Feychting M Mobile phone use and the risk of acoustic neuroma. Epidemiology. 2004;15(6):653–659. 10.1097/01.ede.0000142519.00772.bf 15475713
208 Hardell L Mild KH Carlberg M Söderqvist F Tumour risk associated with use of cellular telephones or cordless desktop telephones. World J Surg Oncol. 2006;4(1):74. 10.1186/1477-7819-4-74 17034627
209 Hardell L Carlberg M Söderqvist F Mild KH Morgan LL Long-term use of cellular phones and brain tumours: increased risk associated with use for⩾ 10 years. Occup Environ Med. 2007;64(9):626–632. 10.1136/oem.2006.029751 17409179
210 Hardell L Carlberg M Mobile phones, cordless phones and the risk for brain tumours. Int J Oncol. 2009;35(1):5–17. 10.3892/ijo_00000307 19513546
211 Recio L Hobbs C Caspary W Witt KL Dose-response assessment of four genotoxic chemicals in a combined mouse and rat micronucleus (MN) and Comet assay protocol. J Toxicol Sci. 2010;35(2):149–162. 10.2131/jts.35.149 20371966
212 Rundell MS Wagner ED Plewa MJ The comet assay: Genotoxic damage or nuclear fragmentation? Environ Mol Mutag. 2003; 42(2):61-67. 10.1002/em.10175
213 Lorenzo Y Costa S Collins AR Azqueta A The comet assay, DNA damage, DNA repair and cytotoxicity: hedgehogs are not always dead. Mutagenesis. 2013;28(4):427–432. 10.1093/mutage/get018 23630247
214 MacGregor JT Bishop ME McNamee JP Hayashi M Asano N Wakata A Nakajima M Saito J Aidoo A Moore MM Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: II. An efficient method of monitoring chromosomal damage in the rat. Toxicol Sci. 2006;94(1):92–107. 10.1093/toxsci/kfl076 16888079
215 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008;649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
216 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res Genet Toxicol Environ Mutagen. 2007;634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117