# Conclusions

## GSM-modulated RFR

Under the conditions of this 2-year whole-body exposure study, there was clear evidence of carcinogenic activity^m^ of GSM-modulated cell phone RFR at 900 MHz in male Hsd:Sprague Dawley^®^ SD^®^ rats based on the incidences of malignant schwannoma of the heart. The incidences of malignant glioma of the brain and benign, malignant, or complex pheochromocytoma (combined) of the adrenal medulla were also related to RFR exposure. The incidences of benign or malignant granular cell tumors of the brain, adenoma or carcinoma (combined) of the prostate gland, adenoma of the pars distalis of the pituitary gland, and pancreatic islet cell adenoma or carcinoma (combined) may have been related to RFR exposure. There was equivocal evidence of carcinogenic activity of GSM-modulated cell phone RFR at 900 MHz in female Hsd:Sprague Dawley^®^ SD^®^ rats based on the incidences of schwannomas of the heart.

m See Explanation of Levels of Evidence of Carcinogenic Activity. See summary of the peer review panel comments and the public discussion on this Technical Report appears in Appendix L.

Increases in non-neoplastic lesions of the heart, brain, and prostate gland in male rats, and of the heart, thyroid gland, and adrenal gland in female rats occurred with exposures to GSM-modulated RFR at 900 MHz.

## CDMA-modulated RFR

Under the conditions of this 2-year whole-body exposure study, there was clear evidence of carcinogenic activity of CDMA-modulated cell phone RFR at 900 MHz in male Hsd:Sprague Dawley^®^ SD^®^ rats based on the incidences of malignant schwannoma of the heart. The incidences of malignant glioma of the brain were also related to RFR exposure. The incidences of adenoma of the pars distalis of the pituitary gland and adenoma or carcinoma (combined) of the liver may have been related to RFR exposure. There was equivocal evidence of carcinogenic activity of CDMA-modulated cell phone RFR at 900 MHz in female Hsd:Sprague Dawley^®^ SD^®^ rats based on the incidences of malignant schwannoma of the heart, malignant glioma of the brain, and benign, malignant, or complex pheochromocytoma (combined) of the adrenal medulla. Increases in non-neoplastic lesions of the heart, brain, and prostate gland in male rats, and of the brain in female rats occurred with exposures to CDMA-modulated RFR at 900 MHz.