# Discussion

The U.S. Food and Drug Administration nominated the radio frequency radiation (RFR) emissions of wireless communication devices for toxicology and carcinogenicity testing based on several factors. Current exposure guidelines are based on protection from acute injury from thermal effects, and little was known about the potential for health effects of long-term exposure. Epidemiology and toxicology studies have not definitively demonstrated an association between cell phone RFR exposure and any specific health problems in humans; however, the results of these studies are mixed and further complicated by confounding factors (including potential recall biases of the study participants that could impact the assessment of exposure). For epidemiology studies, exposures in the general population may not have occurred for a long enough period of time to accommodate the long latency period for some types of cancers in humans. Studies in laboratory animals have been complicated by limitations that researchers have faced in conducting robust studies designed to characterize the toxicity and carcinogenicity of RFR used by cell phones.

To improve on prior methods of exposing laboratory animals to RFR, the National Toxicology Program (NTP) collaborated with technical experts from the National Institute of Standards and Technology (Boulder, CO) and the Foundation for Research on Information Technologies in Society (Zurich, Switzerland) to design, construct, and validate a novel system of exposing rodents to RFR. The exposure system was designed to expose unrestrained, individually housed animals to a statistically uniform field of RFR at frequencies (900 MHz in rats and 1,900 MHz in mice) and with modulations [Global System for Mobile Communications (GSM) or Code Division Multiple Access (CDMA)] used in cellular communication devices. The exposure facility was installed at IIT Research Institute (Chicago, IL), where all animal studies were conducted following system testing and RFR exposure validation. The design and performance characteristics for the exposure system are reported fully in Capstick et al.,^148^ and detailed tissue-specific RFR exposure modeling at these frequencies is presented in Gong et al.^147^

Studies assessing the effects of GSM- and CDMA-modulated cell phone RFR on body temperatures of rats, including exposure in dams, were previously reported in Wyde et al.^146^ Following these initial studies, the NTP conducted 28-day and 2-year studies to characterize the potential toxicity and carcinogenicity of whole-body exposure to RFR in rats beginning in utero with exposures continuing throughout gestation and lactation and for an additional 28 days, 14 weeks, or 2 years. Due to the exposure and use pattern of cell phones by pregnant women and women of childbearing age, exposures were initiated in utero.

Hsd:Sprague Dawley^®^ SD^®^ rats received whole-body exposure to GSM- or CDMA-modulated cell phone RFR (900 MHz) for 9 hours and 10 minutes a day over an 18-hour exposure period starting during gestation and continuing throughout lactation and for an additional 28 days, 14 weeks, or 2 years. Exposures for the GSM- and CDMA-modulated cell phone RFR studies were conducted in parallel with a common non-exposed (sham) control group that was housed in an identical chamber that differed from the RFR exposure chambers only in the absence of RFR emission during the exposure periods.

The absorption of nonionizing RFR transfers energy to biological tissues through a process that results in some degree of heating of the exposed tissue. It has been well established that exposure to excessive levels of RFR can cause damage to tissues through overt thermal changes for which the body is unable to compensate. However, exposure to such high levels of RFR is not reflective of the scenario of human exposure from cell phones and other wireless communication devices, which involves episodic exposure to much lower power levels. To characterize the thermal effects of RFR in male and female Hsd:Sprague Dawley^®^ SD^®^ rats, a series of short-term pilot studies was conducted. The goal of these studies was to further investigate the overt thermal effect of RFR, characterize the impact of body size and pregnancy status on body temperature following exposure to RFR, and to identify adequately challenging exposure levels [specific absorption rates (SARs)] of RFR below those that raised body temperature by more than 1°C.^146^

In general, the studies by Wyde et al.^146^ demonstrated a significant SAR-dependent increase in body temperature that was greater in larger, older rats than in smaller, young rats. Exposures to 10 W/kg RFR or greater (both modulations) for up to 5 days induced excessively high body temperatures compared to sham controls, leading to mortality in many cases and increased resorptions in pregnant rats at 12 W/kg. These data suggest that exposure at these levels resulted in the potential exceedance of the thermoregulatory capacity in rats. In these studies, body temperatures were higher with increasing SAR compared to sham controls at exposures of 6 W/kg or greater for both modulations. Male rats were more sensitive than females to RFR-induced rises in body temperature compared to sham controls. In the current 28-day studies, body temperature was higher in the F0 dams compared to sham controls during perinatal exposure at 6 and 9 W/kg. These findings were consistent with the effects observed in the thermal pilot studies in pregnant dams at similar SARs.^146^ No increases in body temperature were observed in the F1 offspring at 6 or 9 W/kg.

Based on temperature changes (>1°C) in adult rats at 8 W/kg or greater in the thermal pilot studies,^146^ increased body temperature in F0 dams at 9 W/kg, and decreased F1 pup survival at 9 W/kg in the current 28-day studies, the highest exposure level selected for the 2-year studies was 6 W/kg. This exposure level was selected to provide an exposure considered adequate to challenge the animals without causing disruption of the thermoregulatory process. The lowest whole-body exposure level selected for the 2-year studies in rats, 1.5 W/kg, is close to the current Federal Communications Commission guidelines for localized exposure of 1.6 W/kg for cellular communication devices in the United States. The localized (1.6 W/kg) and whole-body exposure limits (0.08 W/kg) are based on protection from acute injury induced by thermal effects of RFR.^198^ While core body temperature is a good general surrogate for the heating effects of RFR, it must be noted that core body temperature does not address the potential for localized heating in certain tissues at exposures that do not induce higher core temperature compared to control animals. This concept is further illustrated in the relative tissue SAR modeling studies of Gong et al.,^147^ which demonstrates a differing distribution of energy absorption in various tissues. These differences are based on the size, shape, nature of surrounding tissues, and the dielectric properties of the tissue. Due to logistical constraints, core body temperature measurements were not collected in the 2-year studies as they were in the 28-day studies.

Significant biological effects occurred during the perinatal exposure period in dams (F0) and their offspring (F1) that were associated with exposure to RFR in both the 28-day and 2-year studies, regardless of modulation (GSM or CDMA). In the F0 RFR-exposed dams, lower body weights and body weight gains compared to sham controls were observed during the gestation and lactation periods. In both the 28-day and 2-year studies, lower body weight gains late in gestation (gestation day 15 through 21) were observed at 9 and 6 W/kg, respectively, which may be related to the lower pup weights on postnatal day (PND) 1. During the lactation period, maternal body weight gains were decreased and body weights in the 6 and 9 W/kg groups were lower in both the 28-day and 2-year studies compared to sham controls. In general, body weights were lower with increasing SAR.

In the F1 offspring, body weights were lower than those of the sham controls on PND 1 and throughout the lactation period. Males appeared to be slightly more susceptible to the effects of RFR on body weight. The lack of further decreases in body weight over the course of the 2-year studies suggests that the RFR-mediated effects on body weight in the F1 offspring may be specific to the perinatal period. There was no effect on live litter size throughout lactation; however, in the 28-day GSM study, there was a significantly lower survival ratio at 9 W/kg compared to sham controls early in the lactation period (PND 1 to 4) prior to culling litters to a standard size. Additionally, there was significantly greater pup mortality during the lactation period (PND 4 to 21) in the 2-year CDMA study at 6 W/kg than in sham controls, which was not observed in the 28-day CDMA study at the same exposure level.

The results from the perinatal portions of these studies indicate that RFR at these exposures could impact normal development. However, the occurrence of early pup deaths and slowed pup weight gain with RFR exposure compared to sham controls could also be secondary to effects on the dams. For example, changes in maternal behavior or capacity to properly nourish their pups may have contributed to these effects as the magnitude of the lower pup body weights appeared to increase during early lactation and then decrease as the pups aged and required less maternal care. Unfortunately, behavioral abnormalities could not be directly observed in the current studies because the design of the chambers prohibited observation during the 18-hour daily RFR exposure periods. Further research would be required to elucidate the mechanism by which RFR induces these effects in pups.

At the end of the 2-year studies, survival was significantly greater in all groups of exposed male rats in the GSM study (50% to 68%) and at 3 and 6 W/kg in the CDMA study (48% to 62%) compared to the male sham control group (28%). In the male sham control group, survival declined more rapidly after week 75 than in all exposed groups, reflecting a higher rate of moribund sacrifices. The resulting 28% survival rate in sham control males was lower than the range observed in the historical controls (40% to 60%); however, survival of the GSM- and CDMA-exposed groups (48% to 68%) was similar to the historical control range. When including control groups of rats from additional studies that have not yet been reported by the NTP, survival in the male control groups is highly variable, ranging from 24% to 72%.^196^ The differences in survival in male rats may reflect the inherent variability in survival observed among the control groups in the Hsd:Sprague Dawley^®^ SD^®^ male rat. The duration of NTP 2-year rodent cancer studies is near the average life span of the Hsd:Sprague Dawley^®^ SD^®^ rat, and slight variations in the mortality rate can result in large apparent differences when only considering the 2-year time point. In female rats, survival in the sham control and exposed groups was within the historical control range (42% to 60%), except for the CDMA 6 W/kg group (68%) which exceeded the concurrent sham controls (54%) and the historical control range.

The higher mortality in the sham control males compared to the exposed males was largely attributed to a high severity of chronic progressive nephropathy in the kidneys that resulted in moribund removal of a large number of male rats from the studies. Chronic progressive nephropathy is a common cause of death in Sprague Dawley rats as well as other rat strains, and typically occurs to some degree in many aged rats, although with greater severity in males. Of note, the severity of chronic progressive nephropathy in males decreased with increasing SAR exposure to either modulation when compared to the sham control group.

Advanced chronic progressive nephropathy can result in markedly impaired renal function and a host of secondary lesions in other organs. In males, a broad spectrum of non-neoplastic lesions considered to be secondary to chronic progressive nephropathy (including parathyroid gland hyperplasia, mineralization in multiple tissues, and fibrous osteodystrophy of bone) was seen in all groups (sham control and exposed), with the highest incidences in the sham control group and decreasing with increasing SAR exposure. Chronic progressive nephropathy can also cause an increased incidence of polyarteritis nodosa, a spontaneous vascular disease that most commonly affects medium-sized arteries in the mesentery, pancreas, kidney, pancreaticoduodenal artery, and testis, although arteries in most other organs can also be affected.^199^ In the current studies, there were a number of organs with arterial inflammation consistent with polyarteritis nodosa. The incidence of these vascular lesions was greater in the sham control group than in exposed groups, correlating to the high severity of chronic progressive nephropathy in the sham control group. The apparent SAR-dependent effects in males and the slight effects (decreased incidence of nephropathy) observed in females suggest that the decrease in chronic progressive nephropathy may have been related to RFR exposure. Whether this reflects a direct effect of RFR on possible suppression of inflammatory processes through stimulation of stress response pathways,^200^ or is secondary to a possible reduction in feed intake leading to a reduction in the severity of nephropathy,^201,202^ remains to be established. The heart, brain, and adrenal gland were target organs for RFR exposure in males. The heart and brain were affected by both GSM- and CDMA-modulated RFR, whereas the adrenal medulla was a target only for GSM-modulated RFR exposure.

In the heart of male rats, exposure to RFR for 2 years resulted in a statistically significant positive trend in the incidences of cardiac schwannoma for both GSM and CDMA modulations. The incidence at 6 W/kg for CDMA was statistically significantly increased compared to sham controls. Additionally, cardiac Schwann cell hyperplasia occurred in groups of male rats exposed to both GSM- and CDMA-modulated cell phone RFR. These hyperplastic lesions are relevant to the evaluation of neoplasms because Schwann cell hyperplasia in the heart may progress to cardiac schwannoma.^203,204^ No cardiac schwannomas or Schwann cell hyperplasia were observed in the sham control male rats. The 5.5% and 6.6% incidences of malignant schwannoma observed in the 6 W/kg GSM- and CDMA-modulated cell phone RFR groups, respectively, exceed the highest rate observed in a single historical control group (2%) of completed peer reviewed studies^l^. The absence of these lesions in sham control males in the current studies was not considered to be related to the shorter longevity in controls. The 28% survival rate of the sham control male rats in the current studies was relatively low compared to other recent NTP studies in Hsd:Sprague Dawley^®^ SD^®^ rats.^196^ However, while most (13/19) of the malignant schwannomas were observed at terminal necropsy, some (6/19) were observed at 70 to 94 weeks, a time when survival in the sham control male rats was greater than 65%. Based on the rarity of these lesions, the presence of preneoplastic Schwann cell hyperplasia, and the higher incidence of these malignant tumors in the highest exposure group with both modulations, malignant schwannomas in the heart were considered to result from exposure to RFR. This was the basis for the conclusion of clear evidence for carcinogenic activity for both GSM- and CDMA-modulated cell phone RFR in male rats.

l The historical control rate reported in Wyde et al.158. Wyde M, Cesta M, Blystone C, Elmore S, Foster P, Hooth M, Kissling G, Malarkey D, Stills R, Stout M et al. Report of partial findings from the National Toxicology Program carcinogenesis studies of cell phone radiofrequency radiation in Hsd: Sprague Dawley® SD rats (whole body exposures). 2016. https://doi.org/10.1101/055699was9/699 (range 0% to 6%) because control groups from NTP studies using the Hsd:Sprague Dawley^®^ SD^®^ rat model that had not yet been peer reviewed were included.

In females, there were two occurrences of schwannoma in the heart in the groups exposed to 3 W/kg GSM-modulated RFR or 1.5 or 6 W/kg CDMA-modulated RFR. Single occurrences of Schwann cell hyperplasia were also observed in each of the CDMA exposed groups of females. With consideration of the significant increase observed for both modulations in males, this was an uncertain finding in female rats that may have been related to RFR exposures and was considered equivocal evidence of carcinogenic activity for both GSM- and CDMA-modulated cell phone RFR.

Schwannomas occurred in organs other than the heart in both male and female rats, but the incidences of these extra-cardiac schwannomas were not affected by RFR exposures. These results suggest that the proliferative effects of RFR on Schwann cells was specific to the heart. It is possible that these heart-specific effects are a result of higher SAR exposures in the heart compared to some of the other tissues based on the dielectric properties of the heart, which can affect tissue-specific RFR absorption.^147^ A recent study by Falcioni et al.^205^ reported low incidences of cardiac schwannoma in male rats exposed to whole-body GSM-modulated RFR at 5, 25, or 50 V/m, 1,800 MHz for 19 hours a day. The incidence of schwannoma at a constant 50 V/m (0.1 W/kg estimated SAR) was statistically significant in male rats.

In the current studies, RFR exposure also induced higher incidences and severity of cardiomyopathy of the right ventricular free wall in male rats exposed to either GSM- or CDMA-modulated cell phone RFR and in female rats exposed to GSM-modulated RFR. The effect of RFR on cardiomyopathy appears to be specific to the right ventricle in these groups because incidences of cardiomyopathy in the whole heart were unchanged in males and CDMA females and lower in the GSM females compared to sham controls. Higher incidences of cardiomyopathy in the right ventricle of male rats exposed to GSM-modulated cell phone RFR compared to sham controls were also observed at the 14-week interim evaluation. For males exposed to CDMA-modulated cell phone RFR for 14 weeks, higher incidences of cardiomyopathy were observed relative to sham controls across the whole heart, not specifically in the right ventricle. Cardiomyopathy is a common spontaneous disease in rats that typically has no clinical manifestations. The observation of this lesion at the 14-week interim evaluation in 3 and 6 W/Kg GSM males and the relatively higher modeled organ-specific SAR for heart for both males and females compared to other organs^147^ further suggest that the heart is a specific target organ for RFR.

In the brain, incidences of malignant gliomas were observed in RFR-exposed male rats, whereas none were observed in any of the sham controls. Malignant gliomas are poorly differentiated neoplasms of glial cells in the central nervous system. They may arise from or differentiate into astrocytes, oligodendrocytes, microglial cells, or ependymal cells. Similar to the occurrence of cardiac schwannomas, glial cell lesions in the brain were observed only in RFR-exposed male rats and not in any of the sham controls. The findings of malignant gliomas in the brain of male rats were not as robust as those observed for cardiac schwannomas, however the differences between these responses may be related to a relatively low predicted absorption rate (SAR) in the cerebral hemisphere in relation to other tissues based on the SAR estimates modeled by Gong et al.^147^ Malignant gliomas were observed at all SARs in the GSM study, and at 6 W/kg in the CDMA study, although not in an exposure-related manner, or with statistical significance. However, glial cell hyperplasia, a potentially preneoplastic lesion that may progress to a malignant glioma, was also observed at all SARs in the GSM study and at 1.5 and 6 W/kg in the CDMA study. No malignant gliomas or glial cell hyperplasias were observed in any of the sham control males. These data support an association between the observed incidences of malignant glioma in male rats and RFR exposure. Unlike the cardiac schwannomas, nearly all (10/11) of the malignant gliomas in males were observed at 101 weeks or later and more than half (6/10) of the glial cell hyperplasias were observed at terminal necropsy. Therefore, the occurrence in exposed males but not sham control males may in part reflect differences in survival, where sham control animals did not survive long enough to develop a tumor. However, taken together, these tumors were also considered to be related to RFR exposure.

In females, there were occurrences of malignant glioma of the brain at 1.5 and 6 W/kg in the CDMA and GSM studies, respectively, and single instances of glial cell hyperplasia at 3 W/kg in the GSM study and at 3 and 6 W/kg in the CDMA study. None were observed in any of the female sham controls. The occurrence of malignant gliomas was judged to be equivocal evidence of carcinogenic activity of CDMA-modulated RFR in female rats.

The schwannomas observed in the heart and the malignant gliomas observed in the brain arise from a similar functional cell type. Schwannomas are tumors of Schwann cell origin occurring in the peripheral nervous system (PNS). Schwann cells are classified as glial cells of the PNS. They are similar to glial cells in the brain in that they are specialized non-neuronal supportive cells whose functions include maintaining homeostasis, forming myelin, and providing support and protection for neurons of the PNS. In the central nervous system (CNS), glial cells include astrocytes, oligodendrogliocytes, microglial cells, and ependymal cells. In the PNS, Schwann cells produce myelin and are analogous to oligodendrocytes of the CNS. Generally, glial neoplasms in the rat are aggressive, poorly differentiated, and usually classified as malignant.

Granular cell tumors, which arise within the meninges from a different type of cell than the schwannomas and malignant gliomas, were also observed in the brain in all GSM-exposed male groups. The combined incidences of granular cell tumors (3% to 4%) were higher than the concurrent sham control (1%) but not the historical control range (0% to 4%^196^), and they were not statistically different from the sham control incidences.

The granular cell tumors were not considered to be biologically related to the malignant gliomas because these lesions arise from different tissues. Consequently, the carcinogenic activity of RFR with respect to the granular cell tumors was considered independently from the malignant gliomas. While the higher incidences in the exposed groups suggest an association with exposure, the occurrence of this lesion in a sham control animal combined with the low magnitude of the increase in exposed rats and the lack of statistical significance reduces the confidence that this effect is attributable to the GSM cell phone RFR exposure. Therefore, the higher incidences of granular cell tumors of the meninges in the brain of males exposed to GSM-modulated RFR may or may not have been related to RFR exposure.

In the adrenal medulla, there were higher combined incidences of benign, malignant, or complex pheochromocytoma in GSM-exposed males and CDMA-exposed females. In GSM-exposed males, there were higher incidences of benign, malignant, or complex pheochromocytoma (combined) in the 1.5 and 3 W/kg groups compared to sham controls. The incidence in the 1.5 W/kg group (27%) exceeded the historical control incidence (20.1%), while the incidence in the 3 W/kg group (31%) exceeded both the historical control incidence and range (16% to 28%). The incidence at 6 W/kg was marginally higher than in sham controls, but it did not exceed the historical control range. The higher incidences of benign, malignant, or complex pheochromocytoma (combined) that were observed in GSM-exposed males were considered to be related to RFR exposure. In CDMA-exposed females, there were higher incidences of benign pheochromocytoma and benign, malignant, or complex pheochromocytoma (combined) in the 1.5 W/kg group compared to sham controls. The higher incidence (8% vs. 1% in sham controls) of benign pheochromocytoma occurred only at the lowest exposure and was outside the historical control range (0% to 6%). No effect was observed in the incidences of hyperplasia in any of the exposed female groups. The isolated increased incidences of these neoplasms in the low-exposure female group reduces the confidence that this effect is attributable to the RFR exposure. Therefore, the higher incidence of benign, malignant, or complex pheochromocytoma (combined) in females was judged to be equivocal evidence of carcinogenic activity of CDMA-modulated RFR.

The increased incidences of pheochromocytoma in the adrenal medulla in the 2-year studies may suggest a stress response; however, not enough endpoints were evaluated in the current studies to elucidate the role of stress, if any, in these findings. Other parameters that would provide a clearer insight into whether these effects were related to a stress response, such as measurements of feed consumption, activity, or serum stress hormones, were not evaluated in the current studies. Further studies of RFR should include the evaluation of stress as a potential mechanism for these effects.

Incidences of hepatocellular adenoma or carcinoma (combined) in the liver were observed in all groups of male rats exposed to CDMA-modulated RFR; none were observed in the sham control group. Hepatocellular adenomas and carcinomas appear to be rare in the Hsd:Sprague Dawley^®^ SD^®^ rat (1/150 and 0/150, respectively, in other NTP studies), and the combined incidence at 3 W/kg (4%) in CDMA RFR-exposed male rats exceeded the highest incidence seen in single studies in the historical controls (2%). However, the increased incidence in only the 3 W/kg group reduces the confidence that this is attributable to the RFR exposure, so this increase may or may not have been related to RFR exposure.

The incidences of adenoma or carcinoma (combined) in pancreatic islets were higher in all groups of male rats exposed to GSM-modulated cell phone RFR compared to the sham controls; however, only the incidence at 1.5 W/kg was significantly increased compared to sham controls. The incidences in all groups of GSM-exposed rats (19% to 30%) exceeded the range in the historical controls (4% to 16%). The lack of an exposure-response gradient reduced the confidence that this was attributable to RFR exposure. Therefore, the higher incidences of neoplasms of the pancreatic islets may or may not have been related to RFR exposure.

The incidences of adenoma of the pituitary gland (pars distalis) were increased in most groups of male rats exposed to either GSM- or CDMA-modulated cell phone RFR, compared to the sham controls. In the GSM study, the incidences in all groups of exposed male rats exceeded the incidence in the historical controls. However, the incidences of adenoma were similar between all exposed groups regardless of SAR. In the CDMA study, there was a significantly higher incidence of adenoma in the 3 W/kg male group compared to sham controls with a similar (nonsignificant) response at 1.5 W/kg. The incidence in the 6 W/kg group was lower than in sham controls. There were no differences in the incidences of hyperplasia in any of the GSM- or CDMA-exposed male groups when compared to sham controls. Based on these findings, the higher incidences of pituitary gland (pars distalis) adenoma in RFR-exposed males may or may not have been related to exposure to RFR.

In GSM-exposed males, there were higher incidences of prostate gland adenoma (7%) and adenoma or carcinoma (combined) (8%) in the 3 W/kg group versus the sham control (2%). Although these incidences were not statistically significant compared to sham controls, these neoplasms have not been observed in historical controls (0/150). These neoplasms are considered rare in Hsd:Sprague Dawley^®^ SD^®^ rats. Preneoplastic lesions of epithelial hyperplasia were higher in the exposed groups, but the incidences were not statistically higher compared to sham controls. The higher incidence of prostate gland adenoma or carcinoma (combined) in the 3 W/kg group may have been related to GSM-modulated cell phone RFR exposure, although the lack of an exposure response reduces the confidence that the increased incidence is attributable to exposure, therefore, this was considered an equivocal finding. No effect in prostate gland neoplasms was observed in the CDMA study; however, prostate gland epithelial hyperplasia was higher compared to sham controls in all CDMA groups, with a significant increase in the 6 W/kg group versus sham controls and a statistically significant positive trend across exposure groups.

Subsets of male and female rats from the 2-year studies were examined at 14-week interim evaluations for biomarkers of genotoxicity. Chromosomal damage was evaluated using the peripheral blood erythrocyte micronucleus (MN) assay, and DNA damage was evaluated in the frontal cortex, hippocampus, cerebellum, liver, and peripheral blood using the comet assay. Results of the MN assays were negative, but higher levels of DNA damage were observed in some tissues of male rats (hippocampus and frontal cortex in the CDMA modulation). In general, results of the comet assay suggested that CDMA induced more effects than GSM, and male rats showed greater sensitivity than female rats. However, the difference between the response in males and females may have been related to the longer interval between cessation of exposure and tissue sampling that occurred for the females, potentially allowing for an increased amount of DNA repair to take place.

There were several instances in which one or two animals within a group of RFR-exposed rats showed high levels of DNA damage compared to the rest of the animals within the exposure group, while levels of DNA damage in sham control animals tended to be more tightly clustered. Interanimal variation in response to RFR might be due to the genetic heterogeneity of these Hsd:Sprague Dawley^®^ SD^®^ rats, which are maintained as an outbred stock. However, tissues from a single rat rarely tracked together with regard to the extent of DNA damage (i.e., there was never a case in which all of the tissues from one rat had the highest mean percent comet tail DNA). This observation suggests intertissue variability in response, as has also been seen with chemicals.^195^ Although the markedly higher levels of DNA damage observed in some rats were suggestive of an exposure-related effect, the high degree of interanimal variation within an exposure group resulted in nonsignificant statistical tests in most instances (for example, male rat cerebellum exposed to CDMA and female rat peripheral blood exposed to CDMA).

Unlike ionizing radiation or ultraviolet radiation, RFR is not sufficiently energetic, by several orders of magnitude, to directly damage macromolecules,^4^ and little is known about the mechanisms by which RFR could induce DNA damage in the absence of thermal effects. Proposed mechanisms include, for example, induction of oxygen radicals and interference with DNA repair mechanisms.^54,206^

No histopathologic assessments of cytotoxicity (apoptosis and necrosis) were conducted in the brain or liver tissues that were examined for DNA damage, which leaves open the possibility that apoptosis or necrosis may have confounded the comet assay results. However, this seems unlikely as brain sections from other groups of rats at the 14-week interim evaluations and in the 2-year studies did undergo histopathologic assessment and no significant findings were reported. Unlike ionizing radiation or ultraviolet radiation, RFR is not sufficiently energetic, by several orders of magnitude, to directly damage macromolecules,^4^ and little is known about the mechanism by which RFR could induce DNA damage in the absence of a thermal effect. Proposed mechanisms include, for example, induction of oxygen radicals and interference with DNA repair mechanisms.^54,206^

The primary effects of RFR in rats included perinatal effects on body weights and body weight gains in the F0 dams and the F1 offspring, higher body temperatures in the F0 dams, and higher incidences of neoplasms of the heart (malignant schwannoma), brain (malignant glioma), and adrenal gland (pheochromocytoma) in males. There were also several histopathologic lesions that occurred in single or lower exposure groups, lacked a clear exposure response, or occurred at incidences that did not differ from those observed in control groups in past NTP studies. With reduced confidence that these increased incidences were attributable to the RFR exposure, these uncertain findings may or may not have been related to RFR exposure. The greater survival in RFR-exposed males compared to sham controls was attributed to decreased chronic progressive nephropathy, which may be a result of RFR exposure. Many of these findings occurred with both modulations suggesting the modulations had minimal, if any impact on the responses to the 900 MHz cell phone RFR exposure.

With a few exceptions, male rats seemed more sensitive to effects of RFR than females. In pilot studies of effects of RFR on body temperature in young and aged rats, temperatures were generally higher in aged males than females at SARs of 10 W/kg and above with both GSM and CDMA modulation.^146^ The higher incidences of right ventricular cardiomyopathy compared to sham controls observed at 14 weeks and 2 years also occurred to a greater extent in males than in females. Heart schwannomas were related to exposure in RFR-exposed males, but the incidences in females may or may not have been related to exposure. More instances of marginally higher incidences in lesions compared to sham controls in other tissues that may have been related to RFR exposure were observed in males [brain (granular cell tumors), pituitary gland, prostate gland, and pancreas] than in females (brain and adrenal gland). Finally, reduced chronic progressive nephropathy in RFR-exposed male rats compared to sham controls in the 2-year studies was the likely basis for the higher survival rate of RFR-exposed males (in particular in the GSM exposure groups). Reasons for these sex differences remain to be explored.

Some epidemiology studies have suggested an association between cell phone radio frequency radiation exposure and potential health effects.^95,96,124,131,207-210^ Based on available studies, a working group of the International Agency for Research on Cancer^93^ classified radiofrequency electromagnetic fields as possibly carcinogenic to humans. Of particular concern was the possible association (limited evidence) with brain glioma and acoustic neuroma (vestibular schwannoma) in the region of the head that is most exposed to RFR when a wireless phone is used at the ear. The malignant schwannomas of the heart observed in male rats in the current studies and the malignant gliomas observed in the brain of male rats, arise from the same cell type as the acoustic neuromas (vestibular schwannomas) observed in humans, though in a different location. This lends credence to the possible association of these tumors with cellular phone use. The cellular origin of malignant gliomas in the rat brain is unclear, but they do arise from glial cells (support cells in the brain), as do human glioblastomas, so it is possible that such an association exists for these tumors as well. However, the interpretation of these findings with respect to specific risks to humans from cellular telephone use is beyond the scope of the current studies. Further efforts to characterize the molecular basis by which RFR elicits its effects in rats, and a more complete assessment of the exposure conditions in the current studies in relation to exposures to humans from cellular telephone technologies should provide context to aid understanding of the implications of the current findings to human health.