# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-595.

## GSM

### Twenty-eight-day Study

#### Perinatal Study

No exposure-related effects were observed on survival or littering rates (littering/pregnant ratio) (Table 2). Gestation body weights were unaffected by exposure to GSM-modulated cell phone RFR by pairwise comparison (Table 3). A significant negative trend was observed in gestation day (GD) 21 body weights that was likely due to reduced body weight gain in late gestation in the 9 W/kg group (Table 3). There was an overall (GD 6 to GD 21) lower body weight gain of 9% in the 9 W/kg group compared to that of the sham controls.

Table 2 Summary of Disposition during Perinatal Exposure and F_1_ Allocation in the 28-day Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Time-mated Females | 20 | 20 | 20 | 20
Pregnant Females | 20 | 19 | 18 | 20
Nonpregnant Females | 0 | 1 | 2 | 0
Pregnant Dams Not Delivering | 0 | 0 | 0 | 0
Died | 0 | 0 | 0 | 0
Littered | 20 | 19 | 18 | 20
Pregnant/Mated Percentage^a^ | 100.0% | 95.0% | 90.0% | 100.0%
Littered/Pregnant Percentage^a^ | 100.0% | 100.0% | 100.0% | 100.0%
Litters Removed (Insufficient Size) (PND 4) | 0 | 0 | 0 | 0
Litters Post Standardization (PND 4) | 20 | 19 | 18 | 20
Weaned/Sex (PND 21)^b^ | 30 | 30 | 30 | 30

^a^ Number in the numerator as proportion of the number in the denominator was tested using the Fisher exact test for pairwise comparisons against the sham control group.

^b^ Total number of weaned animals per sex from 10 litters.

Table 3 Mean Body Weights and Mean Body Weight Gains of F_0_ Female Rats during Gestation in the 28-day Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Gestation Day
6 | 238.3 ± 2.2 (20)^b^ | 236.7 ± 2.4 (19) | 238.8 ± 2.6 (18) | 238.3 ± 2.3 (20)
9 | 250.7 ± 2.4 (20) | 249.8 ± 2.2 (19) | 251.4 ± 2.5 (18) | 249.8 ± 2.5 (20)
12 | 266.2 ± 2.5 (20) | 263.0 ± 2.3 (19) | 265.9 ± 2.6 (18) | 264.2 ± 2.6 (20)
15 | 282.5 ± 2.9 (20) | 280.7 ± 2.8 (19) | 283.0 ± 2.9 (18) | 281.3 ± 2.5 (20)
18 | 319.3 ± 3.0 (20) | 316.9 ± 3.2 (19) | 319.4 ± 3.6 (18) | 313.6 ± 2.6 (20)
21 | 366.4 ± 4.3 (20) ^▲▲^ | 360.2 ± 4.8 (19) | 363.6 ± 4.5 (18) | 354.8 ± 3.3 (20)
Gestation Day Interval
6–9 | 12.5 ± 1.2 (20) | 13.1 ± 0.9 (19) | 12.6 ± 1.1 (18) | 11.5 ± 0.5 (20)
9–12 | 15.5 ± 1.1 (20) | 13.3 ± 0.8 (19) | 14.5 ± 0.6 (18) | 14.4 ± 0.7 (20)
12–15 | 16.3 ± 1.0 (20) | 17.7 ± 1.0 (19) | 17.1 ± 0.5 (18) | 17.1 ± 0.6 (20)
15–18 | 36.7 ± 0.9 (20) ^▲▲^ | 36.2 ± 1.3 (19) | 36.4 ± 1.1 (18) | 32.3 ± 0.8 (20)**
18–21 | 47.1 ± 1.8 (20) ^▲▲^ | 43.3 ± 2.0 (19) | 44.2 ± 1.3 (18) | 41.2 ± 1.5 (20)*
6–21 | 128.1 ± 3.3 (20) ^▲▲^ | 123.5 ± 4.3 (19) | 124.8 ± 3.0 (18) | 116.5 ± 2.6 (20)*

^▲▲^Significant trend (P ≤ 0.01).

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Body weights and body weight gains in grams. Data are displayed as mean ± standard error. Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ Number of dams.

Total and live litter size on postnatal day (PND) 1 was unaffected by exposure and there was no statistically significant effect on live litter size throughout lactation (Table 4). However, there were higher numbers of dead pups in the exposed groups from PND 1 to 4 and single incidences in the 6 and 9 W/kg groups from PND 5 to 21 (Table 5). The number of dead pups per litter was significantly increased from PND 1 to 4 in addition to a decreased survival ratio in the 9 W/kg group.

Table 4 Mean Number of Surviving F_1_ Male and Female Rats during Lactation in the 28-day Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Total Pups per Litter
PND 1 | 11.95 ± 0.38 (20)^b^ | 11.74 ± 0.55 (19) | 12.78 ± 0.37 (18) | 12.40 ± 0.48 (20)
Live Pups per Litter
PND 1 | 11.90 ± 0.39 (20) | 11.63 ± 0.54 (19) | 12.78 ± 0.37 (18) | 12.20 ± 0.51 (20)
PND 4 (preculling) | 11.85 ± 0.39 (20) | 11.53 ± 0.54 (19) | 12.44 ± 0.37 (18) | 11.45 ± 0.51 (20)
PND 4 (postculling) | 7.95 ± 0.05 (20) | 7.84 ± 0.28 (19) | 7.94 ± 0.06 (18) | 7.90 ± 0.07 (20)
PND 7 | 7.95 ± 0.05 (20) | 7.84 ± 0.28 (19) | 7.89 ± 0.08 (18) | 7.90 ± 0.07 (20)
PND 10 | 7.95 ± 0.05 (20) | 7.84 ± 0.28 (19) | 7.89 ± 0.08 (18) | 7.90 ± 0.07 (20)
PND 14 | 7.95 ± 0.05 (20) | 7.84 ± 0.28 (19) | 7.89 ± 0.08 (18) | 7.85 ± 0.08 (20)
PND 17 | 7.95 ± 0.05 (20) | 7.84 ± 0.28 (19) | 7.89 ± 0.08 (18) | 7.85 ± 0.08 (20)
PND 21 | 7.95 ± 0.05 (20) | 7.84 ± 0.28 (19) | 7.89 ± 0.08 (18) | 7.85 ± 0.08 (20)
Live Males per Litter
PND 1 | 6.10 ± 0.42 (20) | 5.95 ± 0.39 (19) | 6.72 ± 0.52 (18) | 5.80 ± 0.55 (20)
PND 4 (preculling) | 6.05 ± 0.41 (20) | 5.74 ± 0.38 (19) | 6.50 ± 0.52 (18) | 5.45 ± 0.54 (20)
PND 4 (postculling) | 4.00 ± 0.15 (20) | 3.95 ± 0.18 (19) | 3.94 ± 0.13 (18) | 3.75 ± 0.24 (20)
Live Females per Litter
PND 1 | 5.80 ± 0.42 (20) | 5.68 ± 0.36 (19) | 6.06 ± 0.45 (18) | 6.40 ± 0.60 (20)
PND 4 (preculling) | 5.80 ± 0.43 (20) | 5.79 ± 0.37 (19) | 5.94 ± 0.40 (18) | 6.00 ± 0.50 (20)
PND 4 (postculling) | 3.95 ± 0.14 (20) | 3.89 ± 0.11 (19) | 4.00 ± 0.14 (18) | 4.15 ± 0.24 (20)

^a^ All values shown as mean ± standard error; PND = postnatal day. Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^b^ Number of dams.

Table 5 Offspring Mortality and Survival Ratio of Rats during Lactation in the 28-day Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

Pup Survival per Litter | Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Total Dead PND 1–4^b^ | 2 (238/20) | 4 (221/19) | 6 (230/18) | 19 (244/20)
Total Dead PND 5–21 | 0 (159/20) | 0 (149/19) | 1 (143/18) | 1 (158/20)
Dead/Litter PND 1–4 | 0.100 ± 0.069 (20)^▲▲^ | 0.211 ± 0.123 (19) | 0.333 ± 0.229 (18) | 0.950 ± 0.223 (20)**
Dead/Litter PND 4–21 | 0.000 ± 0.000 (20) | 0.000 ± 0.000 (19) | 0.056 ± 0.056 (18) | 0.050 ± 0.050 (20)
Survival Ratio PND 1–4^c^ | 0.996 ± 0.004 (20)^▲▲^ | 0.991 ± 0.006 (19) | 0.976 ± 0.016 (18) | 0.940 ± 0.014 (20)**
Survival Ratio PND 4–21^d^ | 1.000 ± 0.000 (20) | 1.000 ± 0.000 (19) | 0.993 ± 0.007 (18) | 0.994 ± 0.006 (20)

^▲▲^Significant trend (P ≤ 0.01).

** Significantly different (P ≤ 0.01) from the sham control group.

^a^ All values shown as mean ± standard error; PND = postnatal day. Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^b^ Number of pups/number of dams.

^c^ Number of pups preculling on PND 4/total number of viable pups on PND 1 (does not include pups dead on PND 1).

^d^ Number of pups alive on PND 21/number of pups at postculling on PND 4.

Exposed dams had decreased weight gain during lactation (PND 1 through 21), and maternal body weights of the 9 W/kg group were up to 11% lower than those of the sham controls (Table 6). Combined F_1_ body weights were 8% lower starting on PND 1 in the 9 W/kg group when adjusted for litter size (Table 7). As lactation progressed, the adjusted pup weights (combined) were up to 17% lower in the 9 W/kg group and up to 8% lower in the 6 W/kg group compared to sham controls. The magnitude of the effect was consistent between males and females.

Table 6 Mean Body Weights and Mean Body Weight Gains of F_0_ Female Rats during Lactation in the 28-day Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Postnatal Day
1 | 272.7 ± 2.7 (20)b | 267.8 ± 2.3 (19) | 271.6 ± 2.7 (18) | 263.5 ± 2.5 (20)*
4 | 263.8 ± 3.6 (20) | 265.1 ± 2.9 (19) | 269.9 ± 4.2 (18) | 264.1 ± 2.2 (20)
7 | 284.1 ± 2.7 (20)▲▲ | 280.3 ± 1.9 (19) | 281.8 ± 2.7 (18) | 270.0 ± 2.3 (20)**
14 | 292.4 ± 2.6 (20)▲▲ | 289.9 ± 2.9 (19) | 286.4 ± 2.8 (18) | 266.1 ± 2.6 (20)**
21 | 279.7 ± 3.5 (20)▲▲ | 267.3 ± 3.7 (19)** | 265.8 ± 3.6 (11)** | 248.5 ± 2.3 (20)**
Postnatal Day Interval
1–4 | −8.9 ± 3.2 (20)▲ | −2.7 ± 2.8 (19) | −1.7 ± 2.8 (18) | 0.6 ± 1.5 (20)*
4–7 | 20.2 ± 2.3 (20)▲▲ | 15.2 ± 2.0 (19) | −12.0 ± 2.6 (18)** | 5.9 ± 1.1 (20)**
7–14 | 8.3 ± 1.4 (20)▲▲ | 9.6 ± 2.1 (19) | 4.6 ± 2.0 (18) | −4.0 ± 1.5 (20)**
4–21 | −12.7 ± 3.5 (20) | −22.7 ± 3.2 (19)* | −16.9 ± 3.1 (11) | −17.6 ± 1.7 (20)
1–21 | 7.0 ± 3.8 (20)^▲▲^ | −0.5 ± 2.6 (19) | −1.9 ± 2.5 (11) | −15.0 ± 1.8 (20)**

^▲^Significant trend (P ≤ 0.05).

^▲▲^P ≤ 0.01.

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Body weights and body weight gains in grams. Data are displayed as mean ± standard error. Statistical analysis performed by Jonckheere’s test (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ Number of dams.

Table 7 Adjusted Mean Body Weights of F_1_ Male and Female Rats during Lactation in the 28-day Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Adjusted Male Live Pup Weight
PND 1b | 6.70 ± 0.10 (20)^▲▲c^ | 6.71 ± 0.09 (19) | 6.46 ± 0.10 (18) | 5.99 ± 0.09 (20)^▲▲^
PND 4 (preculling) | 9.68 ± 0.14 (121/20)**^d^ | 9.59 ± 0.13 (109/19) | 9.08 ± 0.13 (117/18)* | 8.09 ± 0.19 (108/20)**
PND 4 (postculling) | 9.75 ± 0.13 (81/20)** | 9.67 ± 0.14 (74/19) | 9.18 ± 0.13 (71/18)* | 8.20 ± 0.16 (75/20)**
PND 7 | 16.22 ± 0.19 (81/20)** | 15.56 ± 0.21 (74/19) | 14.84 ± 0.28 (71/18)** | 13.06 ± 0.31 (75/20)**
PND 14 | 31.52 ± 0.42 (81/20)** | 31.29 ± 0.31 (74/19) | 30.05 ± 0.42 (71/18)* | 26.63 ± 0.47 (75/20)**
PND 21 | 53.19 ± 0.72 (81/20)** | 52.86 ± 0.61 (74/19) | 51.20 ± 0.71 (71/18) | 45.52 ± 0.94 (75/20)**
Adjusted Female Live Pup Weight
PND 1 | 6.28 ± 0.10 (20)^▲▲^ | 6.43 ± 0.07 (19) | 6.17 ± 0.11 (18) | 5.89 ± 0.09 (20)^▲▲^
PND 4 (preculling) | 9.09 ± 0.15 (116/20)** | 9.16 ± 0.14 (110/19) | 8.76 ± 0.16 (107/18) | 7.95 ± 0.18 (121/20)**
PND 4 (postculling) | 9.13 ± 0.16 (79/20)** | 9.23 ± 0.14 (73/19) | 8.74 ± 0.16 (73/18) | 8.11 ± 0.17 (83/20)**
PND 7 | 15.17 ± 0.24 (79/20)** | 14.91 ± 0.23 (73/19) | 13.96 ± 0.30 (72/18)** | 12.95 ± 0.31 (83/20)**
PND 14 | 29.76 ± 0.40 (79/20)** | 30.03 ± 0.36 (73/19) | 28.67 ± 0.48 (72/18) | 26.41 ± 0.42 (82/20)**
PND 21 | 49.78 ± 0.73 (79/20)** | 49.45 ± 0.58 (73/19) | 48.47 ± 0.76 (72/18) | 44.25 ± 0.87 (82/20)**
Adjusted Combined Live Pup Weight
PND 1 | 6.48 ± 0.10 (20)^▲▲^ | 6.57 ± 0.08 (19) | 6.33 ± 0.10 (18) | 5.95 ± 0.08 (20)^▲▲^
PND 4 (preculling) | 9.38 ± 0.13 (237/20)** | 9.38 ± 0.14 (219/19) | 8.94 ± 0.13 (224/18) | 8.05 ± 0.17 (229/20)**
PND 4 (postculling) | 9.44 ± 0.13 (160/20)** | 9.45 ± 0.14 (147/19) | 8.96 ± 0.14 (144/18) | 8.16 ± 0.16 (158/20)**
PND 7 | 15.69 ± 0.19 (160/20)** | 15.24 ± 0.21 (147/19) | 14.40 ± 0.27 (143/18)** | 13.00 ± 0.30 (158/20)**
PND 14 | 30.62 ± 0.39 (160/20)** | 30.66 ± 0.32 (147/19) | 29.35 ± 0.43 (143/18) | 26.51 ± 0.43 (157/20)**
PND 21 | 51.46 ± 0.67 (160/20)** | 51.17 ± 0.55 (147/19) | 49.84 ± 0.70 (143/18) | 44.87 ± 0.88 (157/20)**

^▲▲^Significantly different (P ≤ 0.01) for PND 1 endpoint (statistical significance in the sham control group column indicates a significant trend test; statistical significance in a treatment group column indicates a significant pairwise comparison against the sham control group).

* Significantly different (P ≤ 0.05) for PNDs after PND 1 endpoints (statistical significance in the sham control group column indicates a significant trend test; statistical significance in a treatment group column indicates a significant pairwise comparison against the sham control group).

** P ≤ 0.01.

^a^ Body weights in grams. Data are displayed as mean ± standard error. PND = postnatal day. Values listed as PND 1 refer to the total pup weight divided by the number of pups in litter at PND 1, and the statistical analysis performed is by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests. Values listed for all other days refer to individual pups, and the statistical analysis is for linear trends performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dose groups to sham control group were performed using mixed models with categorical dose and dam ID (litter) as random effect with Dunnett-Hsu adjustment method. Individual pup body weights first adjusted for live PND 1 litter size via the analysis of covariance.

^b^ Values listed as PND 1 refer to the total pup weight divided by the number of pups in litter at PND 1.

^c^ Number of dams.

^d^ Number of pups/number of dams.

#### Postnatal Study

All rats survived to the end of the study (Table 8). There were lower mean body weights in the male 6 (6% to 9%) and 9 (16% to 19%) W/kg groups compared to sham controls at all time points including terminal sacrifice (Table 8 and Figure 6). Mean body weight gains were also lower in these groups (10% to 16%) (Data not presented). In 3 W/kg males, mean body weights were lower on day 22 (5%) and at terminal sacrifice (7%), but body weight gains were comparable to that of the sham controls. In females, mean body weights were lower on days 1, 8, 15, and 22 in the 9 W/kg group (8% to 11%) and on days 8 and 15 in the 6 W/kg group (5%). However, mean body weights at terminal sacrifice and mean body weight gains in all exposed female groups were similar to those of the sham controls. There were no notable clinical observations in either sex during the study.

Table 8 Mean Body Weights and Survival of Rats Exposed to GSM-modulated Cell Phone RFR for 28 Days

Day | Sham Control | | 3 W/kg | | | 6 W/kg | | | 9 W/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt.(g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 60.8 | 10 | 60.3 | 99.1 | 10 | 57.4 | 94.3 | 11 | 50.8 | 83.5 | 10
8 | 94.9 | 10 | 91.3 | 96.3 | 10 | 87.1 | 91.9 | 11 | 77.3 | 81.5 | 10
15 | 144.5 | 10 | 137.2 | 94.9 | 10 | 132.4 | 91.6 | 11 | 117.7 | 81.4 | 10
22 | 195.3 | 10 | 184.7 | 94.5 | 10 | 178.0 | 91.1 | 11 | 158.6 | 81.2 | 10
29 | 248.7 | 10 | 231.3 | 93.0 | 10 | 227.0 | 91.3 | 10 | 204.6 | 82.3 | 10
Female
1 | 55.9 | 10 | 54.4 | 97.3 | 10 | 53.7 | 96.1 | 10 | 49.6 | 88.8 | 10
8 | 83.1 | 10 | 80.0 | 96.2 | 10 | 78.9 | 94.9 | 10 | 73.6 | 88.5 | 10
15 | 119.8 | 10 | 114.8 | 95.8 | 10 | 113.9 | 95.1 | 10 | 107.5 | 89.7 | 10
22 | 146.5 | 10 | 142.9 | 97.6 | 10 | 143.1 | 97.7 | 10 | 134.6 | 91.9 | 10
30 | 166.5 | 10 | 163.1 | 98.0 | 10 | 168.0 | 100.9 | 10 | 155.7 | 93.5 | 10

Figure 6

Growth Curves for Rats Exposed to GSM-modulated Cell Phone RFR for 28 Days

The average temperature over gestation (GD 7 through 16) was increased compared to sham controls in the 6 and 9 W/kg groups by 0.4 and 0.5 degrees, respectively (Table 9). During lactation, the average (LD 1 through 14) temperature was also increased in the 6 and 9 W/kg groups by 0.7 and 1.0 degrees, respectively. In the F1 offspring, average (study day 16 through 27; ~PND 37 through 48) body temperatures were decreased by 0.5 degrees in the 3 W/kg male group and by 0.9 degrees in the 6 W/kg female group (Table 9 and Table G-1).

Table 9 Mean Body Temperatures of Rats Exposed to GSM-modulated Cell Phone RFR for 28 Days^a^

Day | Sham Control | | 3 W/kg | | 6 W/kg | | 9 W/kg
Day | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured
F0 Female^b^
GD 6 | 36.7 ± 0.1 | 10^c^ | 37.4 ± 0.2** | 9 | 36.5 ± 0.1 | 9 | 36.8 ± 0.2 | 10
GD 7 | 36.6 ± 0.1^▲▲^ | 10 | 36.7 ± 0.1 | 9 | 37.1 ± 0.1* | 9 | 37.2 ± 0.1** | 10
GD 11 | 36.7 ± 0.2^▲▲^ | 10 | 36.5 ± 0.1 | 9 | 37.1 ± 0.1 | 9 | 37.2 ± 0.1* | 10
GD 16 | 36.5 ± 0.1^▲▲^ | 10 | 36.5 ± 0.1 | 9 | 36.8 ± 0.1 | 9 | 37.0 ± 0.1** | 10
GD 7–16^d^ | 36.6 ± 0.1^▲▲^ | 10 | 36.6 ± 0.1 | 9 | 37.0 ± 0.1** | 9 | 37.1 ± 0.0** | 10
LD 1 | 37.7 ± 0.1^▲▲^ | 10 | 37.8 ± 0.1 | 9 | 38.1 ± 0.2 | 9 | 38.4 ± 0.2** | 10
LD 4 | 36.7 ± 0.1^▲▲^ | 10 | 37.1 ± 0.2 | 9 | 37.5 ± 0.2** | 9 | 37.9 ± 0.1** | 10
LD 7 | 36.8 ± 0.2 | 10 | 37.1 ± 0.2 | 9 | 37.2 ± 0.2 | 9 | 37.2 ± 0.2 | 10
LD 14 | 36.9 ± 0.2^▲▲^ | 10 | 37.1 ± 0.1 | 9 | 37.8 ± 0.2** | 9 | 38.3 ± 0.2** | 8
LD 1–14^d^ | 37.0 ± 0.1^▲▲^ | 10 | 37.3 ± 0.1 | 9 | 37.7 ± 0.1** | 9 | 38.0 ± 0.1** | 10
F1 Male^e^
16 | 37.4 ± 0.2 | 4 | 37.0 ± 0.1 | 4 | 37.2 ± 0.2 | 4 | 37.2 ± 0.1 | 4
20 | 37.6 ± 0.1 | 4 | 37.0 ± 0.1** | 4 | 37.2 ± 0.2 | 4 | 37.4 ± 0.1 | 4
27 | 37.3 ± 0.2 | 4 | 37.0 ± 0.1 | 4 | 37.2 ± 0.0 | 3 | 37.4 ± 0.1 | 4
16–27^d^ | 37.5 ± 0.1 | 4 | 37.0 ± 0.0* | 4 | 37.2 ± 0.1 | 4^f^ | 37.4 ± 0.1 | 4
F1 Female^e^
16 | 38.0 ± 0.3 | 4 | 37.0 ± 0.2** | 4 | 37.0 ± 0.1* | 4 | 37.4 ± 0.1 | 4
20 | 38.1 ± 0.2 | 4 | 37.6 ± 0.1 | 4 | 37.0 ± 0.1** | 4 | 37.6 ± 0.1 | 4
27 | 37.9 ± 0.2 | 4 | 37.8 ± 0.3 | 4 | 37.3 ± 0.3 | 4 | 37.6 ± 0.0 | 4
16–27^d^ | 38.0 ± 0.2^▲^ | 4 | 37.4 ± 0.1 | 4 | 37.1 ± 0.1** | 4 | 37.5 ± 0.0 | 4

^▲^Significant trend (P ≤ 0.05).

^▲▲^P ≤ 0.01.

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Temperatures are given as mean ± standard error. GD = gestation day; LD = lactation day.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^c^ For F_0_ females, number measured refers to individual animals; for F_1_ pups, number measured refers to litters.

^d^ Average of days.

^e^ Statistical analysis for linear trends was performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dose groups to sham control were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett-Hsu adjustment method.

^f^ There were three litters on day 27.

The relative brain and testis weights in exposed male groups were increased compared to the sham control group, but this was considered to be due to the lower necropsy body weights (8%, 10%, and 20% lower than sham controls in the 3, 6, and 9 W/kg groups, respectively) and not an exposure-related effect (Table G-2). Significant decreases in absolute heart weights were observed in 6 and 9 W/kg males (14% and 22%, respectively), but the relative heart weights were not affected. Similarly, absolute right kidney and liver weights were decreased in 9 W/kg males (24% and 19%, respectively), but without corresponding effects in the relative weights. These decreases in organ weights could be related to the lower body weights in males. No effects in organ weights were observed in female rats.

In females, there were increased incidences of chronic progressive nephropathy in the kidney of 3 and 9 W/kg groups (sham controls, 0/10; 3 W/kg, 4/10; 6 W/kg, 3/10; 9 W/kg, 4/10) compared to the sham controls. The severity of these lesions was minimal (1.0). Chronic progressive nephropathy was characterized by scattered tubular segments with basophilic epithelial cells with crowded nuclei, slightly thickened basement membranes, and occasional mononuclear inflammatory cells. There were no exposure-related renal lesions in male rats.

Exposure Level Selection Rationale: Based on pup mortality, reduced maternal and pup body weights, increased F0 dam body temperature measurements at 9 W/kg in the 28-day studies, and increased body temperature in adult rats at ≥8 W/kg in the thermal pilot studies,^146^ the highest exposure level selected for the 2-year studies was 6 W/kg. In the thermal pilot studies and in the 28-day study, exposure to 6 W/kg resulted in some increases in core body temperature, but these increases were less than 1°C. Therefore, 6 W/kg would provide an exposure adequate to challenge the animals without causing excessive heating or disruption of the thermoregulatory process. The lowest exposure level selected for the 2-year studies was 1.5 W/kg, which is close to the 1.6 W/kg maximum output limit for cell phone devices in the United States.

### Two-year Study

#### Perinatal Exposure

No exposure-related effects were observed on pregnancy status, maternal survival, or the percent of pregnant animals that littered (Table 10). Maternal body weights during gestation were similar to those of the sham control group (Table 11). Body weight gains were generally unaffected across time intervals except in the 6 W/kg group at the GD 5 through 18 interval where body weight gain was 10% lower than that of the sham control group and the GD 6 through 21 interval where body weight gain was 7% lower than that of the sham control group.

Table 10 Summary of Disposition during Perinatal Exposure and F_1_ Allocation in the Two-year Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Time-mated Females | 56 | 56 | 56 | 56
Pregnant Females | 52 | 50 | 50 | 52
Nonpregnant Females | 4 | 6 | 6 | 4
Pregnant Dams Not Delivering | 2 | 3 | 3 | 4
Died^a^ | 1 | 0 | 0 | 0
Littered | 50 | 47 | 47 | 48
Pregnant/Mated Percentage^b^ | 92.9% | 89.3% | 89.3% | 92.9%
Littered/Pregnant Percentage^b^ | 96.2% | 94.0% | 94.0% | 92.3%
Litters Removed (Insufficient Size) | 2 | 4 | 5 | 2
Litters Post Standardization | 48 | 43 | 42 | 46
Weaned/Sex^c^ | 105 | 105 | 105 | 105

^a^ One pregnant female died on GD 25 with pups in uterus.

^b^ Number in the numerator as proportion of the number in the denominator was tested using the Fisher exact test for pairwise comparison against sham control group.

^c^ Total number of weaned animals per sex from 35 litters.

Table 11 Mean Body Weights and Mean Body Weight Gains of F_0_ Female Rats during Gestation in the Two-year Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Gestation Day
6 | 238.4 ± 1.4 (51)b | 239.9 ± 1.4 (47) | 239.0 ± 1.4 (47) | 238.9 ± 1.3 (48)
9 | 256.2 ± 1.6 (51) | 256.3 ± 1.6 (47) | 254.9 ± 1.6 (47) | 254.7 ± 1.3 (48)
12 | 270.5 ± 1.6 (51) | 270.4 ± 1.7 (47) | 269.2 ± 1.6 (47) | 268.1 ± 1.4 (48)
15 | 290.0 ± 1.9 (51) | 289.7 ± 2.0 (47) | 288.8 ± 1.8 (47) | 287.6 ± 1.6 (48)
18 | 332.7 ± 2.3 (51)^▲^ | 329.8 ± 2.6 (47) | 328.9 ± 2.2 (47) | 326.1 ± 2.1 (48)
21 | 380.2 ± 2.8 (51)^▲^ | 376.9 ± 3.6 (47) | 374.6 ± 3.5 (47) | 371.2 ± 3.0 (48)
Gestation Day Interval
6–9 | 17.7 ± 0.8 (51) | 16.4 ± 0.6 (47) | 15.9 ± 0.6 (47) | 15.8 ± 0.5 (48)
9–12 | 14.3 ± 0.6 (51) | 14.1 ± 0.5 (47) | 14.2 ± 0.5 (47) | 13.4 ± 0.5 (48)
12–15 | 19.6 ± 0.6 (51) | 19.3 ± 0.8 (47) | 19.7 ± 0.6 (47) | 19.5 ± 0.6 (48)
15–18 | 42.7 ± 1.0 (51)^▲▲^ | 40.2 ± 1.1 (47) | 40.1 ± 0.9 (47) | 38.5 ± 0.9 (48)**
18–21 | 47.5 ± 1.0 (51) | 47.1 ± 1.5 (47) | 45.6 ± 1.5 (47) | 45.1 ± 1.3 (48)
6–21 | 141.7 ± 2.2 (51)^▲▲^ | 137.0 ± 3.3 (47) | 135.5 ± 2.9 (47) | 132.3 ± 2.6 (48)*

^▲^Significant trend (P ≤ 0.05).

^▲▲^P ≤ 0.01.

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Body weights and body weight gains in grams. Data are displayed as mean ± standard error. Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ Number of dams.

Total litter size on PND 1 and live litter size at all time points were unaffected by exposure with no effects observed in pup mortality or survival ratio in early postnatal development (PND 1 through 4) or thereafter (PND 4 through 21) (Table 12 and Table 13).

Table 12 Mean Number of Surviving F_1_ Male and Female Rats during Lactation in the Two-year Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Total Pups per Litter
PND 1 | 12.76 ± 0.32 (50)^b^ | 12.06 ± 0.43 (47) | 12.26 ± 0.51 (47) | 12.31 ± 0.39 (48)
Live Pups per Litter
PND 1 | 12.56 ± 0.40 (50) | 12.04 ± 0.43 (47) | 12.23 ± 0.51 (47) | 12.29 ± 0.39 (48)
PND 4 (preculling) | 12.73 ± 0.30 (48) | 12.65 ± 0.26 (43) | 12.98 ± 0.27 (42) | 12.41 ± 0.32 (46)
PND 4 (postculling) | 8.00 ± 0.00 (48) | 8.00 ± 0.00 (43) | 8.00 ± 0.00 (42) | 8.00 ± 0.00 (46)
PND 7 | 8.00 ± 0.00 (48) | 7.98 ± 0.02 (43) | 7.95 ± 0.03 (42) | 7.98 ± 0.02 (46)
PND 10 | 8.00 ± 0.00 (48) | 7.98 ± 0.02 (43) | 7.93 ± 0.04 (42) | 7.98 ± 0.02 (46)
PND 14 | 8.00 ± 0.00 (48) | 7.98 ± 0.02 (43) | 7.93 ± 0.04 (42) | 7.98 ± 0.02 (46)
PND 17 | 8.00 ± 0.00 (48) | 7.98 ± 0.02 (43) | 7.93 ± 0.04 (42) | 7.98 ± 0.02 (46)
PND 21 | 8.00 ± 0.00 (48) | 7.98 ± 0.02 (43) | 7.93 ± 0.04 (42) | 7.98 ± 0.02 (46)
Live Males per Litter
PND 1 | 6.20 ± 0.30 (50) | 6.00 ± 0.34 (47) | 6.11 ± 0.38 (47) | 6.02 ± 0.32 (48)
PND 4 (preculling) | 6.33 ± 0.28 (48) | 6.35 ± 0.30 (43) | 6.62 ± 0.32 (42) | 6.15 ± 0.30 (46)
PND 4 (postculling) | 3.96 ± 0.05 (48) | 3.98 ± 0.07 (43) | 4.00 ± 0.07 (42) | 4.02 ± 0.10 (46)
Live Females per Litter
PND 1 | 6.36 ± 0.28 (50) | 6.04 ± 0.32 (47) | 6.13 ± 0.33 (47) | 6.27 ± 0.33 (48)
PND 4 (preculling) | 6.40 ± 0.25 (48) | 6.30 ± 0.26 (43) | 6.36 ± 0.30 (42) | 6.26 ± 0.34 (46)
PND 4 (postculling) | 4.04 ± 0.05 (48) | 4.02 ± 0.07 (43) | 4.00 ± 0.07 (42) | 3.98 ± 0.10 (46)

^a^ All values shown as mean ± standard error; PND = postnatal day. Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^b^ Number of dams.

Table 13 Offspring Mortality and Survival Ratio of Rats during Lactation in the Two-year Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

Pup Survival per Litter | Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Total Dead PND 1–4^b^ | 19 (628/49)^c^ | 4 (566/43) | 12 (575/42) | 10 (590/46)
Total Dead PND 5–21 | 0 (348/48) | 1 (344/43) | 3 (336/42) | 1 (368/46)
Dead/Litter PND 1–4 | 0.388 ± 0.193 (49) | 0.093 ± 0.045 (43) | 0.286 ± 0.104 (42) | 0.217 ± 0.076 (46)
Dead/Litter PND 4–21 | 0.000 ± 0.000 (48) | 0.023 ± 0.023 (43) | 0.071 ± 0.040 (42) | 0.022 ± 0.022 (46)
Survival Ratio PND 1–4^d^ | 0.986 ± 0.005 (48) | 0.994 ± 0.003 (43) | 0.981 ± 0.007 (42) | 0.985 ± 0.005 (46)
Survival Ratio PND 4–21^e^ | 1.000 ± 0.000 (48) | 0.997 ± 0.003 (43) | 0.991 ± 0.005 (42) | 0.997 ± 0.003 (46)

^a^ All values shown as mean ± standard error; PND = postnatal day. Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^b^ Includes dead on PND 1. Survival information on PND 4 was not available for some non-acceptable litters, so these were excluded from the analysis.

^c^ Number of pups/number of dams.

^d^ Number of pups preculling on PND 4/total number of viable pups on PND 1 (does not include pups dead on PND 1).

^e^ Number of pups alive on PND 21/number of pups at postculling on PND 4.

During the lactation period, maternal body weights of the 3 and 6 W/kg groups were significantly decreased (up to 5% and 9%, respectively) compared to those of sham controls from PND 4 through 21 (Table 14). At PND 1, male and female pup weights in the 6 W/kg groups were 4% to 5% less than those of the sham controls (Table 15). Male and female pup weights were also significantly decreased compared to the sham controls with a 4% to 8% decrease across most time points in the 3 W/kg groups and a 6% to 8% decrease across all time points in the 6 W/kg groups.

Table 14 Mean Body Weights and Mean Body Weight Gains of F_0_ Female Rats during Lactation in the Two-year Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Postnatal Day
1 | 280.9 ± 2.0 (50)^▲▲b^ | 280.6 ± 2.0 (47) | 277.0 ± 1.7 (47) | 275.9 ± 1.7 (48)
4 | 289.7 ± 2.1 (48)^▲▲^ | 288.7 ± 2.0 (43) | 284.3 ± 1.9 (42) | 280.6 ± 1.8 (46)**
7 | 297.1 ± 2.2 (48)^▲▲^ | 293.7 ± 2.1 (43) | 290.4 ± 1.9 (42)* | 286.4 ± 1.9 (46)**
14 | 314.4 ± 2.0 (48)^▲▲^ | 310.1 ± 2.3 (43) | 302.3 ± 1.8 (42)** | 290.7 ± 2.2 (46)**
17 | 313.9 ± 2.2 (48)^▲▲^ | 309.2 ± 2.4 (43) | 299.2 ± 1.8 (42)** | 285.3 ± 2.5 (46)**
21 | 299.7 ± 2.2 (48)^▲▲^ | 295.9 ± 2.4 (43) | 287.6 ± 1.8 (42)** | 278.1 ± 2.4 (45)**
Postnatal Day Interval
1–4 | 9.2 ± 0.9 (48)^▲▲^ | 8.1 ± 1.0 (43) | 7.3 ± 1.1 (42) | 4.8 ± 1.1 (46)**
4–7 | 7.4 ± 1.5 (48) | 5.0 ± 1.2 (43) | 6.1 ± 1.3 (42) | 5.8 ± 0.9 (46)
7–14 | 17.4 ± 1.4 (48)^▲▲^ | 16.4 ± 1.4 (43) | 11.9 ± 1.1 (42)** | 4.3 ± 1.2 (46)**
14–17 | –0.6 ± 1.0 (48)^▲▲^ | –0.9 ± 1.4 (43) | –3.1 ± 1.0 (42) | –5.5 ± 1.1 (46)**
17–21 | –14.1 ± 1.3 (48)^▲▲^ | –13.3 ± 1.7 (43) | –11.6 ± 1.2 (42) | –7.1 ± 1.8 (45)**
1–21 | 19.3 ± 1.5 (48)^▲▲^ | 15.3 ± 1.3 (43) | 10.6 ± 1.8 (42)** | 2.4 ± 2.0 (45)**

^▲▲^Significant trend (P ≤ 0.01).

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Body weights and body weight gains in grams. Data are displayed as mean ± standard error. Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ Number of dams.

Table 15 Adjusted Mean Body Weights of F_1_ Male and Female Rats during Lactation in the Two-year Perinatal and Postnatal Study of GSM-modulated Cell Phone RFR^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Adjusted Male Live Pup Weight
PND 1^b^ | 7.22 ± 0.07 (49)^▲▲c^ | 7.18 ± 0.06 (46) | 7.06 ± 0.07 (46) | 6.84 ± 0.08 (48)^▲▲^
PND 4 | 10.90 ± 0.12 (190/48)**^d^ | 10.70 ± 0.12 (171/43) | 10.24 ± 0.14 (168/42)** | 9.90 ± 0.12 (185/46)**
PND 7 | 17.22 ± 0.19 (189/48)** | 17.21 ± 0.19 (170/43) | 15.97 ± 0.26 (166/42)** | 15.64 ± 0.21 (185/46)**
PND 14 | 35.22 ± 0.43 (181/46)** | 34.56 ± 0.35 (166/42) | 33.04 ± 0.53 (162/41)** | 32.37 ± 0.37 (185/46)**
PND 17 | 42.46 ± 0.48 (190/48)** | 41.97 ± 0.43 (165/42) | 40.75 ± 0.59 (162/41)* | 39.79 ± 0.45 (185/46)**
PND 21 | 58.50 ± 0.62 (190/48)** | 58.40 ± 0.61 (170/43) | 56.36 ± 0.78 (166/42) | 54.99 ± 0.67 (185/46)**
Adjusted Female Live Pup Weight
PND 1^b^ | 6.83 ± 0.06 (49)^▲▲^ | 6.84 ± 0.08 (47) | 6.68 ± 0.09 (46) | 6.54 ± 0.07 (48)^▲▲^
PND 4 | 10.46 ± 0.11 (194/48)** | 10.23 ± 0.12 (172/43) | 9.78 ± 0.14 (168/42)** | 9.57 ± 0.15 (183/46)**
PND 7 | 16.49 ± 0.18 (194/48)** | 16.53 ± 0.18 (172/43) | 15.35 ± 0.22 (168/42)** | 15.05 ± 0.23 (182/46)**
PND 14 | 33.89 ± 0.38 (192/48)** | 33.47 ± 0.31 (165/41) | 32.42 ± 0.37 (164/41)* | 31.34 ± 0.38 (181/46)**
PND 17 | 40.82 ± 0.44 (194/48)** | 40.42 ± 0.36 (168/42) | 39.65 ± 0.42 (167/42) | 38.30 ± 0.45 (182/46)**
PND 21 | 55.42 ± 0.53 (194/48)** | 55.28 ± 0.45 (169/42) | 54.17 ± 0.53 (167/42) | 52.24 ± 0.64 (182/46)**
Adjusted Combined Live Pup Weight
PND 1^b^ | 7.03 ± 0.06 (49)^▲▲^ | 7.00 ± 0.08 (47) | 6.92 ± 0.08 (47) | 6.71 ± 0.07 (48)^▲▲^
PND 4 | 10.68 ± 0.11 (384/48)** | 10.47 ± 0.11 (343/43) | 10.01 ± 0.13 (336/42)** | 9.74 ± 0.13 (368/46)**
PND 7 | 16.84 ± 0.18 (383/48)** | 16.87 ± 0.18 (342/43) | 15.66 ± 0.22 (334/42)** | 15.35 ± 0.21 (367/46)**
PND 14 | 34.48 ± 0.40 (373/48)** | 34.01 ± 0.31 (331/42) | 32.70 ± 0.41 (326/42)** | 31.86 ± 0.36 (366/46)**
PND 17 | 41.62 ± 0.46 (384/48)** | 41.19 ± 0.38 (333/42) | 40.20 ± 0.46 (329/42) | 39.06 ± 0.43 (367/46)**
PND 21 | 56.93 ± 0.56 (384/48)** | 56.88 ± 0.50 (339/43) | 55.23 ± 0.60 (333/42) | 53.65 ± 0.63 (367/46)**

^▲▲^Significantly different (P ≤ 0.01) for PND 1 endpoint (statistical significance in the sham control group column indicates a significant trend test; statistical significance in a treatment group column indicates a significant pairwise comparison against the sham control group).

* Significantly different (P ≤ 0.05) for PNDs after PND 1 endpoints (statistical significance in the sham control group column indicates a significant trend test; statistical significance in a treatment group column indicates a significant pairwise comparison against the sham control group).

** P ≤ 0.01

^a^ Body weights in grams. Data are displayed as mean ± standard error. PND = postnatal day. Values listed as PND 1 refer to the total pup weight divided by the number of pups in litter at PND 1, and the statistical analysis performed is by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests. Values listed for all other days refer to individual pups, and the statistical analysis is for linear trends performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dose groups to sham control group were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett-Hsu adjustment method. Individual pup body weights first adjusted for live PND 1 litter size via the analysis of covariance.

^b^ Values listed as PND 1 refer to the total pup weight divided by the number of pups in litter at PND 1.

^c^ Number of dams.

^d^ Number of pups/number of dams.

#### Postnatal Exposure

##### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 16 and in the Kaplan-Meier survival curves (Figure 7). Survival of all male exposed groups was significantly greater than that of the sham controls. Decreased survival in the sham control group was largely attributed to the higher severity of chronic progressive nephropathy in the kidney. Survival of exposed females was similar to that of the sham controls.

Table 16 Survival of Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation^a^ | 15 | 15 | 15 | 15
Accidental deathsb | 1 | 0 | 0 | 1
Moribund | 44 | 24 | 19 | 13
Natural deaths | 20 | 21 | 21 | 16
Animals surviving to study termination | 25 | 45 | 50 | 60
Percent probability of survival at end of study^c^ | 28 | 50 | 56 | 68
Mean survival (days)^d^ | 642 | 675 | 690 | 684
Survival analysis^e^ | P < 0.001N | P = 0.002N | P ≤ 0.001N | P ≤ 0.001N
Female
Animals initially in study | 105 | 105 | 105 | 105
Fourteen-week interim evaluation | 15 | 15 | 15 | 15
Accidental death | 1 | 0 | 0 | 0
Moribund | 30 | 26 | 31 | 22
Natural deaths | 11 | 11 | 11 | 11
Animals surviving to study termination | 48^f^ | 53^f^ | 48^f^ | 57
Percent probability of survival at end of study | 54 | 59 | 53 | 63
Mean survival (days) | 659 | 682 | 662 | 676
Survival analysis | P = 0.300N | P = 0.412N | P = 1.000 | P = 0.226N

^a^ Excluded from survival analysis.

^b^ Censored in the survival analysis.

^c^ Kaplan-Meier determinations.

^d^ Mean of all deaths (uncensored, censored, and terminal euthanasia).

^e^ The result of the life table trend test^161^ is in the sham control column, and the results of the life table pairwise comparisons^160^ with the sham controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^f^ Includes one animal that died during the last week of the study.

Figure 7

Kaplan-Meier Survival Curves for Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

##### Body Weights and Clinical Observations

In 6 W/kg males, mean body weights were lower (3% to 6%) at all time points through day 401 (Table 17 and Figure 8); however, from day 541 to terminal sacrifice the mean body weights were greater than those of the sham controls (up to 7.2% greater on day 681). In the 1.5 and 3 W/kg male groups, mean body weights were 5% to 7% greater than the sham controls at some time points, but the increases were sporadic. However, at the end of the study, the mean body weights of these male groups were similar to those of the sham controls. In exposed female groups, the mean body weights and mean body weight gains were similar to those of the sham controls throughout the study (Table 18 and Figure 8). There were no exposure-related clinical observations in males or females.

Table 17 Mean Body Weights and Survival of Male Rat Litters Exposed to GSM-modulated Cell Phone RFR for Two Years

Day | Sham Control | | 1.5 W/kg | | | 3 W/kg | | | 6 W/kg
Day | Av. Wt. (g) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 64.3 | 35 | 63.9 | 99.4 | 35 | 62.0 | 96.5 | 35 | 60.9 | 94.8 | 35
5 | 78.7 | 35 | 77.6 | 98.7 | 35 | 75.1 | 95.4 | 35 | 74.3 | 94.4 | 35
9 | 99.0 | 35 | 98.1 | 99.1 | 35 | 94.9 | 95.8 | 35 | 93.9 | 94.9 | 35
12 | 117.6 | 35 | 115.7 | 98.4 | 35 | 112.9 | 96.0 | 35 | 111.6 | 94.9 | 35
16 | 145.5 | 35 | 143.1 | 98.4 | 35 | 139.5 | 95.9 | 35 | 137.9 | 94.8 | 35
19 | 167.0 | 35 | 165.4 | 99.1 | 35 | 161.1 | 96.5 | 35 | 159.2 | 95.3 | 35
23 | 197.8 | 35 | 194.9 | 98.5 | 35 | 189.9 | 96.0 | 35 | 187.1 | 94.6 | 35
26 | 217.1 | 35 | 213.7 | 98.4 | 35 | 209.6 | 96.5 | 35 | 205.0 | 94.4 | 35
30 | 246.5 | 35 | 241.3 | 97.9 | 35 | 236.6 | 96.0 | 35 | 231.7 | 94.0 | 35
33 | 264.3 | 35 | 260.4 | 98.5 | 35 | 254.7 | 96.4 | 35 | 249.2 | 94.3 | 35
37 | 290.4 | 35 | 285.9 | 98.4 | 35 | 280.2 | 96.5 | 35 | 274.1 | 94.4 | 35
40 | 304.5 | 35 | 298.7 | 98.1 | 35 | 294.9 | 96.8 | 35 | 287.3 | 94.4 | 35
44 | 322.9 | 35 | 318.0 | 98.5 | 35 | 313.7 | 97.1 | 35 | 306.4 | 94.9 | 35
47 | 333.8 | 35 | 329.8 | 98.8 | 35 | 324.3 | 97.1 | 35 | 313.9 | 94.0 | 35
51 | 349.0 | 35 | 343.7 | 98.5 | 35 | 338.9 | 97.1 | 35 | 331.4 | 95.0 | 35
54 | 357.6 | 35 | 353.5 | 98.8 | 35 | 348.5 | 97.5 | 35 | 341.0 | 95.3 | 35
58 | 370.2 | 35 | 366.4 | 99.0 | 35 | 361.3 | 97.6 | 35 | 350.7 | 94.7 | 35
61 | 379.1 | 35 | 370.9 | 97.8 | 35 | 370.2 | 97.6 | 35 | 357.2 | 94.2 | 35
65 | 389.6 | 35 | 383.0 | 98.3 | 35 | 380.3 | 97.6 | 35 | 370.2 | 95.0 | 35
68 | 395.2 | 35 | 389.9 | 98.6 | 35 | 387.0 | 97.9 | 35 | 377.4 | 95.5 | 35
72 | 404.0 | 35 | 395.9 | 98.0 | 35 | 395.2 | 97.8 | 35 | 384.1 | 95.1 | 35
75 | 409.0 | 35 | 402.5 | 98.4 | 35 | 400.0 | 97.8 | 35 | 389.2 | 95.2 | 35
79 | 417.9 | 35 | 408.3 | 97.7 | 35 | 408.0 | 97.6 | 35 | 396.5 | 94.9 | 35
82 | 422.7 | 35 | 412.2 | 97.5 | 35 | 413.1 | 97.7 | 35 | 401.4 | 95.0 | 35
86 | 427.7 | 35 | 420.4 | 98.3 | 35 | 418.5 | 97.8 | 35 | 409.1 | 95.7 | 35
89 | 432.4 | 35 | 422.6 | 97.7 | 35 | 422.7 | 97.8 | 35 | 410.2 | 94.9 | 35
93 | 439.3 | 35 | 432.3 | 98.4 | 35 | 429.8 | 97.8 | 35 | 419.3 | 95.4 | 35
121^a^ | 471.3 | 35 | 470.7 | 99.9 | 35 | 465.0 | 98.7 | 35 | 458.3 | 97.3 | 35
149 | 501.7 | 35 | 496.8 | 99.0 | 35 | 494.4 | 98.5 | 35 | 481.9 | 96.1 | 35
177 | 522.0 | 35 | 518.6 | 99.3 | 35 | 514.1 | 98.5 | 35 | 503.8 | 96.5 | 35
205 | 540.4 | 35 | 539.0 | 99.7 | 35 | 532.9 | 98.6 | 35 | 523.0 | 96.8 | 35
233 | 560.8 | 35 | 558.1 | 99.5 | 35 | 552.1 | 98.4 | 35 | 539.5 | 96.2 | 35
261 | 575.2 | 35 | 573.9 | 99.8 | 35 | 568.3 | 98.8 | 35 | 555.4 | 96.5 | 35
289 | 590.2 | 35 | 589.6 | 99.9 | 35 | 583.4 | 98.8 | 35 | 570.3 | 96.6 | 35
317 | 608.0 | 35 | 606.3 | 99.7 | 35 | 597.4 | 98.3 | 35 | 585.0 | 96.2 | 35
345 | 618.4 | 35 | 617.4 | 99.8 | 35 | 608.4 | 98.4 | 35 | 596.3 | 96.4 | 35
373 | 628.4 | 35 | 632.3 | 100.6 | 35 | 619.4 | 98.6 | 35 | 606.0 | 96.4 | 35
401 | 636.3 | 35 | 641.2 | 100.8 | 35 | 630.1 | 99.0 | 35 | 615.0 | 96.6 | 35
429 | 641.4 | 35 | 646.9 | 100.9 | 35 | 637.2 | 99.4 | 35 | 624.5 | 97.4 | 35
457 | 639.9 | 35 | 652.0 | 101.9 | 35 | 641.3 | 100.2 | 35 | 630.3 | 98.5 | 35
485 | 645.0 | 35 | 659.8 | 102.3 | 35 | 652.3 | 101.1 | 35 | 640.1 | 99.2 | 35
513 | 654.1 | 35 | 675.1 | 103.2 | 35 | 667.1 | 102.0 | 35 | 650.2 | 99.4 | 35
541 | 649.5 | 35 | 687.0 | 105.8 | 35 | 676.3 | 104.1 | 35 | 657.5 | 101.2 | 35
569 | 651.2 | 33 | 686.5 | 105.4 | 35 | 672.1 | 103.2 | 35 | 659.9 | 101.3 | 35
597 | 659.2 | 32 | 687.6 | 104.3 | 35 | 679.4 | 103.1 | 34 | 664.7 | 100.8 | 35
625 | 652.8 | 32 | 685.7 | 105.0 | 35 | 672.9 | 103.1 | 34 | 667.1 | 102.2 | 35
639 | 645.9 | 32 | 682.5 | 105.7 | 35 | 670.2 | 103.8 | 33 | 665.3 | 103.0 | 33
653 | 630.8 | 31 | 675.3 | 107.1 | 35 | 663.5 | 105.2 | 33 | 664.8 | 105.4 | 33
667 | 632.9 | 28 | 673.2 | 106.4 | 34 | 659.0 | 104.1 | 33 | 668.1 | 105.6 | 33
681 | 621.0 | 26 | 657.9 | 105.9 | 33 | 652.9 | 105.1 | 33 | 668.1 | 107.6 | 33
695 | 625.8 | 21 | 656.3 | 104.9 | 32 | 638.8 | 102.1 | 33 | 663.3 | 106.0 | 32
709 | 624.0 | 20 | 650.5 | 104.2 | 30 | 638.1 | 102.3 | 31 | 650.9 | 104.3 | 32
723 | 624.9 | 19 | 637.1 | 101.9 | 29 | 633.1 | 101.3 | 28 | 641.4 | 102.6 | 31
Mean for Weeks
1–14 | 297.9 | – | 292.9 | 98.3 | – | 289.7 | 97.2 | – | 282.6 | 94.9 | –
15–52 | 554.2 | – | 552.3 | 99.7 | – | 546.2 | 98.6 | – | 534.8 | 96.5 | –
53–104 | 639.0 | – | 663.9 | 103.9 | – | 653.2 | 102.2 | – | 649.2 | 101.6 | –

^a^ Interim evaluation occurred during week 14.

Figure 8

Growth Curves for Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

Table 18 Mean Body Weights and Survival of Female Rat Litters Exposed to GSM-modulated Cell Phone RFR for Two Years

Day | Sham Control | | 1.5 W/kg | | | 3 W/kg | | | 6 W/kg
Day | Av. Wt. (g) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 60.4 | 35 | 59.9 | 99.3 | 35 | 58.7 | 97.2 | 35 | 58.0 | 96.1 | 35
5 | 72.1 | 35 | 71.0 | 98.5 | 35 | 70.4 | 97.7 | 35 | 69.6 | 96.5 | 35
9 | 88.7 | 35 | 87.2 | 98.3 | 35 | 85.8 | 96.7 | 35 | 85.0 | 95.8 | 35
12 | 103.3 | 35 | 100.7 | 97.5 | 35 | 99.6 | 96.5 | 35 | 98.6 | 95.5 | 35
16 | 123.2 | 35 | 120.1 | 97.5 | 35 | 118.8 | 96.4 | 35 | 117.8 | 95.6 | 35
19 | 136.3 | 35 | 134.4 | 98.6 | 35 | 133.0 | 97.6 | 35 | 131.2 | 96.3 | 35
23 | 151.5 | 35 | 150.4 | 99.3 | 35 | 148.6 | 98.0 | 35 | 147.7 | 97.5 | 35
26 | 158.5 | 35 | 160.3 | 101.1 | 35 | 156.78 | 98.9 | 35 | 155.8 | 98.3 | 35
30 | 169.1 | 35 | 170.2 | 100.7 | 35 | 166.4 | 98.4 | 35 | 167.2 | 98.9 | 35
33 | 176.4 | 35 | 178.3 | 101.1 | 35 | 175.0 | 99.2 | 35 | 174.6 | 99.0 | 35
37 | 188.7 | 35 | 190.8 | 101.1 | 35 | 185.1 | 98.1 | 35 | 186.4 | 98.8 | 35
40 | 195.8 | 35 | 196.8 | 100.5 | 35 | 193.2 | 98.7 | 35 | 192.3 | 98.2 | 35
44 | 203.7 | 35 | 205.4 | 100.9 | 35 | 201.8 | 99.1 | 35 | 202.2 | 99.3 | 35
47 | 209.9 | 35 | 210.9 | 100.5 | 35 | 208.5 | 99.3 | 35 | 207.1 | 98.7 | 35
51 | 218.1 | 35 | 220.7 | 101.2 | 35 | 214.5 | 98.3 | 35 | 216.4 | 99.2 | 35
54 | 220.1 | 35 | 225.2 | 102.3 | 35 | 220.6 | 100.2 | 35 | 220.7 | 100.3 | 35
58 | 228.6 | 35 | 230.6 | 100.9 | 35 | 225.8 | 98.8 | 35 | 226.7 | 99.2 | 35
61 | 233.9 | 35 | 235.2 | 100.6 | 35 | 230.2 | 98.4 | 35 | 229.9 | 98.3 | 35
65 | 239.0 | 35 | 238.7 | 99.9 | 35 | 236.2 | 98.8 | 35 | 235.2 | 98.4 | 35
68 | 241.7 | 35 | 242.5 | 100.3 | 35 | 240.5 | 99.5 | 35 | 240.6 | 99.5 | 35
72 | 244.9 | 35 | 243.9 | 99.6 | 35 | 242.0 | 98.8 | 35 | 240.7 | 98.3 | 35
75 | 247.6 | 35 | 246.6 | 99.6 | 35 | 246.7 | 99.7 | 35 | 246.3 | 99.5 | 35
79 | 251.6 | 35 | 251.4 | 99.9 | 35 | 249.7 | 99.3 | 35 | 249.2 | 99.1 | 35
82 | 253.5 | 35 | 252.9 | 99.8 | 35 | 252.2 | 99.5 | 35 | 250.9 | 99.0 | 35
86 | 254.4 | 35 | 255.8 | 100.6 | 35 | 253.8 | 99.8 | 35 | 253.5 | 99.6 | 35
89 | 256.2 | 35 | 255.1 | 99.5 | 35 | 255.5 | 99.7 | 35 | 254.1 | 99.2 | 35
93 | 257.4 | 35 | 261.3 | 101.4 | 35 | 257.2 | 99.8 | 35 | 258.8 | 100.5 | 35
121^a^ | 275.6 | 35 | 278.4 | 101.0 | 35 | 274.3 | 99.5 | 35 | 274.9 | 99.7 | 35
149 | 284.8 | 35 | 287.3 | 100.9 | 35 | 283.0 | 99.4 | 35 | 285.1 | 100.1 | 35
177 | 295.0 | 35 | 296.7 | 100.6 | 35 | 294.0 | 99.7 | 35 | 295.7 | 100.2 | 35
205 | 302.8 | 35 | 307.5 | 101.5 | 35 | 302.4 | 99.9 | 35 | 304.4 | 100.5 | 35
233 | 311.4 | 35 | 315.6 | 101.4 | 35 | 311.3 | 100.0 | 35 | 314.1 | 100.9 | 35
261 | 317.9 | 35 | 323.3 | 101.7 | 35 | 317.3 | 99.8 | 35 | 321.8 | 101.2 | 35
289 | 330.8 | 35 | 330.0 | 99.7 | 35 | 329.4 | 99.6 | 35 | 325.5 | 98.4 | 35
317 | 340.8 | 35 | 340.9 | 100.0 | 35 | 336.3 | 98.7 | 35 | 337.1 | 98.9 | 35
345 | 348.2 | 35 | 347.5 | 99.8 | 35 | 345.0 | 99.1 | 35 | 343.7 | 98.7 | 35
373 | 355.2 | 35 | 355.1 | 100.0 | 35 | 355.0 | 99.9 | 35 | 348.8 | 98.2 | 35
401 | 366.7 | 35 | 366.0 | 99.8 | 35 | 365.3 | 99.6 | 34 | 359.4 | 98.0 | 35
429 | 375.9 | 35 | 375.6 | 99.9 | 35 | 376.5 | 100.2 | 34 | 367.4 | 97.7 | 35
457 | 386.6 | 35 | 384.0 | 99.3 | 35 | 387.9 | 100.3 | 34 | 375.3 | 97.1 | 35
485 | 400.1 | 35 | 395.1 | 98.7 | 33 | 396.1 | 99.0 | 33 | 389.5 | 97.4 | 35
513 | 410.3 | 35 | 411.7 | 100.3 | 33 | 403.2 | 98.3 | 33 | 401.8 | 97.9 | 35
541 | 421.4 | 35 | 423.8 | 100.6 | 33 | 413.3 | 98.1 | 33 | 411.4 | 97.6 | 35
570 | 426.0 | 35 | 432.9 | 101.6 | 33 | 423.3 | 99.4 | 33 | 425.9 | 100.0 | 34
598 | 433.7 | 35 | 439.3 | 101.3 | 33 | 433.6 | 100.0 | 33 | 437.4 | 100.9 | 34
626 | 447.7 | 34 | 446.6 | 99.8 | 33 | 436.4 | 97.5 | 32 | 451.3 | 100.8 | 34
640 | 454.9 | 33 | 453.2 | 99.6 | 33 | 442.2 | 97.2 | 32 | 455.2 | 100.1 | 34
654 | 459.5 | 33 | 454.9 | 99.0 | 33 | 445.8 | 97.0 | 32 | 456.3 | 99.3 | 34
668 | 448.5 | 31 | 463.2 | 103.3 | 33 | 450.5 | 100.4 | 32 | 458.8 | 102.3 | 34
682 | 450.7 | 31 | 471.6 | 104.6 | 33 | 443.1 | 98.3 | 31 | 460.8 | 102.2 | 34
696 | 450.0 | 31 | 488.4 | 108.5 | 33 | 449.9 | 100.0 | 31 | 461.5 | 102.5 | 34
710 | 447.9 | 30 | 464.7 | 103.8 | 30 | 455.4 | 101.7 | 30 | 471.8 | 105.3 | 34
724 | 448.8 | 30 | 464.8 | 103.6 | 29 | 463.7 | 103.3 | 30 | 468.1 | 104.3 | 34
Mean for Weeks
1–14 | 192.0 | – | 192.5 | 100.3 | – | 189.9 | 98.9 | – | 189.5 | 98.7 | –
15–52 | 311.9 | – | 314.1 | 100.7 | – | 310.3 | 99.5 | – | 311.4 | 99.8 | –
53–104 | 422.6 | – | 428.9 | 101.5 | – | 420.1 | 99.4 | – | 423.6 | 100.2 | –

^a^ Interim evaluation occurred during week 14.

### Fourteen-week Interim Evaluation

There were significantly decreased leukocyte and lymphocyte counts (22%) in 3 W/kg females (Table F-1). While these decreases may have been stress related, they only occurred in the 3 W/kg group and only in females, thus the biological relevance is uncertain. In 6 W/kg females, there were significant decreases in cholesterol (19%) and triglyceride (38%) concentrations. These decreases may have been due to changes in lipid metabolism.

In males, the absolute left and right kidney weights were significantly decreased in the 1.5 (9% and 10%, respectively) and 6 W/kg (15% and 11%, respectively) groups (Table G-4). The absolute liver weight of 6 W/kg males was also significantly decreased (10%). The relative weights of these organs were not significantly decreased, which was likely due to the lower terminal mean body weights of the 1.5 (4%) and 6 W/kg (8%) groups. In females, the relative brain weights of the 1.5 and 6 W/kg groups were significantly increased, which was likely due to lower mean body weights in these two groups (Table G-4). The absolute left kidney weights were significantly decreased in all exposed female groups (9% to 14%). Similarly, the absolute right kidney weights were significantly decreased in the 3 and 6 W/kg females (8% and 12%, respectively). There were also significant decreases in the absolute lung weight in 6 W/kg females (16%) and the absolute thymus weights in 1.5 (18%) and 6 W/kg (22%) females. The absolute liver weights were significantly decreased in 1.5 and 6 W/kg females (17% and 20%, respectively), with corresponding decreased relative weights. None of these changes were associated with histopathologic findings.

There were no GSM exposure-related effects on reproductive organ weights, testis spermatid concentrations, caudal epididymal sperm concentrations, or sperm motility in males (Table H-1). Due to the poor diagnostic quality of the cytology slides, the estrous cycle in females was not evaluated.

In the heart, the incidences of cardiomyopathy in the right ventricle only in males was greater in the 3 and 6 W/kg groups compared to the sham controls, although the increases were not statistically significant (Table 19). In the entire heart (i.e., all sites combined) in males, the incidences of cardiomyopathy were increased in the 3 and 6 W/kg groups compared to the sham controls, but only the increase in the 3 W/kg group was statistically significant. The average severity was comparable to that of the sham control group. Cardiomyopathy was initially diagnosed separately in the right ventricle, but was also seen in the left ventricular free wall and interventricular septum. The incidences of cardiomyopathy in the left ventricle and interventricular septum (i.e., excluding the right ventricle) were similar in all exposed groups compared to the sham controls. In females, the incidence of cardiomyopathy in the exposed groups was not considered to be related to exposure to GSM-modulated cell phone RFR.

Table 19 Incidences of Selected Non-neoplastic Lesions at the 14-week Interim Evaluation in Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 w/kg
Male
Heart^a^ | 10 | 10 | 10 | 10
Cardiomyopathy (Excluding Right Ventricle)^b^ | 2 (1.5)^c^ | 4 (1.0) | 3 (1.0) | 4 (1.0)
Ventricle Right, Cardiomyopathy | 1 (1.0) | 1 (2.0) | 5 (1.2) | 5 (1.0)
Cardiomyopathy, All Sites | 3 (1.3) | 5 (1.2) | 8* (1.1) | 7 (1.0)
Lymph Node, Mandibular | 10 | 10 | 10 | 10
Hyperplasia, Lymphocyte | 0 | 0 | 0 | 4* (1.0)
Proliferation, Plasma Cell | 0 | 0 | 0 | 2 (1.0)
Female
Heart | 10 | 10 | 10 | 10
Cardiomyopathy (Excluding Right Ventricle) | 0 | 2 (1.0) | 1 (1.0) | 2 (1.0)
Ventricle Right, Cardiomyopathy | 0 | 0 | 1 (1.0) | 0
Cardiomyopathy, All Sites | 0 | 2 (1.0) | 2 (1.0) | 2 (1.0)
Lymph Node, Mandibular | 10 | 10 | 10 | 10
Hyperplasia, Lymphocyte | 0 | 0 | 0 | 2 (1.0)
Proliferation, Plasma Cell | 0 | 0 | 0 | 3 (1.0)

* Significantly different (P ≤ 0.05) from the sham control group by the Fisher exact test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Cardiomyopathy was characterized by degeneration and necrosis of myofibers with a mild inflammatory response of macrophages and lymphocytes with occasional neutrophils. In the right ventricle, the cardiomyopathy was most prominent in the subepicardial region in the lower half (toward the apex) of the heart. In more severe cases, the lesions in the right ventricle extended deeper into the myocardium. In some areas, there appeared to be areas of cardiomyocyte loss, characterized by linear, clear areas containing a few scattered cell nuclei and variable amounts of linear, eosinophilic material (likely collagen bundles).

In the mandibular lymph node of males, there was an increased incidence of lymphocyte hyperplasia in the 6 W/kg group compared to the sham control group (Table 19). In all cases, the severity of the lesions was minimal. There were no similar findings in other lymph nodes or in females in either modulation.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and non-neoplastic lesions of the heart, brain, adrenal medulla, prostate gland, pituitary gland (pars distalis), pancreatic islets, thyroid gland, adrenal cortex, kidney and other organs, mammary gland, pancreas, and seminal vesicle. Summaries of the incidences of neoplasms and non-neoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix A for male rats and Appendix B for female rats.

Heart: Malignant schwannomas were observed in all exposed male groups. No schwannomas were observed in the sham controls. The incidences in the exposed groups occurred with a significant positive trend (Table 20, Table A-1, and Table A-2). In females, schwannoma occurred in two 3 W/kg animals (Table 20 and Table B-1). Endocardial Schwann cell hyperplasia, a putative preneoplastic Schwann cell lesion, was diagnosed in one 1.5 W/kg male and two 6 W/kg males (Table 20 and Table A-9); there were none in females. Schwannomas were seen in other organs, including the pituitary gland, tri-geminal nerve, salivary glands, Harderian gland, eye, thymus gland, uterus, ovary, and vagina. When the incidences of schwannoma in all organs (including the heart) were combined, they were generally higher in exposed males, but not significantly different from the sham controls.

Table 20 Incidences of Malignant Schwannoma and Neoplasms and Non-neoplastic Lesions of the Heart in Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Heart^a^ | 90 | 90 | 90 | 90
Cardiomyopathy^b^ | 79 (1.9)^c^ | 82 (1.8) | 78 (2.1) | 79 (1.6)
Ventricle Right, Cardiomyopathy | 54 (1.1) | 62 (1.5) | 72* (1.9) | 74** (1.8)
Endocardium, Hyperplasia, Schwann Cell | 0 | 1 (1.0) | 0 | 2 (2.0)
Endocardium, Schwannoma Malignant | 0 | 1 | 1 | 2
Myocardium, Schwannoma Malignant | 0 | 1 | 0 | 3
Malignant Schwannoma^d^
Overall rate^e^ | 0/90 (0%) | 2/90 (2%) | 1/90 (1%) | 5/90 (6%)
Litters rate^f^ | 0/35 (0%) | 2/35 (6%) | 1/35 (3%) | 5/35 (14%)
Adjusted rate^g^ | 0.0% | 2.7% | 1.3% | 6.4%
Terminal rate^h^ | 0/25 (0%) | 2/45 (4%) | 1/50 (2%) | 3/60 (5%)
First incidence (days) | –^j^ | 730 (T) | 730 (T) | 582
Rao-Scott adjusted Poly-3 test^i^ | P = 0.041 | P = 0.297 | P = 0.540 | P = 0.080
All Organs: Malignant Schwannoma^k^
Overall rate | 3/90 (3%) | 3/90 (3%) | 5/90 (6%) | 7/90 (8%)
Litters rate | 3/35 (9%) | 3/35 (9%) | 5/35 (14%) | 7/35 (20%)
Adjusted rate | 4.5% | 4.0% | 6.4% | 8.9%
Terminal rate | 1/25 (4%) | 2/45 (4%) | 3/50 (6%) | 4/60 (7%)
First incidence (days) | 555 | 720 | 661 | 582
Rao-Scott adjusted Poly-3 test | P = 0.133 | P = 0.577N | P = 0.435 | P = 0.238
Female
Heart | 90 | 90 | 90 | 90
Cardiomyopathy | 40 (1.1) | 30* (1.2) | 39 (1.1) | 27* (1.1)
Ventricle Right, Cardiomyopathy | 4 (1.0) | 9 (1.1) | 14* (1.1) | 15* (1.2)
Endocardium, Schwannoma Malignant | 0 | 0 | 1 | 0
Myocardium, Schwannoma Malignant | 0 | 0 | 1 | 0
Malignant Schwannoma^l^
Overall rate | 0/90 (0%) | 0/90 (0%) | 2/90 (2%) | 0/90 (0%)
Litters rate | 0/35 (0%) | 0/35 (0%) | 2/35 (6%) | 0/35 (0%)
Adjusted rate | 0.0% | 0.0% | 2.8% | 0.0%
Terminal rate | 0/48 (0%) | 0/53 (0%) | 1/48 (2%) | 0/57 (0%)
First incidence (days) | – | – | 578 | –
Rao-Scott adjusted Poly-3 test | P = 0.640 | –^m^ | P = 0.365 | –
All Organs: Malignant Schwannoma^n^
Overall rate | 4/90 (4%) | 1/90 (1%) | 5/90 (6%) | 2/90 (2%)
Litters rate | 3/35 (9%) | 1/35 (3%) | 5/35 (14%) | 2/35 (6%)
Adjusted rate | 5.7% | 1.3% | 7.0% | 2.7%
Terminal rate | 2/48 (4%) | 0/53 (0%) | 2/48 (4%) | 1/57 (2%)
First incidence (days) | 489 | 480 | 578 | 622
Rao-Scott adjusted Poly-3 test | P = 0.428N | P = 0.212N | P = 0.519 | P = 0.354N

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

** P ≤ 0.01.

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for other 2-year studies (all routes): 1/50, 1/50, 0/50.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with animals with neoplasm per number of litters necropsied.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal euthanasia.

^i^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^j^ Not applicable; no neoplasms in animal group.

^k^ Historical control incidence for other 2-year studies (all routes): 1/50, 2/50, 0/50.

^l^ Historical control incidence for other 2-year studies (all routes): 0/49, 0/50, 0/50.

^m^ Value of statistic cannot be computed.

^n^ Historical control incidence for other 2-year studies (all routes): 0/50, 2/50, 2/50.

In the heart, some schwannomas were endocardial (Plates 1, 2, and 3) and others were myocardial (Plates 4 and 5). They were not recorded separately in the final data because their biological behavior and morphology are similar. The endocardial schwannomas typically arose in the subendocardial region of the left ventricle, though some were found in the right ventricle. They were composed of two morphologically distinct cell populations, both of which have indistinct cell boundaries. One population, immediately adjacent to the endocardium, was elongated and had ovoid nuclei, prominent nucleoli, and scant, pale cytoplasm. The other population, which was far more abundant, was more spindloid, with fusiform, hyperchromatic nuclei oriented in parallel.

The schwannomas were invasive, dissecting between cariomyocytes. In a few larger neoplasms, the nuclei of the spindle-shaped cells lined up adjacent to each other (early palisading of nuclei) or exhibited a wavy pattern. The myocardial schwannomas had a similar appearance, but they were less cellular than endocardial schwannomas. They were composed of spindle-shaped cells in a loose arrangement. Endocardial Schwann cell hyperplasia (Plate 6) was similar in appearance to endocardial schwannomas, but was less extensive and did not invade into the adjacent myocardium.

Cardiomyopathy of the right ventricular free wall was seen in all male and female groups (including sham controls) (Table 20, Table A-9, and Table B-7). In males and females, the incidences were higher in all exposed groups compared to sham controls; the increases were statistically significant in the 3 and 6 W/kg groups. There was also a slight elevation in the severity in 3 and 6 W/kg males, but there was no such elevation in females. Cardiomyopathy was diagnosed separately in the right ventricle because the study pathologist observed an unusual predilection for, and a slightly different morphology in the right ventricle as compared to the left ventricular free wall and the interventricular septum. A higher incidence was found in the right ventricle in the 6 W/kg groups compared to the sham controls. Cardiomyopathy is a very common spontaneous disease in rats and was also seen in other sites in the heart (most notably the left ventricular free wall, but also the interventricular septum). In the current study, it was more prominent in the apex and lower half (toward the apex) of the heart. When cardiomyopathy was evaluated in the entire heart (including the right ventricle), there was no significant difference in the incidences or average severities in exposed male groups when compared to sham controls. In females, there were significantly decreased incidences of cardiomyopathy of the whole heart in the 1.5 and 6 W/kg groups. Cardiomyopathy (Plate 7) was characterized by degeneration and necrosis of myofibers with a mild inflammatory response of macrophages and lymphocytes with occasional neutrophils. In later stages of the disease, fibrosis may be prominent. In the right ventricle, the cardiomyopathy was most prominent in the subepicardial region in the lower half (toward the apex) of the heart. In more severe cases, the lesions extended deeper into the right ventricular wall. The lesions were similar to those described above. In some areas, there appeared to be areas of cardiomyocyte loss, characterized by linear, clear areas containing a few scattered cell nuclei and variable amounts of linear, eosinophilic material (likely collagen bundles). Fibrosis was sometimes fairly prominent. The effect of GSM-modulated cell phone RFR on the incidence of cardiomyopathy appears to be specific to the right ventricular free wall.

Brain: In males, malignant glioma and glial cell hyperplasia occurred in all exposed groups (Table 21, Table A-1, and Table A-9) and neither lesion occurred in the sham control group; however, the incidences were not significant compared to those in the sham controls. In females, malignant glioma occurred in one 6 W/kg animal and glial cell hyperplasia occurred one 3 W/kg animal (Table 21, Table B-1, and Table B-7).

Table 21 Incidences of Neoplasms and Non-neoplastic Lesions of the Brain in Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Number Examined Microscopically | 90 | 90 | 90 | 90
Glial Cell, Hyperplasia^a^ | 0 | 2 (2.0)^b^ | 3 (3.0) | 1 (4.0)
Meninges, Hyperplasia, Granular Cell | 1 (1.0) | 0 | 1 (1.0) | 0
Glioma Malignant^c^
Overall rate^d^ | 0/90 (0%) | 3/90 (3%) | 3/90 (3%) | 2/90 (2%)
Litters rate^e^ | 0/35 (0%) | 3/35 (9%) | 3/35 (9%) | 2/35 (6%)
Adjusted rate^f^ | 0.0% | 4.0% | 3.8% | 2.6%
Terminal rate^g^ | 0/25 (0%) | 2/45 (4%) | 1/50 (2%) | 1/60 (2%)
First incidence (days) | –^i^ | 715 | 649 | 716
Rao-Scott adjusted Poly-3 test^h^ | P = 0.382 | P = 0.155 | P = 0.166 | P = 0.277
Meninges, Granular Cell Tumor Benign^j^
Overall rate | 1/90 (1%) | 3/90 (3%) | 3/90 (3%) | 3/90 (3%)
Litters rate | 1/35 (3%) | 3/35 (9%) | 3/35 (9%) | 3/35 (9%)
Adjusted rate | 1.5% | 4.0% | 3.9% | 3.9%
Terminal rate | 1/25 (4%) | 1/45 (2%) | 3/50 (6%) | 3/60 (5%)
First incidence (days) | 730 (T) | 655 | 730 (T) | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.350 | P = 0.328 | P = 0.342 | P = 0.341
Meninges, Granular Cell Tumor Malignant^k^ | 0 | 0 | 1 | 0
Meninges, Granular Cell Tumor Benign or Malignant^j^
Overall rate | 1/90 (1%) | 3/90 (3%) | 4/90 (4%) | 3/90 (3%)
Litters rate | 1/35 (3%) | 3/35 (9%) | 4/35 (11%) | 3/35 (9%)
Adjusted rate | 1.5% | 4.0% | 5.1% | 3.9%
Terminal rate | 1/25 (4%) | 1/45 (2%) | 3/50 (6%) | 3/60 (5%)
First incidence (days) | 730 (T) | 655 | 699 | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.343 | P = 0.327 | P = 0.220 | P = 0.340
Female
Number Examined Microscopically | 90 | 90 | 90 | 90
Glial Cell, Hyperplasia | 0 | 0 | 1 (4.0) | 0
Meninges, Hyperplasia, Granular Cell | 1 (3.0) | 0 | 1 (3.0) | 0
Glioma Malignant^l^
Overall rate | 0/90 (0%) | 0/90 (0%) | 0/90 (0%) | 1/90 (1%)
Litters rate | 0/35 (0%) | 0/35 (0%) | 0/35 (0%) | 1/35 (3%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 1.3%
Terminal rate | 0/48 (0%) | 0/53 (0%) | 0/48 (0%) | 0/57 (0%)
First incidence (days) | – | – | – | 669
Rao-Scott adjusted Poly-3 test | –^m^ | – | – | –
Meninges, Granular Cell Tumor Benign^n^
Overall rate | 1/90 (1%) | 1/90 (1%) | 2/90 (2%) | 0/90 (0%)
Litters rate | 1/35 (3%) | 1/35 (3%) | 2/35 (6%) | 0/35 (0%)
Adjusted rate | 1.4% | 1.3% | 2.8% | 0.0%
Terminal rate | 1/48 (2%) | 1/53 (2%) | 1/48 (2%) | 0/57 (0%)
First incidence (days) | 730 (T) | 737 (T) | 669 | –
Rao-Scott adjusted Poly-3 test | P = 0.375N | P = 0.722N | P = 0.503 | P = 0.489N
Meninges, Granular Cell Tumor Malignant^k^ | 0 | 0 | 0 | 1
Meninges, Granular Cell Tumor Benign or Malignant^n^
Overall rate | 1/90 (1%) | 1/90 (1%) | 2/90 (2%) | 1/90 (1%)
Litters rate | 1/35 (3%) | 1/35 (3%) | 2/35 (6%) | 1/35 (3%)
Adjusted rate | 1.4% | 1.3% | 2.8% | 1.3%
Terminal rate | 1/48 (2%) | 1/53 (2%) | 1/48 (2%) | 1/57 (2%)
First incidence (days) | 737 (T) | 737 (T) | 669 | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.594 | P = 0.712N | P = 0.485 | P = 0.713N

(T) = terminal euthanasia.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for other 2-year studies (all routes): 0/50, 2/50.

^d^ Number of animals with neoplasm per number of animals with brain examined microscopically.

^e^ Number of litters with animals with neoplasm per number of litters with brain examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ Not applicable; no neoplasms in animal group.

^j^ Historical control incidence for other 2-year studies (all routes): 2/50, 0/50.

^k^ Historical control incidence for other 2-year studies (all routes): 0/50, 0/50.

^l^ Historical control incidence for other 2-year studies (all routes): 0/50, 1/50.

^m^ Value of statistic cannot be computed.

^n^ Historical control incidence for other 2-year studies (all routes): 1/50, 0/50.

The malignant gliomas (Plates 8, 9, and 10) were generally large neoplasms with indistinct borders. The cells were typically densely packed and were clustered around blood vessels (perivascular cuffing) or aggregated around neurons (satellitosis). The cells invaded the meninges in some cases. The cells had small to moderate amounts of eosinophilic cytoplasm and indistinct cell margins. They had small, round to elongated, hyperchromatic nuclei. A few mitotic figures were present. Glial cell hyperplasia (Plate 11) had a similar appearance, but was smaller with less densely packed cells (all cells were separated by neuropil). Satellitosis and perivascular cuffing were minimal and there was no meningeal invasion and no mitotic figures. In the glial cell hyperplasia, there were no reactive, degenerative, or necrotic elements within the associated parenchyma or other evidence of damage (e.g., hemorrhage, edema). The hyperplastic cells were sometimes hypertrophied, but there were no gitter cells or gemistocytes.

In males, there were three benign granular cell tumors of the meninges in each exposed group and one in the sham control group (Table 21 and Table A-1). There was also a single malignant granular cell tumor in the 3 W/kg group. Granular cell hyperplasia, which is thought to be on a continuum with benign and malignant granular cell tumors, occurred in one sham control male and one 3 W/kg male (Table 21 and Table A-9). In females, the incidences of granular cell tumors were 1%, 1%, 2%, 0% in the sham control, 1.5, 3, and 6 W/kg groups, respectively (Table 21 and Table B-1). There was also a single malignant granular cell tumor in a 6 W/kg female. Granular cell hyperplasia occurred in one female each from the sham control and 3 W/kg groups.

Granular cell tumors were observed in the meninges or choroid plexus and were composed of sheets of large, densely packed polygonal cells. The cells had abundant, eosinophilic, granular cytoplasm with indistinct cell borders and small, uniform, round to oval nuclei. A few smaller cells with dark basophilic nuclei and sparser, less granular cytoplasm were also present. No mitotic figures were observed. Benign granular cell tumors were discrete, non-invasive masses that caused variable compression of the adjacent brain parenchyma. Granular cell hyperplasias were similar in appearance, but were smaller, non-invasive, and non-compressive. Malignant granular cell tumors were invasive, extending into the underlying neuropil, and had some nuclear pleomorphism.

Adrenal Medulla: In males, there were significantly increased incidences of benign pheochromocytoma and benign, malignant, or complex pheochromocytoma (combined) in the 1.5 and 3 W/kg groups (Table 22, Table A-1, and Table A-2). The incidence of malignant pheochromocytoma was slightly increased in 3 W/kg males, but none were recorded in 6 W/kg males. The upper range of benign pheochromocytoma in the available historical control data for male Hsd:Sprague Dawley^®^ SD^®^ rats is 24% (mean historical incidence is 16%) (Table A-5). There were decreased incidences of hyperplasia in exposed male groups, and the severity was similar to that in the sham controls (Table 22 and Table A-9). In females, there were slightly increased incidences of benign pheochromocytoma in exposed groups, (Table 22 and Table B-1). There was a significant positive trend in the incidences of hyperplasia and the incidence in 6 W/kg females was significant; however, as in males, the average severities in the exposed groups were similar to that in the sham controls (Table 22 and Table B-7). Benign pheochromocytomas were characterized by a well-delineated mass that compressed the adjacent tissue and was composed of cells arranged in large solid clusters or thick trabeculae. Cells exhibited mild to marked alteration in size, shape, and/or staining qualities. Cellular atypia and pleomorphism were common. A diagnosis of malignant pheochromocytoma was made when there was evidence of invasion of the capsule or metastasis.

Table 22 Incidences of Neoplasms and Non-neoplastic Lesions of the Adrenal Medulla in Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Number Examined Microscopically | 88 | 90 | 89 | 87
Hyperplasia^a^ | 42 (2.0)^b^ | 24** (2.1) | 26** (1.9) | 35 (2.0)
Benign Pheochromocytom^a^, Bilateral | 1 | 2 | 4 | 0
Benign Pheochromocytom^a^, Multiple | 1 | 0 | 2 | 0
Benign Pheochromocytoma (includes bilateral and multiple)^c^
Overall rate^d^ | 10/88 (11%) | 23/90 (26%) | 25/89 (28%) | 14/87 (16%)
Litters rate^e^ | 8/35 (23%) | 19/35 (54%) | 21/35 (60%) | 12/35 (34%)
Adjusted rate^f^ | 15.2% | 29.9% | 31.7% | 18.3%
Terminal rate^g^ | 3/23 (13%) | 13/45 (29%) | 14/49 (29%) | 11/59 (19%)
First incidence (days) | 510 | 599 | 526 | 631
Rao-Scott adjusted Poly-3 test^h^ | P = 0.472N | P = 0.030 | P = 0.017 | P = 0.384
Malignant Pheochromocytoma, Bilateral^i^ | 0 | 1 | 0 | 0
Malignant Pheochromocytoma (includes bilateral)^i^ | 1 | 1 | 4 | 0
Complex Pheochromocytoma^j^ | 1 | 0 | 0 | 0
Benign, Malignant, or Complex Pheochromocytoma^k^
Overall rate | 11/88 (13%) | 24/90 (27%) | 28/89 (31%) | 14/87 (16%)
Litters rate | 9/35 (26%) | 19/35 (54%) | 23/35 (66%) | 12/35 (34%)
Adjusted rate | 16.7% | 31.1% | 35.3% | 18.3%
Terminal rate | 3/23 (13%) | 13/45 (29%) | 15/49 (31%) | 11/59 (19%)
First incidence (days) | 510 | 599 | 526 | 631
Rao-Scott adjusted Poly-3 test | P = 0.409N | P = 0.035 | P = 0.010 | P = 0.472
Female
Number Examined Microscopically | 86 | 90 | 90 | 86
Hyperplasia | 13 (1.5) | 19 (1.2) | 14 (1.4) | 25* (1.8)
Benign Pheochromocytoma, Bilateral | 0 | 0 | 0 | 1
Benign Pheochromocytoma (includes bilateral)^l^
Overall rate | 1/86 (1%) | 3/90 (3%) | 3/90 (3%) | 2/86 (2%)
Litters rate | 1/35 (3%) | 3/35 (9%) | 3/35 (9%) | 2/35 (6%)
Adjusted rate | 1.5% | 4.0% | 4.2% | 2.8%
Terminal rate | 1/45 (2%) | 3/53 (6%) | 3/48 (6%) | 2/53 (4%)
First incidence (days) | 737 (T) | 737 (T) | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.486 | P = 0.347 | P = 0.319 | P = 0.500

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

** P ≤ 0.01.

(T) = terminal euthanasia.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for other 2-year studies (all routes): 9/50, 5/50, 12/50.

^d^ Number of animals with neoplasm per number of animals with adrenal medulla examined microscopically.

^e^ Number of litters with animals with neoplasm per number of litters with adrenal medulla examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend is indicated by N.

^i^ Historical control incidence for other 2-year studies (all routes): 3/50, 2/50, 2/50.

^j^ Historical control incidence for other 2-year studies (all routes): 0/50, 1/50, 0/50.

^k^ Historical control incidence for other 2-year studies (all routes): 12/50, 8/50, 14/50.

^l^ Historical control incidence for other 2-year studies (all routes): 3/50, 0/50, 0/49.

Prostate Gland: There were increased incidences of adenoma and adenoma or carcinoma (combined) in the 3 W/kg groups compared to sham controls, but the increase was not statistically significant (Table 23, Table A-1, and Table A-2). A single carcinoma occurred in the 3 W/kg group. Prostate gland carcinomas are rare neoplasms in rats, with a mean historical control incidence of 0/240 in Hsd:Sprague Dawley^®^ SD^®^ rats (Table A-3), 0.57% in Wistar Han rats (range 0%–2%), and 0.43% in F344/N rats (range 0%–4%); the combined incidence in the 3 W/kg group exceeded the historical control ranges for all rat strains that have been used by the National Toxicology Program.^196^ The incidences and severities of epithelial hyperplasia were slightly increased in all exposed groups (Table 23 and Table A-9). Prostate gland adenomas were expansile lesions that filled the lumen of at least one acinus and compressed the adjacent tissue. The cuboidal to columnar cells formed papillary or cribriform patterns, and there was little cellular pleomorphism.

Table 23 Incidences of Neoplasms and Non-neoplastic Lesions of the Prostate Gland in Male Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Number Examined Microscopically | 90 | 90 | 90 | 90
Epithelium, Hyperplasia^a^ | 5 (1.2)^b^ | 13 (1.6) | 11 (1.9) | 11 (2.4)
Adenoma^c^
Overall rate^d^ | 2/90 (2%) | 2/90 (2%) | 6/90 (7%) | 3/90 (3%)
Litters rate^e^ | 2/35 (6%) | 2/35 (6%) | 5/35 (14%) | 3/35 (9%)
Adjusted rate^f^ | 3.0% | 2.7% | 7.7% | 3.9%
Terminal rate^g^ | 1/25 (4%) | 0/45 (0%) | 6/50 (12%) | 3/60 (5%)
First incidence (days) | 642 | 591 | 730 (T) | 730 (T)
Rao-Scott adjusted Poly-3 test^h^ | P = 0.419 | P = 0.625N | P = 0.224 | P = 0.566
Carcinoma^c^ | 0 | 0 | 1 | 0
Adenoma or Carcinoma^c^
Overall rate | 2/90 (2%) | 2/90 (2%) | 7/90 (8%) | 3/90 (3%)
Litters rate | 2/35 (6%) | 2/35 (6%) | 6/35 (17%) | 3/35 (9%)
Adjusted rate | 3.0% | 2.7% | 9.0% | 3.9%
Terminal rate | 1/25 (4%) | 0/45 (0%) | 6/50 (12%) | 3/60 (5%)
First incidence (days) | 642 | 591 | 717 | 730 (T)
Rao-Scott adjusted Poly-3 test | P = 0.412 | P = 0.626N | P = 0.161 | P = 0.566

(T) = terminal euthanasia.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for other 2-year studies (all routes): 0/50, 0/50, 0/50.

^d^ Number of animals with neoplasm per number of animals with prostate gland examined microscopically.

^e^ Number of litters with animals with neoplasm per number of litters with prostate gland examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A lower incidence in an exposure group is indicated by N.

Pituitary Gland (Pars Distalis): There were increased incidences of adenoma in all exposed male groups compared to the sham controls, but none were statistically significant (Table 24, Table A-1, and Table A-2). In females, the incidences of adenoma in the 1.5 and 6 W/kg groups were significantly decreased (Table 24, Table B-1, and Table B-2). The incidences and severities of hyperplasia in exposed groups of males and females were similar to those of the sham controls (Table 24, Table A-9, and Table B-7).

Table 24 Incidences of Neoplasms and Non-neoplastic Lesions of the Pituitary Gland (Pars Distalis) in Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Number Examined Microscopically | 89 | 90 | 90 | 90
Hyperplasia^a^ | 32 (2.4)^b^ | 34 (2.4) | 35 (2.4) | 32 (2.2)
Cyst | 5 | 9 | 15* | 16*
Adenoma, Multiple | 0 | 0 | 1 | 0
Adenoma (includes multiple)^c^
Overall rate^d^ | 17/89 (19%) | 28/90 (31%) | 26/90 (29%) | 26/90 (29%)
Litters rate^e^ | 13/35 (37%) | 23/35 (66%) | 19/35 (54%) | 22/35 (63%)
Adjusted rate^f^ | 24.9% | 35.2% | 32.2% | 32.4%
Terminal rate^g^ | 5/25 (20%) | 15/45 (33%) | 17/50 (34%) | 19/60 (32%)
First incidence (days) | 527 | 309 | 537 | 384
Rao-Scott adjusted Poly-3 test^h^ | P = 0.301 | P = 0.126 | P = 0.216 | P = 0.210
Female
Number Examined Microscopically | 90 | 90 | 90 | 90
Hyperplasia | 20 (2.5) | 26 (2.0) | 22 (1.9) | 22 (2.0)
Adenoma, Multiple | 1 | 3 | 3 | 0
Adenoma (includes multiple)^i^
Overall rate | 43/90 (48%) | 33/90 (37%) | 38/90 (42%) | 32/90 (36%)
Litters rate | 28/35 (80%) | 24/35 (69%) | 26/35 (74%) | 23/35 (66%)
Adjusted rate | 57.1% | 42.5% | 51.2% | 41.6%
Terminal rate | 28/48 (58%) | 23/53 (43%) | 24/48 (50%) | 24/57 (42%)
First incidence (days) | 464 | 578 | 545 | 565
Rao-Scott adjusted Poly-3 test | P = 0.077N | P = 0.049N | P = 0.283N | P = 0.038N

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for other 2-year studies (all routes): 14/50, 5/50, 11/50.

^d^ Number of animals with neoplasm per number of animals with pituitary gland examined microscopically.

^e^ Number of litters with animals with neoplasm per number of litters with pituitary gland examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ Historical control incidence for other 2-year studies (all routes): 19/50, 18/50, 18/50.

Adenomas were characterized by a well-delineated mass composed of solid sheets of cells that compressed the adjacent tissue. Cells were often hypertrophied and cellular atypia and pleomorphism were not uncommon. Vascular patterns were often altered. The incidences of cysts in males also increased with increasing exposure SAR; the incidences were statistically significant by the Rao-Scott adjusted Poly-3 test in the 3 and 6 W/kg exposure groups (Table 24 and Table B-7). Cysts are generally considered developmental abnormalities and the toxicologic significance of these is uncertain.

Pancreatic Islets: In males, there were increased incidences of adenoma or carcinoma (combined) in all exposed groups, but only the incidence in the 1.5 W/kg group was significant (Table 25, Table A-1, and Table A-2). There were also increased incidences of adenoma in all exposed groups and of carcinoma in the 1.5 and 3 W/kg groups, but they were not statistically significant. In females, the incidences of adenoma and carcinoma were similar to those in the sham controls (Table B-1 and Table B-2). There were decreased incidences of hyperplasia in all exposed male and female groups, and the decreases were statistically significant in 1.5 and 3 W/kg males and 1.5 W/kg females (Table 25, Table A-9, and Table B-7).

Table 25 Incidences of Neoplasms and Non-neoplastic Lesions of the Pancreatic Islets in Male Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Number Examined Microscopically | 90 | 89 | 86 | 85
Hyperplasia^a^ | 12 (1.5)^b^ | 5* (2.8) | 5* (2.0) | 7 (1.7)
Adenoma, Multiple | 0 | 2 | 1 | 1
Adenoma (includes multiple)^c^
Overall rate^d^ | 5/90 (6%) | 14/89 (16%) | 10/86 (12%) | 11/85 (13%)
Litters rate^e^ | 5/35 (14%) | 12/35 (34%) | 9/35 (26%) | 11/35 (31%)
Adjusted rate^f^ | 7.6% | 18.5% | 13.2% | 14.8%
Terminal rate^g^ | 2/25 (8%) | 10/45 (22%) | 9/50 (18%) | 11/60 (18%)
First incidence (days) | 624 | 531 | 677 | 730 (T)
Rao-Scott adjusted Poly-3 test^h^ | P = 0.282 | P = 0.051 | P = 0.204 | P = 0.140
Carcinoma, Multiple | 0 | 2 | 0 | 0
Carcinoma (includes multiple)^i^
Overall rate | 8/90 (9%) | 15/89 (17%) | 10/86 (12%) | 5/85 (6%)
Litters rate | 8/35 (23%) | 12/35 (34%) | 10/35 (29%) | 4/35 (11%)
Adjusted rate | 12.0% | 19.7% | 13.1% | 6.7%
Terminal rate | 3/25 (12%) | 7/45 (16%) | 8/50 (16%) | 4/60 (7%)
First incidence (days) | 663 | 531 | 537 | 544
Rao-Scott adjusted Poly-3 test | P = 0.088N | P = 0.173 | P = 0.517 | P = 0.220N
Adenoma or Carcinoma^c^
Overall rate | 13/90 (14%) | 27/89 (30%) | 19/86 (22%) | 16/85 (19%)
Litters rate | 12/35 (34%) | 19/35 (54%) | 17/35 (50%) | 14/35 (40%)
Adjusted rate | 19.4% | 35.2% | 24.8% | 21.3%
Terminal rate | 5/25 (20%) | 16/45 (36%) | 16/50 (32%) | 15/60 (25%)
First incidence (days) | 624 | 531 | 537 | 544
Rao-Scott adjusted Poly-3 test | P = 0.344N | P = 0.032 | P = 0.282 | P = 0.462

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

(T) = terminal euthanasia.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for other 2-year studies (all routes): 3/50, 2/50, 8/50.

^d^ Number of animals with neoplasm per number of animals with pancreatic islets examined microscopically

^e^ Number of litters with animals with neoplasm per number of litters with pancreatic islets examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ Historical control incidence for other 2-year studies (all routes): 0/50, 0/50, 0/50The adenomas were well circumscribed, occasionally encapsulated nodules that typically compressed the surrounding pancreatic tissue. The polygonal cells were arranged in cords or small nests and there was minimal to mild cellular pleomorphism in some of the larger masses.

Thyroid Gland: In females, the incidences of C-cell hyperplasia were significantly increased in all exposed groups compared to the sham controls (Table 26 and Table B-7). In males, there was a slightly increased incidence of C-cell hyperplasia in the 1.5 W/kg group, but the increase was not significant (Table 26 and Table A-9).

Table 26 Incidences of C-Cell Hyperplasia of the Thyroid Gland in Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Number Examined Microscopically | 89 | 89 | 89 | 87
C-Cell, Hyperplasia^a^ | 16 (1.8)^b^ | 24 (1.9) | 18 (1.9) | 14 (1.6)
Female
Number Examined Microscopically | 90 | 88 | 90 | 88
C-Cell, Hyperplasia | 28 (2.3) | 49** (1.6) | 45** (1.8) | 43* (1.7)

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Adrenal Cortex: The incidence of hypertrophy was significantly increased in 6.0 W/kg males compared to the sham controls (Table 27 and Table A-9). However, the average severity of the lesion did not increase with increasing exposure concentration.

Table 27 Incidences of Non-neoplastic Lesions of the Adrenal Cortex in Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Number Examined Microscopically | 90 | 90 | 90 | 88
Hyperplasia^a^ | 47 (1.7)^b^ | 46 (1.8) | 46 (1.8) | 45 (1.9)
Hypertrophy | 35 (1.5) | 43 (1.6) | 50 (1.4) | 54* (1.3)
Vacuolation, Cytoplasmic | 20 (1.5) | 32 (1.4) | 25 (1.6) | 22 (1.3)
Female
Number Examined Microscopically | 90 | 90 | 89 | 90
Hyperplasia | 14 (1.9) | 26 (1.8) | 40** (1.9) | 26* (1.6)
Hypertrophy | 52 (1.5) | 54 (1.8) | 51 (1.8) | 56 (1.5)
Vacuolation, Cytoplasmic | 18 (1.5) | 21 (1.4) | 11 (1.6) | 8* (1.1)

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

There was a similar finding in the CDMA-exposed males, but there was no such effect in females exposed to either modulation. In females, there were significantly increased incidences of adrenal cortical hyperplasia in the 3 and 6 W/kg groups, but the average severity was similar between exposed and sham control groups (Table 27 and Table B-7). There was a similar response in the CDMA-exposed females, but not in the males exposed to either modulation. In 6 W/kg females, there was a significantly decreased incidence of cytoplasmic vacuolation and the average severity was also slightly decreased for this lesion. The incidences of this lesion in exposed males were similar to those in the sham controls.

Kidney and Other Organs: The severity of chronic progressive nephropathy was lower in all exposed male groups compared to the sham controls (Table 28). There were decreased incidences in a number of lesions in other organs in exposed male groups, some statistically significant, that were thought to be secondary to the chronic progressive nephropathy, either directly or indirectly (Table 28 and Table A-9). These lesions included hyperplasia of the parathyroid gland; mineral in the blood vessels in the cecum, colon, liver, mesentery, pancreas, salivary glands, brain, heart, kidney, skeletal muscle, glandular stomach, and aorta; fibrous osteodystrophy of bone; polyarteritis nodosa (chronic active inflammation of the blood vessels) of the epididymis, testis, cecum, liver, pancreas, salivary glands, and thymus; germ cell degeneration of the testis; edema, erosion, epithelial regeneration, acute inflammation, chronic active inflammation, and ulcer of the cecum; epithelial regeneration of the colon; red pulp atrophy and white pulp atrophy of the spleen; and exfoliated germ cell and hypospermia of the epididymis.

Table 28 Incidences of Non-neoplastic Lesions Associated with the Decreased Severity of Chronic Progressive Nephropathy of the Kidney in Male Rats Exposed to GSM-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Kidney^a^ | 90 | 90 | 90 | 90
Nephropathy, Chronic Progressive^b^ | 88 (3.7)^c^ | 89 (3.2) | 90 (2.9) | 89 (2.6)
Aorta | 90 | 90 | 90 | 90
Mineral | 30 (2.1) | 7** (2.3) | 12** (1.6) | 6** (1.5)
Bone | 90 | 90 | 90 | 90
Fibrous Osteodystrophy | 46 (1.4) | 18** (1.1) | 14** (1.0) | 6** (1.5)
Brain | 90 | 90 | 90 | 90
Mineral | 5 (1.0) | 4 (1.0) | 6 (1.2) | 2 (1.0)
Epididymis | 90 | 90 | 90 | 90
Artery, Inflammation, Chronic Active | 2 (2.5) | 2 (2.0) | 1 (4.0) | 2 (2.5)
Exfoliated Germ Cell | 51 (1.9) | 26** (1.5) | 29** (1.4) | 15** (1.5)
Hypospermia | 28 (3.4) | 20 (3.2) | 23 (3.0) | 8** (3.3)
Heart | 90 | 90 | 90 | 90
Artery, Mineral | 20 (2.5) | 7** (1.9) | 3** (2.0) | 2** (1.5)
Intestine Large, Cecum | 75 | 75 | 79 | 80
Artery, Inflammation, Chronic Active | 20 (2.1) | 9* (2.0) | 5** (1.8) | 6** (1.8)
Artery, Mineral | 1 (2.0) | 0 | 0 | 0
Edema | 11 (2.0) | 1** (2.0) | 0** | 4 (1.8)
Epithelium, Regeneration | 14 (2.4) | 0** | 0** | 2** (2.5)
Erosion | 10 (2.5) | 0** | 0** | 3 (2.0)
Inflammation, Acute | 10 (2.8) | 1* (2.0) | 0** | 2* (1.5)
Inflammation, Chronic Active | 1 (3.0) | 0 | 0 | 0
Ulcer | 6 (2.3) | 0 | 0* | 0*
Intestine Large, Colon | 81 | 83 | 81 | 82
Artery, Mineral | 2 (2.0) | 0 | 0 | 0
Epithelium, Regeneration | 5 (2.6) | 0 | 0 | 2 (1.0)
Intestine Large, Rectum | 83 | 81 | 85 | 87
Epithelium, Regeneration | 3 (2.3) | 0 | 0 | 0
Kidney | 90 | 90 | 90 | 90
Artery, Mineral | 2 (2.0) | 1 (1.0) | 0 | 0
Liver | 90 | 90 | 90 | 90
Artery, Inflammation, Chronic Active | 2 (3.5) | 5 (2.4) | 1 (1.0) | 0
Artery, Mineral | 1 (1.0) | 0 | 0 | 0
Mesentery | 39 | 19 | 17 | 7
Artery, Mineral | 21 (2.1) | 4* (2.3) | 5 (2.6) | 2 (1.5)
Pancreas | 90 | 89 | 88 | 86
Artery, Inflammation, Chronic Active | 48 (2.3) | 28**(2.1) | 26** (2.4) | 14** (2.0)
Artery, Mineral | 11 (1.8) | 3* (1.7) | 3* (2.0) | 1** (3.0)
Parathyroid Gland | 83 | 87 | 87 | 81
Hyperplasia | 51 (2.5) | 35** (2.0) | 46 (2.0) | 28** (1.6)
Salivary Glands | 90 | 90 | 90 | 90
Artery, Inflammation, Chronic Active | 11 (2.5) | 7 (2.6) | 3* (2.7) | 1** (3.0)
Artery, Mineral | 2 (2.5) | 0 | 0 | 0
Skeletal Muscle | 90 | 90 | 90 | 90
Mineral | 2 (1.0) | 0 | 0 | 0
Spleen | 90 | 90 | 89 | 90
Red Pulp, Atrophy | 26 (2.2) | 10** (2.0) | 10** (2.4) | 3** (2.3)
White Pulp, Atrophy | 30 (2.1) | 16** (1.8) | 13** (1.8) | 11** (2.1)
Stomach, Glandular | 86 | 88 | 87 | 86
Mineral | 31 (2.5) | 7** (2.9) | 8** (2.4) | 4** (2.5)
Testis | 90 | 90 | 90 | 90
Artery, Inflammation, Chronic Active | 52 (2.9) | 40* (2.9) | 37** (2.9) | 20** (2.7)
Germ Cell, Degeneration | 51 (2.3) | 35* (2.2) | 42 (2.1) | 20** (2.0)
Thymus | 88 | 86 | 88 | 86
Artery, Inflammation, Chronic Active | 6 (2.7) | 3 (3.0) | 2 (2.5) | 1 (2.0)

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

* P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Chronic progressive nephropathy (Plate 12) in the 2-year study was characterized by dilated tubules with flattened epithelium, primarily in the cortex, but extending into the medulla. Many tubules were atrophied, and some had hyperplastic epithelium. The basement membranes around the renal tubules in the cortex were variably thickened, some markedly so. There was some fibrosis scattered throughout the cortical interstitium, with scattered mononuclear inflammatory cells. In more severe cases, there was fibrosis of the Bowman’s capsule around the glomeruli and varying degrees of glomerular sclerosis. Severity was based on the percentage of the kidney that was affected.

Other Lesions: In females, there was a significant negative trend (P = 0.038) in the incidences of mammary gland adenoma, and the incidences in the 3 and 6 W/kg groups were decreased but not significantly (Table B-2). The incidence in the sham controls (9%) was at the high end of the historical control range for this neoplasm in Hsd:Sprague Dawley^®^ SD^®^ rats, and the incidences in the 3 and 6 W/kg groups (2%) were within the historical control range (15/240 [5.7% ± 4.0%], range 0%-9%). The biological significance of these findings is unclear.

In males, the incidences of acinar hyperplasia of the pancreas were significantly decreased in the 3 and 6 W/kg groups compared to sham controls (Table A-9). The incidences of decreased secretory fluid in the seminal vesicle were significantly decreased in all exposed groups compared to sham controls (Table A-9). The incidences of both lesions decreased in an exposure-related fashion; however, the biological significance of these decreases is unclear.

## CDMA

### Twenty-eight-day Study

#### Perinatal Study

No exposure-related effects were observed on survival or littering rates (littering/pregnant ratio) (Table 29). A single incidence of whole litter resorption was observed in the 9 W/kg group, and it was unclear if this was related to exposure due to the low incidence. Gestation body weights were unaffected by exposure to CDMA (Table 30). An overall (GD 1 through 16) lower body weight gain of 11% compared to sham controls was observed.

Table 29 Summary of Disposition during Perinatal Exposure and F_1_ Allocation in the 28-day Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Time-mated Females | 20 | 20 | 20 | 20
Pregnant Females | 20 | 17 | 17 | 16
Nonpregnant Females | 0 | 3 | 3 | 3
Pregnant Dams Not Delivering | 0 | 0 | 0 | 1
Died | 0 | 0 | 0 | 0
Littered | 20 | 19 | 18 | 20
Pregnant/Mated Percentage^a^ | 100.0% | 85.0% | 85.0% | 80.0%
Littered/Pregnant Percentage^a^ | 100.0% | 100.0% | 100.0% | 94.1%
Litters Removed (Insufficient Size) (PND 4) | 0 | 0 | 0 | 0
Litters Post Standardization (PND 4) | 20 | 17 | 17 | 16
Weaned/Sex (PND 21)^b^ | 30 | 30 | 30 | 30

^a^ Number in the numerator as proportion of the number in the denominator was tested using the Fisher exact test for pairwise comparisons against the sham control group.

^b^ Total number of weaned animals per sex from 10 litters.

Table 30 Mean Body Weights and Mean Body Weight Gains of F_0_ Female Rats during Gestation in the 28-day Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Gestation Day
6 | 238.3 ± 2.2 (20)b | 237.2 ± 1.8 (17) | 236.9 ± 2.6 (17) | 237.8 ± 2.2 (16)
9 | 250.7 ± 2.4 (20) | 250.4 ± 2.4 (17) | 252.3 ± 2.8 (17) | 250.4 ± 2.1 (16)
12 | 266.2 ± 2.5 (20) | 265.1 ± 2.3 (17) | 266.6 ± 3.4 (17) | 263.8 ± 2.5 (16)
15 | 282.5 ± 2.9 (20) | 281.9 ± 2.7 (17) | 283.5 ± 3.6 (17) | 279.8 ± 2.7 (16)
18 | 319.3 ± 3.0 (20) | 316.9 ± 2.3 (17) | 318.0 ± 4.8 (17) | 312.2 ± 3.1 (16)
21 | 366.4 ± 4.3 (20)^▲^ | 359.7 ± 3.5 (17) | 360.0 ± 6.9 (17) | 352.0 ± 3.6 (16)
Gestation Day Interval
6–9 | 12.5 ± 1.2 (20) | 13.2 ± 0.9 (17) | 15.4 ± 0.9 (17) | 12.6 ± 0.8 (16)
9–12 | 15.5 ± 1.1 (20) | 14.7 ± 0.9 (17) | 14.3 ± 1.3 (17) | 13.4 ± 0.8 (16)
2–15 | 16.3 ± 1.0 (20) | 16.8 ± 0.9 (17) | 16.9 ± 1.3 (17) | 16.0 ± 0.7 (16)
15–18 | 36.7 ± 0.9 (20)^▲^ | 35.0 ± 1.1 (17) | 34.5 ± 1.9 (17) | 32.4 ± 0.9 (16)*
18–21 | 47.1 ± 1.8 (20)^▲▲^ | 42.8 ± 1.6 (17) | 42.0 ± 3.0 (17) | 39.7 ± 1.4 (16)*
6–21 | 128.1 ± 3.3 (20)^▲^ | 122.5 ± 2.7 (17) | 123.1 ± 6.2 (17) | 114.2 ± 2.3 (16)*

^▲^Significant trend (P ≤ 0.05).

^▲▲^P ≤ 0.01.

* Significantly different (P ≤ 0.05) from the sham control group.

^a^ Body weights and body weight gains in grams. Data are displayed as mean ± standard error. Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ Number of dams.

Total and live litter size on PND 1 was unaffected by exposure and there was no statistically significant effect on live litter size throughout lactation (Table 31). How-ever, there were higher numbers of dead pups in the exposed groups from PND 1 to 4 and in the 6 and 9 W/kg groups from PND 5 to 21 (Table 32).

Table 31 Mean Number of Surviving F_1_ Male and Female Rats during Lactation in the 28-day Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Total Pups per Litter
PND 1 | 11.95 ± 0.38 (20)b | 11.76 ± 0.30 (17) | 11.18 ± 1.03 (17) | 11.88 ± 0.48 (16)
Live Pups per Litter
PND 1 | 11.90 ± 0.39 (20) | 11.65 ± 0.32 (17) | 10.82 ± 1.04 (17) | 11.63 ± 0.50 (16)
PND 4 (Preculling) | 11.85 ± 0.39 (20) | 11.47 ± 0.33 (17) | 10.47 ± 1.09 (17) | 11.38 ± 0.56 (16)
PND 4 (Postculling) | 7.95 ± 0.05 (20) | 8.00 ± 0.00 (17) | 7.06 ± 0.57 (17) | 8.13 ± 0.09 (16)
PND 7 | 7.95 ± 0.05 (20) | 8.00 ± 0.00 (17) | 6.94 ± 0.57 (17) | 7.75 ± 0.39 (16)
PND 10 | 7.95 ± 0.05 (20) | 8.00 ± 0.00 (17) | 6.88 ± 0.61 (17) | 7.63 ± 0.52 (16)
PND 14 | 7.95 ± 0.05 (20) | 8.00 ± 0.00 (17) | 6.82 ± 0.64 (17) | 7.63 ± 0.52 (16)
PND 17 | 7.95 ± 0.05 (20) | 8.00 ± 0.00 (17) | 6.82 ± 0.64 (17) | 7.63 ± 0.52 (16)
PND 21 | 7.95 ± 0.05 (20) | 8.00 ± 0.00 (17) | 6.82 ± 0.64 (17) | 7.63 ± 0.52 (16)
Live Males per Litter
PND 1 | 6.10 ± 0.42 (20) | 5.71 ± 0.43 (17) | 5.00 ± 0.67 (17) | 6.44 ± 0.47 (16)
PND 4 (Preculling) | 6.05 ± 0.41 (20) | 5.82 ± 0.50 (17) | 5.12 ± 0.63 (17) | 6.25 ± 0.52 (16)
PND 4 (Postculling) | 4.00 ± 0.15 (20) | 4.18 ± 0.23 (17) | 3.53 ± 0.27 (17) | 4.50 ± 0.37 (16)
Live Females per Litter
PND 1 | 5.80 ± 0.42 (20) | 5.94 ± 0.52 (17) | 5.82 ± 0.69 (17) | 5.19 ± 0.56 (16)
PND 4 (Preculling) | 5.80 ± 0.43 (20) | 5.65 ± 0.58 (17) | 5.35 ± 0.65 (17) | 5.13 ± 0.59 (16)
PND 4 (Postculling) | 3.95 ± 0.14 (20) | 3.82 ± 0.23 (17) | 3.53 ± 0.33 (17) | 3.63 ± 0.36 (16)

^a^ All values shown as mean ± standard error; PND = postnatal day. Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^b^ Number of dams.

Table 32 Offspring Mortality and Survival Ratio of Rats during Lactation in the 28-day Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

Pup Survival per Litter | Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Total Dead PND 1–4 | 2 (238/20)^b^ | 5 (198/17) | 12 (184/17) | 8 (186/16)
Total Dead PND 5–21 | 0 (159/20) | 0 (136/17) | 4 (120/17) | 8 (130/16)
Dead/Litter PND 1–4 | 0.100 ± 0.069 (20) | 0.294 ± 0.143 (17) | 0.706 ± 0.318 (17) | 0.500 ± 0.204 (16)
Dead/Litter PND 4–21 | 0.000 ± 0.000 (20) | 0.000 ± 0.000 (17) | 0.235 ± 0.136 (17) | 0.500 ± 0.500 (16)
Survival Ratio PND 1–4^c^ | 0.996 ± 0.004 (20) | 0.985 ± 0.008 (17) | 0.942 ± 0.031 (17) | 0.975 ± 0.011 (16)
Survival Ratio PND 4–21^d^ | 1.000 ± 0.000 (20) | 1.000 ± 0.000 (17) | 0.868 ± 0.081 (17) | 0.938 ± 0.063 (16)

^a^ All values shown as mean ± standard error; PND = postnatal day. Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^b^ Number of pups/number of dams.

^c^ Number of pups preculling on PND 4/total number of viable pups on PND 1 (does not include pups dead on PND 1).

^d^ Number of pups alive on PND 21/number of pups at postculling on PND 4.

During the lactation period, 9 W/kg dams had decreased weight gains, and their body weights were 5% to 12% lower than those in the sham controls from PND 7 through 21 (Table 33). F_1_ body weights were 8% lower starting on PND 1 in the 9 W/kg group whether male, female, or combined when not adjusted or adjusted for litter size (Table 34). As lactation progressed, the adjusted pup weights (combined) were up to 23% lower in the 9 W/kg group and up to 16% lower in the 6 W/kg group compared to sham controls. The magnitude of the effect was consistent between males and females with a recovery in the 6 W/kg group on PND 14 and 21.

Table 33 Mean Body Weights and Mean Body Weight Gains of F_0_ Female Rats during Lactation in the 28-day Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Postnatal Day
1 | 272.7 ± 2.7 (20)^b^ | 268.9 ± 2.4 (17) | 271.7 ± 4.1 (17) | 263.8 ± 2.6 (16)
4 | 263.8 ± 3.6 (20) | 264.1 ± 2.9 (16) | 269.3 ± 4.1 (17) | 264.6 ± 2.1 (16)
7 | 284.1 ± 2.7 (20)^▲▲^ | 282.5 ± 2.7 (17) | 282.1 ± 4.0 (17) | 269.6 ± 1.9 (16)**
14 | 292.4 ± 2.6 (20)^▲▲^ | 293.3 ± 2.7 (17) | 284.9 ± 4.1 (17) | 264.1 ± 3.1 (16)**
21 | 279.7 ± 3.5 (20)^▲▲^ | 282.6 ± 3.0 (17) | 272.9 ± 3.7 (17) | 245.9 ± 3.1 (16)**
Postnatal Day Interval
1–4 | –8.9 ± 3.2 (20)^▲^ | –3.8 ± 3.3 (16) | –2.4 ± 3.1 (17) | 0.8 ± 1.4 (16)
4–7 | 20.2 ± 2.3 (20)^▲▲^ | 18.1 ± 3.2 (16) | 12.8 ± 2.2 (17)* | 5.1 ± 1.2 (16)**
7–14 | 8.3 ± 1.4 (20)^▲▲^ | 10.8 ± 1.8 (17) | 2.9 ± 2.3 (17)* | –5.5 ± 2.0 (16)**
14–21 | –12.7 ± 3.5 (20) | –10.7 ± 2.8 (17) | –12.1 ± 2.7 (17) | –18.2 ± 2.4 (16)
1–21 | 7.0 ± 3.8 (20)^▲▲^ | 13.7 ± 2.7 (17) | 1.1 ± 2.8 (17) | –17.9 ± 3.3 (16)**

^▲^Significant trend (P ≤ 0.05).

^▲▲^P ≤ 0.01.

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Body weights and body weight gains in grams. Data are displayed as mean ± standard error. Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ Number of dams.

Table 34 Adjusted Mean Body Weights of F_1_ Male and Female Rats during Lactation in the 28-day Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
Adjusted Male Live Pup Weight
PND 1^b^ | 6.73 ± 0.10 (20^)▲▲c^ | 6.76 ± 0.11 (17) | 6.52 ± 0.10 (17) | 6.16 ± 0.11 (16)^▲▲^
PND 4 (Preculling) | 9.78 ± 0.14 (121/20)**^d^ | 9.43 ± 0.16 (99/17) | 8.78 ± 0.30 (87/17)** | 8.14 ± 0.28 (100/16)**
PND 4 (Postculling) | 9.84 ± 0.14 (81/20)** | 9.57 ± 0.15 (69/17) | 8.82 ± 0.30 (61/17)** | 8.19 ± 0.27 (71/16)**
PND 7 | 16.33 ± 0.19 (81/20)** | 15.30 ± 0.27 (69/17) | 13.64 ± 0.67 (61/17)** | 12.52 ± 0.61 (64/16)**
PND 14 | 31.61 ± 0.42 (81/20)** | 30.91 ± 0.41 (69/17) | 29.73 ± 0.47 (59/15)** | 26.75 ± 0.47 (63/15)**
PND 21 | 53.33 ± 0.72 (81/20)** | 52.57 ± 0.71 (69/17) | 51.42 ± 0.75 (59/15) | 45.11 ± 0.84 (63/15)**
Adjusted Female Live Pup Weight
PND 1^b^ | 6.30 ± 0.10 (20)^▲▲^ | 6.43 ± 0.11 (17) | 6.14 ± 0.12 (16) | 5.77 ± 0.13 (14)^▲▲^
PND 4 (Preculling) | 9.11 ± 0.16 (116/20)** | 8.85 ± 0.15 (96/17) | 8.75 ± 0.17 (91/15) | 7.86 ± 0.18 (82/14)**
PND 4 (Postculling) | 9.19 ± 0.16 (79/20)** | 9.00 ± 0.15 (67/17) | 8.78 ± 0.17 (59/15) | 7.97 ± 0.19 (57/14)**
PND 7 | 15.26 ± 0.24 (79/20)** | 14.63 ± 0.24 (67/17) | 13.90 ± 0.29 (57/15)** | 12.29 ± 0.36 (57/14)**
PND 14 | 29.82 ± 0.40 (79/20)** | 29.78 ± 0.38 (67/17) | 28.57 ± 0.41 (57/15) | 25.66 ± 0.51 (57/14)**
PND 21 | 49.87 ± 0.73 (79/20)** | 49.50 ± 0.54 (67/17) | 49.03 ± 0.64 (57/15) | 43.24 ± 0.87 (57/14)**
Adjusted Combined Live Pup Weight
PND 1^b^ | 6.51 ± 0.10 (20)^▲▲^ | 6.60 ± 0.11 (17) | 6.33 ± 0.11 (17) | 5.99 ± 0.10 (16)^▲▲^
PND 4 (Preculling) | 9.45 ± 0.13 (237/20)** | 9.17 ± 0.15 (195/17) | 8.51 ± 0.34 (178/17)* | 7.90 ± 0.25 (182/16)**
PND 4 (Postculling) | 9.52 ± 0.13 (160/20)** | 9.30 ± 0.14 (136/17) | 8.57 ± 0.33 (120/17)* | 8.00 ± 0.25 (128/16)**
PND 7 | 15.79 ± 0.19 (160/20)** | 14.97 ± 0.23 (136/17) | 13.29 ± 0.69 (118/17)** | 12.21 ± 0.58 (121/16)**
PND 14 | 30.70 ± 0.39 (160/20)** | 30.33 ± 0.37 (136/17) | 29.17 ± 0.43 (116/15)* | 26.29 ± 0.46 (120/15)**
PND 21 | 51.57 ± 0.67 (160/20)** | 51.07 ± 0.59 (136/17) | 50.29 ± 0.68 (116/15) | 44.31 ± 0.82 (120/15)**

^▲▲^Significantly different (P ≤ 0.01) for PND 1 endpoint (statistical significance in the sham control group column indicates a significant trend test; statistical significance in a treatment group column indicates a significant pairwise comparison against the sham control group).

* Significantly different (P ≤ 0.05) for PNDs after PND 1 endpoints (statistical significance in the sham control group column indicates a significant trend test; statistical significance in the treatment group column indicates a significant pairwise comparison against the sham control group).

** P ≤ 0.01.

^a^ Body weights in grams. Data are displayed as mean ± standard error. PND = postnatal day. Values listed as PND 1 refer to the total pup weight divided by the number of pups in litter at PND 1, and the statistical analysis performed is by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests. Values listed for all other days refer to individual pups, and the statistical analysis is for linear trends performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dose groups to sham control group were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnet-Hsu adjustment method. Individual pup body weights first adjusted for live PND 1 litter size via the analysis of covariance.

^b^ Values listed as PND 1 refer to the total pup weight divided by the number of pups in litter at PND 1.

^c^ Number of dams.

^d^ Number of pups/number of dams.

#### Postnatal Study

All rats survived to the end of the study (Table 35). In males, there were lower mean body weights in the 3 (5% to 7%) and 9 W/kg groups (13% to 15%) compared to the sham controls at all time points including terminal sacrifice (except day 1 for the 3 W/kg group) (Table 35 and Figure 9). In 6 W/kg males, mean body weights were lower (5% to 7%) at all time points except terminal sacrifice. Mean body weight gains were lower (6% to 14%) in all three male exposed groups compared to sham controls (data not presented). In females, mean body weights were lower on days 1, 8, 15, and 22 in the 9 W/kg group (7% to 12%), on days 1, 8, and 15 in the 6 W/kg group (1% to 2%), and on day 8 in the 3 W/kg group (4%). However, at terminal sacrifice, the mean body weights of all exposed female groups were similar to those of the sham controls. Mean body weight gains of all exposed female groups were similar to that of the sham controls. There were no notable clinical observations in any groups of either sex during the study.

Table 35 Mean Body Weights and Survival of Rats Exposed to CDMA-modulated Cell Phone RFR for 28 Days

Day | Sham Control | | 3 W/kg | | | 6 W/kg | | | 9 W/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt.(g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
Male
1 | 60.8 | 10 | 58.4 | 95.9 | 10 | 58.0 | 95.3 | 10 | 52.9 | 87.0 | 10
8 | 94.9 | 10 | 89.8 | 94.6 | 10 | 88.8 | 93.6 | 10 | 80.5 | 84.9 | 10
15 | 144.5 | 10 | 136.1 | 94.1 | 10 | 134.2 | 92.9 | 10 | 123.6 | 85.5 | 10
22 | 195.3 | 10 | 182.8 | 93.6 | 10 | 184.6 | 94.5 | 10 | 169.2 | 86.6 | 10
29 | 248.7 | 10 | 231.1 | 92.9 | 10 | 236.4 | 95.0 | 10 | 215.0 | 86.4 | 10
Female
1 | 55.9 | 10 | 53.5 | 95.8 | 10 | 55.7 | 99.7 | 10 | 49.5 | 88.6 | 10
8 | 83.1 | 10 | 79.5 | 95.6 | 10 | 81.8 | 98.3 | 10 | 73.4 | 88.3 | 10
15 | 119.8 | 10 | 114.4 | 95.5 | 10 | 118.5 | 98.9 | 10 | 107.9 | 90.1 | 10
22 | 146.5 | 10 | 144.6 | 98.7 | 10 | 148.7 | 101.5 | 10 | 136.9 | 93.4 | 10
30 | 166.5 | 10 | 162.7 | 97.7 | 10 | 171.7 | 103.1 | 10 | 159.0 | 95.5 | 10

Figure 9

Growth Curves for Rats Exposed to CDMA-modulated Cell Phone RFR for 28 Days

Body temperatures were significantly, but sporadically, increased in F_0_ females at several time points (Table 36). Body temperature in the F_1_ groups were similar to those of the sham controls throughout the study (Table 36 and Table G-5).

Table 36 Mean Body Temperatures of Rats Exposed to CDMA-modulated Cell Phone RFR for 28 Days^a^

Day | Sham Control | | 3 W/kg | | 6 W/kg | | 9 W/kg
Day | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured | Temperature (°C) | No. Measured
F0 Female^b^
GD 6 | 36.7 ± 0.1 | 10^c^ | 36.8 ± 0.1 | 9 | 36.6 ± 0.2 | 9 | 36.4 ± 0.2 | 8
GD 7 | 36.6 ± 0.1^▲^ | 10 | 36.3 ± 0.2 | 9 | 36.6 ± 0.1 | 9 | 37.2 ± 0.1* | 8
GD 11 | 36.7 ± 0.2 | 10 | 36.4 ± 0.1 | 9 | 36.2 ± 0.2* | 9 | 36.8 ± 0.2 | 8
GD 16 | 36.5 ± 0.1^▲^ | 10 | 36.5 ± 0.2 | 9 | 36.6 ± 0.1 | 9 | 37.2 ± 0.2* | 8
GD 7–16^d^ | 36.6 ± 0.1 | 10 | 36.4 ± 0.1 | 9 | 36.4 ± 0.1 | 9 | 37.1 ± 0.1* | 8
LD 1 | 37.7 ± 0.1 | 10 | 37.3 ± 0.2 | 9 | 37.7 ± 0.1 | 9 | 37.9 ± 0.2 | 8
LD 4 | 36.7 ± 0.1^▲▲^ | 10 | 37.0 ± 0.2 | 9 | 37.3 ± 0.3* | 9 | 38.1 ± 0.2** | 8
LD 7 | 36.8 ± 0.2^▲^ | 10 | 37.0 ± 0.1 | 9 | 37.4 ± 0.2 | 9 | 37.5 ± 0.3 | 8
LD 14 | 36.9 ± 0.2^▲▲^ | 10 | 37.0 ± 0.3 | 9 | 37.6 ± 0.1* | 9 | 38.3 ± 0.3** | 7
LD 7–14^d^ | 37.0 ± 0.1^▲▲^ | 10 | 37.1 ± 0.1 | 9 | 37.5 ± 0.1* | 9 | 37.9 ± 0.2** | 8
F1 Male^e^
16 | 37.4 ± 0.2 | 4 | 37.0 ± 0.0 | 4 | 37.1 ± 0.0 | 4 | 37.2 ± 0.1 | 4
20 | 37.6 ± 0.1 | 4 | 37.2 ± 0.1 | 4 | 37.1 ± 0.1 | 4 | 37.5 ± 0.2 | 4
27 | 37.3 ± 0.2 | 4 | 36.8 ± 0.1 | 4 | 37.0 ± 0.1 | 4 | 37.4 ± 0.1 | 4
16–27^d^ | 37.5 ± 0.1 | 4 | 37.0 ± 0.0 | 4 | 37.1 ± 0.0 | 4 | 37.4 ± 0.1 | 4
F1 Female^e^
16 | 38.0 ± 0.3 | 4 | 37.2 ± 0.2* | 3 | 37.4 ± 0.1 | 4 | 37.5 ± 0.1 | 4
20 | 38.1 ± 0.2^▲^ | 4 | 38.1 ± 0.2 | 4 | 37.5 ± 0.2 | 4 | 37.7 ± 0.2 | 4
27 | 37.9 ± 0.2 | 4 | 37.1 ± 0.1 | 4 | 37.9 ± 0.3 | 4 | 37.9 ± 0.2 | 4
16–27^d^ | 38.0 ± 0.2 | 4 | 37.5 ± 0.1 | 4^f^ | 37.6 ± 0.2 | 4 | 37.7 ± 0.1 | 4

^▲^Significant trend (P ≤ 0.05).

^▲▲^P ≤ 0.01.

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Temperatures are given as mean ± standard error. GD = gestation day; LD = lactation day.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^c^ For F0 females, number measured refers to individual animals; for F1 pups, number measured refers to litters.

^d^ Average of days.

^e^ Statistical analysis for linear trends was performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dose groups to sham control were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett-Hsu adjustment method.

^f^ There were three litters on day 16.

Male body weights were lower in the 9 W/kg group at the end of the 28-day studies. There were a few statistically significant changes in organ weights at this exposure level that were considered secondary to the reduced body weights (Table G-6). There were no biologically significant changes in organ weights in females.

Kidney: There was a increased incidence of chronic progressive nephropathy in the 6 W/kg females compared to sham controls [sham control, 0/10; 3 W/kg, 2/10; 6 W/kg, 4/10*; 9 W/kg, 3/10; significantly different (P ≤ 0.05) from the sham control group by the Fisher exact test]. The severity in all cases was minimal. This lesion was characterized by scattered tubular segments with basophilic epithelial cells with crowded nuclei, slightly thickened basement membranes, and occasional mononuclear inflammatory cells. Chronic progressive nephropathy was not considered to be related to treatment with CDMA-modulated cell phone RFR because there was no exposure-related response and it is a very common background lesion in rats.

Exposure Level Selection Rationale: Based on reduced maternal and pup weights, increased F_0_ dam body temperature measurements at 9 W/kg in the 28-day studies, and increased body temperature in adult rats at ≥8 W/kg in the thermal pilot studies,^146^ the highest exposure level selected for the 2-year studies was 6 W/kg. In the thermal pilot studies and 28-day studies, exposure to 6 W/kg resulted in some increases in core body temperature, but these increases were less than 1°C. Therefore, 6 W/kg would provide an exposure adequate to challenge the animals without causing excessive heating or disruption of the thermoregulatory process. The lowest exposure level selected for the 2-year studies was 1.5 W/kg, which is close to the 1.6 W/kg maximum output limit for cell phone devices in the United States.

### Two-year Study

#### Perinatal Exposure

No exposure-related effects were observed on pregnancy status, maternal survival, or the percent of pregnant animals that littered (Table 37). Maternal body weights during gestation were similar to those of the sham control group (Table 38). Body weight gains were generally unaffected across time intervals except in the 3 W/kg group at the GD 6 through 9 interval where weight gains were lower than that of the sham control group, but this was not considered to be exposure related.

Table 37 Summary of Disposition during Perinatal Exposure and F_1_ Allocation in the Two-year Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Time-mated Females | 56 | 56 | 56 | 56
Pregnant Females | 52 | 50 | 48 | 49
Nonpregnant Females | 4 | 6 | 8 | 7
Pregnant Dams Not Delivering | 2 | 2 | 2 | 1
Died^a^ | 1 | 0 | 0 | 0
Littered | 50 | 48 | 46 | 48
Pregnant/Mated Percentage^b^ | 92.9% | 89.3% | 85.7% | 87.5%
Littered/Pregnant Percentage^b^ | 96.2% | 96.0% | 95.8% | 98.0%
Litters Removed (Insufficient Size) | 2 | 3 | 3 | 2
Litters Post Standardization | 48 | 45 | 43 | 46
Weaned/Sex^c^ | 105 | 105 | 105 | 105

^a^ One pregnant female died on GD 25 with pups in uterus.

^b^ Number in the numerator as proportion of the number in the denominator was tested using the Fisher exact test for pairwise comparisons against the sham control group.

^c^ Total number of weaned animals per sex from 35 litters.

Table 38 Mean Body Weights and Mean Body Weight Gains of F0 Female Rats during Gestation in the Two-year Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Gestation Day
6 | 238.4 ± 1.4 (51)^b^ | 239.0 ± 1.3 (48) | 239.9 ± 1.6 (46) | 237.8 ± 1.6 (48)
9 | 256.2 ± 1.6 (51) | 255.2 ± 1.4 (48) | 254.5 ± 1.8 (46) | 253.7 ± 1.7 (48)
12 | 270.5 ± 1.6 (51) | 268.7 ± 1.4 (48) | 268.8 ± 1.6 (46) | 267.0 ± 1.7 (48)
15 | 290.0 ± 1.9 (51) | 288.5 ± 1.6 (48) | 289.3 ± 1.8 (46) | 287.5 ± 2.0 (48)
18 | 332.7 ± 2.3 (51) | 329.7 ± 2.1 (48) | 329.1 ± 2.3 (46) | 329.0 ± 2.5 (48)
21 | 380.2 ± 2.8 (51) | 375.9 ± 3.0 (48) | 375.1 ± 3.2 (46) | 375.0 ± 3.1 (48)
Gestation Day Interval
6–9 | 17.7 ± 0.8 (51) | 16.1 ± 0.7 (48) | 14.6 ± 1.0 (46)* | 15.9 ± 0.7 (48)
9–12 | 14.3 ± 0.6 (51) | 13.6 ± 0.5 (48) | 14.3 ± 1.0 (46) | 13.3 ± 0.6 (48)
12–15 | 19.6 ± 0.6 (51) | 19.8 ± 0.5 (48) | 20.5 ± 0.7 (46) | 20.5 ± 0.5 (48)
15–18 | 42.7 ± 1.0 (51) | 41.3 ± 1.1 (48) | 39.8 ± 0.8 (46) | 41.5 ± 0.8 (48)
18–21 | 47.5 ± 1.0 (51) | 46.2 ± 1.2 (48) | 46.0 ± 1.2 (46) | 46.0 ± 1.0 (48)
6–21 | 141.7 ± 2.2 (51) | 136.9 ± 2.8 (48) | 135.2 ± 2.5 (46) | 137.1 ± 2.3 (48)

* Significantly different (P ≤ 0.05) from the sham control group.

^a^ Body weights and body weight gains in grams. Data are displayed as mean ± standard error. Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ Number of dams.

On PND 1, there were no effects on total litter size or live litter size (Table 39). However, beginning on PND 7, live litter size was decreased in the 6 W/kg groups compared to the sham control group. There was a higher incidence of pup mortality (found dead or missing and presumed cannibalized) between PNDs 4 and 21 in the 6 W/kg group that corresponded to an increase in average number of dead pups per litter and a reduced survival ratio (Table 40).

Table 39 Mean Number of Surviving F1 Male and Female Rats during Lactation in the Two-year Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Total Pups per Litter
PND 1 | 12.76 ± 0.32 (50)^b^ | 12.42 ± 0.41 (48) | 12.43 ± 0.39 (46) | 12.94 ± 0.35 (48)
Live Pups per Litter
PND 1 | 12.56 ± 0.40 (50) | 12.33 ± 0.42 (48) | 12.39 ± 0.41 (46) | 12.94 ± 0.35 (48)
PND 4 (Preculling) | 12.73 ± 0.30 (48) | 12.72 ± 0.26 (46) | 12.77 ± 0.31 (43) | 12.87 ± 0.30 (46)
PND 4 (Postculling) | 8.00 ± 0.00 (48) | 8.00 ± 0.00 (45) | 8.00 ± 0.00 (43) | 8.00 ± 0.00 (46)
PND 7 | 8.00 ± 0.00 (48)^▲▲^ | 7.98 ± 0.02 (45) | 7.98 ± 0.02 (43) | 7.85 ± 0.06 (46)**
PND 10 | 8.00 ± 0.00 (48)^▲▲^ | 7.98 ± 0.02 (45) | 7.98 ± 0.02 (43) | 7.76 ± 0.08 (46)**
PND 14 | 8.00 ± 0.00 (48)^▲▲^ | 7.98 ± 0.02 (45) | 7.98 ± 0.02 (43) | 7.52 ± 0.11 (46)**
PND 17 | 8.00 ± 0.00 (48)^▲▲^ | 7.98 ± 0.02 (45) | 7.98 ± 0.02 (43) | 7.52 ± 0.11 (46)**
PND 21 | 8.00 ± 0.00 (48)^▲▲^ | 7.98 ± 0.02 (45) | 7.98 ± 0.02 (43) | 7.52 ± 0.11 (46)**
Live Males per Litter
PND 1 | 6.20 ± 0.30 (50) | 6.33 ± 0.30 (48) | 6.07 ± 0.31 (46) | 6.69 ± 0.30 (48)
PND 4 (Preculling) | 6.33 ± 0.28 (48) | 6.78 ± 0.24 (46) | 6.26 ± 0.33 (43) | 6.76 ± 0.29 (46)
PND 4 (Postculling) | 3.96 ± 0.05 (48) | 4.00 ± 0.06 (45) | 3.95 ± 0.09 (43) | 4.04 ± 0.05 (46)
Live Females per Litter
PND 1 | 6.36 ± 0.28 (50) | 6.00 ± 0.32 (48) | 6.33 ± 0.36 (46) | 6.25 ± 0.26 (48)
PND 4 (Preculling) | 6.40 ± 0.25 (48) | 5.93 ± 0.28 (46) | 6.51 ± 0.35 (43) | 6.11 ± 0.24 (46)
PND 4 (Postculling) | 4.04 ± 0.05 (48) | 4.00 ± 0.06 (45) | 4.05 ± 0.09 (43) | 3.96 ± 0.05 (46)

^▲▲^Significant trend (P ≤ 0.01).

** Significantly different (P ≤ 0.01) from the sham control group.

^a^ All values shown as mean ± standard error; PND = postnatal day. Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests. Statistical significance in the sham control group column indicates a significant trend test; statistical significance in a treatment group column indicates a significant pairwise comparison against the sham control group.

^b^ Number of dams.

Table 40 Offspring Mortality and Survival Ratio of Rats during Lactation in the Two-year Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

Pup Survival per Litter | Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Total Dead PND 1–4^b^ | 19 (628/49)^c^ | 9 (592/46) | 6 (570/43) | 16 (621/46)
Total Dead PND 5–21 | 0 (348/48) | 1 (360/45) | 1 (344/43) | 22 (368/46)
Dead/Litter PND 1–4 | 0.388 ± 0.193 (49) | 0.196 ± 0.074 (46) | 0.140 ± 0.063 (43) | 0.348 ± 0.099 (46)
Dead/Litter PND 4–21 | 0.000 ± 0.000 (48)^▲▲^ | 0.022 ± 0.022 (45) | 0.023 ± 0.023 (43) | 0.478 ± 0.106 (46)**
Survival Ratio PND 1–4^d^ | 0.986 ± 0.005 (48) | 0.991 ± 0.004 (46) | 0.989 ± 0.005 (43) | 0.975 ± 0.007 (46)
Survival Ratio PND 4–21^e^ | 1.000 ± 0.000 (48)^▲▲^ | 0.997 ± 0.003 (45) | 0.997 ± 0.003 (43) | 0.940 ± 0.013 (46)**

^▲▲^Significant trend (P ≤ 0.01).

** Significantly different (P ≤ 0.01) from the sham control group.

^a^ All values shown as mean ± standard error; PND = postnatal day. Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^b^ Includes dead on PND 1. Survival information on PND 4 was not available for some non-acceptable litters, so these were excluded from the analysis.

^c^ Number of pups/number of dams.

^d^ Number of pups preculling on PND 4/total number of viable pups on PND 1 (does not include pups dead on PND 1).

^e^ Number of pups alive on PND 21/number of pups at postculling on PND 4.

During the lactation period, maternal body weights and body weight gains (PND 1 through 21) in the 3 and 6 W/kg groups were significantly decreased (up to 3% and 7%, respectively) compared to sham controls (Table 41). At PND 1, male and female pup weights in the 6 W/kg groups were 5% to 6% less than those of the sham controls (Table 42). Male and female pup weights were also significantly decreased compared to the sham controls in the 3 W/kg groups at PND 4 and in the 6 W/kg groups at all time points. The lower weights occurred in similar magnitudes between the sexes with 5% to 6% decreases at PND 4 in the 3 W/kg group and up to 15% decreases in the 6 W/kg group at PND 7.

Table 41 Mean Body Weights and Mean Body Weight Gains of F0 Female Rats during Lactation in the Two-year Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Postnatal Day
1 | 280.9 ± 2.0 (50)^b^ | 278.3 ± 1.7 (48) | 278.2 ± 1.8 (45) | 275.8 ± 2.2 (48)
4 | 289.7 ± 2.1 (48)^▲▲^ | 289.1 ± 2.0 (45) | 286.4 ± 1.8 (43) | 282.3 ± 2.0 (46)**
7 | 297.1 ± 2.2 (48)^▲▲^ | 297.4 ± 1.9 (45) | 293.5 ± 1.8 (43) | 285.3 ± 1.9 (45)**
14 | 314.4 ± 2.0 (48)^▲▲^ | 309.8 ± 1.9 (45) | 306.6 ± 2.1 (43)* | 293.5 ± 2.5 (46)**
17 | 313.9 ± 2.2 (48)^▲▲^ | 307.8 ± 1.9 (45)* | 303.6 ± 2.1 (42)** | 294.9 ± 2.4 (46)**
21 | 299.7 ± 2.2 (48)^▲▲^ | 293.8 ± 2.0 (45)* | 291.2 ± 1.8 (43)** | 277.6 ± 2.2 (46)**
Postnatal Day Interval
1–4 | 9.2 ± 0.9 (48)^▲▲^ | 11.2 ± 1.0 (45) | 7.5 ± 0.8 (42) | 5.7 ± 1.0 (46)**
4–7 | 7.4 ± 1.5 (48)^▲▲^ | 8.2 ± 1.0 (45) | 7.1 ± 1.0 (43) | 3.4 ± 1.3 (45)*
7–14 | 17.4 ± 1.4 (48)^▲▲^ | 12.5 ± 1.0 (45)* | 13.1 ± 1.5 (43)* | 7.7 ± 1.4 (45)**
14–17 | –0.6 ± 1.0 (48) | –2.0 ± 1.2 (45) | –2.6 ± 1.3 (42) | 1.3 ± 1.0 (46)
17–21 | –14.1 ± 1.3 (48) | –14.0 ± 1.4 (45) | –12.7 ± 1.5 (42) | –17.3 ± 1.5 (46)
1–21 | 19.3 ± 1.5 (48)^▲▲^ | 15.9 ± 1.7 (45) | 12.2 ± 1.6 (42)** | 1.0 ± 1.4 (46)**

^▲▲^Significant trend (P ≤ 0.01).

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Body weights and body weight gains in grams. Data are displayed as mean ± standard error. Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ Number of dams.

Table 42 Adjusted Mean Body Weights of F1 Male and Female Rats during Lactation in the Two-year Perinatal and Postnatal Study of CDMA-modulated Cell Phone RFR^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Adjusted Male Live Pup Weight
PND 1^b^ | 7.19 ± 0.07 (49)^▲▲c^ | 7.02 ± 0.07 (47) | 7.09 ± 0.06 (46) | 6.78 ± 0.06 (48)^▲▲^
PND 4 | 10.87 ± 0.12 (190/48)**^d^ | 10.54 ± 0.15 (166/42) | 10.35 ± 0.11 (169/43)** | 9.58 ± 0.11 (178/44)**
PND 7 | 17.18 ± 0.19 (189/48)** | 16.83 ± 0.22 (179/45) | 16.82 ± 0.18 (166/42) | 14.75 ± 0.25 (183/46)**
PND 14 | 35.20 ± 0.43 (181/46)** | 33.89 ± 0.42 (179/45) | 34.48 ± 0.32 (170/43) | 30.81 ± 0.52 (176/46)**
PND 17 | 42.44 ± 0.49 (190/48)** | 41.55 ± 0.50 (179/45) | 41.88 ± 0.40 (170/43) | 38.08 ± 0.60 (175/46)**
PND 21 | 58.46 ± 0.62 (190/48)** | 57.30 ± 0.72 (179/45) | 57.85 ± 0.55 (170/43) | 52.63 ± 0.83 (176/46)**
Adjusted Female Live Pup Weight
PND 1^b^ | 6.79 ± 0.06 (49)^▲▲^ | 6.65 ± 0.09 (47) | 6.73 ± 0.06 (45) | 6.44 ± 0.05 (48)^▲▲^
PND 4 | 10.43 ± 0.11 (194/48)** | 10.16 ± 0.13 (172/43) | 9.80 ± 0.12 (171/43)** | 9.21 ± 0.11 (182/46)**
PND 7 | 16.45 ± 0.18 (194/48)** | 16.16 ± 0.21 (180/45) | 15.90 ± 0.20 (173/43) | 14.12 ± 0.22 (174/45)**
PND 14 | 33.87 ± 0.39 (192/48)** | 32.71 ± 0.38 (180/45) | 32.91 ± 0.37 (169/42) | 29.59 ± 0.50 (170/46)**
PND 17 | 40.80 ± 0.45 (194/48)** | 39.99 ± 0.47 (180/45) | 39.90 ± 0.42 (173/43) | 36.58 ± 0.55 (170/46)**
PND 21 | 55.38 ± 0.53 (194/48)** | 54.23 ± 0.64 (180/45) | 54.37 ± 0.57 (173/43) | 50.29 ± 0.70 (170/46)**
Adjusted Combined Live Pup Weight
PND 1^b^ | 6.99 ± 0.06 (49)^▲▲^ | 6.83 ± 0.09 (48) | 6.90 ± 0.06 (46) | 6.62 ± 0.05 (48)^▲▲^
PND 4 | 10.65 ± 0.11 (384/48)** | 10.36 ± 0.13 (338/44) | 10.07 ± 0.11 (340/43)** | 9.39 ± 0.10 (360/46)**
PND 7 | 16.80 ± 0.18 (383/48)** | 16.50 ± 0.20 (359/45) | 16.34 ± 0.18 (339/43) | 14.45 ± 0.22 (357/46)**
PND 14 | 34.46 ± 0.40 (373/48)** | 33.31 ± 0.38 (359/45) | 33.69 ± 0.32 (339/43) | 30.23 ± 0.48 (346/46)**
PND 17 | 41.60 ± 0.46 (384/48)** | 40.78 ± 0.47 (359/45) | 40.88 ± 0.39 (343/43) | 37.35 ± 0.54 (345/46)**
PND 21 | 56.89 ± 0.56 (384/48)** | 55.77 ± 0.65 (359/45) | 56.10 ± 0.53 (343/43) | 51.51 ± 0.71 (346/46)**

^▲▲^Significantly different (P ≤ 0.01) for PND 1 endpoint (statistical significance in the sham control group column indicates a significant trend test; statistical significance in a treatment group column indicates a significant pairwise comparison against the sham control group).

** Significantly different (P ≤ 0.01) for PNDs after PND 1 endpoints (statistical significance in the sham control group column indicates a significant trend test; statistical significance in a treatment group column indicates a significant pairwise comparison against the sham control group).

^a^ Body weights in grams. Data are displayed as mean ± standard error. PND = postnatal day. Values listed as PND 1 refer to the total pup weight divided by the number of pups in litter at PND 1, and the statistical analysis performed is by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests. Values listed for all other days refer to individual pups, and the statistical analysis is for linear trends performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dose groups to sham control group were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett-Hsu adjustment method. Individual pup body weights first adjusted for live PND 1 litter size via the analysis of covariance.

^b^ Values listed as PND 1 refer to the total pup weight divided by the number of pups in litter at PND 1.

^c^ Number of dams.

^d^ Number of pups/number of dams.

#### Postnatal Study

##### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 43 and in the Kaplan-Meier survival curves (Figure 10). In males, survival was greater in all exposed groups compared to sham controls, though it was statistically significant only in the 1.5 and 3 W/kg groups. Survival in the sham control group was 28% compared to 48%, 62%, and 48% in the 1.5, 3, and 6 W/kg groups, respectively. Decreased survival in the sham control group was largely attributed to the higher severity of chronic progressive nephropathy in the kidney. In females, there was a small, but statistically significant increase in survival in the 6 W/kg group. Survival in the sham control females was similar to that in the 1.5 and 3 W/kg groups.

Table 43 Survival of Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Animals initially in study | 105 | 105 | 105 | 105
14-week interim evaluation^a^ | 15 | 15 | 15 | 15
Accidental death^b^ | 1 | 0 | 0 | 0
Moribund | 44 | 24 | 13 | 6
Natural deaths | 20 | 23 | 21 | 41
Animals surviving to study termination | 25 | 43 | 56f | 43
Percent probability of survival at end of study^c^ | 28 | 48 | 62 | 48
Mean survival (days)^d^ | 642 | 675 | 687 | 637
Survival analysis^e^ | P = 0.070N | P = 0.005N | P < 0.001N | P = 0.072N
Female
Animals initially in study | 105 | 105 | 105 | 105
14-week interim evaluation^a^ | 15 | 15 | 15 | 15
Accidental death | 1 | 0 | 0 | 0
Moribund | 30 | 29 | 28 | 16
Natural deaths | 11 | 15 | 12 | 13
Animals surviving to study termination | 48^f^ | 46^g^ | 50 | 61
Percent probability of survival at end of study | 54 | 50 | 56 | 68
Mean survival (days) | 659 | 673 | 665 | 701
Survival analysis | P = 0.020N | P = 1.000 | P = 0.841N | P = 0.037N

^a^ Excluded from survival analysis.

^b^ Censored in the survival analysis.

^c^ Kaplan-Meier determinations.

^d^ Mean of all deaths (uncensored, censored, and terminal euthanasia).

^e^ The result of the life table trend test^161^ is in the sham control column, and the results of the life table pairwise comparisons^160^ with the sham controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^f^ Includes one animal that died during the last week of the study.

^g^ Includes two animals that died during the last week of the study.

Figure 10

Kaplan-Meier Survival Curves for Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

##### Body Weights and Clinical Observations

In 6 W/kg males, body weights were lower (4% to 9%) than those of the sham controls at all time points through day 457 (Figure 11 and Table 44; however, at the end of the study, the mean body weight was similar to that of the sham controls. In 1.5 and 3 W/kg males, mean body weights were significantly higher (compared to sham controls) at several time points, but at the end of the study, though the mean body weights were higher than in sham controls, the difference was not statistically significant. Mean body weights of exposed females were similar to those of the sham controls throughout the study (Figure 11 and Table 45). There were no clinical observations in males or females related to CDMA-modulated cell phone RFR exposure.

Figure 11

Growth Curves for Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

Table 44 Mean Body Weights and Survival of Male Rat Litters Exposed to CDMA-modulated Cell Phone RFR for Two Years

Day | Sham Control | | 1.5 W/kg | | | 3 W/kg | | | 6 W/kg
Day | Av. Wt. (g) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 64.3 | 35 | 62.7 | 97.5 | 35 | 63.0 | 98.1 | 35 | 59.2 | 92.1 | 35
5 | 78.7 | 35 | 76.0 | 96.6 | 35 | 76.5 | 97.3 | 35 | 71.4 | 90.8 | 35
9 | 99.0 | 35 | 96.2 | 97.2 | 35 | 96.8 | 97.7 | 35 | 90.5 | 91.5 | 35
12 | 117.6 | 35 | 113.7 | 96.7 | 35 | 114.9 | 97.7 | 35 | 107.7 | 91.6 | 35
16 | 145.5 | 35 | 140.4 | 96.5 | 35 | 141.5 | 97.3 | 35 | 132.0 | 90.7 | 35
19 | 167.0 | 35 | 161.7 | 96.8 | 35 | 162.4 | 97.3 | 35 | 153.5 | 92.0 | 35
23 | 197.8 | 35 | 192.2 | 97.2 | 35 | 192.0 | 97.1 | 35 | 181.5 | 91.8 | 35
26 | 217.1 | 35 | 211.6 | 97.4 | 35 | 211.0 | 97.2 | 35 | 200.1 | 92.2 | 35
30 | 246.5 | 35 | 239.5 | 97.2 | 35 | 237.8 | 96.5 | 35 | 226.5 | 91.9 | 35
33 | 264.3 | 35 | 257.4 | 97.4 | 35 | 255.7 | 96.7 | 35 | 245.2 | 92.8 | 35
37 | 290.4 | 35 | 282.6 | 97.3 | 35 | 280.9 | 96.7 | 35 | 269.5 | 92.8 | 35
40 | 304.5 | 35 | 296.4 | 97.3 | 35 | 294.9 | 96.9 | 35 | 283.2 | 93.0 | 35
44 | 322.9 | 35 | 313.4 | 97.0 | 35 | 312.6 | 96.8 | 35 | 301.0 | 93.2 | 35
47 | 333.8 | 35 | 324.6 | 97.2 | 35 | 323.1 | 96.8 | 35 | 310.9 | 93.1 | 35
51 | 349.0 | 35 | 340.3 | 97.5 | 35 | 337.7 | 96.8 | 35 | 326.6 | 93.6 | 35
54 | 357.6 | 35 | 349.4 | 97.7 | 35 | 347.6 | 97.2 | 35 | 335.7 | 93.9 | 35
58 | 370.2 | 35 | 361.8 | 97.8 | 35 | 360.2 | 97.3 | 35 | 348.3 | 94.1 | 35
61 | 379.1 | 35 | 368.0 | 97.1 | 35 | 367.5 | 96.9 | 35 | 356.0 | 93.9 | 35
65 | 389.6 | 35 | 379.1 | 97.3 | 35 | 376.3 | 96.6 | 35 | 365.1 | 93.7 | 35
68 | 395.2 | 35 | 386.3 | 97.7 | 35 | 383.4 | 97.0 | 35 | 371.3 | 94.0 | 35
72 | 404.0 | 35 | 392.9 | 97.2 | 35 | 391.9 | 97.0 | 35 | 380.8 | 94.3 | 35
75 | 409.0 | 35 | 399.7 | 97.7 | 35 | 396.1 | 96.8 | 35 | 383.3 | 93.7 | 35
79 | 417.9 | 35 | 406.8 | 97.3 | 35 | 404.1 | 96.7 | 35 | 391.5 | 93.7 | 35
82 | 422.7 | 35 | 411.3 | 97.3 | 35 | 408.6 | 96.7 | 35 | 395.8 | 93.6 | 35
86 | 427.7 | 35 | 417.1 | 97.5 | 35 | 416.3 | 97.3 | 35 | 403.0 | 94.2 | 35
89 | 432.4 | 35 | 422.0 | 97.6 | 35 | 420.4 | 97.2 | 35 | 407.3 | 94.2 | 35
93 | 439.3 | 35 | 428.6 | 97.6 | 35 | 426.2 | 97.0 | 35 | 412.5 | 93.9 | 35
121^a^ | 471.3 | 35 | 463.4 | 98.3 | 35 | 462.0 | 98.0 | 35 | 451.3 | 95.8 | 35
149 | 501.7 | 35 | 490.2 | 97.7 | 35 | 489.9 | 97.6 | 35 | 470.6 | 93.8 | 35
177 | 522.0 | 35 | 512.3 | 98.1 | 35 | 511.1 | 97.9 | 35 | 493.0 | 94.4 | 35
205 | 540.4 | 35 | 532.4 | 98.5 | 35 | 532.5 | 98.5 | 35 | 510.4 | 94.4 | 35
233 | 560.8 | 35 | 552.4 | 98.5 | 35 | 550.5 | 98.2 | 35 | 530.0 | 94.5 | 35
261 | 575.2 | 35 | 567.9 | 98.7 | 35 | 567.0 | 98.6 | 35 | 545.4 | 94.8 | 35
289 | 590.2 | 35 | 583.9 | 98.9 | 35 | 581.8 | 98.6 | 35 | 560.1 | 94.9 | 35
317 | 608.0 | 35 | 599.6 | 98.6 | 35 | 597.5 | 98.3 | 35 | 575.0 | 94.6 | 35
345 | 618.4 | 35 | 611.9 | 99.0 | 35 | 611.2 | 98.8 | 35 | 588.3 | 95.1 | 35
373 | 628.4 | 35 | 621.5 | 98.9 | 35 | 621.5 | 98.9 | 35 | 592.9 | 94.4 | 35
401 | 636.3 | 35 | 632.5 | 99.4 | 35 | 629.7 | 99.0 | 35 | 601.8 | 94.6 | 35
429 | 641.4 | 35 | 642.7 | 100.2 | 35 | 637.0 | 99.3 | 35 | 609.9 | 95.1 | 35
457 | 639.9 | 35 | 646.3 | 101.0 | 35 | 642.3 | 100.4 | 35 | 613.4 | 95.9 | 35
485 | 645.0 | 35 | 658.0 | 102.0 | 35 | 656.0 | 101.7 | 35 | 622.8 | 96.6 | 35
513 | 654.1 | 35 | 671.5 | 102.7 | 35 | 665.1 | 101.7 | 35 | 636.0 | 97.2 | 35
541 | 649.5 | 35 | 677.3 | 104.3 | 34 | 672.3 | 103.5 | 35 | 638.4 | 98.3 | 35
569 | 651.2 | 33 | 676.0 | 103.8 | 34 | 673.8 | 103.5 | 35 | 641.9 | 98.6 | 33
597 | 659.2 | 32 | 678.6 | 102.9 | 34 | 674.2 | 102.3 | 35 | 640.3 | 97.1 | 33
625 | 652.8 | 32 | 666.3 | 102.1 | 32 | 684.1 | 104.8 | 34 | 639.7 | 98.0 | 32
639 | 645.9 | 32 | 674.7 | 104.5 | 31 | 679.5 | 105.2 | 34 | 635.2 | 98.3 | 32
653 | 630.8 | 31 | 667.7 | 105.9 | 31 | 685.2 | 108.6 | 33 | 642.3 | 101.8 | 31
667 | 632.9 | 28 | 674.5 | 106.6 | 29 | 679.8 | 107.4 | 33 | 638.9 | 101.0 | 30
681 | 621.0 | 26 | 662.9 | 106.8 | 29 | 671.7 | 108.2 | 33 | 635.5 | 102.3 | 30
695 | 625.8 | 21 | 654.7 | 104.6 | 29 | 666.7 | 106.5 | 33 | 626.8 | 100.2 | 30
709 | 624.0 | 20 | 663.0 | 106.3 | 28 | 652.2 | 104.5 | 33 | 624.7 | 100.1 | 30
723 | 624.9 | 19 | 663.0 | 106.1 | 25 | 633.5 | 101.4 | 32 | 618.9 | 99.0 | 28
Mean for Weeks
1–14 | 297.9 | – | 290.1 | 97.4 | – | 288.9 | 97.0 | – | 278.1 | 93.4 | –
15–52 | 554.2 | – | 546.0 | 98.5 | – | 544.8 | 98.3 | – | 524.9 | 94.7 | –
53–104 | 639.0 | – | 660.7 | 103.4 | – | 660.3 | 103.3 | – | 627.0 | 98.1 | –

^a^ Interim evaluation occurred during week 14.

Table 45 Mean Body Weights and Survival of Female Rat Litters Exposed to CDMA-modulated Cell Phone RFR for Two Years

Day | Sham Control | | | | 1.5 W/kg | | | | | | 3 W/kg | | | | | | 6 W/kg
Day | Av. Wt. (g) | | No. of Litters | | Av. Wt. (g) | | Wt. (% of Controls) | | No. of Litters | | Av. Wt. (g) | | Wt. (% of Controls) | | No. of Litters | | Av. Wt. (g) | | Wt. (% of Controls) | | No. of Litters
1 | 60.4 | | 35 | | 59.3 | | 98.2 | | 35 | | 59.6 | | 98.7 | | 35 | | 55.9 | | 92.6 | | 35
5 | 72.1 | | 35 | | 70.2 | | 97.4 | | 35 | | 71.4 | | 99.0 | | 35 | | 66.6 | | 92.5 | | 35
9 | 88.7 | | 35 | | 85.8 | | 96.7 | | 35 | | 87.1 | | 98.2 | | 35 | | 81.7 | | 92.1 | | 35
12 | 103.3 | | 35 | | 99.6 | | 96.5 | | 35 | | 101.1 | | 97.9 | | 35 | | 95.2 | | 92.1 | | 35
16 | 123.2 | | 35 | | 119.7 | | 97.1 | | 35 | | 120.7 | | 97.9 | | 35 | | 113.9 | | 92.4 | | 35
19 | 136.3 | | 35 | | 133.7 | | 98.1 | | 35 | | 134.8 | | 98.9 | | 35 | | 128.1 | | 94.0 | | 35
23 | 151.5 | | 35 | | 150.7 | | 99.4 | | 35 | | 150.8 | | 99.5 | | 35 | | 144.8 | | 95.6 | | 35
26 | 158.5 | | 35 | | 159.3 | | 100.5 | | 35 | | 160.0 | | 100.9 | | 35 | | 152.8 | | 96.4 | | 35
30 | | 169.1 | | 35 | | 168.4 | | 99.6 | | 35 | | 169.9 | | 100.5 | | 35 | | 162.8 | | 96.3 | | 35
33 | | 176.4 | | 35 | | 177.2 | | 100.4 | | 35 | | 177.7 | | 100.7 | | 35 | | 170.6 | | 96.7 | | 35
37 | | 188.7 | | 35 | | 190.2 | | 100.8 | | 35 | | 190.2 | | 100.8 | | 35 | | 181.4 | | 96.1 | | 35
40 | | 195.8 | | 35 | | 197.3 | | 100.8 | | 35 | | 198.0 | | 101.1 | | 35 | | 188.6 | | 96.3 | | 35
44 | | 203.7 | | 35 | | 205.3 | | 100.8 | | 35 | | 206.3 | | 101.3 | | 35 | | 197.6 | | 97.0 | | 35
47 | | 209.9 | | 35 | | 210.9 | | 100.5 | | 35 | | 211.8 | | 100.9 | | 35 | | 204.3 | | 97.4 | | 35
51 | | 218.1 | | 35 | | 218.4 | | 100.1 | | 35 | | 221.3 | | 101.5 | | 35 | | 211.5 | | 97.0 | | 35
54 | | 220.1 | | 35 | | 224.4 | | 102.0 | | 35 | | 225.9 | | 102.6 | | 35 | | 215.8 | | 98.0 | | 35
58 | | 228.6 | | 35 | | 230.4 | | 100.8 | | 35 | | 232.9 | | 101.9 | | 35 | | 222.6 | | 97.4 | | 35
61 | | 233.9 | | 35 | | 234.6 | | 100.3 | | 35 | | 237.4 | | 101.5 | | 35 | | 228.0 | | 97.5 | | 35
65 | | 239.0 | | 35 | | 238.7 | | 99.9 | | 35 | | 238.1 | | 99.6 | | 35 | | 230.5 | | 96.5 | | 35
68 | | 241.7 | | 35 | | 244.0 | | 100.9 | | 35 | | 242.3 | | 100.2 | | 35 | | 234.6 | | 97.1 | | 35
72 | | 244.9 | | 35 | | 244.9 | | 100.0 | | 35 | | 246.2 | | 100.5 | | 35 | | 239.2 | | 97.7 | | 35
75 | | 247.6 | | 35 | | 249.2 | | 100.7 | | 35 | | 248.9 | | 100.5 | | 35 | | 239.5 | | 96.7 | | 35
79 | | 251.6 | | 35 | | 252.4 | | 100.3 | | 35 | | 251.2 | | 99.9 | | 35 | | 242.1 | | 96.2 | | 35
82 | | 253.5 | | 35 | | 253.3 | | 99.9 | | 35 | | 253.3 | | 99.9 | | 35 | | 243.7 | | 96.1 | | 35
86 | | 254.4 | | 35 | | 257.8 | | 101.4 | | 35 | | 260.0 | | 102.2 | | 35 | | 249.0 | | 97.9 | | 35
89 | | 256.2 | | 35 | | 258.9 | | 101.0 | | 35 | | 259.6 | | 101.3 | | 35 | | 251.0 | | 97.9 | | 35
93 | | 257.6 | | 35 | | 260.8 | | 101.3 | | 35 | | 262.8 | | 102.0 | | 35 | | 251.2 | | 97.5 | | 35
121^a^ | | 275.6 | | 35 | | 277.6 | | 100.7 | | 34 | | 280.7 | | 101.9 | | 35 | | 270.5 | | 98.1 | | 35
149 | | 284.8 | | 35 | | 286.9 | | 100.8 | | 34 | | 289.8 | | 101.8 | | 35 | | 279.4 | | 98.1 | | 35
177 | | 295.0 | | 35 | | 299.0 | | 101.4 | | 34 | | 300.3 | | 101.8 | | 35 | | 288.4 | | 97.8 | | 35
205 | | 302.8 | | 35 | | 307.9 | | 101.7 | | 34 | | 309.8 | | 102.3 | | 35 | | 298.9 | | 98.7 | | 35
233 | | 311.4 | | 35 | | 315.6 | | 101.4 | | 34 | | 319.8 | | 102.7 | | 35 | | 308.4 | | 99.0 | | 35
261 | | 317.9 | | 35 | | 328.6 | | 103.4 | | 34 | | 331.6 | | 104.3 | | 35 | | 316.0 | | 99.4 | | 35
289 | | 330.8 | | 35 | | 338.6 | | 102.4 | | 34 | | 339.7 | | 102.7 | | 35 | | 323.9 | | 97.9 | | 35
317 | | 340.8 | | 35 | | 347.7 | | 102.0 | | 34 | | 349.8 | | 102.7 | | 35 | | 330.9 | | 97.1 | | 35
345 | | 348.2 | | 35 | | 359.3 | | 103.2 | | 34 | | 358.8 | | 103.0 | | 35 | | 341.6 | | 98.1 | | 35
373 | | 355.2 | | 35 | | 366.3 | | 103.1 | | 34 | | 364.5 | | 102.6 | | 35 | | 348.3 | | 98.0 | | 35
401 | | 366.7 | | 35 | | 378.3 | | 103.2 | | 34 | | 375.6 | | 102.4 | | 35 | | 357.1 | | 97.4 | | 35
429 | | 375.9 | | 35 | | 387.4 | | 103.1 | | 34 | | 384.5 | | 102.3 | | 35 | | 364.5 | | 97.0 | | 35
457 | | 386.6 | | 35 | | 397.9 | | 102.9 | | 34 | | 392.2 | | 101.5 | | 35 | | 372.5 | | 96.4 | | 35
485 | | 400.1 | | 35 | | 410.2 | | 102.5 | | 34 | | 405.5 | | 101.3 | | 35 | | 384.1 | | 96.0 | | 35
513 | | 410.3 | | 35 | | 424.4 | | 103.4 | | 34 | | 413.6 | | 100.8 | | 34 | | 397.6 | | 96.9 | | 35
541 | | 421.4 | | 35 | | 434.8 | | 103.2 | | 34 | | 424.4 | | 100.7 | | 34 | | 411.7 | | 97.7 | | 35
570 | | 426.0 | | 35 | | 440.6 | | 103.4 | | 34 | | 437.5 | | 102.7 | | 33 | | 426.8 | | 100.2 | | 35
598 | | 433.7 | | 35 | | 450.1 | | 103.8 | | 34 | | 447.8 | | 103.2 | | 33 | | 432.1 | | 99.6 | | 35
626 | | 447.7 | | 34 | | 455.1 | | 101.6 | | 34 | | 456.5 | | 102.0 | | 33 | | 441.3 | | 98.6 | | 35
640 | | 454.9 | | 33 | | 457.7 | | 100.6 | | 34 | | 462.0 | | 101.6 | | 32 | | 444.2 | | 97.7 | | 35
654 | | 459.5 | | 33 | | 456.4 | | 99.3 | | 34 | | 467.8 | | 101.8 | | 32 | | 449.6 | | 97.8 | | 34
668 | | 448.5 | | 31 | | 455.5 | | 101.6 | | 33 | | 461.9 | | 103.0 | | 32 | | 452.3 | | 100.9 | | 34
682 | | 450.7 | | 31 | | 457.7 | | 101.5 | | 33 | | 462.2 | | 102.5 | | 31 | | 455.6 | | 101.1 | | 33
696 | | 450.0 | | 31 | | 458.6 | | 101.9 | | 33 | | 461.2 | | 102.5 | | 31 | | 457.6 | | 101.7 | | 33
710 | | 447.9 | | 30 | | 450.7 | | 100.6 | | 33 | | 461.7 | | 103.1 | | 31 | | 456.6 | | 102.0 | | 33
724 | | 448.8 | | 30 | | 435.4 | | 97.0 | | 32 | | 474.9 | | 105.8 | | 29 | | 454.2 | | 101.2 | | 32
Mean for Weeks
1–14 | | 192.0 | | – | | 192.4 | | 100.2 | | – | | 193.3 | | 100.7 | | – | | 185.3 | | 96.5 | | –
15–52 | | 311.9 | | – | | 317.9 | | 101.9 | | – | | 320.0 | | 102.6 | | – | | 306.4 | | 98.2 | | –
53–104 | | 422.6 | | – | | 430.4 | | 101.8 | | – | | 432.6 | | 102.4 | | – | | 418.0 | | 98.9 | | –

^a^ Interim evaluation occurred during week 14.

##### Fourteen-week Interim Evaluation

There were no changes to the hematology or clinical chemistry variables attributable to CDMA exposure (Table F-2).

In 6 W/kg males, there were significantly lower absolute left and right kidney weights (13% to 15%) and absolute (14%) and relative liver weights compared to the sham controls (Table G-8). In females, the absolute left and right kidney weights were significantly lower (13% to 15%) in the 6 W/kg group, and the left absolute kidney weights were significantly lower in the 1.5 and 3 W/kg groups (10% and 8%, respectively). The mean relative kidney weights were not similarly decreased, which was likely due to the decrease in mean body weight of the 6 W/kg group compared to the sham controls. These changes did not correlate with any histopathologic findings. There were no CDMA exposure-related effects on reproductive organ weights, testis spermatid concentrations, caudal epididymal sperm concentrations, or sperm motility in males (Table H-2). Due to the frequency of poor slide quality, the estrous cycle in females was not evaluated.

In males, the incidences of cardiomyopathy of the right ventricle in all exposed groups were increased compared to that in sham controls but the increases were not statistically significant, and the severities were minimal in all cases (Table 46). There were marginally increased incidences of cardiomyopathy of the heart in 3 and 6 W/kg females, but they were not statistically significant. Cardiomyopathy is a common spontaneous disease in rats that typically has no clinical manifestations. It is characterized by degeneration and necrosis of myofibers with a mild inflammatory response of macrophages and lymphocytes with occasional neutrophils. In later stages of the disease, fibrosis may be prominent.

Table 46 Incidences of Non-neoplastic Lesions of the Heart at the 14-week Interim Evaluation in Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 w/kg
Male
Number Examined Microscopically | 10 | 10 | 10 | 10
Cardiomyopathy (excluding right ventricle)^a^ | 2 (1.5)^b^ | 0 | 3 (1.0) | 6 (1.0)
Ventricle Right, Cardiomyopathy | 1 (1.0) | 5 (1.0) | 4 (1.0) | 4 (1.0)
Cardiomyopathy, All Sites | 3 (1.3) | 5 (1.0) | 6 (1.0) | 6 (1.0)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10
Cardiomyopathy (excluding right ventricle) | 0 | 0 | 2 (1.0) | 2 (1.0)
Ventricle Right, Cardiomyopathy | 0 | 0 | 1 (1.0) | 1 (1.0)
Cardiomyopathy, All Sites | 0 | 0 | 3 (1.0) | 3 (1.0)

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

##### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and non-neoplastic lesions of the heart, brain, pituitary gland (pars distalis), liver, adrenal medulla, prostate gland, kidney and other organs, pancreas, mammary gland, adrenal cortex, and thymus. Summaries of the incidences of neoplasms and non-neoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male rats and Appendix D for female rats.

Heart: Malignant schwannomas were observed in all exposed male groups (Table 47, Table C-1, and Table C-2). No schwannomas were observed in sham controls. The incidence in the 6 W/kg group was significant, as was the positive trend. The 6 W/kg incidence slightly exceeded the historical control range for all exposure routes (Table C-3). Endocardial Schwann cell hyperplasia, a putative preneoplastic Schwann cell lesion, was seen in three 6 W/kg males, resulting in a significant positive trend (P = 0.044; Table 47 and Table C-7).

Table 47 Incidences of Malignant Schwannoma and Neoplasms and Non-neoplastic Lesions of the Heart in Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Heart^a^ | 90 | 90 | 90 | 90
Cardiomyopathy^b^ | 79 (1.9)^c^ | 84 (1.9) | 83 (1.8) | 85 (1.3)
Ventricle Right, Cardiomyopathy | 54 (1.1) | 45 (1.2) | 62 (1.3) | 74* (1.7)
Endocardium, Hyperplasia, Schwann Cell | 0 | 0 | 0 | 3 (2.0)
Malignant Schwannoma^d^
Overall rate^e^ | 0/90 (0%) | 2/90 (2%) | 3/90 (3%) | 6/90 (7%)
Litters rate^f^ | 0/35 (0%) | 2/35 (6%) | 3/35 (9%) | 6/35 (17%)
Adjusted rate^g^ | 0.0% | 2.7% | 3.8% | 8.8%
Terminal rate^h^ | 0/25 (0%) | 2/43 (5%) | 2/56 (4%) | 3/43 (7%)
First incidence (days) | –j | 730 (T) | 642 | 488
Rao-Scott adjusted Poly-3 test^i^ | P = 0.011 | P = 0.273 | P = 0.175 | P = 0.030
All Organs: Malignant Schwannoma^k^
Overall rate | 3/90 (3%) | 4/90 (4%) | 4/90 (4%) | 8/90 (9%)
Litters rate | 3/35 (9%) | 4/35 (11%) | 4/35 (11%) | 7/35 (20%)
Adjusted rate | 4.5% | 5.4% | 5.1% | 11.6%
Terminal rate | 1/25 (4%) | 2/43 (5%) | 2/56 (4%) | 4/43 (9%)
First incidence (days) | 555 | 573 | 619 | 153
Rao-Scott adjusted Poly-3 test | P = 0.075 | P = 0.551 | P = 0.582 | P = 0.136
Female
Heart | 90 | 90 | 90 | 90
Cardiomyopathy | 40 (1.1) | 43 (1.1) | 33 (1.2) | 45 (1.1)
Ventricle Right, Cardiomyopathy | 4 (1.0) | 7 (1.0) | 9 (1.0) | 9 (1.0)
Endocardium, Hyperplasia, Schwann Cell | 0 | 1 (3.0) | 1 (1.0) | 1 (1.0)
Malignant Schwannoma^l^
Overall rate | 0/90 (0%) | 2/90 (2%) | 0/90 (0%) | 2/90 (2%)
Litters rate | 0/35 (0%) | 2/34 (6%) | 0/35 (0%) | 2/35 (6%)
Adjusted rate | 0.0% | 2.7% | 0.0% | 2.5%
Terminal rate | 0/48 (0%) | 1/45 (2%) | 0/50 (0%) | 2/61 (3%)
First incidence (days) | – | 649 | – | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.343 | P = 0.317 | –^m^ | P = 0.342
All Organs: Malignant Schwannoma^n^
Overall rate | 4/90 (4%) | 2/90 (2%) | 2/90 (2%) | 4/90 (4%)
Litters rate | 3/35 (9%) | 2/34 (6%) | 2/35 (6%) | 4/35 (11%)
Adjusted rate | 5.7% | 2.7% | 2.8% | 5.0%
Terminal rate | 2/48 (4%) | 1/45 (2%) | 2/50 (4%) | 4/61 (7%)
First incidence (days) | 489 | 649 | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.561 | P = 0.346N | P = 0.354N | P = 0.577N

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for other 2-year studies (all routes): 1/50, 1/50, 0/50.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with animals with neoplasm per number of litters necropsied.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal euthanasia.

^i^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A lower incidence in an exposure group is indicated by N.

^j^ Not applicable; no neoplasms in animal group.

^k^ Historical control incidence for other 2-year studies (all routes): 1/50, 2/50, 0/50.

^l^ Historical control incidence for other 2-year studies (all routes): 0/49, 0/50, 0/50.

^m^ Value of statistic cannot be computed.

^n^ Historical control incidence for other 2-year studies (all routes): 0/50, 2/50, 2/50.

In females, there were two malignant schwannomas each in the 1.5 and 6 W/kg groups (Table 47 and Table D-1). Neither of these incidences nor the positive trend were statistically significant. These incidences were also within the historical control range for all routes of exposure (Table D-3). A single incidence of endocardial Schwann cell hyperplasia was diagnosed in each of the three exposure groups, but there were none in the sham control group (Table 47 and Table D-7).

The malignant schwannomas and Schwann cell hyperplasias in males and females were morphologically similar to those seen in the rats exposed to GSM-modulated cell phone RFR.

Cardiomyopathy of the right ventricular free wall was seen in all male and female groups, including the sham controls (Table 47, Table C-7, and Table D-7). In males and females, the incidences in exposed groups were increased compared to the sham controls; the increased incidence in 6 W/kg males was statistically significant. There was also a slight elevation in the severity of this non-neoplastic lesion in 6 W/kg males, but there was no similar elevation in severity in females. Cardiomyopathy was diagnosed separately in the right ventricle because the study pathologist observed an unusual predilection for, and a slightly different morphology in the right ventricle as compared to the left ventricular free wall and the interventricular septum. An increased incidence was found in the right ventricle in the 6 W/kg males compared to the sham controls. Cardiomyopathy in the CDMA-exposed rats was morphologically identical to that described previously for the GSM-exposed rats.

Brain: In males, there three malignant gliomas in the 6 W/kg group, resulting in a significant positive trend (Table 48 and Table C-1). In females, malignant glioma occurred in three 1.5 W/kg animals; no malignant gliomas were observed in the other exposed groups or in the sham controls (Table 48 and Table D-1). There was no significant positive trend for this neoplasm in females, and the increased incidence was not significant. Glial cell hyperplasia occurred in most exposed groups of males and females, but none of the incidences were significantly increased (Table 48, Table C-7, and Table D-7). The proliferative glial cell lesions were morphologically similar to those seen in the rats exposed to GSM-modulated RFR.

Table 48 Incidences of Neoplasms and Non-neoplastic Lesions of the Brain in Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Number Examined Microscopically | 90 | 90 | 90 | 90
Glial Cell, Hyperplasia^a^ | 0 | 2 (1.5)^b^ | 0 | 2 (2.5)
Glioma Malignantc
Overall rate^d^ | 0/90 (0%) | 0/90 (0%) | 0/90 (0%) | 3/90 (3%)
Litters rate^e^ | 0/35 (0%) | 0/35 (0%) | 0/35 (0%) | 3/35 (9%)
Adjusted rate^f^ | 0.0% | 0.0% | 0.0% | 4.5%
Terminal rate^g^ | 0/25 (0%) | 0/43 (0%) | 0/56 (0%) | 3/43 (7%)
First incidence (days) | –^i^ | – | – | 730 (T)
Rao-Scott adjusted Poly-3 test^h^ | P = 0.044 | –^j^ | – | P = 0.221
Female
Number Examined Microscopically | 90 | 90 | 90 | 90
Glial Cell, Hyperplasia | 0 | 0 | 1 (2.0) | 1 (2.0)
Glioma Malignant^k^
Overall rate | 0/90 (0%) | 3/90 (3%) | 0/90 (0%) | 0/90 (0%)
Litters rate | 0/35 (0%) | 3/34 (9%) | 0/35 (0%) | 0/35 (0%)
Adjusted rate | 0.0% | 4.1% | 0.0% | 0.0%
Terminal rate | 0/48 (0%) | 2/45 (4%) | 0/50 (0%) | 0/61 (0%)
First incidence (days) | – | 550 | – | –
Rao-Scott adjusted Poly-3 test | P = 0.384N | P = 0.236 | – | –

(T) = terminal euthanasia.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for other 2-year studies (all routes): 0/50, 2/50.

^d^ Number of animals with neoplasm per number of animals with brain examined microscopically.

^e^ Number of litters with animals with neoplasm per number of litters with brain examined microscopically.

fPoly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend is indicated by N.

^i^ Not applicable; no neoplasms in animal group.

^j^ Value of statistic cannot be computed.

^k^ Historical control incidence for other 2-year studies (all routes): 0/50, 1/50.

Pituitary Gland (Pars Distalis): In males, there were increased incidences of adenoma in the 1.5 and 3 W/kg groups, but only the 3 W/kg incidence was significant (Table 49, Table C-1, and Table C-2). No carcinomas occurred in males and there was no significant increase in the incidence or severity of hyperplasia (Table 49, Table C-1, and Table C-7). In females exposed to 3 W/kg, there were significantly decreased incidences of adenoma and adenoma or carcinoma (combined) (Table 49, Table D-1, and Table D-2). There were no increased incidences of carcinoma or hyperplasia in females (Table 49, Table D-1, and Table D-8). In the males, there was a significantly increased incidence of cyst in the 1.5 W/kg group (Table 49 and Table C-7). In the females, there was a significantly decreased incidence of cyst in the 6 W/kg group (Table 49 and Table D-8). Pituitary gland cysts are considered developmental anomalies and are fairly common, so the toxicologic significance of these changes is unclear.

Table 49 Incidences of Neoplasms and Non-neoplastic Lesions of the Pituitary Gland (Pars Distalis) in Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Number Examined Microscopically | 89 | 90 | 90 | 90
Cyst^a^ | 5 | 15* | 7 | 6
Hyperplasia | 32 (2.4)^b^ | 32 (2.4) | 34 (2.5) | 27 (2.2)
Adenoma, Multiple | 0 | 0 | 1 | 2
Adenoma (includes multiple)^c^
Overall rate^d^ | 17/89 (19%) | 25/90 (28%) | 34/90 (38%) | 13/90 (14%)
Litters rate^e^ | 13/35 (37%) | 18/35 (51%) | 24/35 (69%) | 12/35 (34%)
Adjusted rate^f^ | 24.9% | 32.7% | 41.8% | 19.0%
Terminal rate^g^ | 5/25 (20%) | 16/43 (37%) | 22/56 (39%) | 6/43 (14%)
First incidence (days) | 527 | 605 | 471 | 567
Rao-Scott adjusted Poly-3 test^h^ | P = 0.226N | P = 0.208 | P = 0.030 | P = 0.273N
Female
Number Examined Microscopically | 90 | 89 | 89 | 90
Cyst | 7^▲^ | 5 | 3 | 1*
Hyperplasia | 20 (2.5) | 22 (2.2) | 26 (1.9) | 22 (2.8)
Adenoma, Multiple | 1 | 1 | 0 | 0
Adenoma (includes multiple)^i^
vOverall rate | 43/90 (48%) | 41/89 (46%) | 30/89 (34%) | 40/90 (44%)
Litters rate | 28/35 (80%) | 26/34 (76%) | 21/35 (60%) | 25/35 (71%)
Adjusted rate | 57.1% | 52.9% | 39.5% | 49.0%
Terminal rate | 28/48 (58%) | 20/45 (44%) | 16/50 (32%) | 31/61 (51%)
First incidence (days) | 464 | 578 | 493 | 626
Rao-Scott adjusted Poly-3 test | P = 0.156N | P = 0.360N | P = 0.026N | P = 0.204N
Carcinoma^j^ | 1 | 1 | 1 | 0
Adenoma or Carcinoma^i^
Overall rate | 44/90 (49%) | 42/89 (47%) | 31/89 (35%) | 40/90 (44%)
Litters rate | 29/35 (83%) | 26/34 (76%) | 21/35 (60%) | 25/35 (71%)
Adjusted rate | 57.9% | 54.1% | 40.7% | 49.0%
Terminal rate | 28/48 (58%) | 20/45 (44%) | 16/50 (32%) | 31/61 (51%)
First incidence (days) | 464 | 578 | 493 | 626
Rao-Scott adjusted Poly-3 test | P = 0.131N | P = 0.381N | P = 0.030N | P = 0.180N

^▲^Significant trend (P ≤ 0.05) by the Rao-Scott adjusted Poly-3 test.

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for other 2-year studies (all routes): 14/50, 5/50, 11/50.

^d^ Number of animals with neoplasm per number of animals with pituitary gland examined microscopically.

^e^ Number of litters with animals with neoplasm per number of litters with pituitary gland examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ Historical control incidence for other 2-year studies (all routes): 19/50, 18/50, 18/50.

^j^ Historical control incidence for other 2-year studies (all routes): 0/50, 0/50, 0/50.

Liver: In males, there were increased incidences of hepatocellular adenoma in the 1.5 and 3 W/kg groups compared to sham controls (Table 50 and Table C-1). There were also hepatocellular carcinomas, one each in the 3 and 6 W/kg groups. The incidences of hepatocellular adenoma or carcinoma (combined) were increased in all exposed groups, but none of the incidences were significant. In 6 W/kg females, there was a decreased incidence of hepatocellular adenoma with a significant negative trend (Table 50, Table D-1, and Table D-2). The NTP historical control incidence of hepatocellular adenoma in male Hsd:Sprague Dawley^®^ SD^®^ rats by all routes of exposure is 1/240, and no hepatocellular carcinomas have been seen in this strain of rat in the NTP historical control data. In females, the historical control incidence of hepatocellular adenoma in NTP studies by all routes of exposure is 11/240, and as with males, no hepatocellular carcinomas have been seen. In males, the incidences of mixed cell focus were increased in all exposed groups, but only the incidence in the 1.5 W/kg group was significant (Table 50 and Table C-7).

Table 50 Incidences of Neoplasms and Non-neoplastic Lesions of the Liver in Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Male
Number Examined Microscopically | 90 | 90 | 89 | 88
Mixed Cell Focus^a^ | 32 | 51* | 47 | 37
Hepatocellular Adenoma^b^
Overall rate^c^ | 0/90 (0%) | 2/90 (2%) | 4/89 (4%) | 0/88 (0%)
Litters rate^d^ | 0/35 (0%) | 2/35 (6%) | 4/35 (11%) | 0/35 (0%)
Adjusted rate^e^ | 0.0% | 2.7% | 5.1% | 0.0%
Terminal rate^f^ | 0/25 (0%) | 2/43 (5%) | 4/56 (7%) | 0/43 (0%)
First incidence (days) | –^h^ | 730 (T) | 730 (T) | –
Rao-Scott adjusted Poly-3 test^g^ | P = 0.556N | P = 0.310 | P = 0.132 | –^i^
Hepatocellular Carcinoma^j^ | 0 | 0 | 1 | 1
Hepatocellular Adenoma or Carcinoma^b^
Overall rate | 0/90 (0%) | 2/90 (2%) | 4/89 (4%) | 1/88 (1%)
Litters rate | 0/35 (0%) | 2/35 (6%) | 4/35 (11%) | 1/35 (3%)
Adjusted rate | 0.0% | 2.7% | 5.1% | 1.5%
Terminal rate | 0/25 (0%) | 2/43 (5%) | 4/56 (7%) | 0/43 (0%)
First incidence (days) | – | 730 (T) | 730 (T) | 594
Rao-Scott adjusted Poly-3 test | P = 0.416 | P = 0.281 | P = 0.113 | P = 0.475
Female
Hepatocellular Adenoma^k^
Overall rate | 7/90 (8%) | 2/90 (2%) | 2/90 (2%) | 1/90 (1%)
Litters rate | 6/35 (17%) | 2/34 (6%) | 2/35 (6%) | 1/35 (3%)
Adjusted rate | 10.1% | 2.7% | 2.8% | 1.3%
Terminal rate | 6/48 (13%) | 1/45 (2%) | 2/50 (4%) | 1/61 (2%)
First incidence (days) | 707 | 493 | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.042N | P = 0.118N | P = 0.125N | P = 0.052N
Hepatocellular Carcinoma^j^ | 0 | 0 | 0 | 1

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

(T) = terminal euthanasia.

^a^ Number of animals with lesion.

^b^ Historical control incidence for other 2-year studies (all routes): 0/50, 1/50, 0/50.

^c^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^d^ Number of litters with animals with neoplasm per number of litters with liver examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal euthanasia.

^g^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^h^ Not applicable; no neoplasms in animal group.

^i^ Value of statistic cannot be computed.

^j^ Historical control incidence for other 2-year studies (all routes): 0/50, 0/50, 0/50.

^k^ Historical control incidence for other 2-year studies (all routes): 0/50, 2/50, 2/50.

Adrenal Medulla: In females, there were increased incidences of benign pheochromocytoma and benign, malignant, or complex pheochromocytoma (combined) in all exposed groups, but only the incidence of benign, malignant, or complex pheochromocytoma (combined) at 1.5 W/kg was significant (Table 51, Table D-1, and Table D-2). There were increased incidences of malignant pheochromocytoma in the 1.5 and 3 W/kg groups compared to sham controls. There were increased incidences of hyperplasia in all exposed female groups, but the incidences were not significant (Table 51 and Table D-8).

Table 51 Incidences of Neoplasms and Non-neoplastic Lesions of the Adrenal Medulla in Female Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Number Examined Microscopically | 86 | 89 | 87 | 88
Hyperplasia^a^ | 13 (1.5)^b^ | 20 (1.7) | 20 (1.3) | 18 (1.9)
Benign Pheochromocytoma^c^
Overall rate^d^ | 1/86 (1%) | 7/89 (8%) | 3/87 (3%) | 4/88 (5%)
Litters rate^e^ | 1/35 (3%) | 7/34 (21%) | 3/35 (9%) | 4/35 (11%)
Adjusted rate^f^ | 1.5% | 9.6% | 4.4% | 5.2%
Terminal rate^g^ | 1/45 (2%) | 5/44 (11%) | 3/48 (6%) | 4/60 (7%)
First incidence (days) | 737 (T) | 464 | 737 (T) | 737 (T)
Rao-Scott adjusted Poly-3 test^h^ | P = 0.466 | P = 0.059 | P = 0.322 | P = 0.248
Malignant Pheochromocytoma^i^ | 0 | 2 | 1 | 0
Complex Pheochromocytoma^j^ | 0 | 0 | 1 | 0
Benign, Malignant, or Complex Pheochromocytoma^k^
Overall rate | 1/86 (1%) | 9/89 (10%) | 5/87 (6%) | 4/88 (5%)
Litters rate | 1/35 (3%) | 9/34 (26%) | 5/35 (14%) | 4/35 (11%)
Adjusted rate | 1.5% | 12.3% | 7.2% | 5.2%
Terminal rate | 1/45 (2%) | 7/44 (16%) | 4/48 (8%) | 4/60 (7%)
First incidence (days) | 737 (T) | 464 | 652 | 737 (T)
Rao-Scott adjusted Poly-3 test | P = 0.546 | P = 0.022 | P = 0.126 | P = 0.242

(T) = terminal euthanasia.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for other 2-year studies (all routes): 3/50, 0/50, 0/49.

^d^ Number of animals with neoplasm per number of animals with adrenal medulla examined microscopically.

^e^ Number of litters with animals with neoplasm per number of litters with adrenal medulla examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal euthanasia.

^h^ Beneath the sham control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the sham controls and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation.

^i^ Historical control incidence for other 2-year studies (all routes): 2/50, 0/50, 0/49.

^j^ Historical control incidence for other 2-year studies (all routes): 0/50, 0/50, 0/49.

^k^ Historical control incidence for other 2-year studies (all routes): 5/50, 0/50, 0/49.

Prostate Gland: The incidences of epithelial hyperplasia were increased in all exposed groups compared to the sham controls (Table C-7), and the severity increased slightly. Only the incidence in the 6 W/kg group was significant (sham control, 5/90; 1.5 W/kg, 11/90; 3 W/kg, 9/90; 6 W/kg, 15/85). Epithelial hyperplasia of the prostatic epithelium was characterized as infoldings or papillary projections of epithelial cells into the lumen of a prostatic gland. The cells did not fill or distend the gland, and there was no atypia and no mitotic figures.

Kidney and Other Organs: The severity of chronic progressive nephropathy was lower in all exposed male groups compared to the sham controls (Table 52). The chronic progressive nephropathy was morphologically similar to that seen in the rats exposed to GSM-modulated RFR. There were decreased incidences in a number of lesions in other organs in exposed male groups, some statistically significant, that were thought to be secondary to the chronic progressive nephropathy, either directly or indirectly (Table 52 and Table C-7). These lesions included hyperplasia of the parathyroid gland; mineral in the blood vessels in the colon, liver, mesentery, pancreas, salivary glands, brain, heart, kidney, skeletal muscle, glandular stomach, spleen, and aorta; mineral in the heart, salivary gland, and stomach; fibrous osteodystrophy of bone; polyarteritis nodosa (chronic active inflammation of the blood vessels) of the epididymis, testis, cecum, liver, pancreas, glandular stomach, and thymus; germ cell degeneration of the testis; edema, erosion, epithelial regeneration, acute inflammation, and ulcer of the cecum; epithelial regeneration of the colon; epithelial regeneration and acute inflammation of the rectum; red pulp atrophy and white pulp atrophy of the spleen; and exfoliated germ cell and hypospermia of the epididymis.

Table 52 Incidences of Non-neoplastic Lesions Associated with the Decreased Severity of Chronic Progressive Nephropathy of the Kidney in Male Rats Exposed to CDMA-modulated Cell Phone RFR for Two Years

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
Kidney^a^ | 90 | 90 | 90 | 87
Nephropathy, Chronic Progressive^b^ | 88 (3.7)^c^ | 90 (3.3) | 90 (3.0) | 8 6(2.3)
Aorta | 90 | 90 | 90 | 90
Mineral | 30 (2.1) | 8** (2.8) | 6** (2.2) | 2** (1.5)
Bone | 90 | 90 | 90 | 90
Fibrous Osteodystrophy | 46 (1.4) | 20** (1.7) | 15** (1.6) | 5** (1.6)
Brain | 90 | 90 | 90 | 90
Mineral | 5 (1.0) | 3 (1.0) | 4 (1.0) | 4 (1.0)
Epididymis | 90 | 90 | 90 | 90
Artery, Inflammation, Chronic Active | 2 (2.5) | 3 (3.0) | 3 (2.3) | 3 (2.7)
Exfoliated Germ Cell | 51 (1.9) | 33** (1.7) | 33** (1.7) | 17** (1.5)
Hypospermia | 28 (3.4) | 24 (3.1) | 13** (3.7) | 13* (3.0)
Heart | 90 | 90 | 90 | 90
Artery, Mineral | 20 (2.5) | 7* (2.1) | 2** (2.0) | 1** (2.0)
Intestine Large, Cecum | 75 | 76 | 74 | 68
Artery, Inflammation, Chronic Active | 20 (2.1) | 8* (1.9) | 7* (1.9) | 2** (2.5)
Edema | 11 (2.0) | 0** | 0** | 0**
Epithelium, Regeneration | 14 (2.4) | 1** (2.0) | 0** | 1** (2.0)
Erosion | 10 (2.5) | 1* (3.0) | 1* (4.0) | 1* (2.0)
Inflammation, Acute | 10 (2.8) | 1** (2.0) | 0** | 1* (2.0)
Ulcer | 6 (2.3) | 0* | 0* | 0
Intestine Large, Colon | 81 | 83 | 82 | 76
Artery, Mineral | 2 (2.0) | 0 | 0 | 0
Epithelium, Regeneration | 5 (2.6) | 0 | 0 | 0
Intestine Large, Rectum | 83 | 81 | 80 | 76
Epithelium, Regeneration | 3 (2.3) | 0 | 0 | 0
Inflammation, Acute | 2 (2.5) | 0 | 0 | 0
Kidney | 90 | 90 | 90 | 87
Artery, Mineral | 2 (2.0) | 0 | 0 | 0
Liver | 90 | 90 | 89 | 88
Artery, Inflammation, Chronic Active | 2 (3.5) | 1 (2.0) | 0 | 0
Artery, Mineral | 1 (1.0) | 1 (1.0) | 0 | 0
Mesentery | 39 | 19 | 17 | 6
Artery, Mineral | 21 (2.1) | 5* (2.0) | 2** (2.5) | 0*
Pancreas | 90 | 88 | 87 | 78
Artery, Inflammation, Chronic Active | 48 (2.3) | 28** (2.0) | 23** (2.0) | 5** (2.2)
Artery, Mineral | 11 (1.8) | 2* (2.5) | 0** | 0**
Parathyroid Gland | 83 | 83 | 83 | 82
Hyperplasia | 51 (2.5) | 35* (2.5) | 32** (2.0) | 17** (1.8)
Salivary Glands | 90 | 90 | 90 | 86
Artery, Mineral | 2 (2.5) | 1 (2.0) | 1 (2.0) | 0
Skeletal Muscle | 90 | 90 | 90 | 90
Mineral | 2 (1.0) | 0 | 1 (1.0) | 0
Spleen | 90 | 90 | 90 | 85
Arteriole, Mineral | 1 (2.0) | 0 | 0 | 0
Red Pulp, Atrophy | 26 (2.2) | 14* (1.9) | 12** (2.1) | 13* (2.0)
White Pulp, Atrophy | 30 (2.1) | 11** (2.3) | 10** (2.4) | 24 (1.9)
Stomach, Glandular | 86 | 86 | 85 | 78
Artery, Inflammation, Chronic Active | 3 (2.3) | 0 | 0 | 0
Mineral | 31 (2.5) | 9** (3.1) | 6** (2.7) | 1** (2.0)
Testis | 90 | 89 | 90 | 90
Artery, Inflammation, Chronic Active | 52 (2.9) | 37** (2.8) | 30** (2.5) | 12** (3.1)
Germ Cell, Degeneration | 51 (2.3) | 37* (2.6) | 31** (2.2) | 24** (2.1)
Thymus | 88 | 85 | 87 | 82
Artery, Inflammation, Chronic Active | 6 (2.7) | 3 (2.3) | 2 (1.5) | 1 (2.0)

* Significantly different (P ≤ 0.05) from the sham control group by the Rao-Scott adjusted Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Other Lesions: In males, there were significantly decreased incidences of adenoma and adenoma or carcinoma (combined) of the pancreas in the 6 W/kg group, although the incidences in 1.5 and 3 W/kg groups were slightly increased compared to the sham controls (Table C-1 and Table C-2). One male in the 3 W/kg group had a carcinoma but no adenoma.

In females, there were significantly decreased incidences of adenoma (sham control, 8/90; 1.5 W/kg, 4/90; 3 W/kg, 1/90; 6 W/kg, 2/90) and adenoma or carcinoma (combined) (16/90, 12/90, 7/90, 6/90) of the mammary gland (Table D-1 and Table D-2).

In males, the incidences of adrenal cortex hypertrophy were increased in all exposed groups compared to the sham controls, and the incidence in the 3 W/kg group was significant (35/90, 42/90, 55/90, 44/89; P = 0.013) (Table C-7). In 6 W/kg males, there were significantly increased incidences of lung congestion (13/90, 13/90, 11/90, 33/90) and thymic hemorrhage (2/88, 2/85, 2/87, 20/82).

## Genetic Toxicology

Twenty tissue samples obtained from animals at the 14-week interim evaluation in the 2-year study were evaluated for DNA damage using the comet assay (two sexes, two cell phone RFR modulations, five tissues). Results are based on the standard 100-cell scoring approach in use at the time these data were collected; data obtained using a 150-cell scoring approach, recommended in a recently adopted international guideline for the in vivo comet assay, are noted here for the few instances where results differed between the two methods. The complete 100-cell and 150-cell data are presented in Appendix E data tables. A significant increase in DNA damage (% comet tail DNA) was observed in hippocampus cells of male rats exposed to the CDMA modulation (Table E-1). Although the levels of DNA damage in hippocampus cells were also increased in an exposure-related fashion using the 150-cell scoring approach, the increases were not statistically significant (Table E-3). An exposure-related increase (trend test P = 0.004) in DNA damage was seen in the cells of the frontal cortex of male rats exposed to the CDMA modulation (Table E-1); however, no individual exposure groups were significantly elevated over the sham control group and the result was therefore judged to be equivocal. For male rat blood leukocytes exposed to either the CDMA or GSM modulation (Table E-1 and Table E-2), results from scoring 100 cells were negative; however, these leukocyte samples showed equivocal responses with the 150-cell method due to a significant trend test (P = 0.012) or pairwise test (P = 0.021) for CDMA- and GSM-exposed rats, respectively (Table E-3 and Table E-4). No statistically significant increases in the % comet tail DNA were observed in any of the female rat samples scored with the 100-cell approach (Table E-5 and Table E-6). The 150-cell scoring approach yielded a significant trend test (P = 0.013) in peripheral blood leukocytes of female rats exposed to the CDMA modulation, but these results were driven by data from a single animal (Table E-7).

In contrast to what was seen in the mice,^197^ a high degree of interanimal variability was observed in the % comet tail DNA values in rats within a treatment group, and this level of variability reduced the statistical power to detect increases in DNA migration, although the magnitudes of the increases observed in some rats suggested these were treatment-related effects. To rule out any influence from technical artifacts or protocol features, % tail DNA values and percent hedgehogs were correlated to the position of slides in the electrophoresis chambers, the interval from exposure cessation to tissue collection, and the date of slide preparation; no patterns emerged for any of these variables and the level of DNA damage observed. The possibility that the longer interval from exposure cessation to tissue collection for the female rats may have been a factor in the absence of any detectable exposure-related increases in DNA damage cannot be ruled out due to the increased opportunity for DNA repair during this interval.

The possibility that the longer interval from exposure cessation to tissue collection for the female rats may have been a factor in the absence of any detectable exposure-related increases in DNA damage cannot be ruled out due to the increased opportunity for DNA repair during this interval.

Similar to what was seen in the mice, no significant effects on the frequency of micronucleated red blood cells or the % PCEs were observed in rats of either sex exposed to either modulation of cell phone RFR (Table E-9).