# Materials and Methods

## Overview

The establishment of the National Toxicology Program (NTP) research program on radio frequency radiation (RFR) has required the coordination of expertise from multiple scientific and engineering disciplines. At the initiation of the RFR research program, a collaboration was established with technical experts from the Radio-Frequency Fields Group in the Radio Frequency (RF) Technology Division, which is part of the Communications Technology Laboratory (CTL) at the National Institute of Standards and Technology (NIST, Boulder, CO). NIST evaluated the existing exposure systems and identified the types of improvements that would be required to provide a system of sufficient size and power to conduct robust toxicology and carcinogenicity studies with uniform RFR exposures in unrestrained, individually housed animals for a minimum of 6 hours a day at frequencies and modulations that reflected those in use at the time. The design of the chambers and toxicology studies required special consideration of logistical, financial, and engineering limitations.

NIST tested the feasibility of a reverberation chamber-type exposure system by conducting a series of studies on field strengths, field uniformity, and power requirements under various conditions of RFR exposure in such chambers. These studies provided critical information for the design of experimental studies with respect to the number of cages that could be placed in specific size chambers, the arrangement of cages within each chamber, and the input power requirements.

Concurrent with the collaboration with NIST, the NTP also worked with the Foundation for Research on Information Technologies in Society (IT’IS, Zurich, Switzerland), which conducted studies using computational models that simulated RFR dosimetry to provide estimates of whole-body and organ-specific internal field strengths and specific absorption rates (SARs) during exposure. Based on information and parameters obtained during the NIST feasibility studies, IT’IS built a prototype reverberation chamber as the basis for an exposure system to study health effects of long-term exposure of laboratory animals. Following completion, NIST evaluated the prototype exposure chamber to determine if it met the requirements specified by the NTP.

Institution and Role:

- National Institute of Standards and Technology (NIST) (Boulder, CO)
  - Suggested reverberation chamber exposure system
  - Conducted feasibility studies for reverberation chambers
  - Established various technical parameters for chambers
  - Evaluated the prototype chamber built by IT’IS Foundation
  - Validated the system prior to the conduct of studies at IITRI
  - Reevaluated RFR exposures prior to and after 2-year studies
- IT’IS Foundation (Zurich, Switzerland)
  - Constructed and tested prototype chamber
  - Refined technical parameters
  - Built the chambers for the NTP exposure facility
  - Installed chambers at IITRI
  - Monitored system performance throughout all phases of the studies
  - Conducted maintenance on exposure system hardware and software
- IIT Research Institute (IITRI) (Chicago, IL)
  - Tested exposure system after installation
  - Conducted maintenance of exposure system hardware
  - Conducted all toxicology and carcinogenicity studies
  - Conducted day-to-day operations

After prototype-testing by IT’IS Foundation and NIST, the IT’IS Foundation built the reverberation chambers required for the NTP RFR exposure facility. Chambers were installed at the Illinois Institute of Technology (IIT) Research Institute (IITRI, Chicago, IL). Following the installation and initial testing of the exposure system by IT’IS and IITRI, technical experts from NIST conducted an independent validation of the system. NIST confirmed that the probe readings in the system were consistent, that field uniformity was within expected specifications, and that the signal quality was acceptable. NIST performed additional evaluations prior to initiation of the 2-year studies and after completion of the studies to determine if any changes occurred in the signal quality, field uniformity, or consistency of in-chamber field measurements. All studies were conducted at IITRI with real-time monitoring of the system performance at IT’IS Foundation.

## Reverberation Chamber Method of Exposure

The use of the reverberation exposure chamber as a method for exposing rats and mice to cell phone RFR was conceptualized by the NIST and further designed and tested by NIST and the IT’IS Foundation. A reverberation chamber is a resonant box where the resonances and field structure are continuously modified under the influence of metallic stirrers, introduced to change the effective geometry, such that when averaged over time, the field strength is uniform over the entire exposure volume. A reverberation chamber exposure system was chosen for the NTP for the primary benefit that controlled exposures can be achieved in unrestrained animals (rats and mice) with extended daily RFR exposure periods compared to other methods of exposure for up to 2 years.

Preliminary studies were first conducted at the NIST to test the concept of reverberation chambers. In these studies, field strengths and field uniformity were measured under various conditions of RFR exposure, including an empty chamber and a chamber loaded with water bottles (simulating animals) at different locations in the chamber. Power requirements were evaluated to achieve desired SAR levels. The effects of proximity between water bottles were also investigated to avoid electromagnetic coupling. These studies provided critical information for the design of experimental studies with respect to the number of cages that could be placed in specific size chambers, the arrangement of cages within each chamber, and the input power requirements. The results of these investigations demonstrated that while variations occurred over time and space the average RFR field was uniform over the large volume of the chamber. These studies also demonstrated that RFR field exposure occurred from all directions and all polarizations, and that there was uniformity of SAR in reverberation chambers. Based on the information and parameters obtained during the NIST feasibility studies, a custom-built prototype reverberation chamber was constructed and tested by the IT’IS Foundation. The development of the prototype chamber involved the design of amplifiers and antennas for signal generation, the design of vertical and horizontal stirrers to improve the homogeneity of experimentally generated RF fields, the development of both hardware and software for the control and monitoring of experimentally generated RF signals and testing of chamber performance. During the design of the prototype exposure chamber, engineering studies were performed to optimize the following prior to construction:

- The uniform field volume within each chamber to minimize spatial variability in the characteristics of generated RF fields within a chamber such that all animals housed within the chamber space were exposed to comparable RF field strengths.
- The design and placement of stirrers in each chamber in order to maximize homogeneity of experimentally generated RF fields.
- The design and location of RF antennas in each chamber.
- The location of cage racks within the exposure chamber in order to provide appropriate separation of individual animal cages and cage racks from all reflective surfaces (chamber walls, chamber floor and ceiling, antennas, and stirrers) in the reverberation chamber.
- Chamber volume to provide adequate space for staff to observe animals, collect data, and perform routine animal husbandry operations, while minimizing overall chamber volume to minimize the chamber size/footprint and the RF power required to maintain target SARs.

The final reverberation chamber design for use in these studies was a fully shielded room constructed of stainless steel, equipped with a shielded room door to eliminate leakage of RFR signals, two rotating stirrers (one horizontal and one vertical), ventilation structures, and RFR excitation antennas. A detailed rationale for the selection of reverberation chambers for exposure to RFR and a full description of the exposure system are provided in Capstick et al.^148^ and Gong et al.^147^ and in a video^c^ (day 1 a.m. at 54 minutes) on the NTP website.^3^

c https://doi.org/10.22427/NTP-VIDEO-41.

As part of the validation of the reverberation chamber exposure system design, a team of engineers from NIST conducted an independent evaluation of chamber design and exposure system operation in order to evaluate the suitability of the reverberation chamber model for use in the program. NIST engineers evaluated the design and operation of the prototype chamber and performed an extensive series of RF measurements to support an evaluation of system performance. Further information on the exposure verification is found in the video^d^ (day 1 p.m. at 0 minutes) by John Ladbury.^3^

d https://doi.org/10.22427/NTP-VIDEO-42.

## RFR Exposure Facility

The exposure facility was specifically designed to expose rats in reverberation chambers to three different power levels of modulated cell phone RFR [Global System for Mobile Communications (GSM) or Code Division Multiple Access (CDMA)] at 900 MHz for up to 2 years to evaluate toxicity and carcinogenicity. The completed exposure facility consisted of a total of 21 RFR reverberation exposure chambers (14 designated for rats); the RFR signal generation, amplification, and monitoring systems; software for chamber operation; and hardware and software for monitoring of environmental and exposure conditions within each chamber. All system hardware and software was installed by the IT’IS Foundation.

During exposures, modulated (GSM or CDMA) RFR signals were generated by a signal generator, amplifiers amplified the signals, and the signals were delivered by antennas in the reverberation chambers. RFR field strengths were monitored in real time and were adjusted throughout the studies to achieve specific exposure levels [based on SARs quantitated in watts (W) per kg body weight]. Environmental conditions were also monitored and controlled in real time throughout the study. RFR exposures and environmental conditions were monitored and controlled by a computer in a control room at the study laboratory at IITRI; the IT’IS Foundation was also capable of remote system monitoring and control.

### Facility Design and Reverberation Chambers

Each reverberation chamber was permanently programmed for a specified modulation (GSM or CDMA) of the 900 MHz RFR specified for the rat studies. Designated SARs for each chamber were selected prior to exposures. The field strength required to achieve a given target SAR (W/kg) exposure level is a function of animal body weight (kg) and were adjusted to provide consistent SARs as the animals grew. However, separate chambers were required for male and female rats because their body weights differ by almost a factor of two after a few weeks of development. To conduct robust toxicology studies with three exposure groups (low, medium, and high), six chambers were required for different levels of exposures for GSM modulation and six for CDMA modulation. Two sham exposure chambers without any cell phone RFR signal provided shared control groups for the parallel studies of the two modulations. As per these requirements, the cell phone RFR exposure facility consisted of 14 reverberation chambers for exposures in rats including:

- Three power levels for F_0_ females and F_1_ males exposed to GSM-modulated cell phone RFR at 900 MHz.
- Three power levels for F_1_ females exposed to GSM-modulated cell phone RFR at 900 MHz.
- Three power levels for F_0_ females and F_1_ males exposed to CDMA-modulated cell phone RFR at 900 MHz.
- Three power levels for F_1_ females exposed to CDMA-modulated cell phone RFR at 900 MHz.
- One sham control chamber for F_0_ females and F_1_ males with no RFR exposure.
- One sham control chamber for F_1_ females with no RFR exposure.

The chamber size was designed to accommodate the RF field stirring paddles (described below), approximately 110 individually housed rats, and a minimum distance (3/4 of a wavelength) between the cages and the walls, floor, ceiling and stirrers, respectively. The interior of the chamber was suitable for cleaning using high-pressure water (after the RF antennas were protected). The internal dimensions of the chambers were 2.2 m (width) × 3.7 m (length) × 2.6 m (height); the exterior dimensions were 2.3 m (width) × 3.8 m (length) × 2.85 m (height). A floorplan for the exposure facility and images of the interior and exterior of the chambers are presented in Figure 4 and Figure 5.

Figure 4

Exposure Facility Floor Plan for the Cell Phone RFR Studies

(Not shown are the Ethernet connections to computers in the control room.) Rat chamber designations: F_0_ females and F_1_ males−low GSM = 9; medium GSM = 5; high GSM = 6; low CDMA = 10; medium CDMA = 8; high CDMA = 7; sham = 4; F_1_ females - low GSM = 20; medium GSM = 16; high GSM = 17; low CDMA = 21; medium CDMA = 18; high CDMA = 19; sham = 15. The seven other chambers (including six for cell phone RFR exposure and one for sham control) were designated for concurrent mouse studies.

Figure 5

Exterior View of Chambers, Empty Chamber Showing the Vertical and Horizontal Stirrers, and Chamber with Cage Racks in Place

Each chamber contained two motor-controlled stirring paddles (one vertical and one horizontal) with adjustable speed control (1 to 50 rpm) and large asymmetrical reflecting surfaces. Stirring paddles were placed off center in the chamber for maximum scattering of the RFR fields to generate a statistically homogeneous field distribution when averaged over time. The horizontal stirrer was mounted on the ceiling of the chamber. The vertical stirrer was at the rear of the chamber and was protected by rack guides that prevented contact with the animal cage racks.

### Cage Racks and Watering System

Cages, cage racks, and watering systems for standard laboratory use contain elements that have the ability to alter the exposure of the animals or introduce potential confounding factors. Because cage racks and the drinking water delivery system were contained inside the chambers during exposure periods, it was required that these components be constructed of durable materials that had essentially no impact on the RF fields generated in the chamber. Metallic cage rack components, cage lids, feed dispensers, and cage grommets all needed to be eliminated. Hence, custom engineering was required to overcome the challenges regarding potential RFR exposure-altering aspects of the caging and cage racks used to house the animals during the studies. The safe provision of drinking water provided the largest challenge for the studies.

The absorption of RFR energy by water if supplied by nonmetallic sipper tubes and distribution systems or bottles, could lead to dose-dependent elevated water temperatures. At the same time, the potential for enhanced exposure fields by metallic sipper tubes or lixits precluded the use of water bottles or a standard automatic watering system in the reverberation chambers. The absorption of RFR energy by water could result in significant heating of the drinking water, thereby decreasing water palatability, and increasing the required RFR power to achieve the desired exposure field strength, potentially to the extent that the exposure levels could not be met. To overcome theses challenges, adaptations were made to an automatic watering system so that the delivery of drinking water to the animals would not interfere with RFR dosimetry. The water system was constructed from stainless steel ensuring no dose-dependent energy absorption in the water (avoiding exposure-dependent water temperature) and in structures around the lixits to ensure no enhanced fields that could lead to excessive SAR in the animals while drinking.

Customized, nonmetallic animal cage racks for the reverberation chambers were designed by IITRI to minimize any absorption of RFR or disruption of RF field homogeneity. Cage racks were constructed primarily of box beam fiberglass (with some angle beam fiberglass used in nonweight-bearing areas of the rack). The shelves/cage lids were constructed of a clear polycarbonate sheet with slots for increased airflow. The potential impact of the racks on RF fields was evaluated in the prototype reverberation chamber by the IT’IS Foundation. Cage racks were designed to accommodate the automatic watering system and position the perimeter of each animal cage at least one-half wavelength from any reflecting surface. The specific considerations for design and further details of the custom-designed cage racks and adapted automated watering system are provided in Capstick et al.^148^ and in the video presentation^e^ by Dr. Myles Capstick.^3^

e https://doi.org/10.22427/NTP-VIDEO-41.

### RFR Exposure System Control

The hardware and chambers designated for rats (using an exposure frequency of 900 MHz) were connected to a dedicated computer control system using an Ethernet protocol. The computerized control system managed and monitored the RFR exposures and environmental conditions in the chambers. A more detailed description of the computer control of RFR exposure is provided in Capstick et al.^148^

The control computer managed the exposure schedule, stirrer rotation speeds, exposure signal and level, and monitored air flow, temperature, humidity, light, and the electric and magnetic fields (E- and H-fields, respectively) in each chamber. The hardware for the exposure system consisted of the control computer and a rack containing communications interfaces and instrumentation for signal generation, data acquisition, signal monitoring, signal amplifiers, and the chamber hardware (which included the stirrer motors and environmental and RFR sensors). The instrumentation rack contained the equipment that generated the RFR signal, acquired RFR field strengths and environmental data, and provided an interface between the components and the control computer.

## RFR Signal Generation

GSM-modulated and CDMA-modulated cell phone RFR signals were generated experimentally via a SMIQ02B vector signal generator with options SMIQB11 and SMIQB20 and software options 100421–100423 (Rohde and Schwarz, Munich, Germany). Signals were amplified using 12 LSE™ amplifiers (LSE, Spanga, Sweden) in the exposure system. The outputs of each individual amplifier were set by real-time controllers on a slot-by-slot basis for GSM or CDMA modulation to control the E-field strength in each chamber. Each chamber contained at least one standard gain antenna (two half-wave dipoles) that was mounted a quarter of a wavelength in front of a reflector plate. Antennas were directed towards one of the two stirrers to maximize scattering and obtain acceptable E-field homogeneity within the chamber space. The computerized control system managed the exposure schedule, stirrer rotation speeds, and exposure signal type and level.

The RFR power introduced into a given chamber was adjusted to achieve target field strengths: to maintain constant exposure levels (W/kg) in a given chamber, the field strengths [measured in volts (V) per meter] were regularly adjusted to reflect changes in the average mass of the exposed animals. The relationship between animal mass, field strength, and SAR was determined from numerical dosimetry and programmed into the control software, hence the required exposure field strength was computed from the average animal weights entered for each exposure group. The interval at which animal weights were updated was determined on how rapidly the animals were growing, at the start of the exposure period this was once per week, and as long as up to every 4 weeks later in the studies.

## Verification of RFR Exposure

Prior to initiation of the animal studies, the RF Fields Group in the Communications Technology Laboratory at the NIST performed an independent, detailed evaluation of each of the reverberation chambers (excluding the sham control chambers; Figure 4) to verify the RFR exposure fields, chamber characteristics (field uniformity), and signal quality to determine the accuracy of field values reported by the developers of the exposure system (IT’IS Foundation). This information provided in the video^f^ (day 1 p.m. at 0 minutes) by John Ladbury.^3^ Full reports detailing the procedures for measurements and calculations are available from the NTP. NIST performed two additional detailed evaluations: 1) in the interim period between completion of the 28-day studies and prior to initiation of the 2-year studies, and 2) following completion of the 2-year studies.

f https://doi.org/10.22427/NTP-VIDEO-42.

All E-field measurements were within the estimated uncertainty bounds, indicating that the chamber fields measured by the NIST agreed with the measurements provided by the IT’IS Foundation probes. During validation, it was determined that the H-field probes at higher signal levels in the mid- and high-power GSM chambers reported higher fields than indicated by other measurements, potentially leading to a modest overestimation of chamber field strengths. In these chambers, H-field probes were replaced with E-field probes, which provided more accurate measurements of the RF fields. The magnitude of field variation throughout the volume of a fully loaded chamber was consistent with earlier values reported for the prototype chamber. However, it was determined that there may have been up to ± 2.5 dB of variation in the exposure field depending on location in the cage racks. To mitigate this positional variation, cages were routinely rotated to various locations within and between the cage racks. The quality of the modulated signals was found to be acceptable with regard to distortion and harmonic content.

Overall, NIST confirmed that the RFR reverberation chamber exposure system was operating correctly and RFR exposures were within specifications.

## RFR Exposure Monitoring

During all exposure periods, experimentally generated RFR was continuously monitored by the control system via two RF sensors (E- and/or H-field probes) in each exposure chamber that measured real-time signal strengths. The use of two probes provided two independent measurements of RF field strengths and ensured that appropriate quantitation of experimentally generated RF fields continued even in the unlikely event that one probe failed. The E-field sensor measured electric field strength (V/m). The H-field sensor measured magnetic field strength [measured in amperes (A) per meter]. All chambers were instrumented either with one E-field sensor (ER3DV6) and one H-field sensor (H3DV6) [both from Schmid and Partner Engineering AG (SPEAG), Zurich, Switzerland], except for the medium- and high-power GSM chambers. These chambers were instrumented with two E-field probes because H-field probes saturated at high field strengths. This change in hardware did not result in the loss of monitoring capability. The measured E- and H-fields were communicated to the control computer in order to maintain exposure to selected levels of RFR. During daily shutdown periods when RFR exposures were not active, RF sensors monitored ambient RF fields in the exposure chambers. RF sensors were calibrated twice by the manufacturer (SPEAG); once prior to initiation of any of the animal studies and once prior to initiation of the 2-year studies. All E-field probes were calibrated in air from 100 MHz to 3.0 GHz, and had an absolute accuracy of ± 6.0% (k = 2) with a spherical isotropy of better than ± 0.4 dB. All H-field probes were calibrated in air from 200 MHz to 3.0 GHz and had an absolute accuracy of ± 6.0% (k = 2) with a spherical isotropy of better than ± 0.2 dB. Placement of probes within the chambers is discussed in the video^g^ (day 1 a.m. at 1 hours, 31 minutes).^3^

g https://doi.org/10.22427/NTP-VIDEO-41.

Data collected by the RF sensors were transmitted to the exposure and monitoring system on a real-time basis and were recorded throughout the studies. Chamber field strengths are reported as V/m and animal exposure levels (SAR values) are reported as W/kg. The chamber field strength is the average effective E-field strength from both probes. E- and H-field strengths are related by the impedance of free space which is ~377 Ohms. Where an H-field probe was used, the value in A/m was multiplied by 377 to calculate the equivalent E-field strength in V/m; it is this effective E-field value that was used to report the chamber field strength. Field strength data reported for each day of exposure included mean ± standard deviation, minimum field strength, maximum field strength, total number of readings in range/total number of readings for the period, and percentage of readings in range. After each exposure day, RFR exposure data were downloaded onto DVDs for long-term archival. Summaries of the 2-year RFR exposure data from the studies are presented in Appendix I. The SAR and chamber-fields in the exposure chambers were within the target ranges (defined as ± 2 dB) for >99.97% of recorded measurements over the course of the 2-year study; ≥99.25% of recorded E-field and H-field measurements were within the target ranges. All recorded broadband field measurements (<40 MHz to >6 GHz) were below the limit of detection of the probes within the sham chamber showing that there was no significant confounding exposure. In the 28-day studies, the performance of the sham control and exposure chambers was similar for SAR and field measurements as in the 2-year studies (data not shown).

As previously stated, the performance of the RFR exposure and monitoring system was independently validated by engineers from the NIST prior to the initiation of the animal studies.

## Monitoring and Maintenance of Environmental Conditions

Environmental conditions including temperature, humidity, and airflow in all exposure chambers, as well as in other areas of the IITRI RFR exposure facility, were maintained by a computer-controlled environmental management system (Siemens Industries, Inc.). Monitoring instrumentation for each chamber was located in the air exhaust duct. Each chamber was fitted by the IT’IS Foundation with a sensor box that contained sensors for temperature and humidity (Type EE06; E + E Elektronik GmbH, Engerwitzdorf, Austria), oxygen level (Pewatron Type FCX-MC25; Zurich, Switzerland), air speed (model EE65A; E + E Elektronik GmbH), light (light-dependent resistor), noise (design based on WL-93 microphone; Shure Brothers, Inc., Evanston, IL), and RFR. Outputs from the sensor box were monitored using Agilent data acquisition units, with the exception of the RF sensor. The RF sensor was directly wired to a warning light as a safety precaution to indicate active RFR exposures and not intended to quantitatively measure RFR field strengths.

Exposure chambers were equipped with incandescent lights located on light bars in each corner of the chamber. All connections were RF-filtered. Chamber lighting was controlled using an adjustable daily cycle of 12 hours on, 12 hours off. In order to minimize the heat load generated by the incandescent lights, low wattage bulbs were used that maintained chamber lighting within a range that was sufficient to support normal in vivo operations, while minimally affecting chamber temperature. Further discussion of chamber lighting is found in the video^h^ (day 1 a.m. at 1 hours, 27 minutes).^3^

h https://doi.org/10.22427/NTP-VIDEO-41.

Differences in noise levels in the exposure chambers that resulted from the heating, ventilation, and air conditioning system were equalized by the installation of sound baffles in various ducts within the system. An audible signal generated by the high intensity GSM signal was detected and equalized in all chambers by the introduction of a “pink noise” masking sound; this masking noise equalized sound levels in all chambers. As a result of the combination of these efforts, noise levels in all chambers were essentially equivalent at approximately 62 dBA and met the NC-35 noise specification. The noise criterion (NC) is a widely accepted numerical index commonly used to define the maximum allowable noise. It primarily applies to the noise produced by ventilation systems, but is applied to other noise sources, as well. Standards organizations, such as the American National Standards Institute (ANSI), Acoustical Society of American (ASA), and International Standards Organization, provide definitions of various NCs for ambient noise in enclosed spaces. The ANSI/ASA standard (S12.2-2008) recommends NCs for various types of rooms, including private residences (NC 25-40), schools (NC 25-35), offices (NC 25-40), libraries (NC 30-35), and restaurants (NC 40-45). For further discussion of noise control in these studies see the video8 (day 1 a.m. at 2 hours, 0 minutes).^3^

## Animal Source

Time-mated (F0) female Hsd:Sprague Dawley^®^ SD^®^ rats were obtained from Harlan Laboratories, Inc. (now Envigo, Indianapolis, IN), for use in the 28-day and 2-year studies.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the IITRI Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

### Twenty-eight-day Studies

The 28-day studies were conducted to evaluate the cumulative effects of repeated GSM- or CDMA-modulated cell phone RFR exposure and to determine the appropriate RFR power levels to be used in the 2-year studies. The exposure levels in these studies were selected based on the findings of minimal increases in body temperature observed in 5-day studies at exposures up to 12 W/kg RFR.^146^ Beginning gestation day (GD) 6, separate groups of F0 female rats were housed in reverberation chambers and received whole-body exposures to GSM- or CDMA-modulated cell phone RFR at power levels of 0 (sham control), 3, 6, or 9 W/kg, for 9 hours and 10 minutes per day for 5 or 7 days per week with continuous cycling of 10 minutes on and 10 minutes off during a period of 18 hours and 20 minutes each day. The sham control animals were housed in reverberation chambers identical to those used for the exposed groups, but they were not exposed to RFR; shared groups of unexposed rats served as sham controls for both RFR modulations.

In order to evaluate potential toxicity that arises from in utero and early postnatal exposure, these developmental windows were included in the cell phone RFR studies in rats. F0 female rats were approximately 11 to 14 weeks old upon receipt. GD 1 was defined as day with evidence of mating, and F0 females were received on GD 2 and held in quarantine until GD 5. Animals were randomly assigned to GSM or CDMA exposure groups (20 F0 females/RFR power level per modulation) with a single group of 20 F0 females serving as the sham control group for both the GSM and CDMA modulations. Randomization was based on body weights that produced a similar group mean value (ToxData, version 2.1.E.11, PDS Pathology Data Systems, Inc., Basel, Switzerland).

In 10 F0 females per group, subcutaneously implanted temperature microchips and monitoring equipment (Bio Medic Data Systems, Seaford, DE) were used to monitor individual animal body temperatures. Body temperature measurements were taken prior to initial exposure (GD 6) and on GDs 7, 11, and 16 and postnatal days (PND) 1, 4, 7, and 14 within 3.5 (GDs) or 2 (PNDs) minutes of exposure pauses at the end of the second to the last “on” cycle.

F0 females were housed individually during gestation and with their respective litters during lactation. During gestation, F0 females were weighed on GDs 6, 9, 12, 15, 18, and 21. During lactation, F0 females were weighed on PNDs 1, 4, 7, 14, 17, and 21 and individual F1 pup weights were recorded on PNDs 4, 7, 14, 17, and 21. The day of parturition was considered PND 0. From GD 20 to 25, F0 females were observed twice daily for parturition. All F0 females that did not deliver within 3 to 4 days of the anticipated delivery date were euthanized and the uteruses were examined for uterine implantations/ resorptions. On the day after parturition (PND 1), the number of live and dead F1 pups, sex ratio, whole litter weights, and litter weights/sex were recorded.

F1 litters were standardized on PND 4 to eight pups/litter, preferably with four males and four females each to equalize lactational pressure on F0 females. Litters that did not meet a minimum of eight pups were removed from the study. For continuation of exposure after weaning, three males and three females per litter from 10 F1 litters were randomly selected per exposure group. Weaning occurred on PND 21. Pups not selected and all F0 females were euthanized with 100% carbon dioxide without necropsy. Weaning marked the beginning of the 28-day prechronic phase of the study.

Groups of 10 male and 10 female F1 rats were housed in the same reverberation chambers and continued to receive whole-body exposures to GSM- or CDMA-modulated RFR at the same power levels for 9 hours and 10 minutes per day for 5 or 7 (last week of study) days per week for at least 28 days, with continuous cycling of 10 minutes on and 10 minutes off during a period of 8 hours and 20 minutes each day.

The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K). All test results were negative.

Animals were observed twice daily and weighed weekly. Clinical findings were recorded weekly. Subcutaneously implanted temperature microchips and monitoring equipment (Bio Medic Data Systems, Seaford, DE) were used to monitor individual animal body temperatures. Body temperature measurements were taken on day 8 after microchip implantation and on days 16, 20, and 27 within 5 minutes of exposure pauses at the end of the second to the last “on” cycle. Rats were housed individually. Feed and water were available ad libitum. To avoid interference with RFR dosimetry, feed was provided in glass (nonmetallic) jars and water was delivered in an adapted automatic watering system. Cages were changed weekly and rotated within the racks weekly; racks were changed biweekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix J.

Table 1 Experimental Design and Materials and Methods in the Whole-body Exposure Studies of GSM- and CDMA-modulated Cell Phone RFR

Twenty-eight-day Studies | Two-year Studies
Study Laboratory
IIT Research Institute (Chicago, IL) | Same as 28-day studies
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Same as 28-day studies
Animal Source
Harlan Laboratories, Inc. (Indianapolis, IN) | Same as 28-day studies
Time Held Before Studies
4 days (F0 females) | 3 days (F0 females)
Average Age When Studies Began
13 to 16 weeks (F0 females) | 12 to 15 weeks (F0 females)
Date of First Exposure
November 1, 2010 (F0 females) December 9, 2010 (F1 rats) | August 8, 2012 (F0 females) September 16, 2012 (F1 rats)
Duration of Exposure
9 hours and 10 minutes per day, over an 18-hour and 20-minute period as exposures cycled between modulations every 10 minutes, 7 days per week for perinatal phase and last week of prechronic phase, and 5 days per week otherwise | 9 hours and 10 minutes per day, over an 18-hour and 20-minute period as exposures cycled between modulations every 10 minutes, 7 days per week for 14 weeks (interim evaluation) or 106 (males) or 107 (females) weeks (2-year studies)
Date of Last Exposure
December 9, 2010 (F0 females) January 6-7, 2011 (F1 groups) | September 16, 2012 (F0 females) December 18 and 20 (males) or 17 and 20 (females), 2012 (interim evaluation) September 15-22 (males) or 22-30 (females), 2014 (chronic study)
Necropsy Dates
January 6-7, 2011 (F1 groups) | December 18 and 20 (males) or 17 and 20 (females), 2012 (interim evaluation) September 15-22 (males) or 22-30 (females), 2014 (chronic study)
Age at Necropsy
7 to 8 weeks | Interim: 17 weeks Study termination: 108 to 109 weeks (males) or 109 to 110 weeks (females)
Size of Study Groups
F0 females: 20 per exposure group F1 rats: 10 males and 10 females | F0 females: 56 per exposure group F1 core study: 90 males and 90 females F1 interim evaluation: 10 males and 10 females F1 genetic toxicity: five males and five females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 28-day studies
Animals per Cage
1 except during lactation when pups were housed with nursing dams | Same as 28-day studies
Method of Animal Identification
F0 females: Tail marking with permanent pen F1 rats: Tail tattoo | Same as 28-day studies
Diet
Irradiated NIH-07 rodent wafer diet (perinatal phase) or irradiated NTP-2000 rodent wafer diet (prechronic phase) (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, glass jars changed weekly | Same as 28-day studies, except ceramic bowls
Water
Tap water (Chicago municipal supply) via an adapted automatic watering system (SE Lab Group, Cincinnati, OH), available ad libitum | Same as 28-day studies
Cages
Solid polycarbonate (Allentown Caging, Allentown, NJ), changed and rotated weekly, except rotated every 2 weeks during parturition | Same as 28-day studies
Bedding
Certified, irradiated hardwood bedding (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly | Same as 28-day studies
Racks
Custom-designed fiberglass cage racks (Ultra, Inc., Milwaukee, WI), changed every 2 weeks | Same as 28-day studies
Reverberation Chambers
Fully-shielded, stainless steel room equipped with a stainless steel door to eliminate leakage of RFR signals, RFR excitation antennas, and two rotating stirrers; chambers were cleaned at least once weekly. | Same as 28-day studies
Reverberation Chamber Environment
Temperature: 72° ± 3° F Relative humidity: 50% ± 15% Room incandescent light: 12 hours/day Chamber air changes: at least 10/hour | Same as 28-day studies
Exposure Concentrations
Time-averaged whole-body SARs of 0 (sham control), 3, 6, and 9 W/kg GSM- or CDMA-modulated cell phone RFR | Time-averaged whole-body SARs of 0 (sham control), 1.5, 3, and 6 W/kg GSM- or CDMA-modulated cell phone RFR
Type and Frequency of Observation
F0 females: Observed twice daily. Body temperature was measured on GD 6 and within 3.5 minutes of exposure pauses at the end of the second to last “on” cycle on GDs 7, 11, and 16. Body temperature during lactation was measured within 2 minutes of exposure pauses at the end of the second to last “on” cycle on PNDs 1, 4, 7, and 14. Animals were weighed on GDs 6, 9, 12, 15, 18, and 21, and PNDs 1, 4, 7, 14, and 21. Clinical findings were recorded weekly. F1 rats: Observed twice daily. Body temperature was measured on day 8 and within 5 minutes of exposure pauses at the end of the second to last “on” cycle on study days 16, 20, and 27. Animals were weighed during the perinatal phase on PND 1 (litter weights by sex), 4, 7, 14, and 21 and weekly during the prechronic phase. Clinical findings were recorded weekly. | F0 females: Observed twice daily; animals were weighed on GDs 6, 9, 12, 15, 18, and 21, and on PNDs 1, 4, 7, 14, and 21. Clinical findings were recorded on GD 6 through PND 21. F1 rats: Observed twice daily; during perinatal phase, number, sex, and viability status were determined on PND 1. Animals were weighed on PNDs 1 (litter weights by sex), 4, 7, 14, 17, and 21. During the chronic phase, animals were weighed on day 1, twice a week through week 13, at 4-week intervals during weeks 14 to 86, and then every 2 weeks from week 90 until the end of the studies. Clinical findings were recorded at 4-week intervals.
Method of Euthanasia
Carbon dioxide asphyxiation | Same as 28-day studies
Necropsy
Necropsies were performed on all rats. Organs weighed were the right adrenal gland, brain, heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all rats. Organs weighed in 10 rats per exposure group at 14 weeks were the brain, heart, kidney (left and right), liver, lung, ovary (left and right), testis (left and right) with epididymis (left and right), and thymus
Clinical Pathology
None | Blood was collected from the retroorbital sinus of 10 rats per group at 14 weeks for hematology and clinical chemistry. Hematology: hematocrit (auto and manual); hemoglobin concentration; erythrocyte, reticulocyte, nucleated erythrocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials. Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, cholesterol, triglycerides, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acid.
Histopathology
Complete histopathology was performed on all 0 (sham control) and 9 W/kg groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, aorta, bone with marrow, brain, clitoral gland, epididymis, esophagus, eyes, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis, thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed on 10 F1 rats from each exposure group at 14 weeks, on all rats that died early, and on all rats surviving to the end of the studies. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, aorta, bone with marrow, brain, clitoral gland, esophagus, eyes, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung with bronchi, lymph nodes (mandibular and mesenteric), mammary gland, muscle, nerve (sciatic, trigeminal, and peripheral), nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spinal cord, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Count and Vaginal Cytology
None | Spermatid and sperm samples were collected from 10 male rats in each group at 14 weeks. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected from 10 females in each group for 16 days prior to the 14-week interim evaluation.

Necropsies were performed on all F1 rats on PND 29 or 30. Organs weighed were the right adrenal gland, brain, heart, right kidney, liver, lung, right testis, and thymus. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, testis with epididymis, and vaginal tunics were first fixed in Davidson’s solution or modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on all 0 (sham control) and 9 W/kg GSM- and 9 W/kg CDMA-modulated cell phone RFR core study F1 rats. Table 1 lists the tissues and organs examined.

The laboratory reports and selected histopathology slides were reviewed by a quality assessment pathologist (QAP). Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review (PPR). A pathology peer review typically consists of a small group (three to eight) pathologists who examine the lesions around a multiheaded microscope. It is frequently used to review lesions in short-term studies, issues of terminology, or examine single issues that have arisen during a pathology working group (PWG – see below). Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologist (SP), NTP pathologist, and QAP. Details of these review procedures have been described, in part, by Maronpot and Boorman^149^ and Boorman et al.^150^

A further discussion of pathology review procedures is found in the video^i^ (day 2 a.m. at 1 hours, 0 minutes).^3^

i https://doi.org/10.22427/NTP-VIDEO-43.

## Two-year Studies

### Study Design

Beginning on GD 5, groups of F0 female rats were housed in reverberation chambers and received whole-body exposures to GSM- or CDMA-modulated cell phone RFR at power levels of 0 (sham control), 1.5, 3, or 6 W/kg, for 9 hours and 10 minutes per day for 7 days per week with continuous cycling of 10 minutes on and 10 minutes off during a period of 18 hours and 20 minutes each day. The sham control animals were housed in reverberation chambers identical to those used for the exposed groups but were not exposed to RFR; shared groups of unexposed rats served as sham controls for both RFR modulations.

F0 female rats were approximately 11 to 14 weeks old upon receipt. GD 1 was defined as day with evidence of mating, and F0 females were received on GD 2 and held in quarantine until GD 4. Animals were randomly assigned to GSM or CDMA exposure groups (56 F0 females/cell phone RFR power level per modulation) with a single group of 56 F0 females serving as the sham control group for both the GSM and CDMA modulations. Randomization was stratified by body weight that produced similar group mean weights (ToxData, version 3.0, PDS Pathology Data Systems, Inc., Basel, Switzerland).

F0 females were housed individually during gestation and with their respective litters during lactation. During gestation, F0 females were weighed on GDs 6, 9, 12, 15, 18, and 21. During lactation, F0 females were weighed on PNDs 1, 4, 7, 14, 17, and 21 and individual F1 pup weights were recorded on PNDs 4, 7, 14, 17, and 21. The day of parturition was considered PND 0. All time-mated females that did not deliver within 3 to 4 days of the anticipated delivery date were euthanized and the uteruses were stained for uterine implantations/ resorptions. On the day after parturition (PND 1), the number of live and dead F1 pups, sex ratio, whole litter weights, and litter weights/sex were recorded.

F1 litters were standardized on PND 4 to eight pups/litter, preferably with four males and four females each to equalize lactational pressure on F0 females. Litters that did not meet a minimum of eight pups were removed from the study. For continuation of exposure after weaning, three males and three females per litter from 35 F1 litters were randomly selected per exposure group. Weaning occurred over PND 21 and 22 and F1 rats were housed individually. Pups not selected and the F0 females were euthanized with 100% carbon dioxide without necropsy. Weaning marked the beginning of the 2-year chronic phase of the study.

Groups of 105 male and 105 female F1 rats were housed in reverberation chambers and continued to receive whole-body exposures to GSM- or CDMA-modulated cell phone RFR at the same power levels for 9 hours and 10 minutes per day for 7 days per week for 106 to 107 weeks, with continuous cycling of 10 minutes on and 10 minutes off during a period of 18 hours and 20 minutes each day. At 14 weeks, 10 rats per group were randomly selected for interim evaluation and five were designated for genetic toxicity evaluation.

The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix K). All test results were negative.

Feed and water were available ad libitum. To avoid interference with RFR dosimetry, feed was provided in ceramic (nonmetallic) bowls and water was delivered in an adapted automatic watering system (see video^j^, day 1 a.m. at 2 hours, 5 minutes).^3,148^ Cages were changed weekly and rotated within the racks biweekly; racks were changed biweekly. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix J.

j https://doi.org/10.22427/NTP-VIDEO-41.

### Clinical Examinations and Pathology

Animals were observed twice daily and were weighed initially, twice a week for the first 13 weeks, and at 4-week intervals from weeks 14 to 86, and then every 2 weeks from week 90 until the end of the studies. Clinical observations were recorded once during quarantine and at least every 4 weeks during the studies.

Blood was collected from 10 male and 10 female interim evaluation rats from each group at 14 weeks. Rats were anesthetized with 70% CO2/30% O2 and blood was collected from the retroorbital plexus. Blood for hematology was placed in tubes containing serum separator gel. Hematology parameters were determined on an ADVIA™ 120 automated hematology analyzer (Bayer Diagnostic Division, Tarrytown, NY), except manual hematocrit determinations were performed using a microcentrifuge. Wright Giemsa stained peripheral blood smears were prepared for the assessment of platelet, leukocyte and erythrocyte morphology and enumeration of any nucleated erythrocytes. Samples for clinical chemistry were centrifuged, the serum harvested, and parameters measured using a Synchron LX20 (Beckman Coulter, Indianapolis, IN) analyzer. The hematology and clinical chemistry parameters measured are listed in Table 1. Blood was collected from the remaining five male and five female interim evaluation rats per exposure group at 14 weeks for use in the comet and micronucleus assays; methods for these assays are presented in Appendix E.

At 14 weeks, samples were collected for sperm motility and count and vaginal cytology evaluations on 10 male and 10 female interim evaluation rats from each group. The parameters evaluated are listed in Table 1. For 16 consecutive days prior to scheduled euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. However, due to inconsistent sample collection and slide staining, an assessment of estrous cyclicity could not be made. Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Modified Tyrode’s buffer was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

A complete necropsy was conducted on every animal at study termination. For the 14-week interim evaluation rats, the cerebellum, frontal cortex, hippocampus, and liver were collected from five male and five female rats per exposure group for use in the comet assay; methods for this assay are presented in Appendix E. Microscopic examinations were performed on 10 male and 10 female interim evaluation rats in each group at 14 weeks and all core study rats, including those found dead or euthanized moribund. At the interim evaluation, the brain, right and left epididymides, heart, right and left kidneys, liver, lung, right and left ovaries, right and left testes, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes, testes, vaginal tunics, and epididymides were first fixed in Davidson’s solution or a modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System Enterprise. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory and NTP PPR. All data and materials are available for review upon request from the NTP Archives.

## NTP Pathology Review Process

Typically, the initial reading of the slides and the first steps of the pathology review are done by an open, or non-blinded, evaluation by the pathologists involved. This is standard practice for the NTP, as well as the toxicologic pathology industry as a whole, and is in accordance with the recommendations of the Society of Toxicologic Pathologists.^151-156^ If issues arise where subtle lesions need to be identified or graded by a blinded evaluation, the pathologist will perform this.

The primary goals of the NTP pathology review are to reach consensus agreement on the diagnosis of all potentially treatment-related findings, confirm the diagnoses of all neoplasms, confirm that consistent and acceptable nomenclature is being used, and confirm the diagnosis of any unusual lesions. There are several elements in this process:

Pathology Data Review (PDR) is a complete review of the pathology data generated by the study laboratory to identify potential target organs and discrepant data and to harmonize terminology. The review involves a multi-disciplinary meeting by the NTP staff and pathology support-contract pathologists to determine the organs and lesions to be reviewed by the quality assessment pathologist (QAP), including all neoplasms.

Audit of Pathology Specimens (APS) is a review of the physical data and residual wet tissues (typically from 10% of the animals) to ensure all gross lesions were evaluated microscopically; of the slides and blocks (typically from 10% of the animals) to ensure correct labeling and quality of sections; and of the submitted reports to ensure accuracy. Also evaluated is whether or not the study laboratory adhered to NTP pathology specifications.

Quality Assessment is a review of the slides of target organs and lesions identified in the PDR by a pathologist from one of the NTP’s pathology support contract laboratories not involved with the initial pathology evaluation of the study. All differences in diagnoses between the study pathologist (SP) and QAP are identified in the Differences Report prepared by the QAP. The NTP pathologist attempts to resolve the discrepant diagnoses between the SP and QAP; those that are not resolved are reviewed by the pathology working group (PWG).

Pathology Working Group is a review of selected slides by a panel of pathologists in order to confirm the diagnoses of all treatment-related neoplastic and non-neoplastic lesions and unusual lesions, resolve discrepancies between the SP, QAP, and NTP pathologist, harmonize nomenclature, propose further characterization of the lesions, and address possible mechanisms. The QAP, with oversight from the NTP pathologist, selects slides for the PWG and conducts the PWG. Typically, experts in a particular organ of interest are invited to participate.

Pathology Peer Review is a peer review meeting that convenes to resolve minor issues or issues limited in scope (such as review of short-term studies with limited findings), or review findings of post-PWG actions. Reports are prepared for all these activities. Once the PWG and/or PPR is complete, all written documentation of data changes is reviewed for accuracy and the study data are updated. The pathology data and all written documentation of data changes are then submitted to an outside independent auditor to ensure the accuracy of the updated data. Once all issues identified by the independent auditor have been addressed, the final pathology data tables are generated. For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of Brix et al.^157^

### Pathology Review of Cell Phone RFR Studies in Rats

The pathology data presented in this report on cell phone RFR were subjected to a rigorous review process. All elements of the NTP review process were performed, but the sequence of events was altered. Identification of increased incidences of lesions in the brain and heart of male rats in the original study laboratory report warranted a more immediate review than would occur in the standard NTP review process. Malignant glioma of the brain and schwannomas have been observed in human studies, so the observation of an apparent increase in these same lesions in the rat study prompted the need for an expedited review given the magnitude of human exposure to cell phone RFR and therefore the need to communicate this information to our regulatory partners and the public as soon as possible. Data for the brain and heart were reported to the U.S. Food and Drug Administration and Federal Communications Commission and published in a partial report.^158^ For this expedited review, an APS (APS 1) was performed on the hearts and brains. This entailed reviewing the residual wet tissues to ensure all gross lesions were trimmed and processed to slide, reviewing the slides and blocks to ensure quality, and reviewing the data tables. For the expedited review, a QA review was done on all lesions in the central and peripheral nervous systems, all proliferative lesions from the heart, and all schwannomas in other organs. The QAPs, with oversight from the NTP pathologist, selected lesions for PWG review. These lesions were reviewed in several PWGs. Four separate PWGs were held for the brains and hearts. The first PWG (PWG 1), held on January 29, 2016, evaluated the proliferative glial lesions and some reactive glial lesions in the brain, some additional non-neoplastic brain lesions, and schwannomas and Schwann cell hyperplasias in the heart. The second PWG (PWG 2) evaluated schwannomas in the head and neck region and nonglial proliferative lesions in the brain (e.g., granular cell tumors and meningiomas). Due to the volume of slides to be reviewed, PWG 2 was conducted over four sessions (February 11, February 12, March 23, and April 11, 2016). Due to the need for definitive criteria for glial cell and Schwann cell hyperplasia, two additional PWGs composed of experts in neuropathology and cardiovascular pathology, respectively, from around the country were convened. The first (PWG 3) reviewed glial lesions in the brain and was held on February 25, 2016. The second (PWG 4), held on March 3, 2016, reviewed cardiac lesions and schwannomas in organs other than the heart and head and neck region. Subsequent to the release of NTP’s Report of Partial Findings,^158^ the remaining tissues were reviewed. After the Report of Partial Findings, the remaining tissues, and the nonproliferative lesions in the heart, were reviewed (including PWGs 5 and 6). These tissues were subjected to the standard NTP pathology review process as described earlier.

## Statistical Methods

P values less than 0.05 were considered statistically significant. Statistical significance is one component of the “weight of evidence” of carcinogenic activity described on page 16 of this Technical Report.

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^159^ and is presented in the form of graphs. Animals found dead of other than natural causes or missing were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^160^ method for testing two groups for equality and Tarone’s^161^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or non-neoplastic lesions are presented in Table A-1, Table A-9, Table B-1, Table B-7, Table C-1, Table C-7, Table D-1, and Table D-8 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all non-neoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study that it survived, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Non-neoplastic Lesion Incidences

Statistical analyses of neoplasm and non-neoplastic lesion incidences took into account two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be taken into account. Also, up to three animals per sex were randomly selected from each litter to participate in the study. The statistical analysis of lesion incidences used the Poly-3 test to account for survival differences, with a Rao-Scott adjustment for litter effects, as described below.

The Poly-k test^162-164^ was used to assess neoplasm and non-neoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died prior to terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^162^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^162^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F1 mice.^165^ Bailer and Portier^162^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^166^ Poly-3 tests used the continuity correction described by Nam.^167^

Because up to three pups per sex per litter were in the core study and in the 28-day study, the Poly-3 test was modified to accommodate litter effects using the Rao-Scott approach.^168^ Litter effects arise when littermates are more similar to each other than they are to animals from other litters. If intra-litter correlations are present but ignored in the statistical analysis, the variance of the data will be underestimated, leading to P values that are too small. The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Poly-3 test as recommended by Fung et al.,^169^ formula ₸RS2.

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Rao-Scott-adjusted Poly-3 tests were used in the analysis of lesion incidence and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N). For neoplasms and non-neoplastic lesions observed without litter structure (e.g., at the interim evaluation), Poly-3 tests that included the continuity correction, but without adjustment for potential litter effects, was used for trend and pairwise comparisons to the control group.

To evaluate litter incidences, the proportions of litters affected by each lesion type were tested among groups. Cochran-Armitage trend tests and Fisher exact tests^170^ were used to test for trends and pairwise differences from the control group, respectively.

The statistical analysis of brain gliomas and heart schwannomas reported in the NTP’s Report of Partial Findings^158^ differed from those presented here. In the previously reported analyses, only gliomas of the brain and schwannomas of the heart were analyzed. Because these are rare tumors and did not occur in more than one animal per litter and because effective statistical methods for litter effect adjustments had not been programmed at that point, Poly-3 and Poly-6 tests were used without adjustment for potential litter effects. The rarity of the tumors and the fact that no litter had more than one animal with the tumors indicated that the adjustment for litter effects would be negligible.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. In the 28-day and 2-year studies, pup organ and body weight data, and body temperatures, which historically have approximately normal distributions, were analyzed with mixed effects linear models, for trend and pairwise tests with a Dunnett^171^-Hsu^172^ adjustment, where litters were the random effect. Body temperatures for dams in all studies were analyzed using the parametric multiple comparison procedures of Dunnett^171^ and Williams.^173,174^ At the 14-week interim evaluations in the 2-year studies, hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the non-parametric multiple comparison methods of Shirley^175^ (as modified by Williams^176^) and Dunn.^177^ Litter sizes, pup survival, implantations, number of resorptions, and proportions of male pups per litter for all studies were also analyzed using these nonparametric methods. For all quantitative endpoints unaffected by litter structure, Jonckheere’s test^178^ was used to assess the significance of the dose-related trends and to determine at the 0.01 level of significance, whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey,^179^ for small samples (n ≤ 20), and Tukey’s outer fences method,^180^ for large samples (n > 20), were examined by NTP personnel, and implausible values were eliminated from the analysis.

Post-weaning body weights were measured on three pups per sex per litter in the 2-year study and up to three pups per sex per litter in the 28-day study (with a total of 10 animals per dose group). More than three pups per sex per litter were possible in pre-weaning body weight measurements. The analyses of pup body weights and body weights adjusted for litter size (described below) of these animals took litter effects into account by use of mixed effects regression, where litters were the random effects. Dam body weights, dam body weights adjusted for litter size during gestation, as well as dam body weights during lactation were analyzed with the parametric multiple comparison procedures of Dunnett^171^ and Williams,^173,174^ depending on whether Jonckheere’s test indicated the use of a trend-sensitive test.

P values for these analyses are two sided.

### Analysis of Gestational and Fertility Indices

Significances of trends in gestational and fertility indices across dose groups was tested using Cochran-Armitage trend tests. Pairwise comparisons of each dosed group with the control group were conducted using the Fisher exact test. P values for these analyses are two sided.

### Body Weight Adjustments

Adjusted dam body weights and adjusted pup body weights were calculated to account for litter size. Dam weights measured during gestation were adjusted for litter size using gestational-day-specific analyses of variance on dam weight as a function of litter size and dose. Dam body weights were adjusted to the overall mean PND 1 total litter size of all groups under analysis, combined, and the residuals from the analyses of covariance were added back in to retain the original variances. Pre-weaning pup body weights were adjusted for PND 1 live litter size using the same analysis of covariance approach, with the additional random effect of litter added to the models to account for litter effects. Although the same sham control group was used to analyze GSM and CDMA exposed groups, adjusted body weights for the sham control group differ between GSM and CDMA because the overall mean PND 1 live litter size differs between the GSM and CDMA analyses. Post-weaning pup body weights were adjusted using a random effect of litter to account for litter effects without accounting for overall mean PND 1 litter size.

### Historical Control Data

The historical control Hsd:Sprague Dawley^®^ SD^®^ rat data used in the current studies are limited to data obtained from three recent finalized studies and differ from the historical control data provided in NTP’s Report of Partial Findings.^158^ When the NTP’s Report of Partial Findings was released very limited data were available describing the prevalence of glial and Schwann cell lesions in Harlan Sprague Dawley rats in NTP studies. Consequently, an effort was made to review control groups from as many comparable studies as possible regardless of whether they had been subjected to peer review.

In NTP’s Report of Partial Findings, control groups of male Harlan Sprague Dawley rats from the cell phone RFR studies and nine (for brain) and 12 (for heart) other recently completed NTP studies were tabulated to increase the sample size of rats from which control rates of malignant gliomas of the brain or schwannoma of the heart could be determined. For evaluation of the heart lesions, the 12 studies included black cohosh, resveratrol, sodium tungstate dehydrate, tris(chloroisopropyl) phosphate, indole-3-carbinol, perfluorooctanoic acid, dietary zinc, p-chloro-α,α,α-trifluorotoluene, dibutyl phthalate, 2-hydroxy-4-methoxy-benzophenone, and diethylhexyl phthalate (2 studies). Three fewer studies were available for evaluation of brain lesions than for the evaluation of heart lesions because of a recent change by the NTP to increase the standard number of examined sections from three to seven. Because the sectioning in these three studies differed, the studies with three brain sections (indole-3-carbinol, perfluorooctanoic acid, and dietary zinc) were excluded from evaluation of brain lesions. For studies in which the in-life portion was completed, but the final pathology data were not yet available, special reviews of the control rat brains for malignant gliomas and hearts for schwannomas were performed.

## Quality Assurance Methods

The 28-day and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^181^ In addition, the 28-day and 2-year study reports were audited retrospectively by an outside independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of GSM- and CDMA-modulated cell phone RFR was assessed by measuring the frequency of micronucleated erythrocytes in peripheral blood and DNA damage in five different tissues of male and female rats following 14 weeks of exposure. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^182,183^ The alkaline (pH > 13) comet assay^184^ (also known as the single cell gel electrophoresis assay) detects DNA damage in any of a variety of eukaryotic cell types^185-188^; cell division is not required. The type of DNA damage detected includes nicks, adducts, strand breaks, and abasic sites that are converted to DNA strand breaks after treatment of cells in an alkaline (pH > 13) solution. Transient DNA strand breaks generated by the process of DNA excision repair may also be detected. DNA damage caused by crosslinking agents has been detected as a reduction of DNA migration.^189,190^ The fate of the DNA damage detected by the comet assay is varied; most of the damage is rapidly repaired resulting in no sustained impact on the tissue but some may result in cell death or may be incorrectly processed by repair proteins and result in a fixed mutation or chromosomal alteration. The detailed protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have grown out of an earlier effort by the NTP to develop a comprehensive database permitting a critical anticipation of a test article’s carcinogenicity in experimental animals based on the results from a number of in vitro and in vivo short-term tests measuring functionally distinct genotoxicity endpoints. The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^191^ and the somatic mutation theory of cancer.^192,193^ However, it should be noted that not all cancers arise through genotoxic mechanisms, and in these studies, the test article is not a chemical. Many studies have established the genotoxicity of some forms of radiation including, for example, ultraviolet radiation and X-ray radiation, which are both forms of ionizing radiation. Because exposure to RFR requires specialized and highly technical exposure protocols, only in vivo biomarkers associated with genotoxicity could be investigated.

Clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^194^ The relationship between comet assay results and rodent carcinogenicity was investigated previously and a close association was observed^195^; however, this assay is best employed as a hazard identification assay. Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular test article.

Further discussion of the genetic toxicology assays used in these studies can be found in the video^k^ (day 2 a.m. at 2 hours, 48 minutes).^3^

k https://doi.org/10.22427/NTP-VIDEO-43.