# Appendix K Sentinel Animal Program

## K.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the evaluation of test agents. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test agents.

Blood samples were collected and allowed to clot and the serum was separated. All samples were processed appropriately with serology testing performed by IDEXX BioResearch [formerly Research Animal Diagnostic Laboratory (RADIL), University of Missouri], Columbia, MO, for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five rats per sex per time point except for the following:

- 2-year study, arrival collection: 10 females
- 2-year study, 4-week collection: 10 females
- 2-year study, 12-month collection: six females
- 2-year study, end of study collection: 10 males and 10 females

Table K‑1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Twenty-eight-day Study
Multiplex Fluorescent Immunoassay
H-1 (Toolan’s H-1 virus) | Study termination
KRV (Kilham’s rat virus) | Study termination
Mycoplasma pulmonis | Study termination
PVM (pneumonia virus of mice) | Study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Study termination
RMV (rat minute virus) | Study termination
RPV (rat parvovirus) | Study termination
RTV (rat theilovirus) | Study termination
Sendai | Study termination
TMEV (Theiler’s murine encephalomyelitis virus) | Study termination
Two-year Study
Multiplex Fluorescent Immunoassay
H-1 | Arrival^a^, 4 weeks^b^, 9 weeks^c^, 6, 12, and 18 months, study termination
KRV | Arrival, 4 weeks, 9 weeks, 6, 12, and 18 months, study termination
M. pulmonis | Arrival, 4 weeks, 9 weeks, 6, 12, and 18 months, study termination
PVM | Arrival, 4 weeks, 9 weeks, 6, 12, and 18 months, study termination
RCV/SDA | Arrival, 4 weeks, 9 weeks, 6, 12, and 18 months, study termination
RMV | Arrival, 4 weeks, 9 weeks, 6, 12, and 18 months, study termination
RPV | Arrival, 4 weeks, 9 weeks, 6, 12, and 18 months, study termination
RTV | Arrival, 4 weeks, 9 weeks, 6, 12, and 18 months, study termination
Sendai | Arrival, 4 weeks, 9 weeks, 6, 12, and 18 months, study termination
TMEV | Arrival, 4 weeks, 9 weeks, 6, 12, and 18 months, study termination

^a^ Age-matched nonpregnant females.

^b^ Time-mated females that did not have a litter.

^c^ Offspring, 3 weeks post weaning.

## K.2 Results

All test results were negative.