# Appendix I GSM- and CDMA-modulated Cell Phone RFR Exposure Data

## I.1 Overview

Exposure data include SAR (W/kg) (Table I‑1 and Table I‑5), chamber field strength (V/m) (Table I‑2 and Table I‑6), and E- and H‑field measurements (V/m) (Table I‑3, Table I‑4, Table I‑7, and Table I‑8). For the medium- and high-dose GSM chambers, where a second E-field probe was used, the H-field measurements were converted from E-field measurements (E-field divided by 377). Fields were measured continuously throughout the studies and measurements automatically recorded approximately every 20 seconds. For every 20-second interval, the SAR was calculated based on the average H- and/or E-field data. The data presented for each exposure parameter include the mean and standard deviation [expressed in decibels (dB), W/kg or V/m], the total number of measurements recorded during the identified period of exposure (>50,000 calculated SAR per month, and more than 1.4 million over the course of the 2-year studies); the lowest (minimum) and highest measurement (maximum) recorded during the given exposure period; the number of measurements that were within the acceptable range; and the ratio of all measurements within range. The data reported for SAR also include the range of animal body weights (g) over the indicated time period of exposure, and the selected target SAR (W/kg) for each group. The data reported for field strengths (chamber, E‑field, and H-field) include the target range of the field required to maintain appropriate SAR exposures. The minimum and maximum exposure values reported represent a single recorded measurement over the 2-year exposure period. The SAR and chamber-field in the sham and exposure chambers were within the target ranges (defined as ± 2 dB) for >99.97% of recorded measurements over the course of the 2-year study; ≥99.25% of E- and H-field exposures in the sham and exposure chambers were within the target ranges.

The dB is a mathematical transformation of a number or numerical ratio using base 10 logarithms. Multiplication of ratios is transformed into addition of dBs; raising a number to a power is transformed into multiplication of dBs.

In general, dB(power) = 10 × log(R) and dB(field) = 20 × log(R). The formulas differ by a factor of two because power or SAR varies as the square of the fields. For SAR (in W/kg), the decibel formula is calculated as:

SAR(dB) = 10 × log(SARM/SART)

where SARM is the measured value and SART is the target value, and

–2 dB = 10 × log(SARL/SART), where SARL (low) = SART × 10-0.2

+2 dB = 10 × log(SARH/SART), where SARH (high) = SART × 100.2

On this basis, the ± 2 dB range specified by the NTP translates to the following ranges for each SAR used in the 2‑year study:

Target SAR (W/kg) and acceptable SAR range (W/kg; ± 2 dB)

1.5 0.95 to 2.38

3 1.89 to 4.75

6 3.79 to 9.51

## I.2 Summary of GSM-modulated Exposure Data

Table I‑1 Summary of GSM-modulated Cell Phone RFR Exposure Data in Rats – SAR

Chamber | Weight Range [g] | Target [W/kg] | Mean [W/kg] | | Stdev [dB]/[W/kg] | | Min [W/kg] | | Max [W/kg] | In Range/Total | Ratio
August 8 to 31, 2012
Male
Ch06 GSM High | 238.7 to 355.6 | 6.00 | 5.96 | | 0.30/0.07 | | 2.553 | | 11.257 | 42880/42893 | 1.000
Ch05 GSM Med | 238.7 to 355.5 | 3.00 | 2.99 | | 0.25/0.06 | | 1.347 | | 4.987 | 42890/42893 | 1.000
Ch09 GSM Low | 239.9 to 358.9 | 1.50 | 1.49 | | 0.23/0.05 | | 0.654 | | 2.544 | 42890/42893 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 42893/42893 | 1.000
September 1 to 30, 2012
Female
Ch17 GSM High | 58.0 to 303.9 | 6.00 | 5.99 | | 0.30/0.07 | | 3.154 | | 11.061 | 52929/52959 | 0.999
Ch16 GSM Med | 58.7 to 303.9 | 3.00 | 3.00 | | 0.27/0.06 | | 1.634 | | 5.394 | 52953/52959 | 1.000
Ch20 GSM Low | 59.4 to 303.9 | 1.50 | 1.49 | | 0.28/0.07 | | 0.823 | | 3.032 | 52938/52959 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 52959/52959 | 1.000
Male
Ch06 GSM High | 60.9 to 290.7 | 6.00 | 5.99 | | 0.33/0.08 | | 1.483 | | 25.815 | 52932/52959 | 0.999
Ch05 GSM Med | 62.0 to 302.3 | 3.00 | 3.00 | | 0.31/0.07 | | 1.646 | | 10.693 | 52926/52959 | 0.999
Ch09 GSM Low | 63.9 to 309.8 | 1.50 | 1.50 | | 0.30/0.07 | | 0.737 | | 5.732 | 52920/52959 | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 52959/52959 | 1.000
October 1 to 31, 2012
Female
Ch17 GSM High | 117.8 to 202.2 | 6.00 | 5.97 | | 0.27/0.07 | | 4.018 | | 9.604 | 55337/55339 | 1.000
Ch16 GSM Med | 118.8 to 201.8 | 3.00 | 2.98 | | 0.25/0.06 | | 1.870 | | 4.575 | 55338/55339 | 1.000
Ch20 GSM Low | 120.1 to 205.4 | 1.50 | 1.49 | | 0.25/0.06 | | 0.947 | | 2.556 | 55332/55335 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55339/55339 | 1.000
Male
Ch06 GSM High | 137.9 to 306.4 | 6.00 | 5.94 | | 0.30/0.07 | | 3.814 | | 9.705 | 55349/55351 | 1.000
Ch05 GSM Med | 139.5 to 313.7 | 3.00 | 2.98 | | 0.26/0.06 | | 2.110 | | 4.395 | 55351/55351 | 1.000
Ch09 GSM Low | 143.1 to 318.0 | 1.50 | 1.48 | | 0.24/0.06 | | 1.089 | | 2.162 | 55339/55339 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55351/55351 | 1.000
November 1 to 30, 2012
Female
Ch17 GSM High | 207.1 to 246.3 | 6.00 | 5.96 | | 0.27/0.06 | | 4.468 | | 8.847 | 53853/53853 | 1.000
Ch16 GSM Med | 208.5 to 246.7 | 3.00 | 2.98 | | 0.23/0.05 | | 2.407 | | 4.141 | 53853/53853 | 1.000
Ch20 GSM Low | 210.9 to 246.6 | 1.50 | 1.49 | | 0.24/0.06 | | 0.990 | | 2.587 | 53842/53853 | 1.000
Ch15 Sham | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53853/53853 | 1.000
Male
Ch06 GSM High | 313.9 to 389.2 | 6.00 | 5.95 | | 0.29/0.07 | | 4.132 | | 8.526 | 53853/53853 | 1.000
Ch05 GSM Med | 324.3 to 400.0 | 3.00 | 2.99 | | 0.27/0.06 | | 2.271 | | 3.920 | 53853/53853 | 1.000
Ch09 GSM Low | 329.8 to 402.5 | 1.50 | 1.49 | | 0.22/0.05 | | 1.178 | | 2.057 | 53853/53853 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53853/53853 | 1.000
December 1 to 31, 2012
Female
Ch17 GSM High | 246.3 to 259.5 | 6.00 | 5.93 | | 0.28/0.07 | | 3.770 | | 8.873 | 55607/55608 | 1.000
Ch16 GSM Med | 246.7 to 257.1 | 3.00 | 2.97 | | 0.23/0.06 | | 2.283 | | 4.025 | 55608/55608 | 1.000
Ch20 GSM Low | 246.6 to 261.6 | 1.50 | 1.49 | | 0.20/0.05 | | 1.164 | | 2.069 | 55608/55608 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55608/55608 | 1.000
Male
Ch06 GSM High | 389.2 to 419.3 | 6.00 | 5.97 | | 0.30/0.07 | | 4.198 | | 8.500 | 55608/55608 | 1.000
Ch05 GSM Med | 400.0 to 429.8 | 3.00 | 2.99 | | 0.28/0.07 | | 2.109 | | 3.863 | 55608/55608 | 1.000
Ch09 GSM Low | 402.5 to 432.3 | 1.50 | 1.48 | | 0.23/0.06 | | 1.119 | | 1.916 | 55608/55608 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55608/55608 | 1.000
January 1 to 31, 2013
Female
Ch17 GSM High | 259.5 to 275.8 | 6.00 | 5.95 | | 0.27/0.07 | | 4.415 | | 8.955 | 55618/55618 | 1.000
Ch16 GSM Med | 257.1 to 273.1 | 3.00 | 2.98 | | 0.23/0.06 | | 2.271 | | 3.975 | 55619/55619 | 1.000
Ch20 GSM Low | 261.6 to 279.0 | 1.50 | 1.49 | | 0.21/0.05 | | 1.148 | | 2.082 | 55617/55617 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55619/55619 | 1.000
Male
Ch06 GSM High | 419.3 to 458.6 | 6.00 | 5.97 | | 0.32/0.08 | | 4.278 | | 8.641 | 55619/55619 | 1.000
Ch05 GSM Med | 429.8 to 464.1 | 3.00 | 2.97 | | 0.27/0.06 | | 2.242 | | 3.984 | 55619/55619 | 1.000
Ch09 GSM Low | 432.3 to 469.8 | 1.50 | 1.48 | | 0.25/0.06 | | 1.152 | | 2.394 | 55618/55619 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55619/55619 | 1.000
February 1 to 28, 2013
Female
Ch17 GSM High | 275.8 to 286.0 | 6.00 | 5.96 | | 0.26/0.06 | | 4.471 | | 8.310 | 50082/50082 | 1.000
Ch16 GSM Med | 273.1 to 282.0 | 3.00 | 2.98 | | 0.24/0.06 | | 2.326 | | 3.891 | 50082/50082 | 1.000
Ch20 GSM Low | 279.0 to 287.8 | 1.50 | 1.49 | | 0.20/0.05 | | 1.221 | | 1.992 | 50082/50082 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 50082/50082 | 1.000
Male
Ch06 GSM High | 458.6 to 482.5 | 6.00 | 5.98 | | 0.33/0.08 | | 4.282 | | 8.327 | 50082/50082 | 1.000
Ch05 GSM Med | 464.1 to 493.7 | 3.00 | 3.00 | | 0.28/0.07 | | 2.362 | | 3.887 | 50082/50082 | 1.000
Ch09 GSM Low | 469.8 to 496.2 | 1.50 | 1.49 | | 0.24/0.06 | | 1.137 | | 1.931 | 50082/50082 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 50082/50082 | 1.000
March 1 to 31, 2013
Female
Ch17 GSM High | 286.0 to 296.4 | 6.00 | 5.93 | | 0.27/0.06 | | 4.613 | | 8.141 | 55704/55704 | 1.000
Ch16 GSM Med | 282.0 to 292.9 | 3.00 | 2.97 | | 0.25/0.06 | | 2.166 | | 3.911 | 55704/55704 | 1.000
Ch20 GSM Low | 287.8 to 297.0 | 1.50 | 1.48 | | 0.20/0.05 | | 1.198 | | 1.965 | 55704/55704 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55704/55704 | 1.000
Male
Ch06 GSM High | 482.5 to 503.9 | 6.00 | 5.93 | | 0.34/0.08 | | 4.278 | | 8.763 | 55704/55704 | 1.000
Ch05 GSM Med | 493.7 to 513.0 | 3.00 | 3.01 | | 0.28/0.07 | | 2.351 | | 4.000 | 55704/55704 | 1.000
Ch09 GSM Low | 496.2 to 517.8 | 1.50 | 1.49 | | 0.24/0.06 | | 1.150 | | 2.068 | 55704/55704 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55704/55704 | 1.000
April 1 to 30, 2013
Female
Ch17 GSM High | 296.4 to 305.2 | 6.00 | 5.97 | | 0.28/0.07 | | 4.614 | | 8.286 | 53719/53719 | 1.000
Ch16 GSM Med | 292.9 to 300.8 | 3.00 | 2.99 | | 0.25/0.06 | | 2.254 | | 3.933 | 53719/53719 | 1.000
Ch20 GSM Low | 297.0 to 307.9 | 1.50 | 1.49 | | 0.20/0.05 | | 1.215 | | 2.087 | 53719/53719 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53719/53719 | 1.000
Male
Ch06 GSM High | 503.9 to 523.3 | 6.00 | 5.91 | | 0.33/0.08 | | 4.395 | | 8.282 | 53721/53721 | 1.000
Ch05 GSM Med | 513.0 to 531.8 | 3.00 | 3.00 | | 0.29/0.07 | | 2.310 | | 4.013 | 53721/53721 | 1.000
Ch09 GSM Low | 517.8 to 538.7 | 1.50 | 1.49 | | 0.25/0.06 | | 1.207 | | 1.911 | 53719/53719 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53722/53722 | 1.000
May 1 to 31, 2013
Female
Ch17 GSM High | 305.2 to 314.8 | 6.00 | 5.93 | | 0.29/0.07 | | 3.468 | | 8.502 | 52758/52762 | 1.000
Ch16 GSM Med | 300.8 to 309.8 | 3.00 | 2.98 | | 0.26/0.06 | | 1.676 | | 3.984 | 52760/52762 | 1.000
Ch20 GSM Low | 307.9 to 316.0 | 1.50 | 1.48 | | 0.22/0.05 | | 0.817 | | 1.957 | 52759/52762 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 52762/52762 | 1.000
Male
Ch06 GSM High | 523.3 to 539.7 | 6.00 | 5.96 | | 0.35/0.08 | | 3.356 | | 8.858 | 52788/52789 | 1.000
Ch05 GSM Med | 531.8 to 550.9 | 3.00 | 3.00 | | 0.29/0.07 | | 1.145 | | 3.948 | 52788/52790 | 1.000
Ch09 GSM Low | 538.7 to 557.8 | 1.50 | 1.48 | | 0.30/0.07 | | 0.849 | | 2.306 | 52778/52788 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 52790/52790 | 1.000
June 1 to 30, 2013
Female
Ch17 GSM High | 314.8 to 322.9 | 6.00 | 5.98 | | 0.30/0.07 | | 3.712 | | 8.162 | 53536/53537 | 1.000
Ch16 GSM Med | 309.8 to 317.7 | 3.00 | 2.97 | | 0.26/0.06 | | 2.049 | | 3.927 | 53537/53537 | 1.000
Ch20 GSM Low | 316.0 to 324.2 | 1.50 | 1.50 | | 0.22/0.05 | | 1.068 | | 1.913 | 53537/53537 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53537/53537 | 1.000
Male
Ch06 GSM High | 539.7 to 556.0 | 6.00 | 5.93 | | 0.35/0.08 | | 3.758 | | 8.744 | 53543/53544 | 1.000
Ch05 GSM Med | 550.9 to 566.9 | 3.00 | 2.97 | | 0.29/0.07 | | 2.164 | | 4.004 | 53544/53544 | 1.000
Ch09 GSM Low | 557.8 to 574.0 | 1.50 | 1.49 | | 0.25/0.06 | | 1.099 | | 1.953 | 53537/53537 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53544/53544 | 1.000
July 1 to 31, 2013
Female
Ch17 GSM High | 322.9 to 338.2 | 6.00 | 5.99 | | 0.29/0.07 | | 4.603 | | 8.053 | 55527/55527 | 1.000
Ch16 GSM Med | 316.3 to 334.5 | 3.00 | 3.00 | | 0.25/0.06 | | 2.330 | | 3.798 | 55527/55527 | 1.000
Ch20 GSM Low | 324.2 to 341.9 | 1.50 | 1.49 | | 0.21/0.05 | | 1.186 | | 1.863 | 55527/55527 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55527/55527 | 1.000
Male
Ch06 GSM High | 556.0 to 585.8 | 6.00 | 5.92 | | 0.35/0.08 | | 4.259 | | 8.691 | 55531/55531 | 1.000
Ch05 GSM Med | 566.9 to 596.0 | 3.00 | 2.96 | | 0.29/0.07 | | 2.249 | | 4.043 | 55531/55531 | 1.000
Ch09 GSM Low | 574.0 to 607.9 | 1.50 | 1.48 | | 0.27/0.06 | | 1.119 | | 2.044 | 55527/55527 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55531/55531 | 1.000
August 1 to 31, 2013
Female
Ch17 GSM High | 338.2 to 344.5 | 6.00 | 5.98 | | 0.29/0.07 | | 4.360 | | 7.931 | 55952/55952 | 1.000
Ch16 GSM Med | 334.5 to 343.0 | 3.00 | 2.99 | | 0.26/0.06 | | 2.294 | | 4.001 | 55952/55952 | 1.000
Ch20 GSM Low | 341.9 to 348.4 | 1.50 | 1.49 | | 0.20/0.05 | | 1.195 | | 1.858 | 55952/55952 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55952/55952 | 1.000
Male
Ch06 GSM High | 585.8 to 597.1 | 6.00 | 5.89 | | 0.34/0.08 | | 3.819 | | 8.404 | 55955/55955 | 1.000
Ch05 GSM Med | 596.0 to 606.8 | 3.00 | 2.98 | | 0.28/0.07 | | 2.303 | | 3.856 | 55955/55955 | 1.000
Ch09 GSM Low | 607.9 to 619.4 | 1.50 | 1.48 | | 0.25/0.06 | | 1.167 | | 1.959 | 55952/55952 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55955/55955 | 1.000
September 1 to 30, 2013
Female
Ch17 GSM High | 344.5 to 349.8 | 6.00 | 5.95 | | 0.28/0.07 | | 3.800 | | 8.065 | 53696/53696 | 1.000
Ch16 GSM Med | 343.0 to 352.4 | 3.00 | 2.98 | | 0.28/0.07 | | 1.822 | | 4.020 | 53694/53696 | 1.000
Ch20 GSM Low | 348.4 to 355.8 | 1.50 | 1.49 | | 0.22/0.05 | | 1.073 | | 1.968 | 53696/53696 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53696/53696 | 1.000
Male
Ch06 GSM High | 597.1 to 607.0 | 6.00 | 5.94 | | 0.34/0.08 | | 4.168 | | 8.242 | 53703/53703 | 1.000
Ch05 GSM Med | 606.8 to 617.7 | 3.00 | 2.97 | | 0.30/0.07 | | 1.936 | | 4.044 | 53703/53703 | 1.000
Ch09 GSM Low | 619.4 to 633.9 | 1.50 | 1.49 | | 0.25/0.06 | | 1.029 | | 1.959 | 53696/53696 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53703/53703 | 1.000
October 1 to 31, 2013
Female
Ch17 GSM High | 349.8 to 360.2 | 6.00 | 5.96 | | 0.36/0.09 | | 3.397 | | 9.676 | 56717/56748 | 0.999
Ch16 GSM Med | 352.4 to 361.2 | 3.00 | 2.97 | | 0.36/0.09 | | 1.520 | | 4.314 | 56693/56748 | 0.999
Ch20 GSM Low | 355.8 to 366.5 | 1.50 | 1.48 | | 0.26/0.06 | | 0.926 | | 1.910 | 56745/56747 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 56748/56748 | 1.000
Male
Ch06 GSM High | 607.0 to 615.0 | 6.00 | 5.93 | | 0.38/0.09 | | 3.232 | | 8.512 | 56799/56807 | 1.000
Ch05 GSM Med | 617.7 to 628.2 | 3.00 | 3.00 | | 0.34/0.08 | | 2.071 | | 4.172 | 56807/56807 | 1.000
Ch09 GSM Low | 633.9 to 642.8 | 1.50 | 1.49 | | 0.27/0.06 | | 1.027 | | 2.186 | 56748/56748 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 56807/56807 | 1.000
November 1 to 30, 2013
Female
Ch17 GSM High | 360.2 to 368.2 | 6.00 | 5.98 | | 0.29/0.07 | | 3.849 | | 8.198 | 55323/55323 | 1.000
Ch16 GSM Med | 361.2 to 371.8 | 3.00 | 3.00 | | 0.28/0.07 | | 1.907 | | 3.925 | 55323/55323 | 1.000
Ch20 GSM Low | 366.5 to 375.8 | 1.50 | 1.50 | | 0.22/0.05 | | 1.085 | | 2.056 | 55323/55323 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55323/55323 | 1.000
Male
Ch06 GSM High | 615.0 to 625.1 | 6.00 | 5.94 | | 0.33/0.08 | | 4.105 | | 8.973 | 55332/55332 | 1.000
Ch05 GSM Med | 628.2 to 635.6 | 3.00 | 2.99 | | 0.30/0.07 | | 1.778 | | 3.941 | 55331/55332 | 1.000
Ch09 GSM Low | 642.8 to 648.2 | 1.50 | 1.48 | | 0.24/0.06 | | 1.105 | | 2.003 | 55329/55329 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55332/55332 | 1.000
December 1 to 31, 2013
Female
Ch17 GSM High | 368.2 to 376.2 | 6.00 | 6.00 | | 0.30/0.07 | | 4.541 | | 8.484 | 53099/53099 | 1.000
Ch16 GSM Med | 371.8 to 380.7 | 3.00 | 2.99 | | 0.27/0.06 | | 2.251 | | 3.819 | 53099/53099 | 1.000
Ch20 GSM Low | 375.8 to 383.8 | 1.50 | 1.49 | | 0.21/0.05 | | 1.251 | | 1.897 | 53057/53057 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53099/53099 | 1.000
Male
Ch06 GSM High | 625.1 to 631.2 | 6.00 | 5.93 | | 0.33/0.08 | | 4.449 | | 7.962 | 53111/53111 | 1.000
Ch05 GSM Med | 635.6 to 641.1 | 3.00 | 2.98 | | 0.32/0.08 | | 2.021 | | 3.936 | 53111/53111 | 1.000
Ch09 GSM Low | 648.2 to 653.2 | 1.50 | 1.49 | | 0.22/0.05 | | 1.207 | | 1.908 | 53099/53099 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53111/53111 | 1.000
January 1 to 31, 2014
Female
Ch17 GSM High | 376.2 to 390.8 | 6.00 | 5.98 | | 0.30/0.07 | | 4.226 | | 8.481 | 55626/55626 | 1.000
Ch16 GSM Med | 380.7 to 392.7 | 3.00 | 2.97 | | 0.26/0.06 | | 1.924 | | 3.798 | 55626/55626 | 1.000
Ch20 GSM Low | 383.8 to 394.6 | 1.50 | 1.48 | | 0.21/0.05 | | 1.081 | | 2.172 | 55621/55621 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55626/55626 | 1.000
Male
Ch06 GSM High | 631.2 to 641.5 | 6.00 | 5.90 | | 0.33/0.08 | | 4.292 | | 8.752 | 55629/55629 | 1.000
Ch05 GSM Med | 641.1 to 651.7 | 3.00 | 2.99 | | 0.33/0.08 | | 2.235 | | 4.217 | 55629/55629 | 1.000
Ch09 GSM Low | 653.2 to 662.0 | 1.50 | 1.49 | | 0.23/0.05 | | 1.181 | | 1.899 | 55627/55627 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55629/55629 | 1.000
February 1 to 28, 2014
Female
Ch17 GSM High | 390.8 to 401.7 | 6.00 | 5.96 | | 0.30/0.07 | | 4.639 | | 8.584 | 51974/51974 | 1.000
Ch16 GSM Med | 392.7 to 399.4 | 3.00 | 2.98 | | 0.26/0.06 | | 2.235 | | 3.989 | 51974/51974 | 1.000
Ch20 GSM Low | 394.6 to 410.5 | 1.50 | 1.50 | | 0.20/0.05 | | 1.226 | | 1.894 | 51974/51974 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 51974/51974 | 1.000
Male
Ch06 GSM High | 641.5 to 650.2 | 6.00 | 5.92 | | 0.33/0.08 | | 4.376 | | 8.314 | 51980/51980 | 1.000
Ch05 GSM Med | 651.7 to 668.4 | 3.00 | 2.97 | | 0.31/0.07 | | 2.183 | | 4.076 | 51980/51980 | 1.000
Ch09 GSM Low | 662.0 to 676.6 | 1.50 | 1.49 | | 0.23/0.05 | | 1.192 | | 1.888 | 51974/51974 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 51980/51980 | 1.000
March 1 to 31, 2014
Female
Ch17 GSM High | 401.7 to 410.4 | 6.00 | 6.01 | | 0.30/0.07 | | 3.728 | | 8.431 | 55703/55704 | 1.000
Ch16 GSM Med | 399.4 to 408.6 | 3.00 | 2.97 | | 0.28/0.07 | | 1.933 | | 3.849 | 55704/55704 | 1.000
Ch20 GSM Low | 410.5 to 420.7 | 1.50 | 1.49 | | 0.21/0.05 | | 0.992 | | 2.005 | 55704/55704 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55704/55704 | 1.000
Male
Ch06 GSM High | 650.2 to 658.2 | 6.00 | 5.92 | | 0.34/0.08 | | 4.216 | | 9.271 | 55704/55704 | 1.000
Ch05 GSM Med | 668.4 to 679.5 | 3.00 | 2.95 | | 0.33/0.08 | | 2.187 | | 4.010 | 55704/55704 | 1.000
Ch09 GSM Low | 676.6 to 688.8 | 1.50 | 1.50 | | 0.23/0.05 | | 1.190 | | 1.982 | 55704/55704 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55704/55704 | 1.000
April 1 to 30, 2014
Female
Ch17 GSM High | 410.4 to 422.9 | 6.00 | 5.98 | | 0.34/0.08 | | 3.545 | | 8.198 | 53640/53644 | 1.000
Ch16 GSM Med | 408.6 to 418.1 | 3.00 | 2.99 | | 0.30/0.07 | | 1.875 | | 3.870 | 53643/53644 | 1.000
Ch20 GSM Low | 420.7 to 431.1 | 1.50 | 1.48 | | 0.21/0.05 | | 1.096 | | 1.840 | 53643/53643 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53644/53644 | 1.000
Male
Ch06 GSM High | 658.2 to 662.2 | 6.00 | 5.83 | | 0.34/0.08 | | 0.734 | | 8.341 | 53646/53649 | 1.000
Ch05 GSM Med | 676.3 to 679.5 | 3.00 | 2.97 | | 0.32/0.08 | | 2.265 | | 4.191 | 53649/53649 | 1.000
Ch09 GSM Low | 687.5 to 688.8 | 1.50 | 1.51 | | 0.24/0.06 | | 1.181 | | 1.930 | 53645/53645 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53649/53649 | 1.000
May 1 to 31, 2014
Female
Ch17 GSM High | 422.9 to 435.5 | 6.00 | 5.96 | | 0.32/0.08 | | 3.891 | | 8.517 | 55604/55604 | 1.000
Ch16 GSM Med | 418.1 to 429.3 | 3.00 | 2.99 | | 0.27/0.06 | | 2.189 | | 4.205 | 55604/55604 | 1.000
Ch20 GSM Low | 431.1 to 437.8 | 1.50 | 1.48 | | 0.21/0.05 | | 1.086 | | 1.993 | 55602/55602 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55604/55604 | 1.000
Male
Ch06 GSM High | 662.2 to 667.4 | 6.00 | 5.88 | | 0.32/0.08 | | 4.364 | | 8.818 | 55604/55604 | 1.000
Ch05 GSM Med | 676.3 to 679.2 | 3.00 | 2.83 | | 0.32/0.08 | | 2.015 | | 4.391 | 55604/55604 | 1.000
Ch09 GSM Low | 687.5 to 691.2 | 1.50 | 1.50 | | 0.25/0.06 | | 1.195 | | 1.976 | 55604/55604 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55604/55604 | 1.000
June 1 to 30, 2014
Female
Ch17 GSM High | 435.5 to 453.7 | 6.00 | 5.98 | | 0.32/0.08 | | 4.053 | | 8.457 | 53771/53771 | 1.000
Ch16 GSM Med | 429.3 to 440.7 | 3.00 | 2.98 | | 0.28/0.07 | | 1.449 | | 3.889 | 53767/53771 | 1.000
Ch20 GSM Low | 437.8 to 452.4 | 1.50 | 1.49 | | 0.22/0.05 | | 0.702 | | 2.034 | 53763/53767 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53771/53771 | 1.000
Male
Ch06 GSM High | 667.3 to 670.7 | 6.00 | 5.91 | | 0.33/0.08 | | 3.215 | | 9.767 | 53769/53773 | 1.000
Ch05 GSM Med | 670.5 to 679.2 | 3.00 | 2.89 | | 0.35/0.08 | | 0.391 | | 4.215 | 53750/53774 | 1.000
Ch09 GSM Low | 672.8 to 691.2 | 1.50 | 1.51 | | 0.25/0.06 | | 0.292 | | 1.988 | 53767/53773 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 53774/53774 | 1.000
July 1 to 31, 2014
Female
Ch17 GSM High | 458.1 to 465.3 | 6.00 | 5.96 | | 0.32/0.08 | | 3.511 | | 8.111 | 55599/55601 | 1.000
Ch16 GSM Med | 443.4 to 447.0 | 3.00 | 2.98 | | 0.28/0.07 | | 1.763 | | 4.162 | 55600/55601 | 1.000
Ch20 GSM Low | 451.7 to 467.3 | 1.50 | 1.49 | | 0.21/0.05 | | 0.990 | | 1.973 | 55601/55601 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55601/55601 | 1.000
Male
Ch06 GSM High | 667.3 to 670.3 | 6.00 | 5.87 | | 0.32/0.08 | | 3.459 | | 8.639 | 55602/55603 | 1.000
Ch05 GSM Med | 659.4 to 670.5 | 3.00 | 2.96 | | 0.32/0.08 | | 1.787 | | 4.205 | 55602/55603 | 1.000
Ch09 GSM Low | 659.5 to 672.8 | 1.50 | 1.50 | | 0.24/0.06 | | 0.990 | | 1.960 | 55601/55601 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | | –/0.00 | | 0.000 | | 0.000 | 55603/55603 | 1.000
August 1 to 31, 2014
Female
Ch17 GSM High | 464.7 to 473.8 | 6.00 | 5.92 | 0.30/0.07 | | 3.387 | | 8.139 | | 54345/54354 | | 1.000
Ch16 GSM Med | 447.0 to 453.0 | 3.00 | 2.98 | 0.27/0.07 | | 1.868 | | 4.001 | | 54353/54354 | | 1.000
Ch20 GSM Low | 461.2 to 475.4 | 1.50 | 1.49 | 0.21/0.05 | | 1.112 | | 1.875 | | 54354/54354 | | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | | 0.000 | | 54354/54354 | | 1.000
Male
Ch06 GSM High | 655.0 to 670.3 | 6.00 | 5.90 | 0.32/0.08 | | 4.391 | | 8.661 | | 54358/54358 | | 1.000
Ch05 GSM Med | 638.8 to 659.4 | 3.00 | 2.98 | 0.30/0.07 | | 2.247 | | 4.095 | | 54358/54358 | | 1.000
Ch09 GSM Low | 653.6 to 660.1 | 1.50 | 1.49 | 0.22/0.05 | | 1.171 | | 1.819 | | 54354/54354 | | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | | 0.000 | | 54358/54358 | | 1.000
September 1 to 30, 2014
Female
Ch17 GSM High | 471.2 to 475.1 | 6.00 | 5.94 | 0.30/0.07 | | 2.537 | | 11.960 | | 52084/52088 | | 1.000
Ch16 GSM Med | 453.0 to 471.6 | 3.00 | 2.98 | 0.26/0.06 | | 1.802 | | 5.349 | | 52085/52088 | | 1.000
Ch20 GSM Low | 461.2 to 476.1 | 1.50 | 1.48 | 0.20/0.05 | | 1.070 | | 2.533 | | 52086/52088 | | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | | 0.000 | | 52088/52088 | | 1.000
Male
Ch06 GSM High | 650.2 to 655.0 | 6.00 | 5.95 | 0.30/0.07 | | 2.313 | | 11.724 | | 52074/52088 | | 1.000
Ch05 GSM Med | 636.4 to 638.8 | 3.00 | 2.98 | 0.25/0.06 | | 2.239 | | 4.851 | | 52087/52088 | | 1.000
Ch09 GSM Low | 644.0 to 653.6 | 1.50 | 1.48 | 0.22/0.05 | | 0.916 | | 2.468 | | 52085/52088 | | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | | 0.000 | | 52088/52088 | | 1.000
August 8, 2012 to September 30, 2014
Female
Ch17 GSM High | 58.0 to 475.1 | 6.00 | 5.97 | 0.30/0.07 | | 2.537 | | 11.960 | | 1400145/1400254 | | 1.000
Ch16 GSM Med | 58.7 to 471.6 | 3.00 | 2.98 | 0.27/0.06 | | 1.449 | | 5.394 | | 1400178/1400255 | | 1.000
Ch20 GSM Low | 59.4 to 476.1 | 1.50 | 1.49 | 0.22/0.05 | | 0.702 | | 3.032 | | 1400140/1400194 | | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | | 0.000 | | 1400255/1400255 | | 1.000
Male
Ch06 GSM High | 60.9 to 670.7 | 6.00 | 5.93 | 0.33/0.08 | | 0.734 | | 25.815 | | 1400345/1400419 | | 1.000
Ch05 GSM Med | 62.0 to 679.5 | 3.00 | 2.97 | 0.30/0.07 | | 0.391 | | 10.693 | | 1400356/1400421 | | 1.000
Ch09 GSM Low | 63.9 to 691.2 | 1.50 | 1.49 | 0.25/0.06 | | 0.292 | | 5.732 | | 1400229/1400291 | | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | | 0.000 | | 1400422/1400422 | | 1.000

Ch = chamber (e.g., Ch17 = Chamber 17).

Table I‑2 Summary of GSM-modulated Cell Phone RFR Exposure Data in Rats – Chamber Field

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | | Max [V/m] | In Range/Total | Ratio
August 8 to 31, 2012
Male
Ch06 GSM High | 246.10 to 283.80 | 261.74 | 0.30/9.31 | 163.93 | | 357.66 | 85760/85786 | 1.000
Ch05 GSM Med | 174.00 to 200.70 | 185.30 | 0.25/5.39 | 119.06 | | 238.06 | 85780/85786 | 1.000
Ch09 GSM Low | 123.10 to 141.90 | 131.09 | 0.23/3.52 | 82.96 | | 172.00 | 85780/85786 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 85786/85786 | 1.000
September 1 -30, 2012
Female
Ch17 GSM High | 192.60 to 269.00 | 237.79 | 0.30/8.24 | 153.47 | | 362.88 | 105858/105918 | 0.999
Ch16 GSM Med | 136.20 to 190.20 | 167.23 | 0.26/5.13 | 105.81 | | 241.99 | 105906/105918 | 1.000
Ch20 GSM Low | 096.10 to 134.50 | 118.05 | 0.27/3.74 | 75.08 | | 175.15 | 105876/105918 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 105918/105918 | 1.000
Male
Ch06 GSM High | 192.60 to 266.50 | 232.35 | 0.32/8.68 | 106.40 | | 443.91 | 105868/105918 | 1.000
Ch05 GSM Med | 136.20 to 190.20 | 164.81 | 0.30/5.71 | 103.62 | | 285.70 | 105858/105918 | 0.999
Ch09 GSM Low | 096.30 to 134.50 | 116.84 | 0.29/3.90 | 75.03 | | 209.17 | 105848/105918 | 0.999
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 105918/105918 | 1.000
October 1 to 31, 2012
Female
Ch17 GSM High | 193.80 to 232.80 | 214.26 | 0.28/6.95 | 164.06 | | 288.93 | 110674/110678 | 1.000
Ch16 GSM Med | 137.00 to 164.60 | 151.43 | 0.25/4.49 | 112.41 | | 203.02 | 110676/110678 | 1.000
Ch20 GSM Low | 098.50 to 116.40 | 108.14 | 0.25/3.20 | 79.98 | | 143.57 | 110662/110670 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 110678/110678 | 1.000
Male
Ch06 GSM High | 201.30 to 269.00 | 238.81 | 0.30/8.48 | 160.53 | | 326.54 | 110698/110702 | 1.000
Ch05 GSM Med | 142.40 to 192.20 | 170.55 | 0.26/5.18 | 127.50 | | 224.85 | 110702/110702 | 1.000
Ch09 GSM Low | 103.10 to 135.90 | 121.57 | 0.24/3.47 | 89.23 | | 153.28 | 110678/110678 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 110702/110702 | 1.000
November 1 to 30, 2012
Female
Ch17 GSM High | 232.80 to 250.70 | 242.22 | 0.27/7.66 | 200.64 | | 298.50 | 107706/107706 | 1.000
Ch16 GSM Med | 164.60 to 177.30 | 171.90 | 0.24/4.71 | 147.26 | | 201.43 | 107706/107706 | 1.000
Ch20 GSM Low | 118.50 to 125.40 | 122.10 | 0.24/3.47 | 99.98 | | 161.64 | 107684/107706 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 107706/107706 | 1.000
Male
Ch06 GSM High | 271.80 to 292.20 | 282.73 | 0.30/9.97 | 238.55 | | 347.86 | 107706/107706 | 1.000
Ch05 GSM Med | 194.20 to 208.20 | 201.89 | 0.27/6.40 | 176.39 | | 237.97 | 107706/107706 | 1.000
Ch09 GSM Low | 137.40 to 148.20 | 143.02 | 0.22/3.68 | 123.60 | | 164.44 | 107706/107706 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 107706/107706 | 1.000
December 1 to 31, 2012
Female
Ch17 GSM High | 250.70 to 254.90 | 253.13 | 0.28/8.43 | 202.44 | | 310.55 | 111214/111216 | 1.000
Ch16 GSM Med | 177.30 to 180.20 | 179.20 | 0.24/4.96 | 155.02 | | 209.16 | 111216/111216 | 1.000
Ch20 GSM Low | 125.40 to 129.20 | 127.62 | 0.21/3.08 | 112.48 | | 149.98 | 111216/111216 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 111216/111216 | 1.000
Male
Ch06 GSM High | 292.20 to 298.00 | 295.52 | 0.31/10.70 | 248.48 | | 353.56 | 111216/111216 | 1.000
Ch05 GSM Med | 208.20 to 211.70 | 210.50 | 0.28/6.92 | 177.40 | | 240.12 | 111216/111216 | 1.000
Ch09 GSM Low | 148.20 to 150.20 | 148.91 | 0.24/4.13 | 129.81 | | 170.40 | 111216/111216 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 111216/111216 | 1.000
January 1 to 31, 2013
Female
Ch17 GSM High | 254.90 to 261.40 | 257.58 | 0.28/8.39 | 220.72 | | 312.88 | 111236/111236 | 1.000
Ch16 GSM Med | 180.20 to 184.80 | 182.39 | 0.24/5.03 | 157.70 | | 211.28 | 111238/111238 | 1.000
Ch20 GSM Low | 129.20 to 130.70 | 129.57 | 0.21/3.21 | 114.20 | | 153.83 | 111234/111234 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 111238/111238 | 1.000
Male
Ch06 GSM High | 298.00 to 302.10 | 298.69 | 0.33/11.42 | 250.82 | | 361.83 | 111238/111238 | 1.000
Ch05 GSM Med | 211.70 to 214.00 | 212.38 | 0.28/6.89 | 182.92 | | 247.58 | 111238/111238 | 1.000
Ch09 GSM Low | 150.20 to 151.40 | 150.50 | 0.26/4.49 | 132.92 | | 190.45 | 111236/111238 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 111238/111238 | 1.000
February 1 to 28, 2013
Female
Ch17 GSM High | 261.40 to 264.00 | 261.98 | 0.27/8.15 | 228.00 | | 307.30 | 100164/100164 | 1.000
Ch16 GSM Med | 184.80 to 186.70 | 185.40 | 0.25/5.38 | 164.18 | | 212.70 | 100164/100164 | 1.000
Ch20 GSM Low | 130.70 to 132.00 | 131.16 | 0.20/3.13 | 117.78 | | 150.45 | 100164/100164 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 100164/100164 | 1.000
Male
Ch06 GSM High | 302.10 to 304.00 | 302.15 | 0.33/11.82 | 256.65 | | 357.92 | 100164/100164 | 1.000
Ch05 GSM Med | 214.00 to 215.50 | 214.86 | 0.28/7.04 | 190.61 | | 244.53 | 100164/100164 | 1.000
Ch09 GSM Low | 151.40 to 152.40 | 151.39 | 0.24/4.22 | 132.24 | | 172.35 | 100164/100164 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 100164/100164 | 1.000
March 1 to 31, 2013
Female
Ch17 GSM High | 264.00 to 266.50 | 264.63 | 0.27/8.42 | 231.60 | | 307.67 | 111408/111408 | 1.000
Ch16 GSM Med | 186.70 to 188.40 | 187.36 | 0.25/5.58 | 160.59 | | 215.77 | 111408/111408 | 1.000
Ch20 GSM Low | 132.00 to 133.20 | 132.42 | 0.21/3.18 | 119.43 | | 152.94 | 111408/111408 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 111408/111408 | 1.000
Male
Ch06 GSM High | 304.00 to 305.60 | 303.27 | 0.35/12.40 | 258.25 | | 370.03 | 111408/111408 | 1.000
Ch05 GSM Med | 215.50 to 216.80 | 216.06 | 0.28/7.06 | 190.20 | | 250.00 | 111408/111408 | 1.000
Ch09 GSM Low | 152.40 to 153.30 | 152.35 | 0.24/4.31 | 133.03 | | 178.38 | 111408/111408 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | | 0.00 | 111408/111408 | 1.000
April 1 to 30, 2013
Female
Ch17 GSM High | 266.50 to 269.00 | 267.57 | 0.28/8.86 | | 235.78 | 314.88 | 107438/107438 | 1.000
Ch16 GSM Med | 188.40 to 190.20 | 189.34 | 0.26/5.68 | | 164.80 | 217.69 | 107438/107438 | 1.000
Ch20 GSM Low | 133.20 to 134.50 | 133.66 | 0.21/3.22 | | 120.28 | 157.64 | 107438/107438 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107438/107438 | 1.000
Male
Ch06 GSM High | 305.60 to 307.60 | 305.35 | 0.34/12.25 | | 263.80 | 362.58 | 107442/107442 | 1.000
Ch05 GSM Med | 216.80 to 218.30 | 217.81 | 0.29/7.44 | | 191.48 | 252.37 | 107442/107442 | 1.000
Ch09 GSM Low | 153.30 to 154.40 | 153.44 | 0.25/4.47 | | 137.33 | 173.95 | 107438/107438 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107444/107444 | 1.000
May 1 to 31, 2013
Female
Ch17 GSM High | 269.00 to 271.80 | 269.81 | 0.30/9.50 | | 206.91 | 323.99 | 105516/105524 | 1.000
Ch16 GSM Med | 190.20 to 190.20 | 189.49 | 0.27/5.91 | | 142.11 | 219.08 | 105520/105524 | 1.000
Ch20 GSM Low | 134.50 to 135.90 | 135.04 | 0.23/3.57 | | 100.46 | 155.42 | 105518/105524 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 105524/105524 | 1.000
Male
Ch06 GSM High | 307.60 to 308.80 | 307.28 | 0.36/12.95 | | 230.79 | 374.97 | 105576/105578 | 1.000
Ch05 GSM Med | 218.30 to 220.10 | 219.52 | 0.29/7.56 | | 135.92 | 251.57 | 105576/105580 | 1.000
Ch09 GSM Low | 154.40 to 155.60 | 154.43 | 0.31/5.53 | | 117.02 | 191.30 | 105556/105576 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 105580/105580 | 1.000
June 1 to 30, 2013
Female
Ch17 GSM High | 271.80 to 274.70 | 273.16 | 0.31/9.87 | | 215.41 | 319.42 | 107072/107074 | 1.000
Ch16 GSM Med | 190.20 to 192.20 | 191.37 | 0.27/6.01 | | 159.04 | 220.20 | 107074/107074 | 1.000
Ch20 GSM Low | 135.90 to 137.40 | 136.69 | 0.22/3.56 | | 115.55 | 154.63 | 107074/107074 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107074/107074 | 1.000
Male
Ch06 GSM High | 308.80 to 311.30 | 308.73 | 0.36/12.96 | | 246.21 | 375.54 | 107086/107088 | 1.000
Ch05 GSM Med | 220.10 to 221.00 | 220.30 | 0.29/7.53 | | 188.37 | 256.20 | 107088/107088 | 1.000
Ch09 GSM Low | 155.60 to 157.00 | 156.15 | 0.26/4.68 | | 134.23 | 178.92 | 107074/107074 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107088/107088 | 1.000
July 1 to 31, 2013
Female
Ch17 GSM High | 274.70 to 277.70 | 273.91 | 0.29/9.29 | | 239.88 | 317.27 | 111054/111054 | 1.000
Ch16 GSM Med | 192.20 to 196.40 | 193.72 | 0.25/5.73 | | 172.83 | 217.88 | 111054/111054 | 1.000
Ch20 GSM Low | 137.40 to 140.40 | 138.40 | 0.21/3.44 | | 123.31 | 156.56 | 111054/111054 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111054/111054 | 1.000
Male
Ch06 GSM High | 311.30 to 315.30 | 311.45 | 0.36/13.11 | | 264.23 | 378.17 | 111062/111062 | 1.000
Ch05 GSM Med | 221.00 to 223.90 | 222.10 | 0.30/7.70 | | 193.61 | 259.58 | 111062/111062 | 1.000
Ch09 GSM Low | 157.00 to 159.00 | 157.04 | 0.27/5.00 | | 136.56 | 186.11 | 111054/111054 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111062/111062 | 1.000
August 1 to 31, 2013
Female
Ch17 GSM High | 277.70 to 280.80 | 277.49 | 0.29/9.56 | | 236.42 | 318.87 | 111904/111904 | 1.000
Ch16 GSM Med | 196.40 to 198.50 | 196.28 | 0.26/5.94 | | 171.49 | 226.49 | 111904/111904 | 1.000
Ch20 GSM Low | 140.40 to 140.40 | 139.96 | 0.21/3.34 | | 125.38 | 156.35 | 111904/111904 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111904/111904 | 1.000
Male
Ch06 GSM High | 315.30 to 316.70 | 312.96 | 0.35/12.91 | | 252.28 | 374.25 | 111910/111910 | 1.000
Ch05 GSM Med | 223.90 to 224.90 | 222.92 | 0.29/7.53 | | 197.54 | 253.53 | 111910/111910 | 1.000
Ch09 GSM Low | 159.00 to 159.70 | 158.28 | 0.25/4.71 | | 140.65 | 182.22 | 111904/111904 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111910/111910 | 1.000
September 1 to 30, 2013
Female
Ch17 GSM High | 280.80 to 280.80 | 279.69 | 0.29/9.35 | | 223.60 | 325.76 | 107392/107392 | 1.000
Ch16 GSM Med | 198.50 to 200.70 | 198.49 | 0.29/6.69 | | 154.85 | 229.99 | 107388/107392 | 1.000
Ch20 GSM Low | 140.40 to 141.90 | 140.30 | 0.22/3.60 | | 118.81 | 160.92 | 107392/107392 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107392/107392 | 1.000
Male
Ch06 GSM High | 316.70 to 318.10 | 314.99 | 0.35/12.78 | | 265.80 | 370.62 | 107406/107406 | 1.000
Ch05 GSM Med | 224.90 to 225.90 | 224.37 | 0.30/8.01 | | 181.13 | 261.80 | 107406/107406 | 1.000
Ch09 GSM Low | 159.70 to 161.00 | 159.38 | 0.26/4.76 | | 132.09 | 182.21 | 107392/107392 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107406/107406 | 1.000
October 1 to 31, 2013
Female
Ch17 GSM High | 280.80 to 286.80 | 281.83 | 0.37/12.27 | | 215.71 | 356.81 | 113434/113496 | 0.999
Ch16 GSM Med | 200.70 to 202.80 | 200.67 | 0.37/8.80 | | 144.28 | 241.44 | 113388/113496 | 0.999
Ch20 GSM Low | 141.90 to 143.40 | 141.96 | 0.27/4.41 | | 112.11 | 161.75 | 113490/113494 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 113496/113496 | 1.000
Male
Ch06 GSM High | 318.10 to 319.40 | 316.70 | 0.40/14.75 | | 20.95 | 379.83 | 113600/113614 | 1.000
Ch05 GSM Med | 225.90 to 226.80 | 226.15 | 0.34/9.08 | | 188.65 | 268.19 | 113614/113614 | 1.000
Ch09 GSM Low | 161.00 to 161.70 | 160.60 | 0.27/5.14 | | 134.24 | 194.14 | 113496/113496 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 113614/113614 | 1.000
November 1 to 30, 2013
Female
Ch17 GSM High | 286.80 to 286.80 | 286.14 | 0.29/9.81 | | 229.63 | 335.12 | 110646/110646 | 1.000
Ch16 GSM Med | 202.80 to 204.80 | 203.21 | 0.28/6.65 | | 161.63 | 233.48 | 110646/110646 | 1.000
Ch20 GSM Low | 143.40 to 144.80 | 143.51 | 0.22/3.73 | | 122.76 | 168.98 | 110646/110646 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 110646/110646 | 1.000
Male
Ch06 GSM High | 319.40 to 320.80 | 318.24 | 0.33/12.45 | | 263.77 | 389.98 | 110664/110664 | 1.000
Ch05 GSM Med | 226.80 to 227.70 | 226.96 | 0.30/8.01 | | 175.08 | 260.66 | 110662/110664 | 1.000
Ch09 GSM Low | 161.70 to 161.70 | 161.02 | 0.25/4.62 | | 139.23 | 187.46 | 110658/110658 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 110664/110664 | 1.000
December 1 to 31, 2013
Female
Ch17 GSM High | 286.80 to 289.60 | 287.63 | 0.30/10.26 | | 251.13 | 340.91 | 106198/106198 | 1.000
Ch16 GSM Med | 204.80 to 206.70 | 205.25 | 0.27/6.51 | | 176.82 | 231.75 | 106198/106198 | 1.000
Ch20 GSM Low | 144.80 to 146.10 | 144.94 | 0.21/3.57 | | 132.18 | 162.32 | 106114/106114 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 106198/106198 | 1.000
Male
Ch06 GSM High | 320.80 to 322.10 | 319.56 | 0.33/12.50 | | 276.96 | 370.51 | 106222/106222 | 1.000
Ch05 GSM Med | 227.70 to 228.70 | 227.45 | 0.32/8.64 | | 186.67 | 262.62 | 106222/106222 | 1.000
Ch09 GSM Low | 161.70 to 162.40 | 161.63 | 0.22/4.24 | | 145.51 | 182.95 | 106198/106198 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 106222/106222 | 1.000
January 1 to 31, 2014
Female
Ch17 GSM High | 289.60 to 294.50 | 291.48 | 0.31/10.54 | | 247.48 | 345.55 | 111252/111252 | 1.000
Ch16 GSM Med | 206.70 to 208.20 | 206.91 | 0.27/6.43 | | 166.99 | 234.62 | 111252/111252 | 1.000
Ch20 GSM Low | 146.10 to 147.30 | 146.17 | 0.22/3.73 | | 125.15 | 177.44 | 111242/111242 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111252/111252 | 1.000
Male
Ch06 GSM High | 322.10 to 323.40 | 320.41 | 0.34/12.88 | | 272.03 | 391.85 | 111258/111258 | 1.000
Ch05 GSM Med | 228.70 to 229.60 | 228.70 | 0.33/8.88 | | 198.03 | 272.01 | 111258/111258 | 1.000
Ch09 GSM Low | 162.40 to 163.00 | 162.49 | 0.23/4.34 | | 143.93 | 184.14 | 111254/111254 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111258/111258 | 1.000
February 1 to 28, 2014
Female
Ch17 GSM High | 294.50 to 296.40 | 295.29 | 0.30/10.52 | | 260.64 | 355.30 | 103948/103948 | 1.000
Ch16 GSM Med | 208.20 to 208.20 | 207.59 | 0.27/6.51 | | 179.98 | 240.45 | 103948/103948 | 1.000
Ch20 GSM Low | 147.30 to 149.00 | 148.04 | 0.20/3.53 | | 133.39 | 166.89 | 103948/103948 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 103948/103948 | 1.000
Male
Ch06 GSM High | 323.40 to 324.80 | 322.09 | 0.33/12.65 | | 277.08 | 381.92 | 103960/103960 | 1.000
Ch05 GSM Med | 229.60 to 230.60 | 229.42 | 0.32/8.48 | | 197.45 | 269.79 | 103960/103960 | 1.000
Ch09 GSM Low | 163.00 to 163.70 | 163.19 | 0.23/4.39 | | 145.88 | 183.61 | 103948/103948 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 103960/103960 | 1.000
March 1 to 31, 2014
Female
Ch17 GSM High | 296.40 to 298.00 | 297.00 | 0.31/10.72 | | 234.16 | 352.11 | 111404/111408 | 1.000
Ch16 GSM Med | 208.20 to 209.60 | 208.52 | 0.28/6.90 | | 168.58 | 237.91 | 111408/111408 | 1.000
Ch20 GSM Low | 149.00 to 149.70 | 148.83 | 0.21/3.69 | | 121.71 | 172.98 | 111408/111408 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111408/111408 | 1.000
Male
Ch06 GSM High | 324.80 to 324.80 | 321.89 | 0.35/13.20 | | 271.97 | 403.29 | 111408/111408 | 1.000
Ch05 GSM Med | 230.60 to 231.50 | 229.35 | 0.33/8.95 | | 197.64 | 267.59 | 111408/111408 | 1.000
Ch09 GSM Low | 163.70 to 164.40 | 163.82 | 0.23/4.36 | | 145.79 | 188.13 | 111408/111408 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111408/111408 | 1.000
April 1 to 30, 2014
Female
Ch17 GSM High | 298.00 to 299.30 | 298.09 | 0.34/12.08 | | 230.03 | 349.80 | 107280/107288 | 1.000
Ch16 GSM Med | 209.60 to 210.70 | 209.72 | 0.31/7.56 | | 166.05 | 238.56 | 107286/107288 | 1.000
Ch20 GSM Low | 149.70 to 150.20 | 149.58 | 0.22/3.77 | | 128.89 | 166.30 | 107286/107286 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107288/107288 | 1.000
Male
Ch06 GSM High | 324.80 to 326.10 | 321.85 | 0.35/13.36 | | 114.48 | 385.94 | 107292/107298 | 1.000
Ch05 GSM Med | 231.50 to 231.50 | 229.97 | 0.33/8.93 | | 201.12 | 273.57 | 107298/107298 | 1.000
Ch09 GSM Low | 164.40 to 164.40 | 164.03 | 0.24/4.54 | | 145.21 | 185.62 | 107290/107290 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107298/107298 | 1.000
May 1 to 31, 2014
Female
Ch17 GSM High | 299.30 to 300.40 | 300.03 | 0.33/11.60 | | 242.81 | 359.23 | 111208/111208 | 1.000
Ch16 GSM Med | 210.70 to 211.70 | 211.00 | 0.27/6.71 | | 180.74 | 250.53 | 111208/111208 | 1.000
Ch20 GSM Low | 150.20 to 150.20 | 149.77 | 0.22/3.81 | | 128.27 | 173.78 | 111204/111204 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111208/111208 | 1.000
Male
Ch06 GSM High | 326.10 to 326.10 | 323.75 | 0.32/12.29 | | 279.16 | 396.81 | 111208/111208 | 1.000
Ch05 GSM Med | 231.50 to 231.50 | 224.46 | 0.33/8.72 | | 189.71 | 280.03 | 111208/111208 | 1.000
Ch09 GSM Low | 164.40 to 165.10 | 164.89 | 0.25/4.91 | | 147.41 | 189.52 | 111208/111208 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111208/111208 | 1.000
June 1 to 30, 2014
Female
Ch17 GSM High | 300.40 to 302.10 | 300.88 | 0.33/11.52 | | 247.80 | 357.96 | 107542/107542 | 1.000
Ch16 GSM Med | 211.70 to 213.10 | 212.09 | 0.29/7.21 | | 147.07 | 242.76 | 107534/107542 | 1.000
Ch20 GSM Low | 150.20 to 151.00 | 150.43 | 0.22/3.91 | | 103.10 | 175.53 | 107526/107534 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107542/107542 | 1.000
Male
Ch06 GSM High | 326.10 to 327.40 | 324.69 | 0.34/12.95 | | 239.60 | 417.63 | 107538/107546 | 1.000
Ch05 GSM Med | 231.50 to 231.50 | 226.88 | 0.37/9.99 | | 83.52 | 274.36 | 107500/107548 | 1.000
Ch09 GSM Low | 163.70 to 165.10 | 164.18 | 0.26/4.92 | | 72.17 | 190.10 | 107534/107546 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 107548/107548 | 1.000
July 1 to 31, 2014
Female
Ch17 GSM High | 302.10 to 302.70 | 301.45 | 0.33/11.55 | | 230.64 | 352.78 | 111198/111202 | 1.000
Ch16 GSM Med | 213.10 to 213.10 | 212.21 | 0.28/7.05 | | 163.42 | 251.13 | 111200/111202 | 1.000
Ch20 GSM Low | 151.00 to 151.40 | 150.88 | 0.21/3.77 | | 122.47 | 172.90 | 111202/111202 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111202/111202 | 1.000
Male
Ch06 GSM High | 326.10 to 327.40 | 323.48 | 0.33/12.46 | | 248.53 | 392.76 | 111204/111206 | 1.000
Ch05 GSM Med | 229.60 to 231.50 | 229.53 | 0.33/8.75 | | 178.63 | 274.03 | 111204/111206 | 1.000
Ch09 GSM Low | 162.40 to 163.70 | 163.30 | 0.24/4.55 | | 132.94 | 187.07 | 111202/111202 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 111206/111206 | 1.000
August 1 to 31, 2014
Female
Ch17 GSM High | 302.70 to 303.40 | 301.67 | 0.31/10.80 | | 228.28 | 353.86 | 108690/108708 | 1.000
Ch16 GSM Med | 213.10 to 213.60 | 212.27 | 0.28/6.99 | | 168.24 | 246.20 | 108706/108708 | 1.000
Ch20 GSM Low | 151.40 to 151.70 | 151.14 | 0.21/3.78 | | 130.78 | 169.86 | 108708/108708 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 108708/108708 | 1.000
Male
Ch06 GSM High | 324.80 to 327.40 | 323.73 | 0.33/12.36 | | 280.03 | 389.80 | 108716/108716 | 1.000
Ch05 GSM Med | 227.70 to 229.60 | 228.01 | 0.31/8.28 | | 198.54 | 268.03 | 108716/108716 | 1.000
Ch09 GSM Low | 162.40 to 163.00 | 162.22 | 0.22/4.20 | | 144.61 | 179.04 | 108708/108708 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 108716/108716 | 1.000
September 1 to 30, 2014
Female
Ch17 GSM High | 303.40 to 303.40 | 302.18 | 0.30/10.67 | | 197.54 | 428.95 | 104168/104176 | 1.000
Ch16 GSM Med | 213.60 to 214.50 | 212.76 | 0.26/6.52 | | 166.50 | 286.87 | 104170/104176 | 1.000
Ch20 GSM Low | 151.40 to 151.70 | 151.10 | 0.21/3.63 | | 128.30 | 197.41 | 104172/104176 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 104176/104176 | 1.000
Male
Ch06 GSM High | 324.80 to 324.80 | 322.76 | 0.31/11.68 | | 201.44 | 453.53 | 104148/104176 | 1.000
Ch05 GSM Med | 227.70 to 227.70 | 226.73 | 0.25/6.74 | | 196.47 | 289.19 | 104174/104176 | 1.000
Ch09 GSM Low | 161.70 to 162.40 | 161.10 | 0.22/4.12 | | 126.78 | 208.08 | 104170/104176 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 104176/104176 | 1.000
August 8, 2012 to September 30, 2014
Female
Ch17 GSM High | 192.60 to 303.40 | 276.19 | 0.30/9.74 | | 153.47 | 428.95 | 2800286/2800508 | 1.000
Ch16 GSM Med | 136.20 to 214.50 | 195.10 | 0.27/6.17 | | 105.81 | 286.87 | 2800358/2800510 | 1.000
Ch20 GSM Low | 096.10 to 151.70 | 138.52 | 0.22/3.59 | | 75.08 | 197.41 | 2800278/2800388 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 2800510/2800510 | 1.000
Male
Ch06 GSM High | 192.60 to 327.40 | 305.54 | 0.34/12.09 | | 20.95 | 453.53 | 2800696/2800838 | 1.000
Ch05 GSM Med | 136.20 to 231.50 | 217.06 | 0.31/7.84 | | 83.52 | 289.19 | 2800718/2800842 | 1.000
Ch09 GSM Low | 096.30 to 165.10 | 154.30 | 0.25/4.47 | | 72.17 | 209.17 | 2800466/2800582 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | | 0.00 | 0.00 | 2800844/2800844 | 1.000

Ch = chamber (e.g., Ch17 = Chamber 17).

Table I‑3 Summary of GSM-modulated Cell Phone RFR Exposure Data in Rats – E-Field

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | Max [V/m] | In Range/Total | | Ratio
August 8 to 31, 2012
Male
Ch06 GSM High | 246.1 to 283.8 | 246.42 | 0.40/11.69 | 154.4 | 330.2 | 85692/85786 | | 0.999
Ch05 GSM Med | 174.0 to 200.7 | 192.97 | 0.37/8.36 | 124.3 | 252.8 | 85768/85786 | | 1.000
Ch09 GSM Low | 123.1 to 141.9 | 119.12 | 0.32/4.49 | 74.9 | 162.8 | 85742/85786 | | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 85786/85786 | | 1.000
September 1 to 30, 2012
Female
Ch17 GSM High | 192.6 to 269.0 | 231.49 | 0.54/14.83 | 141.4 | 395.5 | 105788/105918 | | 0.999
Ch16 GSM Med | 136.2 to 190.2 | 161.13 | 0.37/7.09 | 101.6 | 244.1 | 105894/105918 | | 1.000
Ch20 GSM Low | 96.1 to 134.5 | 112.92 | 0.39/5.13 | 71.8 | 170.4 | 105878/105918 | | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 105918/105918 | | 1.000
Male
Ch06 GSM High | 192.6 to 266.5 | 221.52 | 0.45/11.71 | 104.2 | 445.8 | 105824/105918 | | 0.999
Ch05 GSM Med | 136.2 to 190.2 | 174.00 | 0.45/9.23 | 110.2 | 323.0 | 105652/105918 | | 0.997
Ch09 GSM Low | 96.3 to 134.5 | 109.88 | 0.38/4.91 | 68.9 | 195.7 | 105852/105918 | | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 105918/105918 | | 1.000
October 1 to 31, 2012
Female
Ch17 GSM High | 193.8 to 232.8 | 193.51 | 0.44/10.00 | 137.3 | 285.2 | 109918/110678 | | 0.993
Ch16 GSM Med | 137.0 to 164.6 | 138.97 | 0.34/5.51 | 108.8 | 184.5 | 110640/110678 | | 1.000
Ch20 GSM Low | 98.5 to 116.4 | 106.63 | 0.36/4.47 | 75.3 | 141.4 | 110658/110670 | | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 110678/110678 | | 1.000
Male
Ch06 GSM High | 201.3 to 269.0 | 222.93 | 0.40/10.56 | 140.8 | 316.8 | 110628/110702 | | 0.999
Ch05 GSM Med | 142.4 to 192.2 | 173.85 | 0.38/7.74 | 128.3 | 226.9 | 110700/110702 | | 1.000
Ch09 GSM Low | 103.1 to 135.9 | 108.94 | 0.30/3.85 | 80.3 | 143.4 | 110474/110678 | | 0.998
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 110702/110702 | | 1.000
November 1 to 30, 2012
Female
Ch17 GSM High | 232.8 to 250.7 | 222.28 | 0.40/10.48 | 178.3 | 284.9 | 107584/107706 | | 0.999
Ch16 GSM Med | 164.6 to 177.3 | 156.73 | 0.35/6.43 | 129.5 | 196.0 | 107652/107706 | | 0.999
Ch20 GSM Low | 118.5 to 125.4 | 116.79 | 0.61/8.50 | 85.0 | 170.5 | 107364/107706 | | 0.997
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107706/107706 | | 1.000
Male
Ch06 GSM High | 271.8 to 292.2 | 263.30 | 0.42/13.17 | 212.1 | 339.0 | 107672/107706 | | 1.000
Ch05 GSM Med | 194.2 to 208.2 | 205.84 | 0.42/10.20 | 164.2 | 257.0 | 107706/107706 | | 1.000
Ch09 GSM Low | 137.4 to 148.2 | 127.09 | 0.31/4.62 | 105.4 | 150.3 | 107422/107706 | | 0.997
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107706/107706 | | 1.000
December 1 to 31, 2012
Female
Ch17 GSM High | 250.7 to 254.9 | 232.81 | 0.41/11.12 | 177.9 | 303.9 | | 110988/111216 | 0.998
Ch16 GSM Med | 177.3 to 180.2 | 165.11 | 0.38/7.41 | 135.9 | 208.6 | | 111180/111216 | 1.000
Ch20 GSM Low | 125.4 to 129.2 | 112.68 | 0.32/4.18 | 94.9 | 136.5 | | 110810/111216 | 0.996
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111216/111216 | 1.000
Male
Ch06 GSM High | 292.2 to 298.0 | 275.64 | 0.45/14.54 | 220.5 | 356.3 | | 111140/111216 | 0.999
Ch05 GSM Med | 208.2 to 211.7 | 219.30 | 0.44/11.41 | 173.0 | 271.3 | | 111208/111216 | 1.000
Ch09 GSM Low | 148.2 to 150.2 | 132.15 | 0.32/4.89 | 113.4 | 153.0 | | 110840/111216 | 0.997
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111216/111216 | 1.000
January 1 to 31, 2013
Female
Ch17 GSM High | 254.9 to 261.4 | 237.27 | 0.41/11.43 | 193.2 | 293.0 | | 111138/111236 | 0.999
Ch16 GSM Med | 180.2 to 184.8 | 167.60 | 0.34/6.66 | 141.7 | 198.4 | | 111220/111238 | 1.000
Ch20 GSM Low | 129.2 to 130.7 | 115.91 | 0.32/4.36 | 99.7 | 140.3 | | 111140/111234 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111238/111238 | 1.000
Male
Ch06 GSM High | 298.0 to 302.1 | 279.82 | 0.47/15.40 | 220.4 | 362.2 | | 111106/111238 | 0.999
Ch05 GSM Med | 211.7 to 214.0 | 221.30 | 0.45/11.71 | 179.9 | 275.1 | | 111236/111238 | 1.000
Ch09 GSM Low | 150.2 to 151.4 | 135.72 | 0.33/5.19 | 114.5 | 174.3 | | 111180/111238 | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111238/111238 | 1.000
February 1 to 28, 2013
Female
Ch17 GSM High | 261.4 to 264.0 | 244.04 | 0.40/11.51 | 201.9 | 309.0 | | 100140/100164 | 1.000
Ch16 GSM Med | 184.8 to 186.7 | 174.32 | 0.38/7.89 | 145.5 | 216.4 | | 100160/100164 | 1.000
Ch20 GSM Low | 130.7 to 132.0 | 116.79 | 0.32/4.36 | 99.0 | 141.3 | | 100012/100164 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 100164/100164 | 1.000
Male
Ch06 GSM High | 302.1 to 304.0 | 276.46 | 0.45/14.58 | 221.6 | 347.2 | | 99924/100164 | 0.998
Ch05 GSM Med | 214.0 to 215.5 | 227.95 | 0.47/12.61 | 186.4 | 279.7 | | 100128/100164 | 1.000
Ch09 GSM Low | 151.4 to 152.4 | 136.55 | 0.32/5.04 | 114.7 | 160.3 | | 100106/100164 | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 100164/100164 | 1.000
March 1 to 31, 2013
Female
Ch17 GSM High | 264.0 to 266.5 | 248.07 | 0.39/11.49 | 197.3 | 308.4 | | 111392/111408 | 1.000
Ch16 GSM Med | 186.7 to 188.4 | 178.55 | 0.38/7.88 | 147.1 | 212.8 | | 111396/111408 | 1.000
Ch20 GSM Low | 132.0 to 133.2 | 117.42 | 0.32/4.39 | 99.1 | 143.9 | | 111142/111408 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111408/111408 | 1.000
Male
Ch06 GSM High | 304.0 to 305.6 | 278.61 | 0.46/15.06 | 224.1 | 380.8 | | 111090/111408 | 0.997
Ch05 GSM Med | 215.5 to 216.8 | 229.50 | 0.45/12.26 | 186.4 | 283.8 | | 111380/111408 | 1.000
Ch09 GSM Low | 152.4 to 153.3 | 136.42 | 0.31/4.94 | 115.9 | 162.5 | | 111286/111408 | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111408/111408 | 1.000
April 1 to 30, 2013
Female
Ch17 GSM High | 266.5 to 269.0 | 250.31 | 0.41/11.95 | 207.4 | 314.9 | | 107404/107438 | 1.000
Ch16 GSM Med | 188.4 to 190.2 | 178.92 | 0.40/8.46 | 147.1 | 219.1 | | 107426/107438 | 1.000
Ch20 GSM Low | 133.2 to 134.5 | 119.19 | 0.32/4.45 | 101.7 | 149.3 | | 107286/107438 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107438/107438 | 1.000
Male
Ch06 GSM High | 305.6 to 307.6 | 280.59 | 0.47/15.43 | 229.2 | 372.4 | | 107104/107442 | 0.997
Ch05 GSM Med | 216.8 to 218.3 | 231.77 | 0.46/12.63 | 189.1 | 288.7 | | 107402/107442 | 1.000
Ch09 GSM Low | 153.3 to 154.4 | 137.80 | 0.32/5.12 | 111.5 | 163.3 | | 107268/107438 | 0.998
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107444/107444 | 1.000
May 1 to 31, 2013
Female
Ch17 GSM High | 269.0 to 271.8 | 256.26 | 0.44/13.37 | 184.1 | 324.2 | | 105446/105524 | 0.999
Ch16 GSM Med | 190.2 to 190.2 | 179.56 | 0.38/8.02 | 138.8 | 219.5 | | 105504/105524 | 1.000
Ch20 GSM Low | 134.5 to 135.9 | 121.06 | 0.33/4.64 | 90.0 | 145.1 | | 105262/105524 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 105524/105524 | 1.000
Male
Ch06 GSM High | 307.6 to 308.8 | 278.54 | 0.46/15.09 | 206.9 | 359.6 | | 104946/105578 | 0.994
Ch05 GSM Med | 218.3 to 220.1 | 237.22 | 0.49/13.63 | 151.8 | 290.6 | | 105468/105580 | 0.999
Ch09 GSM Low | 154.4 to 155.6 | 137.77 | 0.43/7.00 | 88.7 | 209.9 | | 104226/105576 | 0.987
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 105580/105580 | 1.000
June 1 to 30, 2013
Female
Ch17 GSM High | 271.8 to 274.7 | 252.40 | 0.44/13.06 | 194.3 | 343.6 | | 106884/107074 | 0.998
Ch16 GSM Med | 190.2 to 192.2 | 180.43 | 0.40/8.49 | 138.4 | 219.4 | | 106978/107074 | 0.999
Ch20 GSM Low | 135.9 to 137.4 | 121.62 | 0.33/4.72 | 97.5 | 143.3 | | 106782/107074 | 0.997
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107074/107074 | 1.000
Male
Ch06 GSM High | 308.8 to 311.3 | 275.67 | 0.44/14.27 | 212.0 | 349.6 | | 105800/107088 | 0.988
Ch05 GSM Med | 220.1 to 221.0 | 236.86 | 0.48/13.34 | 191.9 | 295.4 | | 107012/107088 | 0.999
Ch09 GSM Low | 155.6 to 157.0 | 140.60 | 0.33/5.40 | 119.5 | 168.0 | | 106942/107074 | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107088/107088 | 1.000
July 1 to 31, 2013
Female
Ch17 GSM High | 274.7 to 277.7 | 253.80 | 0.40/11.87 | 205.8 | 314.3 | | 110994/111054 | 0.999
Ch16 GSM Med | 192.2 to 196.4 | 182.06 | 0.39/8.41 | 151.1 | 219.7 | | 111034/111054 | 1.000
Ch20 GSM Low | 137.4 to 140.4 | 122.97 | 0.32/4.66 | 105.2 | 149.3 | | 110832/111054 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111054/111054 | 1.000
Male
Ch06 GSM High | 311.3 to 315.3 | 278.80 | 0.44/14.64 | 223.1 | 369.0 | | 109898/111062 | 0.990
Ch05 GSM Med | 221.0 to 223.9 | 237.76 | 0.50/14.21 | 189.2 | 300.6 | | 110936/111062 | 0.999
Ch09 GSM Low | 157.0 to 159.0 | 140.17 | 0.33/5.51 | 115.0 | 170.4 | | 110664/111054 | 0.996
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111062/111062 | 1.000
August 1 to 31, 2013
Female
Ch17 GSM High | 277.7 to 280.8 | 257.67 | 0.43/12.95 | 208.3 | 319.3 | | 111830/111904 | 0.999
Ch16 GSM Med | 196.4 to 198.5 | 182.52 | 0.39/8.42 | 151.0 | 222.3 | | 111850/111904 | 1.000
Ch20 GSM Low | 140.4 to 140.4 | 124.67 | 0.33/4.84 | 104.3 | 150.3 | | 111676/111904 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111904/111904 | 1.000
Male
Ch06 GSM High | 315.3 to 316.7 | 279.34 | 0.45/14.72 | 215.4 | 372.8 | | 110478/111910 | 0.987
Ch05 GSM Med | 223.9 to 224.9 | 237.25 | 0.49/13.81 | 192.1 | 293.2 | | 111860/111910 | 1.000
Ch09 GSM Low | 159.0 to 159.7 | 142.43 | 0.32/5.41 | 120.6 | 169.9 | | 111800/111904 | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111910/111910 | 1.000
September 1 to 30, 2013
Female
Ch17 GSM High | 280.8 to 280.8 | 262.26 | 0.42/13.14 | 204.1 | 327.2 | | 107316/107392 | 0.999
Ch16 GSM Med | 198.5 to 200.7 | 185.57 | 0.39/8.61 | 139.3 | 226.1 | | 107296/107392 | 0.999
Ch20 GSM Low | 140.4 to 141.9 | 125.73 | 0.33/4.86 | 106.5 | 148.1 | | 107242/107392 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107392/107392 | 1.000
Male
Ch06 GSM High | 316.7 to 318.1 | 281.16 | 0.48/15.95 | 224.7 | 390.2 | | 105756/107406 | 0.985
Ch05 GSM Med | 224.9 to 225.9 | 238.83 | 0.50/14.05 | 187.3 | 293.1 | | 107356/107406 | 1.000
Ch09 GSM Low | 159.7 to 161.0 | 142.21 | 0.32/5.37 | 119.3 | 173.7 | | 107192/107392 | 0.998
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107406/107406 | 1.000
October 1 to 31, 2013
Female
Ch17 GSM High | 280.8 to 286.8 | 266.84 | 0.48/15.15 | 202.3 | 349.4 | | 113156/113496 | 0.997
Ch16 GSM Med | 200.7 to 202.8 | 191.15 | 0.50/11.29 | 128.8 | 245.9 | | 113068/113496 | 0.996
Ch20 GSM Low | 141.9 to 143.4 | 126.25 | 0.35/5.17 | 96.2 | 153.1 | | 112706/113494 | 0.993
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 113496/113496 | 1.000
Male
Ch06 GSM High | 318.1 to 319.4 | 282.54 | 0.53/17.77 | 38.2 | 423.6 | | 110868/113614 | 0.976
Ch05 GSM Med | 225.9 to 226.8 | 241.27 | 0.54/15.50 | 186.8 | 302.8 | | 113456/113614 | 0.999
Ch09 GSM Low | 161.0 to 161.7 | 143.81 | 0.35/5.96 | 116.8 | 176.8 | | 113012/113496 | 0.996
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 113614/113614 | 1.000
November 1 to 30, 2013
Female
Ch17 GSM High | 286.8 to 286.8 | 273.00 | 0.45/14.54 | 204.0 | 343.4 | | 110616/110646 | 1.000
Ch16 GSM Med | 202.8 to 204.8 | 192.79 | 0.42/9.55 | 148.3 | 241.8 | | 110586/110646 | 0.999
Ch20 GSM Low | 143.4 to 144.8 | 127.11 | 0.34/5.01 | 108.4 | 153.5 | | 110198/110646 | 0.996
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 110646/110646 | 1.000
Male
Ch06 GSM High | 319.4 to 320.8 | 287.34 | 0.48/16.25 | 225.8 | 357.9 | | 109554/110664 | 0.990
Ch05 GSM Med | 226.8 to 227.7 | 241.65 | 0.50/14.42 | 165.6 | 302.3 | | 110582/110664 | 0.999
Ch09 GSM Low | 161.7 to 161.7 | 143.34 | 0.34/5.76 | 114.0 | 178.7 | | 110244/110658 | 0.996
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 110664/110664 | 1.000
December 1 to 31, 2013
Female
Ch17 GSM High | 286.8 to 289.6 | 274.74 | 0.47/15.25 | 222.7 | 356.4 | | 106174/106198 | 1.000
Ch16 GSM Med | 204.8 to 206.7 | 194.33 | 0.40/9.11 | 158.6 | 234.0 | | 106188/106198 | 1.000
Ch20 GSM Low | 144.8 to 146.1 | 129.74 | 0.31/4.64 | 109.5 | 154.2 | | 106008/106114 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 106198/106198 | 1.000
Male
Ch06 GSM High | 320.8 to 322.1 | 286.88 | 0.47/15.93 | 231.5 | 370.7 | | 104998/106222 | 0.988
Ch05 GSM Med | 227.7 to 228.7 | 241.29 | 0.50/14.36 | 188.7 | 304.7 | | 106184/106222 | 1.000
Ch09 GSM Low | 161.7 to 162.4 | 140.55 | 0.32/5.22 | 119.5 | 166.0 | | 105262/106198 | 0.991
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 106222/106222 | 1.000
January 1 to 31, 2014
Female
Ch17 GSM High | 289.6 to 294.5 | 273.60 | 0.44/14.08 | 213.1 | 345.2 | | 111208/111252 | 1.000
Ch16 GSM Med | 206.7 to 208.2 | 197.35 | 0.40/9.31 | 156.6 | 238.4 | | 111238/111252 | 1.000
Ch20 GSM Low | 146.1 to 147.3 | 131.21 | 0.31/4.77 | 110.5 | 164.6 | | 111166/111242 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111252/111252 | 1.000
Male
Ch06 GSM High | 322.1 to 323.4 | 286.59 | 0.45/15.24 | 232.0 | 364.4 | | 109952/111258 | 0.988
Ch05 GSM Med | 228.7 to 229.6 | 241.27 | 0.53/15.06 | 187.2 | 311.8 | | 111150/111258 | 0.999
Ch09 GSM Low | 162.4 to 163.0 | 141.77 | 0.32/5.40 | 114.6 | 169.4 | | 110336/111254 | 0.992
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111258/111258 | 1.000
February 1 to 28, 2014
Female
Ch17 GSM High | 294.5 to 296.4 | 278.51 | 0.43/14.19 | 224.9 | 353.9 | | 103924/103948 | 1.000
Ch16 GSM Med | 208.2 to 208.2 | 198.50 | 0.40/9.28 | 165.0 | 239.6 | | 103946/103948 | 1.000
Ch20 GSM Low | 147.3 to 149.0 | 132.92 | 0.31/4.85 | 112.3 | 157.0 | | 103880/103948 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 103948/103948 | 1.000
Male
Ch06 GSM High | 323.4 to 324.8 | 290.93 | 0.45/15.63 | 229.9 | 371.2 | | 103072/103960 | 0.991
Ch05 GSM Med | 229.6 to 230.6 | 241.40 | 0.50/14.31 | 197.7 | 300.3 | | 103924/103960 | 1.000
Ch09 GSM Low | 163.0 to 163.7 | 143.34 | 0.32/5.39 | 119.8 | 171.2 | | 103444/103948 | 0.995
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 103960/103960 | 1.000
March 1 to 31, 2014
Female
Ch17 GSM High | 296.4 to 298.0 | 281.01 | 0.42/13.93 | 212.2 | 352.2 | | 111382/111408 | 1.000
Ch16 GSM Med | 208.2 to 209.6 | 200.57 | 0.41/9.73 | 161.8 | 246.5 | | 111400/111408 | 1.000
Ch20 GSM Low | 149.0 to 149.7 | 133.58 | 0.32/4.93 | 106.6 | 154.5 | | 111256/111408 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111408/111408 | 1.000
Male
Ch06 GSM High | 324.8 to 324.8 | 290.82 | 0.48/16.36 | 223.2 | 381.3 | | 110096/111408 | 0.988
Ch05 GSM Med | 230.6 to 231.5 | 242.18 | 0.53/15.28 | 194.0 | 312.6 | | 111336/111408 | 0.999
Ch09 GSM Low | 163.7 to 164.4 | 144.23 | 0.32/5.33 | 122.6 | 175.8 | | 111024/111408 | 0.997
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111408/111408 | 1.000
April 1 to 30, 2014
Female
Ch17 GSM High | 298.0 to 299.3 | 279.24 | 0.44/14.60 | 206.0 | 347.1 | | 107100/107288 | 0.998
Ch16 GSM Med | 209.6 to 210.7 | 202.29 | 0.43/10.22 | 153.5 | 249.1 | | 107228/107288 | 0.999
Ch20 GSM Low | 149.7 to 150.2 | 134.98 | 0.32/5.09 | 111.6 | 156.3 | | 107172/107286 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107288/107288 | 1.000
Male
Ch06 GSM High | 324.8 to 326.1 | 293.70 | 0.49/17.15 | 81.1 | 373.8 | | 106068/107298 | 0.989
Ch05 GSM Med | 231.5 to 231.5 | 242.46 | 0.53/15.16 | 196.6 | 306.2 | | 107220/107298 | 0.999
Ch09 GSM Low | 164.4 to 164.4 | 144.09 | 0.32/5.48 | 119.7 | 170.6 | | 106748/107290 | 0.995
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107298/107298 | 1.000
May 1 to 31, 2014
Female
Ch17 GSM High | 299.3 to 300.4 | 285.77 | 0.45/15.19 | 226.9 | 363.3 | | 111176/111208 | 1.000
Ch16 GSM Med | 210.7 to 211.7 | 193.86 | 0.39/8.95 | 154.6 | 239.6 | | 111128/111208 | 0.999
Ch20 GSM Low | 150.2 to 150.2 | 134.45 | 0.34/5.30 | 108.5 | 158.8 | | 111012/111204 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111208/111208 | 1.000
Male
Ch06 GSM High | 326.1 to 326.1 | 296.46 | 0.46/16.14 | 237.1 | 375.6 | | 110684/111208 | 0.995
Ch05 GSM Med | 231.5 to 231.5 | 207.41 | 0.47/11.55 | 162.7 | 306.7 | | 110450/111208 | 0.993
Ch09 GSM Low | 164.4 to 165.1 | 153.28 | 0.43/7.71 | 123.4 | 195.4 | | 111094/111208 | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111208/111208 | 1.000
June 1 to 30, 2014
Female
Ch17 GSM High | 300.4 to 302.1 | 288.24 | 0.47/16.20 | 235.2 | 380.3 | | 107530/107542 | 1.000
Ch16 GSM Med | 211.7 to 213.1 | 200.74 | 0.42/9.91 | 138.6 | 261.5 | | 107508/107542 | 1.000
Ch20 GSM Low | 150.2 to 151.0 | 134.74 | 0.33/5.24 | 95.9 | 177.0 | | 107376/107534 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107542/107542 | 1.000
Male
Ch06 GSM High | 326.1 to 327.4 | 295.01 | 0.46/16.13 | 225.9 | 406.2 | | 106940/107546 | 0.994
Ch05 GSM Med | 231.5 to 231.5 | 207.94 | 0.45/11.15 | 77.9 | 266.6 | | 106192/107548 | 0.987
Ch09 GSM Low | 163.7 to 165.1 | 152.64 | 0.39/7.06 | 64.5 | 187.5 | | 107418/107546 | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 107548/107548 | 1.000
July 1 to 31, 2014
Female
Ch17 GSM High | 302.1 to 302.7 | 289.35 | 0.45/15.51 | 220.3 | 362.7 | | 111178/111202 | 1.000
Ch16 GSM Med | 213.1 to 213.1 | 199.95 | 0.39/9.14 | 160.5 | 244.0 | | 111182/111202 | 1.000
Ch20 GSM Low | 151.0 to 151.4 | 135.12 | 0.31/4.98 | 99.5 | 156.3 | | 111052/111202 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111202/111202 | 1.000
Male
Ch06 GSM High | 326.1 to 327.4 | 289.86 | 0.44/15.18 | 198.9 | 378.9 | | 110010/111206 | 0.989
Ch05 GSM Med | 229.6 to 231.5 | 215.61 | 0.41/10.50 | 174.4 | 265.3 | | 111174/111206 | 1.000
Ch09 GSM Low | 162.4 to 163.7 | 152.19 | 0.36/6.35 | 125.4 | 187.1 | | 111176/111202 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | | 111206/111206 | 1.000
August 1 to 31, 2014
Female
Ch17 GSM High | 302.7 to 303.4 | 290.91 | 0.45/15.30 | 205.3 | 369.6 | 108668/108708 | | 1.000
Ch16 GSM Med | 213.1 to 213.6 | 200.65 | 0.39/9.18 | 153.8 | 243.3 | 108630/108708 | | 0.999
Ch20 GSM Low | 151.4 to 151.7 | 134.02 | 0.36/5.60 | 102.4 | 159.8 | 107888/108708 | | 0.992
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 108708/108708 | | 1.000
Male
Ch06 GSM High | 324.8 to 327.4 | 290.86 | 0.45/15.32 | 231.0 | 374.5 | 107704/108716 | | 0.991
Ch05 GSM Med | 227.7 to 229.6 | 215.05 | 0.41/10.32 | 175.0 | 270.0 | 108704/108716 | | 1.000
Ch09 GSM Low | 162.4 to 163.0 | 153.30 | 0.37/6.76 | 128.0 | 181.8 | 108702/108708 | | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 108716/108716 | | 1.000
September 1 to 30, 2014
Female
Ch17 GSM High | 303.4 to 303.4 | 294.02 | 0.46/15.88 | 194.5 | 436.8 | 104160/104176 | | 1.000
Ch16 GSM Med | 213.6 to 214.5 | 204.29 | 0.41/9.82 | 167.9 | 279.2 | 104168/104176 | | 1.000
Ch20 GSM Low | 151.4 to 151.7 | 138.14 | 0.33/5.32 | 111.3 | 184.1 | 104052/104176 | | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 104176/104176 | | 1.000
Male
Ch06 GSM High | 324.8 to 324.8 | 299.88 | 0.49/17.46 | 204.7 | 441.0 | 103900/104176 | | 0.997
Ch05 GSM Med | 227.7 to 227.7 | 224.63 | 0.61/16.43 | 174.7 | 308.7 | 104148/104176 | | 1.000
Ch09 GSM Low | 161.7 to 162.4 | 158.10 | 0.37/6.84 | 127.6 | 210.1 | 104170/104176 | | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 104176/104176 | | 1.000
August 8, 2012 to September 30, 2014
Female
Ch17 GSM High | 192.6 to 303.4 | 260.77 | 0.47/14.52 | 137.3 | 436.8 | 2797766/2800508 | | 0.999
Ch16 GSM Med | 136.2 to 214.5 | 184.16 | 0.41/8.99 | 101.6 | 279.2 | 2799216/2800510 | | 1.000
Ch20 GSM Low | 96.1 to 151.7 | 124.97 | 0.40/5.95 | 71.8 | 184.1 | 2794544/2800388 | | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 2800510/2800510 | | 1.000
Male
Ch06 GSM High | 192.6 to 327.4 | 278.30 | 0.48/15.93 | 38.2 | 445.8 | 2779842/2800838 | | 0.993
Ch05 GSM Med | 136.2 to 231.5 | 224.32 | 0.65/17.31 | 77.9 | 323.0 | 2797270/2800842 | | 0.999
Ch09 GSM Low | 96.3 to 165.1 | 139.28 | 0.40/6.61 | 64.5 | 210.1 | 2792562/2800582 | | 0.997
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 2800844/2800844 | | 1.000

Ch = chamber (e.g., Ch17 = Chamber 17).

Table I‑4 Summary of GSM-modulated Cell Phone RFR Exposure Data in Rats – H-Field

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | Max [V/m] | In Range/Total | Ratio
August 8 to 31, 2012
Female
Ch17 GSM High | 0.65 to 0.75 | 0.687 | 0.36/0.029 | 0.50 | 0.97 | 85734/85786 | 0.999
Ch16 GSM Med | 0.46 to 0.53 | 0.505 | 0.30/0.018 | 0.40 | 0.67 | 85774/85786 | 1.000
Ch20 GSM Low | 0.33 to 0.38 | 0.370 | 0.30/0.013 | 0.29 | 0.50 | 85714/85786 | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 85786/85786 | 1.000
September 1 to 30, 2012
Female
Ch17 GSM High | 0.51 to 0.71 | 0.647 | 0.59/0.046 | 0.42 | 0.97 | 105690/105918 | 0.998
Ch16 GSM Med | 0.36 to 0.51 | 0.460 | 0.41/0.022 | 0.29 | 0.68 | 105834/105918 | 0.999
Ch20 GSM Low | 0.26 to 0.36 | 0.327 | 0.37/0.014 | 0.21 | 0.50 | 105824/105918 | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 105918/105918 | 1.000
Male
Ch06 GSM High | 0.51 to 0.71 | 0.645 | 0.41/0.031 | 0.29 | 1.17 | 105800/105918 | 0.999
Ch05 GSM Med | 0.36 to 0.51 | 0.413 | 0.37/0.018 | 0.26 | 0.66 | 105892/105918 | 1.000
Ch09 GSM Low | 0.26 to 0.36 | 0.328 | 0.38/0.015 | 0.21 | 0.59 | 105716/105918 | 0.998
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 105918/105918 | 1.000
October 1 to 31, 2012
Female
Ch17 GSM High | 0.51 to 0.62 | 0.623 | 0.46/0.034 | 0.46 | 0.85 | 110476/110678 | 0.998
Ch16 GSM Med | 0.36 to 0.44 | 0.435 | 0.39/0.020 | 0.30 | 0.59 | 110654/110678 | 1.000
Ch20 GSM Low | 0.26 to 0.31 | 0.291 | 0.36/0.012 | 0.22 | 0.40 | 110646/110670 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 110678/110678 | 1.000
Male
Ch06 GSM High | 0.53 to 0.71 | 0.676 | 0.42/0.033 | 0.47 | 0.90 | 110666/110702 | 1.000
Ch05 GSM Med | 0.38 to 0.51 | 0.444 | 0.35/0.018 | 0.32 | 0.61 | 110702/110702 | 1.000
Ch09 GSM Low | 0.27 to 0.36 | 0.356 | 0.35/0.015 | 0.24 | 0.46 | 110620/110678 | 0.999
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 110702/110702 | 1.000
November 1 to 30, 2012
Female
Ch17 GSM High | 0.62 to 0.67 | 0.695 | 0.45/0.037 | 0.56 | 0.92 | 107658/107706 | 1.000
Ch16 GSM Med | 0.44 to 0.47 | 0.496 | 0.39/0.022 | 0.42 | 0.60 | 107694/107706 | 1.000
Ch20 GSM Low | 0.31 to 0.33 | 0.338 | 0.59/0.024 | 0.27 | 0.44 | 107688/107706 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107706/107706 | 1.000
Male
Ch06 GSM High | 0.72 to 0.78 | 0.801 | 0.43/0.041 | 0.63 | 1.04 | 107688/107706 | 1.000
Ch05 GSM Med | 0.52 to 0.55 | 0.525 | 0.38/0.023 | 0.44 | 0.65 | 107706/107706 | 1.000
Ch09 GSM Low | 0.36 to 0.39 | 0.422 | 0.35/0.017 | 0.35 | 0.51 | 107682/107706 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107706/107706 | 1.000
December 1 to 31, 2012
Female
Ch17 GSM High | 0.67 to 0.68 | 0.725 | 0.44/0.037 | 0.58 | 0.90 | 111152/111216 | 0.999
Ch16 GSM Med | 0.47 to 0.48 | 0.513 | 0.41/0.025 | 0.42 | 0.63 | 111202/111216 | 1.000
Ch20 GSM Low | 0.33 to 0.34 | 0.378 | 0.34/0.015 | 0.33 | 0.46 | 111172/111216 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111216/111216 | 1.000
Male
Ch06 GSM High | 0.78 to 0.79 | 0.837 | 0.43/0.043 | 0.69 | 1.04 | 111200/111216 | 1.000
Ch05 GSM Med | 0.55 to 0.56 | 0.535 | 0.37/0.023 | 0.45 | 0.64 | 111216/111216 | 1.000
Ch09 GSM Low | 0.39 to 0.40 | 0.439 | 0.37/0.019 | 0.36 | 0.52 | 111182/111216 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111216/111216 | 1.000
January 1 to 31, 2013
Female
Ch17 GSM High | 0.68 to 0.69 | 0.737 | 0.44/0.039 | 0.60 | 0.95 | 111146/111236 | 0.999
Ch16 GSM Med | 0.48 to 0.49 | 0.523 | 0.38/0.023 | 0.44 | 0.64 | 111226/111238 | 1.000
Ch20 GSM Low | 0.34 to 0.35 | 0.380 | 0.34/0.015 | 0.32 | 0.47 | 111214/111234 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111238/111238 | 1.000
Male
Ch06 GSM High | 0.79 to 0.80 | 0.842 | 0.44/0.043 | 0.70 | 1.05 | 111228/111238 | 1.000
Ch05 GSM Med | 0.56 to 0.57 | 0.540 | 0.33/0.021 | 0.45 | 0.64 | 111238/111238 | 1.000
Ch09 GSM Low | 0.40 to 0.40 | 0.438 | 0.36/0.019 | 0.37 | 0.58 | 111134/111238 | 0.999
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111238/111238 | 1.000
February 1 to 28, 2013
Female
Ch17 GSM High | 0.69 to 0.70 | 0.742 | 0.43/0.037 | 0.61 | 0.91 | 100134/100164 | 1.000
Ch16 GSM Med | 0.49 to 0.50 | 0.521 | 0.37/0.023 | 0.43 | 0.61 | 100164/100164 | 1.000
Ch20 GSM Low | 0.35 to 0.35 | 0.386 | 0.35/0.016 | 0.33 | 0.48 | 100150/100164 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 100164/100164 | 1.000
Male
Ch06 GSM High | 0.80 to 0.81 | 0.870 | 0.47/0.049 | 0.72 | 1.08 | 100074/100164 | 0.999
Ch05 GSM Med | 0.57 to 0.57 | 0.535 | 0.36/0.023 | 0.45 | 0.64 | 100160/100164 | 1.000
Ch09 GSM Low | 0.40 to 0.40 | 0.441 | 0.37/0.019 | 0.37 | 0.53 | 100152/100164 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 100164/100164 | 1.000
March 1 to 31, 2013
Female
Ch17 GSM High | 0.70 to 0.71 | 0.746 | 0.41/0.036 | 0.63 | 0.93 | 111390/111408 | 1.000
Ch16 GSM Med | 0.50 to 0.50 | 0.520 | 0.37/0.023 | 0.43 | 0.63 | 111408/111408 | 1.000
Ch20 GSM Low | 0.35 to 0.35 | 0.391 | 0.34/0.016 | 0.33 | 0.46 | 111396/111408 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111408/111408 | 1.000
Male
Ch06 GSM High | 0.81 to 0.81 | 0.870 | 0.46/0.047 | 0.72 | 1.06 | 111368/111408 | 1.000
Ch05 GSM Med | 0.57 to 0.58 | 0.537 | 0.36/0.022 | 0.45 | 0.64 | 111402/111408 | 1.000
Ch09 GSM Low | 0.40 to 0.41 | 0.446 | 0.36/0.019 | 0.38 | 0.54 | 111396/111408 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111408/111408 | 1.000
April 1 to 30, 2013
Female
Ch17 GSM High | 0.71 to 0.71 | 0.756 | 0.43/0.038 | 0.62 | 0.91 | 107424/107438 | 1.000
Ch16 GSM Med | 0.50 to 0.51 | 0.530 | 0.39/0.025 | 0.44 | 0.62 | 107438/107438 | 1.000
Ch20 GSM Low | 0.35 to 0.36 | 0.393 | 0.34/0.016 | 0.34 | 0.46 | 107430/107438 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107438/107438 | 1.000
Male
Ch06 GSM High | 0.81 to 0.82 | 0.876 | 0.47/0.049 | 0.70 | 1.10 | 107396/107442 | 1.000
Ch05 GSM Med | 0.58 to 0.58 | 0.541 | 0.35/0.022 | 0.46 | 0.64 | 107440/107442 | 1.000
Ch09 GSM Low | 0.41 to 0.41 | 0.449 | 0.37/0.019 | 0.39 | 0.54 | 107406/107438 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107444/107444 | 1.000
May 1 to 31, 2013
Female
Ch17 GSM High | 0.71 to 0.72 | 0.752 | 0.44/0.039 | 0.55 | 0.94 | 105516/105524 | 1.000
Ch16 GSM Med | 0.51 to 0.51 | 0.529 | 0.40/0.025 | 0.39 | 0.62 | 105522/105524 | 1.000
Ch20 GSM Low | 0.36 to 0.36 | 0.395 | 0.33/0.015 | 0.29 | 0.46 | 105514/105524 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 105524/105524 | 1.000
Male
Ch06 GSM High | 0.82 to 0.82 | 0.891 | 0.49/0.052 | 0.68 | 1.17 | 105416/105578 | 0.998
Ch05 GSM Med | 0.58 to 0.58 | 0.535 | 0.35/0.022 | 0.32 | 0.64 | 105564/105580 | 1.000
Ch09 GSM Low | 0.41 to 0.41 | 0.454 | 0.41/0.022 | 0.36 | 0.60 | 105438/105576 | 0.999
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 105580/105580 | 1.000
June 1 to 30, 2013
Female
Ch17 GSM High | 0.72 to 0.73 | 0.780 | 0.46/0.043 | 0.60 | 0.95 | 107056/107074 | 1.000
Ch16 GSM Med | 0.51 to 0.51 | 0.537 | 0.39/0.025 | 0.45 | 0.65 | 107070/107074 | 1.000
Ch20 GSM Low | 0.36 to 0.36 | 0.403 | 0.35/0.016 | 0.34 | 0.47 | 107056/107074 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107074/107074 | 1.000
Male
Ch06 GSM High | 0.82 to 0.83 | 0.907 | 0.50/0.053 | 0.71 | 1.14 | 106866/107088 | 0.998
Ch05 GSM Med | 0.58 to 0.59 | 0.540 | 0.34/0.021 | 0.46 | 0.64 | 107084/107088 | 1.000
Ch09 GSM Low | 0.41 to 0.42 | 0.455 | 0.37/0.020 | 0.37 | 0.54 | 107054/107074 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107088/107088 | 1.000
July 1 to 31, 2013
Female
Ch17 GSM High | 0.73 to 0.74 | 0.780 | 0.45/0.041 | 0.65 | 0.95 | 111028/111054 | 1.000
Ch16 GSM Med | 0.51 to 0.52 | 0.545 | 0.40/0.025 | 0.46 | 0.65 | 111054/111054 | 1.000
Ch20 GSM Low | 0.36 to 0.37 | 0.408 | 0.34/0.016 | 0.34 | 0.48 | 111044/111054 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111054/111054 | 1.000
Male
Ch06 GSM High | 0.83 to 0.84 | 0.913 | 0.49/0.053 | 0.73 | 1.18 | 110836/111062 | 0.998
Ch05 GSM Med | 0.59 to 0.59 | 0.548 | 0.35/0.023 | 0.45 | 0.66 | 111048/111062 | 1.000
Ch09 GSM Low | 0.42 to 0.42 | 0.461 | 0.40/0.022 | 0.39 | 0.57 | 110988/111054 | 0.999
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111062/111062 | 1.000
August 1 to 31, 2013
Female
Ch17 GSM High | 0.74 to 0.75 | 0.789 | 0.44/0.041 | 0.64 | 0.97 | 111878/111904 | 1.000
Ch16 GSM Med | 0.52 to 0.53 | 0.557 | 0.40/0.026 | 0.46 | 0.66 | 111902/111904 | 1.000
Ch20 GSM Low | 0.37 to 0.37 | 0.412 | 0.32/0.016 | 0.36 | 0.48 | 111892/111904 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111904/111904 | 1.000
Male
Ch06 GSM High | 0.84 to 0.84 | 0.919 | 0.49/0.053 | 0.74 | 1.15 | 111660/111910 | 0.998
Ch05 GSM Med | 0.59 to 0.60 | 0.553 | 0.35/0.023 | 0.48 | 0.66 | 111910/111910 | 1.000
Ch09 GSM Low | 0.42 to 0.42 | 0.462 | 0.38/0.021 | 0.38 | 0.55 | 111884/111904 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111910/111910 | 1.000
September 1 to 30, 2013
Female
Ch17 GSM High | 0.75 to 0.75 | 0.788 | 0.44/0.041 | 0.63 | 0.98 | 107388/107392 | 1.000
Ch16 GSM Med | 0.53 to 0.53 | 0.561 | 0.42/0.028 | 0.45 | 0.68 | 107386/107392 | 1.000
Ch20 GSM Low | 0.37 to 0.38 | 0.411 | 0.34/0.016 | 0.35 | 0.49 | 107382/107392 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107392/107392 | 1.000
Male
Ch06 GSM High | 0.84 to 0.84 | 0.925 | 0.50/0.055 | 0.76 | 1.15 | 107170/107406 | 0.998
Ch05 GSM Med | 0.60 to 0.60 | 0.557 | 0.35/0.023 | 0.46 | 0.66 | 107386/107406 | 1.000
Ch09 GSM Low | 0.42 to 0.43 | 0.468 | 0.38/0.021 | 0.37 | 0.56 | 107326/107392 | 0.999
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107406/107406 | 1.000
October 1 to 31, 2013
Female
Ch17 GSM High | 0.75 to 0.76 | 0.787 | 0.50/0.047 | 0.60 | 1.00 | 113450/113496 | 1.000
Ch16 GSM Med | 0.53 to 0.54 | 0.558 | 0.48/0.032 | 0.42 | 0.67 | 113476/113496 | 1.000
Ch20 GSM Low | 0.38 to 0.38 | 0.418 | 0.39/0.019 | 0.33 | 0.49 | 113476/113494 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 113496/113496 | 1.000
Male
Ch06 GSM High | 0.84 to 0.85 | 0.931 | 0.56/0.062 | 0.60 | 1.34 | 113016/113614 | 0.995
Ch05 GSM Med | 0.60 to 0.60 | 0.560 | 0.39/0.025 | 0.46 | 0.69 | 113554/113614 | 0.999
Ch09 GSM Low | 0.43 to 0.43 | 0.471 | 0.38/0.021 | 0.39 | 0.59 | 113456/113496 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 113614/113614 | 1.000
November 1 to 30, 2013
Female
Ch17 GSM High | 0.76 to 0.76 | 0.794 | 0.43/0.041 | 0.62 | 0.99 | 110632/110646 | 1.000
Ch16 GSM Med | 0.54 to 0.54 | 0.567 | 0.41/0.028 | 0.45 | 0.69 | 110644/110646 | 1.000
Ch20 GSM Low | 0.38 to 0.38 | 0.424 | 0.34/0.017 | 0.35 | 0.50 | 110622/110646 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 110646/110646 | 1.000
Male
Ch06 GSM High | 0.85 to 0.85 | 0.926 | 0.49/0.054 | 0.74 | 1.17 | 110468/110664 | 0.998
Ch05 GSM Med | 0.60 to 0.60 | 0.563 | 0.35/0.023 | 0.48 | 0.68 | 110664/110664 | 1.000
Ch09 GSM Low | 0.43 to 0.43 | 0.474 | 0.35/0.020 | 0.41 | 0.58 | 110642/110658 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 110664/110664 | 1.000
December 1 to 31, 2013
Female
Ch17 GSM High | 0.76 to 0.77 | 0.797 | 0.48/0.046 | 0.63 | 0.99 | 106186/106198 | 1.000
Ch16 GSM Med | 0.54 to 0.55 | 0.573 | 0.41/0.028 | 0.47 | 0.69 | 106196/106198 | 1.000
Ch20 GSM Low | 0.38 to 0.39 | 0.425 | 0.32/0.016 | 0.38 | 0.49 | 106106/106114 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 106198/106198 | 1.000
Male
Ch06 GSM High | 0.85 to 0.85 | 0.934 | 0.48/0.053 | 0.78 | 1.19 | 106006/106222 | 0.998
Ch05 GSM Med | 0.60 to 0.61 | 0.567 | 0.37/0.024 | 0.44 | 0.67 | 106114/106222 | 0.999
Ch09 GSM Low | 0.43 to 0.43 | 0.485 | 0.34/0.019 | 0.42 | 0.57 | 106114/106198 | 0.999
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 106222/106222 | 1.000
January 1 to 31, 2014
Female
Ch17 GSM High | 0.77 to 0.78 | 0.821 | 0.46/0.045 | 0.68 | 1.04 | 111214/111252 | 1.000
Ch16 GSM Med | 0.55 to 0.55 | 0.574 | 0.40/0.027 | 0.45 | 0.68 | 111252/111252 | 1.000
Ch20 GSM Low | 0.39 to 0.39 | 0.427 | 0.34/0.017 | 0.35 | 0.51 | 111232/111242 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111252/111252 | 1.000
Male
Ch06 GSM High | 0.85 to 0.86 | 0.940 | 0.48/0.054 | 0.79 | 1.18 | 110934/111258 | 0.997
Ch05 GSM Med | 0.61 to 0.61 | 0.573 | 0.38/0.026 | 0.48 | 0.68 | 111256/111258 | 1.000
Ch09 GSM Low | 0.43 to 0.43 | 0.486 | 0.36/0.020 | 0.42 | 0.58 | 111152/111254 | 0.999
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111258/111258 | 1.000
February 1 to 28, 2014
Female
Ch17 GSM High | 0.78 to 0.79 | 0.828 | 0.45/0.044 | 0.69 | 1.05 | 103936/103948 | 1.000
Ch16 GSM Med | 0.55 to 0.55 | 0.575 | 0.37/0.025 | 0.49 | 0.67 | 103948/103948 | 1.000
Ch20 GSM Low | 0.39 to 0.40 | 0.433 | 0.32/0.016 | 0.37 | 0.51 | 103938/103948 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 103948/103948 | 1.000
Male
Ch06 GSM High | 0.86 to 0.86 | 0.937 | 0.48/0.053 | 0.77 | 1.17 | 103800/103960 | 0.998
Ch05 GSM Med | 0.61 to 0.61 | 0.577 | 0.38/0.025 | 0.48 | 0.67 | 103956/103960 | 1.000
Ch09 GSM Low | 0.43 to 0.43 | 0.486 | 0.35/0.020 | 0.42 | 0.56 | 103898/103948 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 103960/103960 | 1.000
March 1 to 31, 2014
Female
Ch17 GSM High | 0.79 to 0.79 | 0.830 | 0.47/0.046 | 0.66 | 1.04 | 111398/111408 | 1.000
Ch16 GSM Med | 0.55 to 0.56 | 0.574 | 0.38/0.026 | 0.45 | 0.66 | 111408/111408 | 1.000
Ch20 GSM Low | 0.40 to 0.40 | 0.435 | 0.32/0.016 | 0.36 | 0.54 | 111402/111408 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111408/111408 | 1.000
Male
Ch06 GSM High | 0.86 to 0.86 | 0.936 | 0.48/0.053 | 0.78 | 1.18 | 111174/111408 | 0.998
Ch05 GSM Med | 0.61 to 0.61 | 0.574 | 0.37/0.025 | 0.49 | 0.68 | 111408/111408 | 1.000
Ch09 GSM Low | 0.43 to 0.44 | 0.486 | 0.34/0.020 | 0.41 | 0.58 | 111356/111408 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111408/111408 | 1.000
April 1 to 30, 2014
Female
Ch17 GSM High | 0.79 to 0.79 | 0.841 | 0.49/0.049 | 0.63 | 1.04 | 107254/107288 | 1.000
Ch16 GSM Med | 0.56 to 0.56 | 0.576 | 0.41/0.027 | 0.46 | 0.69 | 107288/107288 | 1.000
Ch20 GSM Low | 0.40 to 0.40 | 0.436 | 0.33/0.017 | 0.38 | 0.50 | 107286/107286 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107288/107288 | 1.000
Male
Ch06 GSM High | 0.86 to 0.87 | 0.928 | 0.46/0.050 | 0.39 | 1.17 | 107206/107298 | 0.999
Ch05 GSM Med | 0.61 to 0.61 | 0.577 | 0.37/0.025 | 0.49 | 0.68 | 107298/107298 | 1.000
Ch09 GSM Low | 0.44 to 0.44 | 0.488 | 0.36/0.021 | 0.41 | 0.57 | 107212/107290 | 0.999
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107298/107298 | 1.000
May 1 to 31, 2014
Female
Ch17 GSM High | 0.79 to 0.80 | 0.834 | 0.47/0.047 | 0.67 | 1.03 | 111186/111208 | 1.000
Ch16 GSM Med | 0.56 to 0.56 | 0.605 | 0.40/0.029 | 0.49 | 0.74 | 111192/111208 | 1.000
Ch20 GSM Low | 0.40 to 0.40 | 0.438 | 0.33/0.017 | 0.37 | 0.53 | 111196/111204 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111208/111208 | 1.000
Male
Ch06 GSM High | 0.87 to 0.87 | 0.931 | 0.47/0.051 | 0.78 | 1.23 | 111120/111208 | 0.999
Ch05 GSM Med | 0.61 to 0.61 | 0.641 | 0.45/0.034 | 0.51 | 0.77 | 111208/111208 | 1.000
Ch09 GSM Low | 0.44 to 0.44 | 0.468 | 0.37/0.021 | 0.40 | 0.56 | 111204/111208 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111208/111208 | 1.000
June 1 to 30, 2014
Female
Ch17 GSM High | 0.80 to 0.80 | 0.832 | 0.46/0.046 | 0.67 | 1.03 | 107526/107542 | 1.000
Ch16 GSM Med | 0.56 to 0.57 | 0.593 | 0.40/0.028 | 0.41 | 0.69 | 107516/107542 | 1.000
Ch20 GSM Low | 0.40 to 0.40 | 0.441 | 0.34/0.018 | 0.29 | 0.52 | 107508/107534 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107542/107542 | 1.000
Male
Ch06 GSM High | 0.87 to 0.87 | 0.940 | 0.47/0.053 | 0.67 | 1.16 | 107402/107546 | 0.999
Ch05 GSM Med | 0.61 to 0.61 | 0.652 | 0.49/0.038 | 0.24 | 0.85 | 107538/107548 | 1.000
Ch09 GSM Low | 0.43 to 0.44 | 0.466 | 0.35/0.019 | 0.21 | 0.55 | 107532/107546 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 107548/107548 | 1.000
July 1 to 31, 2014
Female
Ch17 GSM High | 0.80 to 0.80 | 0.832 | 0.48/0.048 | 0.64 | 1.05 | 111188/111202 | 1.000
Ch16 GSM Med | 0.57 to 0.57 | 0.595 | 0.40/0.028 | 0.44 | 0.70 | 111200/111202 | 1.000
Ch20 GSM Low | 0.40 to 0.40 | 0.442 | 0.33/0.017 | 0.37 | 0.52 | 111186/111202 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111202/111202 | 1.000
Male
Ch06 GSM High | 0.87 to 0.87 | 0.947 | 0.47/0.052 | 0.79 | 1.28 | 110960/111206 | 0.998
Ch05 GSM Med | 0.61 to 0.61 | 0.646 | 0.45/0.034 | 0.46 | 0.80 | 111194/111206 | 1.000
Ch09 GSM Low | 0.43 to 0.43 | 0.463 | 0.34/0.018 | 0.36 | 0.54 | 111202/111202 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 111206/111206 | 1.000
August 1 to 31, 2014
Female
Ch17 GSM High | 0.80 to 0.81 | 0.829 | 0.43/0.042 | 0.62 | 1.05 | 108694/108708 | 1.000
Ch16 GSM Med | 0.57 to 0.57 | 0.594 | 0.40/0.028 | 0.47 | 0.71 | 108708/108708 | 1.000
Ch20 GSM Low | 0.40 to 0.40 | 0.446 | 0.39/0.020 | 0.36 | 0.53 | 108626/108708 | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 108708/108708 | 1.000
Male
Ch06 GSM High | 0.86 to 0.87 | 0.946 | 0.46/0.051 | 0.78 | 1.17 | 108550/108716 | 0.998
Ch05 GSM Med | 0.60 to 0.61 | 0.639 | 0.43/0.032 | 0.53 | 0.78 | 108704/108716 | 1.000
Ch09 GSM Low | 0.43 to 0.43 | 0.454 | 0.34/0.018 | 0.39 | 0.54 | 108708/108708 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 108716/108716 | 1.000
September 1 to 30, 2014
Female
Ch17 GSM High | 0.81 to 0.81 | 0.823 | 0.45/0.043 | 0.53 | 1.12 | 104166/104176 | 1.000
Ch16 GSM Med | 0.57 to 0.57 | 0.587 | 0.40/0.028 | 0.44 | 0.78 | 104168/104176 | 1.000
Ch20 GSM Low | 0.40 to 0.40 | 0.435 | 0.33/0.017 | 0.37 | 0.56 | 104156/104176 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 104176/104176 | 1.000
Male
Ch06 GSM High | 0.86 to 0.86 | 0.917 | 0.52/0.056 | 0.53 | 1.24 | 104040/104176 | 0.999
Ch05 GSM Med | 0.60 to 0.60 | 0.607 | 0.60/0.044 | 0.48 | 0.76 | 104174/104176 | 1.000
Ch09 GSM Low | 0.43 to 0.43 | 0.435 | 0.34/0.018 | 0.33 | 0.56 | 104170/104176 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 104176/104176 | 1.000
August 8, 2012 to September 30, 2014
Female
Ch17 GSM High | 0.51 to 0.81 | 0.774 | 0.49/0.045 | 0.42 | 1.12 | 2799438/2800508 | 1.000
Ch16 GSM Med | 0.36 to 0.57 | 0.547 | 0.42/0.027 | 0.29 | 0.78 | 2800262/2800510 | 1.000
Ch20 GSM Low | 0.26 to 0.40 | 0.403 | 0.41/0.020 | 0.21 | 0.56 | 2799794/2800388 | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 2800510/2800510 | 1.000
Male
Ch06 GSM High | 0.51 to 0.87 | 0.883 | 0.49/0.051 | 0.29 | 1.34 | 2796716/2800838 | 0.999
Ch05 GSM Med | 0.36 to 0.61 | 0.556 | 0.53/0.035 | 0.24 | 0.85 | 2800538/2800842 | 1.000
Ch09 GSM Low | 0.26 to 0.44 | 0.449 | 0.42/0.022 | 0.21 | 0.60 | 2799272/2800582 | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | 2800844/2800844 | 1.000

Ch = chamber (e.g., Ch17 = Chamber 17).

Table I‑5 Summary of CDMA-modulated Cell Phone RFR Exposure Data in Rats – SAR

Chamber | Weight Range [g] | Target [W/kg] | Mean [W/kg] | Stdev [dB]/[W/kg] | Min [W/kg] | | Max [W/kg] | In Range/Total | Ratio
August 8 to 31, 2012
Male
Ch07 IS95 High | 237.9 to 358.4 | 6.00 | 5.97 | 0.17/0.04 | 2.109 | | 8.613 | 42889/42893 | 1.000
Ch08 IS95 Med | 238.8 to 354.1 | 3.00 | 2.99 | 0.17/0.04 | 1.077 | | 4.524 | 42889/42893 | 1.000
Ch10 IS95 Low | 239.3 to 361.1 | 1.50 | 1.50 | 0.17/0.04 | 0.593 | | 2.223 | 42889/42893 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 42893/42893 | 1.000
September 1 to 30, 2012
Female
Ch19 IS95 High | 55.9 to 303.9 | 6.00 | 5.99 | 0.19/0.04 | 4.373 | | 9.406 | 52959/52959 | 1.000
Ch18 IS95 Med | 59.6 to 303.9 | 3.00 | 2.99 | 0.19/0.05 | 2.018 | | 4.860 | 52956/52959 | 1.000
Ch21 IS95 Low | 59.3 to 303.9 | 1.50 | 1.50 | 0.20/0.05 | 1.103 | | 2.524 | 52958/52959 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 52959/52959 | 1.000
Male
Ch07 IS95 High | 59.2 to 294.9 | 6.00 | 5.99 | 0.21/0.05 | 4.555 | | 15.811 | 52958/52959 | 1.000
Ch08 IS95 Med | 63.0 to 306.6 | 3.00 | 3.00 | 0.25/0.06 | 2.116 | | 10.629 | 52923/52959 | 0.999
Ch10 IS95 Low | 62.1 to 309.8 | 1.50 | 1.50 | 0.25/0.06 | 0.882 | | 5.060 | 52930/52959 | 0.999
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 52959/52959 | 1.000
October 1 to 31, 2012
Female
Ch19 IS95 High | 114.0 to 197.6 | 6.00 | 5.98 | 0.17/0.04 | 4.850 | | 8.028 | 55335/55335 | 1.000
Ch18 IS95 Med | 120.7 to 206.2 | 3.00 | 2.99 | 0.16/0.04 | 2.437 | | 4.124 | 55335/55335 | 1.000
Ch21 IS95 Low | 119.7 to 205.3 | 1.50 | 1.49 | 0.18/0.04 | 1.089 | | 2.099 | 55335/55335 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 55339/55339 | 1.000
Male
Ch07 IS95 High | 132.0 to 301.0 | 6.00 | 5.96 | 0.18/0.04 | 4.878 | | 7.243 | 55351/55351 | 1.000
Ch08 IS95 Med | 141.5 to 312.6 | 3.00 | 2.98 | 0.19/0.04 | 2.297 | | 4.094 | 55351/55351 | 1.000
Ch10 IS95 Low | 140.4 to 313.4 | 1.50 | 1.49 | 0.19/0.05 | 1.118 | | 1.985 | 55339/55339 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 55351/55351 | 1.000
November 1 to 30, 2012
Female
Ch19 IS95 High | 204.3 to 239.5 | 6.00 | 5.99 | 0.18/0.04 | 4.441 | | 9.544 | 53852/53853 | 1.000
Ch18 IS95 Med | 211.8 to 248.7 | 3.00 | 2.98 | 0.15/0.04 | 2.556 | | 3.879 | 53853/53853 | 1.000
Ch21 IS95 Low | 210.9 to 249.2 | 1.50 | 1.49 | 0.16/0.04 | 1.205 | | 2.100 | 53853/53853 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 53853/53853 | 1.000
Male
Ch07 IS95 High | 310.9 to 383.3 | 6.00 | 5.99 | 0.17/0.04 | 5.166 | | 7.287 | 53853/53853 | 1.000
Ch08 IS95 Med | 323.1 to 396.1 | 3.00 | 2.99 | 0.17/0.04 | 2.432 | | 4.100 | 53853/53853 | 1.000
Ch10 IS95 Low | 324.6 to 399.7 | 1.50 | 1.49 | 0.17/0.04 | 1.251 | | 1.926 | 53853/53853 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 53853/53853 | 1.000
December 1 to 31, 2012
Female
Ch19 IS95 High | 239.5 to 251.0 | 6.00 | 5.96 | 0.16/0.04 | 4.865 | | 7.908 | 55608/55608 | 1.000
Ch18 IS95 Med | 248.7 to 262.3 | 3.00 | 2.98 | 0.15/0.04 | 2.463 | | 3.959 | 55608/55608 | 1.000
Ch21 IS95 Low | 249.2 to 261.3 | 1.50 | 1.49 | 0.17/0.04 | 1.129 | | 2.178 | 55608/55608 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 55608/55608 | 1.000
Male
Ch07 IS95 High | 383.3 to 412.5 | 6.00 | 5.99 | 0.18/0.04 | 5.000 | | 7.717 | 55608/55608 | 1.000
Ch08 IS95 Med | 396.1 to 426.2 | 3.00 | 2.99 | 0.16/0.04 | 2.506 | | 3.711 | 55608/55608 | 1.000
Ch10 IS95 Low | 399.7 to 428.6 | 1.50 | 1.50 | 0.17/0.04 | 1.228 | | 1.934 | 55608/55608 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 55608/55608 | 1.000
January 1 to 31, 2013
Female
Ch19 IS95 High | 250.9 to 270.7 | 6.00 | 5.98 | 0.16/0.04 | 4.937 | | 7.523 | 55617/55617 | 1.000
Ch18 IS95 Med | 262.3 to 280.6 | 3.00 | 3.00 | 0.28/0.07 | 1.426 | | 7.073 | 55545/55617 | 0.999
Ch21 IS95 Low | 261.3 to 277.7 | 1.50 | 1.49 | 0.17/0.04 | 1.188 | | 2.066 | 55617/55617 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 55619/55619 | 1.000
Male
Ch07 IS95 High | 412.5 to 452.2 | 6.00 | 6.01 | 0.18/0.04 | 4.995 | | 7.462 | 55619/55619 | 1.000
Ch08 IS95 Med | 426.2 to 463.0 | 3.00 | 2.98 | 0.16/0.04 | 2.592 | | 3.759 | 55619/55619 | 1.000
Ch10 IS95 Low | 428.6 to 462.1 | 1.50 | 1.49 | 0.17/0.04 | 1.279 | | 1.862 | 55619/55619 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 55619/55619 | 1.000
February 1 to 28, 2013
Female
Ch19 IS95 High | 270.7 to 279.9 | 6.00 | 6.00 | 0.16/0.04 | 5.200 | | 7.619 | 50082/50082 | 1.000
Ch18 IS95 Med | 280.6 to 290.1 | 3.00 | 2.98 | 0.14/0.03 | 2.609 | | 3.700 | 50082/50082 | 1.000
Ch21 IS95 Low | 277.7 to 287.3 | 1.50 | 1.49 | 0.17/0.04 | 1.151 | | 2.119 | 50082/50082 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 50082/50082 | 1.000
Male
Ch07 IS95 High | 452.2 to 472.2 | 6.00 | 5.98 | 0.18/0.04 | 5.098 | | 7.180 | 50082/50082 | 1.000
Ch08 IS95 Med | 463.0 to 491.2 | 3.00 | 2.99 | 0.17/0.04 | 2.585 | | 3.770 | 50082/50082 | 1.000
Ch10 IS95 Low | 462.1 to 488.9 | 1.50 | 1.49 | 0.17/0.04 | 1.253 | | 1.964 | 50082/50082 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 50082/50082 | 1.000
March 1 to 31, 2013
Female
Ch19 IS95 High | 279.9 to 288.7 | 6.00 | 5.98 | 0.16/0.04 | 4.893 | | 7.540 | 55704/55704 | 1.000
Ch18 IS95 Med | 290.1 to 300.4 | 3.00 | 2.99 | 0.15/0.03 | 2.491 | | 3.827 | 55704/55704 | 1.000
Ch21 IS95 Low | 287.3 to 299.3 | 1.50 | 1.48 | 0.17/0.04 | 1.183 | | 2.207 | 55704/55704 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 55704/55704 | 1.000
Male
Ch07 IS95 High | 472.2 to 495.2 | 6.00 | 6.00 | 0.18/0.04 | 5.039 | | 7.261 | 55704/55704 | 1.000
Ch08 IS95 Med | 491.2 to 512.3 | 3.00 | 3.00 | 0.17/0.04 | 2.563 | | 3.628 | 55704/55704 | 1.000
Ch10 IS95 Low | 488.9 to 510.6 | 1.50 | 1.50 | 0.17/0.04 | 1.257 | | 1.872 | 55704/55704 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | 0.000 | | 0.000 | 55704/55704 | 1.000
April 1 to 30, 2013
Female
Ch19 IS95 High | 288.7 to 299.5 | 6.00 | 5.95 | 0.16/0.04 | | 4.951 | 8.160 | 53719/53719 | 1.000
Ch18 IS95 Med | 300.4 to 310.6 | 3.00 | 2.98 | 0.15/0.03 | | 2.534 | 3.787 | 53719/53719 | 1.000
Ch21 IS95 Low | 299.3 to 308.0 | 1.50 | 1.49 | 0.18/0.04 | | 1.154 | 2.118 | 53719/53719 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53719/53719 | 1.000
Male
Ch07 IS95 High | 495.2 to 511.4 | 6.00 | 6.01 | 0.21/0.05 | | 4.216 | 9.118 | 53721/53721 | 1.000
Ch08 IS95 Med | 512.3 to 534.0 | 3.00 | 2.99 | 0.17/0.04 | | 2.515 | 3.740 | 53721/53721 | 1.000
Ch10 IS95 Low | 510.6 to 530.6 | 1.50 | 1.50 | 0.17/0.04 | | 1.260 | 1.985 | 53719/53719 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53722/53722 | 1.000
May 1 to 31, 2013
Female
Ch19 IS95 High | 299.5 to 308.8 | 6.00 | 5.98 | 0.16/0.04 | | 4.581 | 7.657 | 52762/52762 | 1.000
Ch18 IS95 Med | 310.6 to 320.6 | 3.00 | 3.00 | 0.15/0.03 | | 2.318 | 3.891 | 52762/52762 | 1.000
Ch21 IS95 Low | 308.0 to 315.8 | 1.50 | 1.48 | 0.18/0.04 | | 1.117 | 2.169 | 52762/52762 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 52762/52762 | 1.000
Male
Ch07 IS95 High | 511.4 to 530.9 | 6.00 | 5.99 | 0.19/0.04 | | 1.318 | 7.206 | 52788/52789 | 1.000
Ch08 IS95 Med | 534.0 to 552.1 | 3.00 | 2.99 | 0.17/0.04 | | 2.358 | 3.621 | 52788/52788 | 1.000
Ch10 IS95 Low | 530.6 to 550.3 | 1.50 | 1.49 | 0.18/0.04 | | 1.073 | 1.934 | 52762/52762 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 52790/52790 | 1.000
June 1 to 30, 2013
Female
Ch19 IS95 High | 308.8 to 316.4 | 6.00 | 5.97 | 0.16/0.04 | | 5.110 | 7.720 | 53537/53537 | 1.000
Ch18 IS95 Med | 320.6 to 332.1 | 3.00 | 3.00 | 0.15/0.04 | | 2.543 | 4.014 | 53537/53537 | 1.000
Ch21 IS95 Low | 315.8 to 328.3 | 1.50 | 1.50 | 0.19/0.05 | | 1.215 | 2.164 | 53537/53537 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53537/53537 | 1.000
Male
Ch07 IS95 High | 530.9 to 547.2 | 6.00 | 5.93 | 0.19/0.04 | | 4.899 | 7.410 | 53542/53542 | 1.000
Ch08 IS95 Med | 552.1 to 569.1 | 3.00 | 2.95 | 0.27/0.06 | | 1.304 | 3.920 | 53286/53542 | 0.995
Ch10 IS95 Low | 550.3 to 566.3 | 1.50 | 1.48 | 0.17/0.04 | | 1.274 | 1.860 | 53537/53537 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53544/53544 | 1.000
July 1 to 31, 2013
Female
Ch19 IS95 High | 316.4 to 332.3 | 6.00 | 6.02 | 0.16/0.04 | | 5.171 | 8.001 | 55527/55527 | 1.000
Ch18 IS95 Med | 332.1 to 351.4 | 3.00 | 2.98 | 0.14/0.03 | | 2.558 | 3.934 | 55527/55527 | 1.000
Ch21 IS95 Low | 328.3 to 346.1 | 1.50 | 1.49 | 0.18/0.04 | | 1.202 | 2.127 | 55527/55527 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55527/55527 | 1.000
Male
Ch07 IS95 High | 547.2 to 577.0 | 6.00 | 5.93 | 0.18/0.04 | | 4.797 | 7.368 | 55528/55528 | 1.000
Ch08 IS95 Med | 569.1 to 599.6 | 3.00 | 2.97 | 0.17/0.04 | | 2.531 | 3.655 | 55528/55528 | 1.000
Ch10 IS95 Low | 566.3 to 597.9 | 1.50 | 1.49 | 0.18/0.04 | | 1.246 | 1.938 | 55527/55527 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55531/55531 | 1.000
August 1 to 31, 2013
Female
Ch19 IS95 High | 332.3 to 342.8 | 6.00 | 5.99 | 0.16/0.04 | | 5.082 | 7.893 | 55952/55952 | 1.000
Ch18 IS95 Med | 351.4 to 360.3 | 3.00 | 2.97 | 0.15/0.03 | | 2.477 | 3.781 | 55952/55952 | 1.000
Ch21 IS95 Low | 346.1 to 356.6 | 1.50 | 1.48 | 0.18/0.04 | | 1.168 | 2.076 | 55952/55952 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55952/55952 | 1.000
Male
Ch07 IS95 High | 577.0 to 590.3 | 6.00 | 5.98 | 0.19/0.04 | | 5.067 | 7.207 | 55952/55952 | 1.000
Ch08 IS95 Med | 599.6 to 613.4 | 3.00 | 2.99 | 0.18/0.04 | | 2.116 | 4.677 | 55952/55952 | 1.000
Ch10 IS95 Low | 597.9 to 610.1 | 1.50 | 1.50 | 0.18/0.04 | | 1.264 | 1.981 | 55952/55952 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55955/55955 | 1.000
September 1 to 30, 2013
Female
Ch19 IS95 High | 342.8 to 349.6 | 6.00 | 5.97 | 0.17/0.04 | | 5.099 | 7.749 | 53696/53696 | 1.000
Ch18 IS95 Med | 360.3 to 366.3 | 3.00 | 2.99 | 0.15/0.03 | | 2.569 | 3.855 | 53696/53696 | 1.000
Ch21 IS95 Low | 356.6 to 363.7 | 1.50 | 1.48 | 0.18/0.04 | | 1.149 | 2.224 | 53696/53696 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53696/53696 | 1.000
Male
Ch07 IS95 High | 590.3 to 594.1 | 6.00 | 5.98 | 0.20/0.05 | | 3.989 | 7.867 | 53696/53696 | 1.000
Ch08 IS95 Med | 613.4 to 623.8 | 3.00 | 2.99 | 0.16/0.04 | | 2.588 | 3.626 | 53696/53696 | 1.000
Ch10 IS95 Low | 610.1 to 620.5 | 1.50 | 1.50 | 0.18/0.04 | | 1.237 | 1.814 | 53696/53696 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53703/53703 | 1.000
October 1 to 31, 2013
Female
Ch19 IS95 High | 349.6 to 358.7 | 6.00 | 5.96 | 0.18/0.04 | | 3.243 | 7.477 | 56746/56747 | 1.000
Ch18 IS95 Med | 366.3 to 377.2 | 3.00 | 2.99 | 0.19/0.04 | | 1.170 | 3.898 | 56706/56748 | 0.999
Ch21 IS95 Low | 363.7 to 375.4 | 1.50 | 1.49 | 0.19/0.04 | | 0.762 | 2.325 | 56746/56747 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 56748/56748 | 1.000
Male
Ch07 IS95 High | 594.1 to 603.9 | 6.00 | 5.95 | 0.19/0.05 | | 3.609 | 8.358 | 56747/56748 | 1.000
Ch08 IS95 Med | 623.8 to 632.5 | 3.00 | 2.97 | 0.18/0.04 | | 1.622 | 3.648 | 56747/56748 | 1.000
Ch10 IS95 Low | 620.5 to 631.5 | 1.50 | 1.49 | 0.19/0.04 | | 0.769 | 1.850 | 56747/56748 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 56807/56807 | 1.000
November 1 to 30, 2013
Female
Ch19 IS95 High | 358.7 to 366.5 | 6.00 | 5.96 | 0.21/0.05 | | 3.622 | 7.586 | 55322/55323 | 1.000
Ch18 IS95 Med | 377.2 to 385.8 | 3.00 | 3.00 | 0.19/0.05 | | 0.910 | 7.500 | 55319/55323 | 1.000
Ch21 IS95 Low | 375.4 to 384.9 | 1.50 | 1.49 | 0.23/0.05 | | 0.811 | 2.262 | 55322/55323 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55323/55323 | 1.000
Male
Ch07 IS95 High | 603.9 to 611.0 | 6.00 | 5.93 | 0.21/0.05 | | 2.254 | 7.558 | 55329/55330 | 1.000
Ch08 IS95 Med | 632.5 to 640.5 | 3.00 | 2.99 | 0.23/0.05 | | 2.092 | 4.959 | 55326/55329 | 1.000
Ch10 IS95 Low | 631.5 to 641.9 | 1.50 | 1.50 | 0.22/0.05 | | 1.059 | 2.127 | 55329/55329 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55332/55332 | 1.000
December 1 to 31, 2013
Female
Ch19 IS95 High | 366.5 to 374.5 | 6.00 | 6.00 | 0.19/0.05 | | 4.178 | 7.659 | 53057/53057 | 1.000
Ch18 IS95 Med | 385.8 to 393.5 | 3.00 | 2.97 | 0.16/0.04 | | 2.156 | 3.649 | 53099/53099 | 1.000
Ch21 IS95 Low | 384.9 to 395.7 | 1.50 | 1.49 | 0.19/0.05 | | 0.995 | 2.069 | 53057/53057 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53099/53099 | 1.000
Male
Ch07 IS95 High | 611.0 to 614.6 | 6.00 | 5.95 | 0.20/0.05 | | 0.989 | 7.282 | 53106/53108 | 1.000
Ch08 IS95 Med | 640.5 to 646.3 | 3.00 | 2.96 | 0.22/0.05 | | 1.270 | 4.996 | 53020/53106 | 0.998
Ch10 IS95 Low | 641.9 to 645.9 | 1.50 | 1.48 | 0.20/0.05 | | 1.015 | 1.773 | 53099/53099 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53111/53111 | 1.000
January 1 to 31, 2014
Female
Ch19 IS95 High | 374.5 to 386.3 | 6.00 | 5.98 | 0.17/0.04 | | 4.565 | 8.091 | 55621/55621 | 1.000
Ch18 IS95 Med | 393.5 to 405.6 | 3.00 | 2.98 | 0.14/0.03 | | 2.430 | 3.687 | 55626/55626 | 1.000
Ch21 IS95 Low | 395.7 to 408.4 | 1.50 | 1.48 | 0.16/0.04 | | 1.107 | 2.088 | 55621/55621 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55626/55626 | 1.000
Male
Ch07 IS95 High | 614.6 to 625.5 | 6.00 | 5.91 | 0.20/0.05 | | 4.782 | 7.279 | 55627/55627 | 1.000
Ch08 IS95 Med | 646.3 to 661.2 | 3.00 | 2.97 | 0.17/0.04 | | 2.235 | 3.510 | 55627/55627 | 1.000
Ch10 IS95 Low | 645.9 to 658.9 | 1.50 | 1.49 | 0.18/0.04 | | 1.169 | 1.845 | 55627/55627 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55629/55629 | 1.000
February 1 to 28, 2014
Female
Ch19 IS95 High | 386.3 to 401.1 | 6.00 | 5.95 | 0.17/0.04 | | 4.403 | 7.540 | 51974/51974 | 1.000
Ch18 IS95 Med | 405.6 to 417.2 | 3.00 | 2.99 | 0.15/0.04 | | 2.379 | 3.683 | 51974/51974 | 1.000
Ch21 IS95 Low | 408.4 to 423.0 | 1.50 | 1.49 | 0.18/0.04 | | 1.006 | 2.073 | 51974/51974 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 51974/51974 | 1.000
Male
Ch07 IS95 High | 625.5 to 637.7 | 6.00 | 5.92 | 0.19/0.04 | | 4.726 | 7.209 | 51974/51974 | 1.000
Ch08 IS95 Med | 661.2 to 671.2 | 3.00 | 2.98 | 0.16/0.04 | | 2.288 | 3.559 | 51974/51974 | 1.000
Ch10 IS95 Low | 658.9 to 672.1 | 1.50 | 1.50 | 0.18/0.04 | | 1.137 | 1.770 | 51974/51974 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 51980/51980 | 1.000
March 1 to 31, 2014
Female
Ch19 IS95 High | 401.1 to 415.9 | 6.00 | 5.99 | 0.16/0.04 | | 5.177 | 8.398 | 55704/55704 | 1.000
Ch18 IS95 Med | 417.2 to 426.8 | 3.00 | 2.99 | 0.13/0.03 | | 2.635 | 3.825 | 55704/55704 | 1.000
Ch21 IS95 Low | 423.0 to 433.7 | 1.50 | 1.48 | 0.16/0.04 | | 1.217 | 2.018 | 55704/55704 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55704/55704 | 1.000
Male
Ch07 IS95 High | 637.7 to 640.9 | 6.00 | 5.90 | 0.19/0.05 | | 4.851 | 7.304 | 55704/55704 | 1.000
Ch08 IS95 Med | 671.2 to 679.3 | 3.00 | 2.99 | 0.16/0.04 | | 2.519 | 3.608 | 55704/55704 | 1.000
Ch10 IS95 Low | 672.1 to 678.5 | 1.50 | 1.50 | 0.17/0.04 | | 1.262 | 1.804 | 55704/55704 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55704/55704 | 1.000
April 1 to 30, 2014
Female
Ch19 IS95 High | 415.9 to 430.6 | 6.00 | 5.95 | 0.16/0.04 | | 4.801 | 7.534 | 53643/53643 | 1.000
Ch18 IS95 Med | 426.8 to 440.1 | 3.00 | 2.98 | 0.13/0.03 | | 0.964 | 3.533 | 53643/53644 | 1.000
Ch21 IS95 Low | 433.7 to 439.9 | 1.50 | 1.48 | 0.16/0.04 | | 1.132 | 2.033 | 53643/53643 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53644/53644 | 1.000
Male
Ch07 IS95 High | 640.9 to 646.7 | 6.00 | 5.88 | 0.19/0.04 | | 1.418 | 7.181 | 53646/53647 | 1.000
Ch08 IS95 Med | 679.3 to 681.0 | 3.00 | 3.00 | 0.16/0.04 | | 2.308 | 3.621 | 53646/53646 | 1.000
Ch10 IS95 Low | 674.4 to 678.5 | 1.50 | 1.50 | 0.17/0.04 | | 0.894 | 1.966 | 53643/53644 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53649/53649 | 1.000
May 1 to 31, 2014
Female
Ch19 IS95 High | 430.6 to 435.9 | 6.00 | 5.92 | 0.15/0.04 | | 4.846 | 7.433 | 55602/55602 | 1.000
Ch18 IS95 Med | 440.1 to 447.7 | 3.00 | 2.98 | 0.13/0.03 | | 2.611 | 3.979 | 55604/55604 | 1.000
Ch21 IS95 Low | 439.9 to 448.6 | 1.50 | 1.49 | 0.17/0.04 | | 1.185 | 2.158 | 55602/55602 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55604/55604 | 1.000
Male
Ch07 IS95 High | 640.5 to 644.4 | 6.00 | 5.91 | 0.17/0.04 | | 4.656 | 7.371 | 55604/55604 | 1.000
Ch08 IS95 Med | 681.0 to 682.7 | 3.00 | 3.01 | 0.16/0.04 | | 2.370 | 3.513 | 55604/55604 | 1.000
Ch10 IS95 Low | 674.4 to 676.1 | 1.50 | 1.49 | 0.17/0.04 | | 1.210 | 1.822 | 55604/55604 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55604/55604 | 1.000
June 1 to 30, 2014
Female
Ch19 IS95 High | 435.9 to 447.6 | 6.00 | 5.92 | 0.21/0.05 | | 3.191 | 10.116 | 53730/53767 | 0.999
Ch18 IS95 Med | 447.7 to 462.8 | 3.00 | 2.98 | 0.14/0.03 | | 2.589 | 3.773 | 53770/53771 | 1.000
Ch21 IS95 Low | 448.6 to 454.5 | 1.50 | 1.49 | 0.16/0.04 | | 1.221 | 2.005 | 53767/53767 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53771/53771 | 1.000
Male
Ch07 IS95 High | 632.7 to 640.5 | 6.00 | 5.96 | 0.18/0.04 | | 4.891 | 7.698 | 53773/53773 | 1.000
Ch08 IS95 Med | 682.7 to 691.1 | 3.00 | 3.00 | 0.16/0.04 | | 2.562 | 3.605 | 53773/53773 | 1.000
Ch10 IS95 Low | 669.2 to 676.1 | 1.50 | 1.50 | 0.17/0.04 | | 1.255 | 1.785 | 53771/53771 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 53774/53774 | 1.000
July 1 to 31, 2014
Female
Ch19 IS95 High | 450.1 to 455.1 | 6.00 | 5.99 | 0.16/0.04 | | 5.236 | 7.748 | 55601/55601 | 1.000
Ch18 IS95 Med | 466.7 to 473.2 | 3.00 | 2.97 | 0.12/0.03 | | 2.635 | 3.904 | 55601/55601 | 1.000
Ch21 IS95 Low | 454.0 to 456.9 | 1.50 | 1.49 | 0.16/0.04 | | 1.221 | 3.108 | 55598/55601 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55601/55601 | 1.000
Male
Ch07 IS95 High | 633.3 to 638.9 | 6.00 | 5.97 | 0.17/0.04 | | 5.044 | 7.429 | 55601/55601 | 1.000
Ch08 IS95 Med | 675.8 to 689.3 | 3.00 | 3.01 | 0.15/0.04 | | 2.618 | 3.671 | 55601/55601 | 1.000
Ch10 IS95 Low | 661.6 to 671.6 | 1.50 | 1.49 | 0.16/0.04 | | 1.273 | 1.786 | 55601/55601 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 55603/55603 | 1.000
August 1 to 31, 2014
Female
Ch19 IS95 High | 455.1 to 457.3 | 6.00 | 5.99 | 0.17/0.04 | | 4.318 | 7.906 | 54354/54354 | 1.000
Ch18 IS95 Med | 470.8 to 473.2 | 3.00 | 2.97 | 0.13/0.03 | | 2.314 | 3.894 | 54354/54354 | 1.000
Ch21 IS95 Low | 451.0 to 456.9 | 1.50 | 1.49 | 0.18/0.04 | | 1.046 | 2.193 | 54354/54354 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 54354/54354 | 1.000
Male
Ch07 IS95 High | 622.8 to 633.3 | 6.00 | 5.94 | 0.18/0.04 | | 4.629 | 7.561 | 54354/54354 | 1.000
Ch08 IS95 Med | 659.4 to 675.8 | 3.00 | 2.98 | 0.17/0.04 | | 2.209 | 3.803 | 54354/54354 | 1.000
Ch10 IS95 Low | 649.7 to 661.6 | 1.50 | 1.49 | 0.16/0.04 | | 1.090 | 1.855 | 54354/54354 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 54358/54358 | 1.000
September 1 to 30, 2014
Female
Ch19 IS95 High | 454.2 to 455.7 | 6.00 | 5.99 | 0.18/0.04 | | 4.062 | 10.317 | 52080/52088 | 1.000
Ch18 IS95 Med | 467.7 to 471.7 | 3.00 | 2.97 | 0.14/0.03 | | 2.195 | 4.559 | 52088/52088 | 1.000
Ch21 IS95 Low | 445.6 to 453.5 | 1.50 | 1.49 | 0.16/0.04 | | 0.880 | 2.711 | 52086/52088 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 52088/52088 | 1.000
Male
Ch07 IS95 High | 620.1 to 622.8 | 6.00 | 5.93 | 0.16/0.04 | | 4.185 | 9.677 | 52087/52088 | 1.000
Ch08 IS95 Med | 648.3 to 659.4 | 3.00 | 2.97 | 0.16/0.04 | | 2.066 | 4.741 | 52088/52088 | 1.000
Ch10 IS95 Low | 661.1 to 665.3 | 1.50 | 1.48 | 0.15/0.03 | | 1.038 | 2.242 | 52088/52088 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 52088/52088 | 1.000
August 8, 2012 to September 30, 2014
Female
Ch19 IS95 High | 55.9 to 457.3 | 6.00 | 5.97 | 0.17/0.04 | | 2.650 | 10.317 | 1400143/1400194 | 1.000
Ch18 IS95 Med | 59.6 to 473.2 | 3.00 | 2.98 | 0.16/0.04 | | 0.910 | 7.500 | 1400123/1400249 | 1.000
Ch21 IS95 Low | 59.3 to 456.9 | 1.50 | 1.49 | 0.18/0.04 | | 0.653 | 3.108 | 1400183/1400194 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 1400255/1400255 | 1.000
Male
Ch07 IS95 High | 59.2 to 646.7 | 6.00 | 5.96 | 0.19/0.04 | | 0.989 | 15.811 | 1400312/1400324 | 1.000
Ch08 IS95 Med | 63.0 to 691.1 | 3.00 | 2.98 | 0.18/0.04 | | 1.077 | 10.629 | 1399933/1400319 | 1.000
Ch10 IS95 Low | 62.1 to 678.5 | 1.50 | 1.49 | 0.18/0.04 | | 0.593 | 5.060 | 1400227/1400262 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | 0.00 | –/0.00 | | 0.000 | 0.000 | 1400422/1400422 | 1.000

Ch = chamber (e.g., Ch19 = Chamber 19).

Table I‑6 Summary of CDMA-modulated Cell Phone RFR Exposure Data in Rats – Chamber Field

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | Max [V/m] | In Range/Total | | Ratio
August 8 to 31, 2012
Male
Ch07 IS95 High | 246.10 to 283.80 | 262.13 | 0.17/5.16 | 149.00 | 313.07 | 85778/85786 | | 1.000
Ch08 IS95 Med | 174.00 to 200.70 | 185.32 | 0.17/3.59 | 106.47 | 226.74 | 85778/85786 | | 1.000
Ch10 IS95 Low | 123.10 to 143.40 | 131.39 | 0.17/2.54 | 78.99 | 159.09 | 85778/85786 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 85786/85786 | | 1.000
September 1 -30, 2012
Female
Ch19 IS95 High | 192.60 to 269.00 | 237.99 | 0.18/4.99 | 178.91 | 298.61 | 105918/105918 | | 1.000
Ch18 IS95 Med | 135.90 to 190.20 | 167.15 | 0.19/3.68 | 125.16 | 210.93 | 105912/105918 | | 1.000
Ch21 IS95 Low | 096.30 to 134.50 | 118.94 | 0.19/2.66 | 87.59 | 154.09 | 105916/105918 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 105918/105918 | | 1.000
Male
Ch07 IS95 High | 192.20 to 266.50 | 235.04 | 0.21/5.62 | 177.28 | 375.72 | 105916/105918 | | 1.000
Ch08 IS95 Med | 136.20 to 190.20 | 165.57 | 0.23/4.50 | 127.08 | 284.85 | 105854/105918 | | 0.999
Ch10 IS95 Low | 096.30 to 134.50 | 116.96 | 0.23/3.16 | 82.06 | 196.54 | 105864/105918 | | 0.999
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 105918/105918 | | 1.000
October 1 to 31, 2012
Female
Ch19 IS95 High | 193.80 to 228.70 | 213.07 | 0.17/4.14 | 177.92 | 257.59 | 110670/110670 | | 1.000
Ch18 IS95 Med | 139.30 to 164.60 | 152.45 | 0.16/2.82 | 126.67 | 185.53 | 110670/110670 | | 1.000
Ch21 IS95 Low | 096.90 to 116.40 | 107.57 | 0.18/2.21 | 85.78 | 135.10 | 110670/110670 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 110678/110678 | | 1.000
Male
Ch07 IS95 High | 201.30 to 269.00 | 238.68 | 0.19/5.16 | 184.54 | 291.28 | 110702/110702 | | 1.000
Ch08 IS95 Med | 145.90 to 192.20 | 171.66 | 0.19/3.79 | 127.64 | 224.82 | 110702/110702 | | 1.000
Ch10 IS95 Low | 103.10 to 135.90 | 121.30 | 0.20/2.77 | 91.15 | 149.99 | 110678/110678 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 110702/110702 | | 1.000
November 1 to 30, 2012
Female
Ch19 IS95 High | 232.80 to 246.10 | 240.74 | 0.18/4.97 | 207.64 | 304.40 | 107704/107706 | | 1.000
Ch18 IS95 Med | 167.60 to 177.30 | 172.96 | 0.15/3.08 | 157.53 | 202.06 | 107706/107706 | | 1.000
Ch21 IS95 Low | 118.50 to 125.40 | 121.96 | 0.16/2.33 | 106.52 | 148.67 | 107706/107706 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 107706/107706 | | 1.000
Male
Ch07 IS95 High | 271.80 to 292.20 | 282.34 | 0.17/5.61 | 252.88 | 319.04 | 107706/107706 | | 1.000
Ch08 IS95 Med | 194.20 to 208.20 | 201.56 | 0.17/4.01 | 176.59 | 233.27 | 107706/107706 | | 1.000
Ch10 IS95 Low | 137.40 to 147.30 | 142.68 | 0.17/2.76 | 129.54 | 163.57 | 107706/107706 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 107706/107706 | | 1.000
December 1 to 31, 2012
Female
Ch19 IS95 High | 246.10 to 254.90 | 252.54 | 0.16/4.78 | 226.29 | 291.17 | 111216/111216 | | 1.000
Ch18 IS95 Med | 177.30 to 182.70 | 180.85 | 0.15/3.18 | 163.62 | 209.74 | 111216/111216 | | 1.000
Ch21 IS95 Low | 125.40 to 129.20 | 127.68 | 0.17/2.52 | 110.99 | 155.56 | 111216/111216 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111216/111216 | | 1.000
Male
Ch07 IS95 High | 292.20 to 298.00 | 296.07 | 0.18/6.03 | 268.82 | 336.88 | 111216/111216 | | 1.000
Ch08 IS95 Med | 208.20 to 211.70 | 210.45 | 0.16/3.97 | 191.98 | 235.34 | 111216/111216 | | 1.000
Ch10 IS95 Low | 147.30 to 149.70 | 148.95 | 0.17/2.90 | 134.40 | 168.66 | 111216/111216 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111216/111216 | | 1.000
January 1 to 31, 2013
Female
Ch19 IS95 High | 254.90 to 261.40 | 258.29 | 0.16/4.89 | 236.85 | 292.38 | 111234/111234 | | 1.000
Ch18 IS95 Med | 182.70 to 186.70 | 184.88 | 0.25/5.50 | 125.89 | 280.35 | 111090/111234 | | 0.999
Ch21 IS95 Low | 129.20 to 130.70 | 129.67 | 0.17/2.50 | 115.01 | 151.52 | 111234/111234 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111238/111238 | | 1.000
Male
Ch07 IS95 High | 298.00 to 302.10 | 299.87 | 0.18/6.32 | 271.01 | 336.24 | 111238/111238 | | 1.000
Ch08 IS95 Med | 211.70 to 214.00 | 212.58 | 0.16/3.99 | 198.00 | 240.49 | 111238/111238 | | 1.000
Ch10 IS95 Low | 149.70 to 151.40 | 150.39 | 0.18/3.07 | 138.67 | 168.35 | 111238/111238 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111238/111238 | | 1.000
February 1 to 28, 2013
Female
Ch19 IS95 High | 261.40 to 261.40 | 261.07 | 0.16/4.80 | 243.09 | 294.24 | 100164/100164 | | 1.000
Ch18 IS95 Med | 186.70 to 188.40 | 187.39 | 0.14/3.14 | 174.17 | 209.88 | 100164/100164 | | 1.000
Ch21 IS95 Low | 130.70 to 132.00 | 131.14 | 0.17/2.53 | 115.67 | 155.65 | 100164/100164 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 100164/100164 | | 1.000
Male
Ch07 IS95 High | 302.10 to 303.40 | 302.43 | 0.18/6.36 | 278.47 | 332.36 | 100164/100164 | | 1.000
Ch08 IS95 Med | 214.00 to 215.50 | 214.43 | 0.17/4.19 | 199.44 | 240.83 | 100164/100164 | | 1.000
Ch10 IS95 Low | 151.40 to 152.00 | 151.48 | 0.17/2.95 | 138.83 | 173.82 | 100164/100164 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 100164/100164 | | 1.000
March 1 to 31, 2013
Female
Ch19 IS95 High | 261.40 to 264.00 | 262.72 | 0.16/4.86 | 235.81 | 294.38 | 111408/111408 | | 1.000
Ch18 IS95 Med | 188.40 to 190.20 | 189.26 | 0.15/3.30 | 173.24 | 214.74 | 111408/111408 | | 1.000
Ch21 IS95 Low | 132.00 to 133.20 | 132.32 | 0.17/2.63 | 117.29 | 162.11 | 111408/111408 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111408/111408 | | 1.000
Male
Ch07 IS95 High | 303.40 to 304.70 | 303.64 | 0.18/6.44 | 278.43 | 334.23 | 111408/111408 | | 1.000
Ch08 IS95 Med | 215.50 to 216.80 | 215.84 | 0.17/4.25 | 198.63 | 238.10 | 111408/111408 | | 1.000
Ch10 IS95 Low | 152.00 to 153.30 | 152.54 | 0.18/3.12 | 139.06 | 171.02 | 111408/111408 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111408/111408 | | 1.000
April 1 to 30, 2013
Female
Ch19 IS95 High | 264.00 to 266.50 | 265.43 | 0.16/5.03 | 239.94 | 308.04 | | 107438/107438 | 1.000
Ch18 IS95 Med | 190.20 to 192.20 | 191.35 | 0.15/3.29 | 176.86 | 215.07 | | 107438/107438 | 1.000
Ch21 IS95 Low | 133.20 to 134.50 | 133.62 | 0.18/2.84 | 117.93 | 159.75 | | 107438/107438 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 107438/107438 | 1.000
Male
Ch07 IS95 High | 304.70 to 306.60 | 305.73 | 0.21/7.39 | 256.68 | 377.45 | | 107442/107442 | 1.000
Ch08 IS95 Med | 216.80 to 218.30 | 217.43 | 0.17/4.28 | 198.25 | 242.05 | | 107442/107442 | 1.000
Ch10 IS95 Low | 153.30 to 154.40 | 153.76 | 0.17/3.11 | 141.43 | 176.11 | | 107438/107438 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 107444/107444 | 1.000
May 1 to 31, 2013
Female
Ch19 IS95 High | 266.50 to 269.00 | 268.19 | 0.16/5.04 | 234.94 | 303.73 | | 105524/105524 | 1.000
Ch18 IS95 Med | 192.20 to 194.20 | 193.45 | 0.15/3.32 | 170.21 | 220.53 | | 105524/105524 | 1.000
Ch21 IS95 Low | 134.50 to 135.90 | 135.05 | 0.18/2.89 | 117.44 | 161.67 | | 105524/105524 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 105524/105524 | 1.000
Male
Ch07 IS95 High | 306.60 to 308.80 | 307.80 | 0.19/6.77 | 144.64 | 338.21 | | 105576/105578 | 1.000
Ch08 IS95 Med | 218.30 to 220.10 | 219.28 | 0.17/4.41 | 195.00 | 241.33 | | 105576/105576 | 1.000
Ch10 IS95 Low | 154.40 to 155.60 | 155.02 | 0.18/3.21 | 131.56 | 176.60 | | 105524/105524 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 105580/105580 | 1.000
June 1 to 30, 2013
Female
Ch19 IS95 High | 269.00 to 271.80 | 271.14 | 0.16/5.18 | 251.16 | 308.73 | | 107074/107074 | 1.000
Ch18 IS95 Med | 194.20 to 196.40 | 195.78 | 0.15/3.44 | 180.58 | 226.84 | | 107074/107074 | 1.000
Ch21 IS95 Low | 135.90 to 137.40 | 136.65 | 0.19/3.09 | 123.25 | 164.46 | | 107074/107074 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 107074/107074 | 1.000
Male
Ch07 IS95 High | 308.80 to 310.00 | 309.00 | 0.19/6.87 | 281.09 | 345.71 | | 107084/107084 | 1.000
Ch08 IS95 Med | 220.10 to 221.00 | 219.62 | 0.30/7.81 | 145.05 | 251.44 | | 106572/107084 | 0.995
Ch10 IS95 Low | 155.60 to 156.30 | 155.84 | 0.18/3.19 | 144.54 | 174.62 | | 107074/107074 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 107088/107088 | 1.000
July 1 to 31, 2013
Female
Ch19 IS95 High | 271.80 to 277.70 | 274.50 | 0.16/5.16 | 254.24 | 316.25 | | 111054/111054 | 1.000
Ch18 IS95 Med | 196.40 to 200.70 | 198.18 | 0.15/3.36 | 184.01 | 227.52 | | 111054/111054 | 1.000
Ch21 IS95 Low | 137.40 to 140.40 | 138.38 | 0.18/2.96 | 124.13 | 165.13 | | 111054/111054 | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 111054/111054 | 1.000
Male
Ch07 IS95 High | 310.00 to 314.00 | 311.52 | 0.19/6.78 | 280.42 | 347.54 | | 111056/111056 | 1.000
Ch08 IS95 Med | 221.00 to 223.90 | 222.27 | 0.17/4.39 | 205.37 | 246.82 | | 111056/111056 | 1.000
Ch10 IS95 Low | 156.30 to 158.40 | 157.32 | 0.18/3.25 | 144.08 | 179.70 | | 111054/111054 | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | | 111062/111062 | 1.000
August 1 to 31, 2013
Female
Ch19 IS95 High | 277.70 to 280.80 | 277.82 | 0.16/5.30 | 255.25 | 318.10 | 111904/111904 | | 1.000
Ch18 IS95 Med | 200.70 to 202.80 | 200.65 | 0.15/3.46 | 182.96 | 226.03 | 111904/111904 | | 1.000
Ch21 IS95 Low | 140.40 to 141.90 | 140.10 | 0.18/2.95 | 123.98 | 165.26 | 111904/111904 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111904/111904 | | 1.000
Male
Ch07 IS95 High | 314.00 to 316.70 | 313.45 | 0.19/6.88 | 288.22 | 345.98 | 111904/111904 | | 1.000
Ch08 IS95 Med | 223.90 to 225.90 | 223.44 | 0.18/4.66 | 189.39 | 281.55 | 111904/111904 | | 1.000
Ch10 IS95 Low | 158.40 to 159.70 | 158.24 | 0.18/3.30 | 145.14 | 183.22 | 111904/111904 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111910/111910 | | 1.000
September 1 to 30, 2013
Female
Ch19 IS95 High | 280.80 to 280.80 | 280.29 | 0.17/5.48 | 259.03 | 319.31 | 107392/107392 | | 1.000
Ch18 IS95 Med | 202.80 to 202.80 | 202.31 | 0.15/3.44 | 187.61 | 229.81 | 107392/107392 | | 1.000
Ch21 IS95 Low | 141.90 to 143.40 | 141.65 | 0.19/3.06 | 124.62 | 173.37 | 107392/107392 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 107392/107392 | | 1.000
Male
Ch07 IS95 High | 316.70 to 316.70 | 315.70 | 0.21/7.59 | 257.86 | 362.09 | 107392/107392 | | 1.000
Ch08 IS95 Med | 225.90 to 226.80 | 225.46 | 0.16/4.24 | 209.57 | 250.04 | 107392/107392 | | 1.000
Ch10 IS95 Low | 159.70 to 160.40 | 159.61 | 0.18/3.40 | 146.04 | 175.95 | 107392/107392 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 107406/107406 | | 1.000
October 1 to 31, 2013
Female
Ch19 IS95 High | 280.80 to 283.80 | 281.41 | 0.18/5.86 | 206.58 | 313.65 | 113492/113494 | | 1.000
Ch18 IS95 Med | 202.80 to 204.80 | 203.01 | 0.20/4.82 | 126.61 | 231.08 | 113412/113496 | | 0.999
Ch21 IS95 Low | 143.40 to 144.80 | 143.35 | 0.19/3.19 | 102.19 | 178.48 | 113492/113494 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 113496/113496 | | 1.000
Male
Ch07 IS95 High | 316.70 to 318.10 | 315.94 | 0.20/7.20 | 245.25 | 373.22 | 113494/113496 | | 1.000
Ch08 IS95 Med | 226.80 to 227.70 | 226.35 | 0.18/4.72 | 167.22 | 250.80 | 113494/113496 | | 1.000
Ch10 IS95 Low | 160.40 to 161.00 | 160.43 | 0.19/3.55 | 115.17 | 178.59 | 113494/113496 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 113614/113614 | | 1.000
November 1 to 30, 2013
Female
Ch19 IS95 High | 283.80 to 286.80 | 284.53 | 0.22/7.15 | 222.74 | 322.36 | 110644/110646 | | 1.000
Ch18 IS95 Med | 204.80 to 206.70 | 205.34 | 0.19/4.62 | 114.00 | 327.33 | 110638/110646 | | 1.000
Ch21 IS95 Low | 144.80 to 146.10 | 144.71 | 0.23/3.95 | 107.65 | 179.75 | 110644/110646 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 110646/110646 | | 1.000
Male
Ch07 IS95 High | 318.10 to 319.40 | 316.80 | 0.21/7.75 | 195.44 | 357.91 | 110658/110660 | | 1.000
Ch08 IS95 Med | 227.70 to 228.70 | 227.67 | 0.23/6.06 | 191.58 | 294.96 | 110652/110658 | | 1.000
Ch10 IS95 Low | 161.00 to 161.70 | 161.12 | 0.22/4.20 | 136.29 | 193.18 | 110658/110658 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 110664/110664 | | 1.000
December 1 to 31, 2013
Female
Ch19 IS95 High | 286.80 to 289.60 | 287.74 | 0.20/6.62 | 239.22 | 323.90 | 106114/106114 | | 1.000
Ch18 IS95 Med | 206.70 to 208.20 | 206.92 | 0.16/3.94 | 175.52 | 229.96 | 106198/106198 | | 1.000
Ch21 IS95 Low | 146.10 to 147.30 | 146.20 | 0.20/3.39 | 119.22 | 173.18 | 106114/106114 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 106198/106198 | | 1.000
Male
Ch07 IS95 High | 319.40 to 319.40 | 317.36 | 0.21/7.68 | 129.45 | 351.31 | 106212/106216 | | 1.000
Ch08 IS95 Med | 228.70 to 228.70 | 227.86 | 0.24/6.43 | 149.29 | 296.06 | 106040/106212 | | 0.998
Ch10 IS95 Low | 161.70 to 161.70 | 161.31 | 0.20/3.83 | 133.47 | 176.37 | 106198/106198 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 106222/106222 | | 1.000
January 1 to 31, 2014
Female
Ch19 IS95 High | 289.60 to 292.20 | 290.54 | 0.17/5.74 | 255.37 | 335.23 | 111242/111242 | | 1.000
Ch18 IS95 Med | 208.20 to 209.60 | 208.51 | 0.14/3.48 | 188.48 | 232.86 | 111252/111252 | | 1.000
Ch21 IS95 Low | 147.30 to 148.20 | 147.24 | 0.17/2.87 | 126.66 | 175.22 | 111242/111242 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111252/111252 | | 1.000
Male
Ch07 IS95 High | 319.40 to 320.80 | 318.05 | 0.20/7.53 | 284.68 | 354.25 | 111254/111254 | | 1.000
Ch08 IS95 Med | 228.70 to 230.60 | 229.35 | 0.17/4.50 | 198.04 | 248.14 | 111254/111254 | | 1.000
Ch10 IS95 Low | 161.70 to 162.40 | 161.88 | 0.18/3.41 | 143.19 | 179.92 | 111254/111254 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111258/111258 | | 1.000
February 1 to 28, 2014
Female
Ch19 IS95 High | 292.20 to 296.40 | 294.48 | 0.17/5.90 | 254.46 | 333.00 | 103948/103948 | | 1.000
Ch18 IS95 Med | 209.60 to 210.70 | 209.78 | 0.15/3.68 | 187.04 | 232.71 | 103948/103948 | | 1.000
Ch21 IS95 Low | 148.20 to 149.70 | 148.69 | 0.18/3.11 | 122.51 | 175.92 | 103948/103948 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 103948/103948 | | 1.000
Male
Ch07 IS95 High | 320.80 to 322.10 | 319.38 | 0.19/7.15 | 285.45 | 352.56 | 103948/103948 | | 1.000
Ch08 IS95 Med | 230.60 to 231.50 | 230.65 | 0.16/4.37 | 202.15 | 252.10 | 103948/103948 | | 1.000
Ch10 IS95 Low | 162.40 to 163.70 | 163.15 | 0.19/3.52 | 142.50 | 177.01 | 103948/103948 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 103960/103960 | | 1.000
March 1 to 31, 2014
Female
Ch19 IS95 High | 296.40 to 298.00 | 296.72 | 0.16/5.55 | 275.93 | 351.43 | 111408/111408 | | 1.000
Ch18 IS95 Med | 210.70 to 211.70 | 210.79 | 0.13/3.27 | 197.92 | 238.93 | 111408/111408 | | 1.000
Ch21 IS95 Low | 149.70 to 150.20 | 149.49 | 0.16/2.76 | 134.93 | 173.56 | 111408/111408 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111408/111408 | | 1.000
Male
Ch07 IS95 High | 322.10 to 323.40 | 320.78 | 0.19/7.24 | 291.74 | 354.86 | 111408/111408 | | 1.000
Ch08 IS95 Med | 231.50 to 231.50 | 231.09 | 0.16/4.30 | 212.10 | 253.84 | 111408/111408 | | 1.000
Ch10 IS95 Low | 163.70 to 163.70 | 163.52 | 0.17/3.29 | 150.14 | 179.49 | 111408/111408 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111408/111408 | | 1.000
April 1 to 30, 2014
Female
Ch19 IS95 High | 298.00 to 300.40 | 299.05 | 0.16/5.69 | 269.69 | 337.86 | 107286/107286 | | 1.000
Ch18 IS95 Med | 211.70 to 213.10 | 212.13 | 0.14/3.33 | 120.89 | 231.36 | 107286/107288 | | 1.000
Ch21 IS95 Low | 150.20 to 150.20 | 149.60 | 0.16/2.80 | 130.96 | 175.51 | 107286/107286 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 107288/107288 | | 1.000
Male
Ch07 IS95 High | 323.40 to 323.40 | 321.14 | 0.19/7.22 | 157.72 | 354.94 | 107292/107294 | | 1.000
Ch08 IS95 Med | 231.50 to 232.50 | 231.60 | 0.16/4.24 | 203.00 | 254.30 | 107292/107292 | | 1.000
Ch10 IS95 Low | 163.70 to 163.70 | 163.39 | 0.17/3.27 | 126.33 | 187.37 | 107286/107288 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 107298/107298 | | 1.000
May 1 to 31, 2014
Female
Ch19 IS95 High | 300.40 to 300.40 | 299.44 | 0.16/5.43 | 270.97 | 335.58 | 111204/111204 | | 1.000
Ch18 IS95 Med | 213.10 to 213.10 | 212.29 | 0.13/3.28 | 198.92 | 245.53 | 111208/111208 | | 1.000
Ch21 IS95 Low | 150.20 to 150.70 | 150.10 | 0.17/2.90 | 134.01 | 180.82 | 111204/111204 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111208/111208 | | 1.000
Male
Ch07 IS95 High | 323.40 to 323.40 | 321.82 | 0.18/6.66 | 285.79 | 359.61 | 111208/111208 | | 1.000
Ch08 IS95 Med | 232.50 to 232.50 | 231.90 | 0.16/4.25 | 205.74 | 250.46 | 111208/111208 | | 1.000
Ch10 IS95 Low | 163.70 to 163.70 | 163.33 | 0.17/3.31 | 146.99 | 180.37 | 111208/111208 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111208/111208 | | 1.000
June 1 to 30, 2014
Female
Ch19 IS95 High | 300.40 to 301.30 | 299.48 | 0.21/7.42 | 219.87 | 391.50 | 107460/107534 | | 0.999
Ch18 IS95 Med | 213.10 to 214.00 | 213.08 | 0.15/3.59 | 26.52 | 239.11 | 107540/107542 | | 1.000
Ch21 IS95 Low | 150.70 to 151.00 | 150.40 | 0.16/2.76 | 136.04 | 174.27 | 107534/107534 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 107542/107542 | | 1.000
Male
Ch07 IS95 High | 322.10 to 323.40 | 320.57 | 0.18/6.62 | 290.40 | 364.33 | 107546/107546 | | 1.000
Ch08 IS95 Med | 232.50 to 233.40 | 232.22 | 0.16/4.18 | 213.90 | 253.72 | 107546/107546 | | 1.000
Ch10 IS95 Low | 163.00 to 163.70 | 163.46 | 0.17/3.26 | 149.73 | 178.52 | 107542/107542 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 107548/107548 | | 1.000
July 1 to 31, 2014
Female
Ch19 IS95 High | 302.10 to 302.10 | 301.20 | 0.16/5.68 | 281.66 | 342.63 | 111202/111202 | | 1.000
Ch18 IS95 Med | 214.00 to 214.50 | 213.60 | 0.12/3.09 | 201.33 | 245.08 | 111202/111202 | | 1.000
Ch21 IS95 Low | 151.00 to 151.00 | 150.44 | 0.16/2.86 | 136.02 | 217.00 | 111196/111202 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111202/111202 | | 1.000
Male
Ch07 IS95 High | 322.10 to 322.10 | 320.71 | 0.17/6.37 | 294.89 | 357.89 | 111202/111202 | | 1.000
Ch08 IS95 Med | 231.50 to 232.50 | 231.74 | 0.15/4.11 | 216.21 | 256.04 | 111202/111202 | | 1.000
Ch10 IS95 Low | 163.00 to 163.70 | 163.06 | 0.16/3.07 | 150.77 | 178.56 | 111202/111202 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 111206/111206 | | 1.000
August 1 to 31, 2014
Female
Ch19 IS95 High | 302.10 to 302.10 | 301.12 | 0.17/6.05 | 255.77 | 346.10 | 108708/108708 | | 1.000
Ch18 IS95 Med | 214.50 to 214.50 | 213.73 | 0.14/3.37 | 188.69 | 244.76 | 108708/108708 | | 1.000
Ch21 IS95 Low | 151.00 to 151.00 | 150.40 | 0.18/3.13 | 125.88 | 182.30 | 108708/108708 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 108708/108708 | | 1.000
Male
Ch07 IS95 High | 320.80 to 322.10 | 319.89 | 0.18/6.73 | 282.50 | 361.05 | 108708/108708 | | 1.000
Ch08 IS95 Med | 229.60 to 231.50 | 230.28 | 0.17/4.59 | 198.60 | 258.77 | 108708/108708 | | 1.000
Ch10 IS95 Low | 161.70 to 163.00 | 162.21 | 0.17/3.17 | 138.29 | 181.98 | 108708/108708 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 108716/108716 | | 1.000
September 1 to 30, 2014
Female
Ch19 IS95 High | 302.10 to 302.10 | 301.19 | 0.17/6.11 | 248.08 | 395.37 | 104162/104176 | | 1.000
Ch18 IS95 Med | 214.00 to 214.50 | 213.67 | 0.14/3.50 | 183.75 | 264.84 | 104176/104176 | | 1.000
Ch21 IS95 Low | 150.70 to 151.00 | 150.24 | 0.17/2.89 | 115.49 | 202.67 | 104172/104176 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 104176/104176 | | 1.000
Male
Ch07 IS95 High | 320.80 to 320.80 | 319.75 | 0.16/6.09 | 268.63 | 408.47 | 104174/104176 | | 1.000
Ch08 IS95 Med | 228.70 to 229.60 | 228.28 | 0.16/4.23 | 190.37 | 288.41 | 104174/104176 | | 1.000
Ch10 IS95 Low | 163.00 to 163.00 | 162.73 | 0.15/2.84 | 136.12 | 200.08 | 104176/104176 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 104176/104176 | | 1.000
August 8, 2012 to September 30, 2014
Female
Ch19 IS95 High | 192.60 to 302.10 | 275.55 | 0.17/5.49 | 167.01 | 395.37 | 2800288/2800388 | | 1.000
Ch18 IS95 Med | 135.90 to 214.50 | 197.17 | 0.16/3.62 | 26.52 | 327.33 | 2800246/2800498 | | 1.000
Ch21 IS95 Low | 096.30 to 151.00 | 138.76 | 0.18/2.87 | 82.90 | 217.00 | 2800366/2800388 | | 1.000
Ch15 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 2800510/2800510 | | 1.000
Male
Ch07 IS95 High | 192.20 to 323.40 | 304.76 | 0.19/6.72 | 129.45 | 408.47 | 2800624/2800648 | | 1.000
Ch08 IS95 Med | 136.20 to 233.40 | 218.09 | 0.18/4.65 | 106.47 | 296.06 | 2799872/2800638 | | 1.000
Ch10 IS95 Low | 096.30 to 163.70 | 154.21 | 0.18/3.24 | 78.99 | 200.08 | 2800458/2800524 | | 1.000
Ch04 Sham Control | 000.00 to 000.00 | 0.00 | –/0.00 | 0.00 | 0.00 | 2800844/2800844 | | 1.000

Ch = chamber (e.g., Ch19 = Chamber 19).

Table I‑7 Summary of CDMA-modulated Cell Phone RFR Exposure Data in Rats – E-Field

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | Max [V/m] | In Range/Total | Ratio
August 8 to 31, 2012
Male
Ch07 IS95 High | 246.1 to 283.8 | 249.97 | 0.24/6.98 | 136.7 | 310.0 | 85778/85786 | 1.000
Ch08 IS95 Med | 174.0 to 200.7 | 177.30 | 0.22/4.61 | 102.5 | 212.3 | 85778/85786 | 1.000
Ch10 IS95 Low | 123.1 to 143.4 | 124.27 | 0.21/3.05 | 77.3 | 151.3 | 85778/85786 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 85786/85786 | 1.000
September 1 to 30, 2012
Female
Ch19 IS95 High | 192.6 to 269.0 | 239.48 | 0.24/6.85 | 181.6 | 297.4 | 105910/105918 | 1.000
Ch18 IS95 Med | 135.9 to 190.2 | 157.66 | 0.26/4.84 | 114.7 | 202.6 | 105916/105918 | 1.000
Ch21 IS95 Low | 96.3 to 134.5 | 115.70 | 0.45/6.14 | 80.0 | 157.2 | 105916/105918 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 105918/105918 | 1.000
Male
Ch07 IS95 High | 192.2 to 266.5 | 225.11 | 0.25/6.52 | 167.5 | 349.5 | 105916/105918 | 1.000
Ch08 IS95 Med | 136.2 to 190.2 | 159.21 | 0.33/6.15 | 123.1 | 288.1 | 105874/105918 | 1.000
Ch10 IS95 Low | 96.3 to 134.5 | 113.59 | 0.28/3.67 | 81.2 | 192.6 | 105910/105918 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 105918/105918 | 1.000
October 1 to 31, 2012
Female
Ch19 IS95 High | 193.8 to 228.7 | 216.72 | 0.28/7.06 | 179.0 | 264.8 | 110670/110670 | 1.000
Ch18 IS95 Med | 139.3 to 164.6 | 140.84 | 0.24/3.88 | 121.3 | 173.0 | 110670/110670 | 1.000
Ch21 IS95 Low | 96.9 to 116.4 | 93.80 | 0.20/2.16 | 74.5 | 118.2 | 110610/110670 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 110678/110678 | 1.000
Male
Ch07 IS95 High | 201.3 to 269.0 | 227.53 | 0.30/8.03 | 173.4 | 294.1 | 110702/110702 | 1.000
Ch08 IS95 Med | 145.9 to 192.2 | 148.83 | 0.23/3.99 | 112.0 | 203.3 | 110456/110702 | 0.998
Ch10 IS95 Low | 103.1 to 135.9 | 118.65 | 0.31/4.25 | 88.8 | 149.3 | 110678/110678 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 110702/110702 | 1.000
November 1 to 30, 2012
Female
Ch19 IS95 High | 232.8 to 246.1 | 245.80 | 0.29/8.41 | 206.0 | 317.3 | 107678/107706 | 1.000
Ch18 IS95 Med | 167.6 to 177.3 | 158.36 | 0.23/4.24 | 139.2 | 187.4 | 107706/107706 | 1.000
Ch21 IS95 Low | 118.5 to 125.4 | 104.95 | 0.20/2.39 | 92.6 | 131.4 | 107610/107706 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107706/107706 | 1.000
Male
Ch07 IS95 High | 271.8 to 292.2 | 273.49 | 0.30/9.67 | 234.5 | 337.5 | 107706/107706 | 1.000
Ch08 IS95 Med | 194.2 to 208.2 | 174.47 | 0.22/4.47 | 152.3 | 208.3 | 107632/107706 | 0.999
Ch10 IS95 Low | 137.4 to 147.3 | 136.25 | 0.27/4.29 | 117.0 | 159.9 | 107706/107706 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107706/107706 | 1.000
December 1 to 31, 2012
Female
Ch19 IS95 High | 246.1 to 254.9 | 262.13 | 0.28/8.64 | 229.3 | 312.2 | 111216/111216 | 1.000
Ch18 IS95 Med | 177.3 to 182.7 | 166.16 | 0.24/4.65 | 145.9 | 193.7 | 111216/111216 | 1.000
Ch21 IS95 Low | 125.4 to 129.2 | 110.20 | 0.20/2.58 | 94.7 | 141.2 | 111082/111216 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111216/111216 | 1.000
Male
Ch07 IS95 High | 292.2 to 298.0 | 284.03 | 0.30/9.99 | 246.4 | 335.2 | 111216/111216 | 1.000
Ch08 IS95 Med | 208.2 to 211.7 | 183.33 | 0.25/5.27 | 162.5 | 217.1 | 111120/111216 | 0.999
Ch10 IS95 Low | 147.3 to 149.7 | 141.52 | 0.29/4.73 | 122.4 | 163.2 | 111216/111216 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111216/111216 | 1.000
January 1 to 31, 2013
Female
Ch19 IS95 High | 254.9 to 261.4 | 265.88 | 0.28/8.61 | 235.6 | 306.1 | 111234/111234 | 1.000
Ch18 IS95 Med | 182.7 to 186.7 | 167.70 | 0.28/5.41 | 108.4 | 259.5 | 111168/111234 | 0.999
Ch21 IS95 Low | 129.2 to 130.7 | 111.49 | 0.20/2.54 | 96.5 | 132.2 | 111104/111234 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111238/111238 | 1.000
Male
Ch07 IS95 High | 298.0 to 302.1 | 286.80 | 0.30/9.97 | 250.6 | 333.8 | 111238/111238 | 1.000
Ch08 IS95 Med | 211.7 to 214.0 | 190.71 | 0.25/5.56 | 167.5 | 226.3 | 111236/111238 | 1.000
Ch10 IS95 Low | 149.7 to 151.4 | 140.71 | 0.28/4.62 | 122.8 | 164.2 | 111238/111238 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111238/111238 | 1.000
February 1 to 28, 2013
Female
Ch19 IS95 High | 261.4 to 261.4 | 266.69 | 0.25/7.85 | 238.4 | 306.1 | 100164/100164 | 1.000
Ch18 IS95 Med | 186.7 to 188.4 | 172.86 | 0.21/4.27 | 154.2 | 198.3 | 100164/100164 | 1.000
Ch21 IS95 Low | 130.7 to 132.0 | 113.76 | 0.20/2.71 | 99.6 | 137.0 | 100046/100164 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 100164/100164 | 1.000
Male
Ch07 IS95 High | 302.1 to 303.4 | 290.09 | 0.31/10.66 | 253.4 | 342.9 | 100164/100164 | 1.000
Ch08 IS95 Med | 214.0 to 215.5 | 198.37 | 0.27/6.30 | 173.0 | 229.6 | 100164/100164 | 1.000
Ch10 IS95 Low | 151.4 to 152.0 | 139.08 | 0.26/4.29 | 124.1 | 165.2 | 100164/100164 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 100164/100164 | 1.000
March 1 to 31, 2013
Female
Ch19 IS95 High | 261.4 to 264.0 | 268.11 | 0.26/8.10 | 228.7 | 311.7 | 111408/111408 | 1.000
Ch18 IS95 Med | 188.4 to 190.2 | 173.32 | 0.22/4.37 | 154.8 | 200.4 | 111408/111408 | 1.000
Ch21 IS95 Low | 132.0 to 133.2 | 114.08 | 0.20/2.65 | 100.5 | 139.9 | 111270/111408 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111408/111408 | 1.000
Male
Ch07 IS95 High | 303.4 to 304.7 | 292.56 | 0.30/10.38 | 254.0 | 342.3 | 111408/111408 | 1.000
Ch08 IS95 Med | 215.5 to 216.8 | 201.55 | 0.25/5.99 | 178.1 | 229.9 | 111408/111408 | 1.000
Ch10 IS95 Low | 152.0 to 153.3 | 141.64 | 0.28/4.60 | 123.3 | 171.0 | 111408/111408 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111408/111408 | 1.000
April 1 to 30, 2013
Female
Ch19 IS95 High | 264.0 to 266.5 | 273.12 | 0.27/8.76 | 236.1 | 324.4 | 107438/107438 | 1.000
Ch18 IS95 Med | 190.2 to 192.2 | 176.82 | 0.21/4.26 | 161.1 | 204.2 | 107438/107438 | 1.000
Ch21 IS95 Low | 133.2 to 134.5 | 114.99 | 0.21/2.82 | 98.1 | 141.4 | 107112/107438 | 0.997
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107438/107438 | 1.000
Male
Ch07 IS95 High | 304.7 to 306.6 | 292.26 | 0.31/10.78 | 239.3 | 382.8 | 107440/107442 | 1.000
Ch08 IS95 Med | 216.8 to 218.3 | 202.70 | 0.26/6.24 | 181.2 | 235.9 | 107442/107442 | 1.000
Ch10 IS95 Low | 153.3 to 154.4 | 141.39 | 0.26/4.34 | 124.8 | 165.1 | 107438/107438 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107444/107444 | 1.000
May 1 to 31, 2013
Female
Ch19 IS95 High | 266.5 to 269.0 | 277.77 | 0.28/9.13 | 233.4 | 325.0 | 105524/105524 | 1.000
Ch18 IS95 Med | 192.2 to 194.2 | 176.25 | 0.21/4.38 | 152.7 | 205.0 | 105522/105524 | 1.000
Ch21 IS95 Low | 134.5 to 135.9 | 116.63 | 0.23/3.07 | 98.1 | 140.2 | 105172/105524 | 0.997
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 105524/105524 | 1.000
Male
Ch07 IS95 High | 306.6 to 308.8 | 294.02 | 0.31/10.66 | 136.5 | 344.2 | 105576/105578 | 1.000
Ch08 IS95 Med | 218.3 to 220.1 | 205.31 | 0.28/6.81 | 180.4 | 240.7 | 105576/105576 | 1.000
Ch10 IS95 Low | 154.4 to 155.6 | 144.69 | 0.30/5.15 | 120.2 | 171.5 | 105522/105524 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 105580/105580 | 1.000
June 1 to 30, 2013
Female
Ch19 IS95 High | 269.0 to 271.8 | 281.70 | 0.27/8.80 | 248.5 | 327.6 | 107074/107074 | 1.000
Ch18 IS95 Med | 194.2 to 196.4 | 179.48 | 0.22/4.60 | 160.6 | 214.7 | 107074/107074 | 1.000
Ch21 IS95 Low | 135.9 to 137.4 | 117.99 | 0.22/2.96 | 105.2 | 146.6 | 106772/107074 | 0.997
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107074/107074 | 1.000
Male
Ch07 IS95 High | 308.8 to 310.0 | 294.60 | 0.32/10.97 | 256.1 | 354.5 | 107084/107084 | 1.000
Ch08 IS95 Med | 220.1 to 221.0 | 196.86 | 0.37/8.48 | 117.2 | 227.5 | 106566/107084 | 0.995
Ch10 IS95 Low | 155.6 to 156.3 | 144.10 | 0.30/5.01 | 125.1 | 172.4 | 107074/107074 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107088/107088 | 1.000
July 1 to 31, 2013
Female
Ch19 IS95 High | 271.8 to 277.7 | 287.00 | 0.27/8.92 | 256.8 | 342.3 | 111054/111054 | 1.000
Ch18 IS95 Med | 196.4 to 200.7 | 180.29 | 0.21/4.33 | 163.3 | 209.1 | 111054/111054 | 1.000
Ch21 IS95 Low | 137.4 to 140.4 | 120.20 | 0.20/2.84 | 106.0 | 145.9 | 110840/111054 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111054/111054 | 1.000
Male
Ch07 IS95 High | 310.0 to 314.0 | 298.96 | 0.32/11.20 | 255.1 | 350.2 | 111056/111056 | 1.000
Ch08 IS95 Med | 221.0 to 223.9 | 200.01 | 0.25/5.80 | 176.8 | 237.8 | 111052/111056 | 1.000
Ch10 IS95 Low | 156.3 to 158.4 | 146.34 | 0.28/4.77 | 129.0 | 173.4 | 111054/111054 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111062/111062 | 1.000
August 1 to 31, 2013
Female
Ch19 IS95 High | 277.7 to 280.8 | 285.33 | 0.28/9.36 | 249.9 | 335.8 | 111904/111904 | 1.000
Ch18 IS95 Med | 200.7 to 202.8 | 184.94 | 0.21/4.62 | 166.9 | 215.2 | 111904/111904 | 1.000
Ch21 IS95 Low | 140.4 to 141.9 | 122.00 | 0.21/2.95 | 106.6 | 148.1 | 111758/111904 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111904/111904 | 1.000
Male
Ch07 IS95 High | 314.0 to 316.7 | 298.56 | 0.31/10.91 | 257.5 | 354.7 | 111904/111904 | 1.000
Ch08 IS95 Med | 223.9 to 225.9 | 202.11 | 0.25/5.95 | 177.1 | 254.5 | 111902/111904 | 1.000
Ch10 IS95 Low | 158.4 to 159.7 | 145.77 | 0.30/5.20 | 125.4 | 175.7 | 111898/111904 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111910/111910 | 1.000
September 1 to 30, 2013
Female
Ch19 IS95 High | 280.8 to 280.8 | 290.94 | 0.28/9.36 | 258.5 | 341.8 | 107392/107392 | 1.000
Ch18 IS95 Med | 202.8 to 202.8 | 184.37 | 0.22/4.62 | 165.6 | 215.7 | 107392/107392 | 1.000
Ch21 IS95 Low | 141.9 to 143.4 | 122.62 | 0.22/3.14 | 105.5 | 152.3 | 107002/107392 | 0.996
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107392/107392 | 1.000
Male
Ch07 IS95 High | 316.7 to 316.7 | 302.84 | 0.33/11.56 | 247.3 | 354.3 | 107378/107392 | 1.000
Ch08 IS95 Med | 225.9 to 226.8 | 205.80 | 0.25/5.96 | 181.1 | 237.0 | 107392/107392 | 1.000
Ch10 IS95 Low | 159.7 to 160.4 | 148.83 | 0.30/5.18 | 128.0 | 173.1 | 107392/107392 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107406/107406 | 1.000
October 1 to 31, 2013
Female
Ch19 IS95 High | 280.8 to 283.8 | 291.26 | 0.28/9.50 | 218.6 | 333.1 | 113492/113494 | 1.000
Ch18 IS95 Med | 202.8 to 204.8 | 178.28 | 0.33/6.85 | 102.4 | 215.2 | 113226/113496 | 0.998
Ch21 IS95 Low | 143.4 to 144.8 | 124.81 | 0.23/3.29 | 89.9 | 151.7 | 113288/113494 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 113496/113496 | 1.000
Male
Ch07 IS95 High | 316.7 to 318.1 | 300.02 | 0.30/10.59 | 228.1 | 355.7 | 113492/113496 | 1.000
Ch08 IS95 Med | 226.8 to 227.7 | 207.25 | 0.27/6.42 | 155.1 | 243.1 | 113494/113496 | 1.000
Ch10 IS95 Low | 160.4 to 161.0 | 148.27 | 0.29/5.10 | 100.6 | 175.3 | 113482/113496 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 113614/113614 | 1.000
November 1 to 30, 2013
Female
Ch19 IS95 High | 283.8 to 286.8 | 296.51 | 0.31/10.60 | 230.6 | 338.6 | 110646/110646 | 1.000
Ch18 IS95 Med | 204.8 to 206.7 | 176.06 | 0.25/5.07 | 102.4 | 304.9 | 109814/110646 | 0.992
Ch21 IS95 Low | 144.8 to 146.1 | 126.33 | 0.25/3.76 | 92.3 | 158.7 | 110042/110646 | 0.995
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 110646/110646 | 1.000
Male
Ch07 IS95 High | 318.1 to 319.4 | 299.24 | 0.31/10.89 | 186.9 | 352.4 | 110646/110660 | 1.000
Ch08 IS95 Med | 227.7 to 228.7 | 204.39 | 0.28/6.62 | 171.0 | 265.5 | 110464/110658 | 0.998
Ch10 IS95 Low | 161.0 to 161.7 | 148.39 | 0.31/5.42 | 124.1 | 187.1 | 110620/110658 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 110664/110664 | 1.000
December 1 to 31, 2013
Female
Ch19 IS95 High | 286.8 to 289.6 | 297.13 | 0.29/10.16 | 241.1 | 344.8 | 106114/106114 | 1.000
Ch18 IS95 Med | 206.7 to 208.2 | 173.06 | 0.22/4.50 | 140.4 | 199.2 | 104002/106198 | 0.979
Ch21 IS95 Low | 146.1 to 147.3 | 126.41 | 0.22/3.28 | 101.1 | 150.9 | 105674/106114 | 0.996
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 106198/106198 | 1.000
Male
Ch07 IS95 High | 319.4 to 319.4 | 299.40 | 0.31/10.95 | 120.2 | 350.5 | 106202/106216 | 1.000
Ch08 IS95 Med | 228.7 to 228.7 | 203.24 | 0.31/7.46 | 114.4 | 258.8 | 105908/106212 | 0.997
Ch10 IS95 Low | 161.7 to 161.7 | 149.99 | 0.32/5.63 | 122.6 | 178.0 | 106162/106198 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 106222/106222 | 1.000
January 1 to 31, 2014
Female
Ch19 IS95 High | 289.6 to 292.2 | 299.08 | 0.27/9.44 | 261.9 | 355.6 | 111242/111242 | 1.000
Ch18 IS95 Med | 208.2 to 209.6 | 175.32 | 0.20/4.07 | 155.1 | 198.6 | 110204/111252 | 0.991
Ch21 IS95 Low | 147.3 to 148.2 | 127.63 | 0.19/2.87 | 108.0 | 153.6 | 111094/111242 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111252/111252 | 1.000
Male
Ch07 IS95 High | 319.4 to 320.8 | 300.75 | 0.32/11.25 | 259.2 | 355.8 | 111254/111254 | 1.000
Ch08 IS95 Med | 228.7 to 230.6 | 205.87 | 0.26/6.19 | 173.4 | 239.9 | 111232/111254 | 1.000
Ch10 IS95 Low | 161.7 to 162.4 | 149.74 | 0.30/5.23 | 128.5 | 178.9 | 111254/111254 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111258/111258 | 1.000
February 1 to 28, 2014
Female
Ch19 IS95 High | 292.2 to 296.4 | 306.93 | 0.27/9.79 | 257.6 | 355.4 | 103948/103948 | 1.000
Ch18 IS95 Med | 209.6 to 210.7 | 180.40 | 0.22/4.53 | 157.1 | 208.9 | 103744/103948 | 0.998
Ch21 IS95 Low | 148.2 to 149.7 | 129.10 | 0.21/3.15 | 106.5 | 160.4 | 103764/103948 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 103948/103948 | 1.000
Male
Ch07 IS95 High | 320.8 to 322.1 | 305.52 | 0.31/11.28 | 266.4 | 355.0 | 103948/103948 | 1.000
Ch08 IS95 Med | 230.6 to 231.5 | 206.84 | 0.24/5.88 | 179.0 | 237.2 | 103940/103948 | 1.000
Ch10 IS95 Low | 162.4 to 163.7 | 153.91 | 0.32/5.79 | 129.9 | 180.0 | 103946/103948 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 103960/103960 | 1.000
March 1 to 31, 2014
Female
Ch19 IS95 High | 296.4 to 298.0 | 306.62 | 0.26/9.46 | 271.2 | 388.9 | 111406/111408 | 1.000
Ch18 IS95 Med | 210.7 to 211.7 | 179.74 | 0.21/4.34 | 161.9 | 205.3 | 111206/111408 | 0.998
Ch21 IS95 Low | 149.7 to 150.2 | 130.12 | 0.20/2.98 | 116.8 | 156.9 | 111388/111408 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111408/111408 | 1.000
Male
Ch07 IS95 High | 322.1 to 323.4 | 304.23 | 0.32/11.46 | 264.8 | 365.8 | 111408/111408 | 1.000
Ch08 IS95 Med | 231.5 to 231.5 | 206.39 | 0.24/5.85 | 184.2 | 235.2 | 111408/111408 | 1.000
Ch10 IS95 Low | 163.7 to 163.7 | 153.63 | 0.30/5.35 | 133.9 | 178.2 | 111408/111408 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111408/111408 | 1.000
April 1 to 30, 2014
Female
Ch19 IS95 High | 298.0 to 300.4 | 306.92 | 0.27/9.72 | 264.0 | 362.4 | 107286/107286 | 1.000
Ch18 IS95 Med | 211.7 to 213.1 | 179.35 | 0.20/4.08 | 100.9 | 207.4 | 106834/107288 | 0.996
Ch21 IS95 Low | 150.2 to 150.2 | 130.62 | 0.20/3.09 | 115.5 | 156.4 | 107260/107286 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107288/107288 | 1.000
Male
Ch07 IS95 High | 323.4 to 323.4 | 304.21 | 0.29/10.50 | 154.1 | 364.7 | 107292/107294 | 1.000
Ch08 IS95 Med | 231.5 to 232.5 | 206.77 | 0.23/5.63 | 175.3 | 235.2 | 107290/107292 | 1.000
Ch10 IS95 Low | 163.7 to 163.7 | 153.19 | 0.28/4.94 | 117.4 | 180.0 | 107284/107288 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107298/107298 | 1.000
May 1 to 31, 2014
Female
Ch19 IS95 High | 300.4 to 300.4 | 310.23 | 0.26/9.46 | 278.7 | 361.9 | 111204/111204 | 1.000
Ch18 IS95 Med | 213.1 to 213.1 | 181.02 | 0.20/4.21 | 160.2 | 213.0 | 110928/111208 | 0.997
Ch21 IS95 Low | 150.2 to 150.7 | 130.02 | 0.20/3.01 | 116.2 | 160.0 | 111138/111204 | 0.999
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111208/111208 | 1.000
Male
Ch07 IS95 High | 323.4 to 323.4 | 301.79 | 0.28/9.78 | 260.5 | 350.8 | 111208/111208 | 1.000
Ch08 IS95 Med | 232.5 to 232.5 | 207.87 | 0.24/5.84 | 183.8 | 239.2 | 111204/111208 | 1.000
Ch10 IS95 Low | 163.7 to 163.7 | 156.28 | 0.33/6.00 | 133.8 | 188.0 | 111208/111208 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111208/111208 | 1.000
June 1 to 30, 2014
Female
Ch19 IS95 High | 300.4 to 301.3 | 305.71 | 0.35/12.62 | 201.8 | 415.4 | 107452/107534 | 0.999
Ch18 IS95 Med | 213.1 to 214.0 | 181.65 | 0.22/4.69 | 28.4 | 210.4 | 107186/107542 | 0.997
Ch21 IS95 Low | 150.7 to 151.0 | 131.33 | 0.20/3.01 | 117.0 | 158.9 | 107524/107534 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107542/107542 | 1.000
Male
Ch07 IS95 High | 322.1 to 323.4 | 300.92 | 0.27/9.67 | 258.0 | 353.6 | 107546/107546 | 1.000
Ch08 IS95 Med | 232.5 to 233.4 | 206.99 | 0.24/5.68 | 181.2 | 235.7 | 107534/107546 | 1.000
Ch10 IS95 Low | 163.0 to 163.7 | 155.78 | 0.29/5.34 | 134.9 | 182.9 | 107542/107542 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 107548/107548 | 1.000
July 1 to 31, 2014
Female
Ch19 IS95 High | 302.1 to 302.1 | 309.91 | 0.27/9.74 | 274.2 | 367.1 | 111202/111202 | 1.000
Ch18 IS95 Med | 214.0 to 214.5 | 180.86 | 0.18/3.69 | 163.2 | 213.4 | 110936/111202 | 0.998
Ch21 IS95 Low | 151.0 to 151.0 | 133.65 | 0.20/3.14 | 118.5 | 198.6 | 111190/111202 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111202/111202 | 1.000
Male
Ch07 IS95 High | 322.1 to 322.1 | 298.86 | 0.28/9.65 | 257.8 | 360.2 | 111202/111202 | 1.000
Ch08 IS95 Med | 231.5 to 232.5 | 206.55 | 0.22/5.37 | 183.6 | 236.4 | 111200/111202 | 1.000
Ch10 IS95 Low | 163.0 to 163.7 | 153.76 | 0.28/5.01 | 134.7 | 175.0 | 111202/111202 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 111206/111206 | 1.000
August 1 to 31, 2014
Female
Ch19 IS95 High | 302.1 to 302.1 | 301.60 | 0.26/9.21 | 252.8 | 352.3 | 108708/108708 | 1.000
Ch18 IS95 Med | 214.5 to 214.5 | 183.36 | 0.21/4.42 | 158.5 | 222.5 | 108518/108708 | 0.998
Ch21 IS95 Low | 151.0 to 151.0 | 131.88 | 0.24/3.69 | 107.2 | 164.6 | 108494/108708 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 108708/108708 | 1.000
Male
Ch07 IS95 High | 320.8 to 322.1 | 297.12 | 0.28/9.67 | 245.4 | 349.2 | 108704/108708 | 1.000
Ch08 IS95 Med | 229.6 to 231.5 | 207.72 | 0.26/6.27 | 171.0 | 246.6 | 108676/108708 | 1.000
Ch10 IS95 Low | 161.7 to 163.0 | 153.23 | 0.27/4.91 | 127.2 | 175.6 | 108706/108708 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 108716/108716 | 1.000
September 1 to 30, 2014
Female
Ch19 IS95 High | 302.1 to 302.1 | 300.56 | 0.26/9.05 | 247.7 | 395.6 | 104162/104176 | 1.000
Ch18 IS95 Med | 214.0 to 214.5 | 187.43 | 0.23/4.98 | 166.7 | 242.6 | 104170/104176 | 1.000
Ch21 IS95 Low | 150.7 to 151.0 | 138.88 | 0.32/5.13 | 115.5 | 199.1 | 104172/104176 | 1.000
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 104176/104176 | 1.000
Male
Ch07 IS95 High | 320.8 to 320.8 | 299.37 | 0.22/7.51 | 250.7 | 395.7 | 104174/104176 | 1.000
Ch08 IS95 Med | 228.7 to 229.6 | 212.35 | 0.31/7.69 | 182.0 | 276.7 | 104176/104176 | 1.000
Ch10 IS95 Low | 163.0 to 163.0 | 155.34 | 0.25/4.55 | 129.6 | 193.5 | 104176/104176 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 104176/104176 | 1.000
August 8, 2012 to September 30, 2014
Female
Ch19 IS95 High | 192.6 to 302.1 | 282.98 | 0.30/9.79 | 164.5 | 415.4 | 2800246/2800388 | 1.000
Ch18 IS95 Med | 135.9 to 214.5 | 175.09 | 0.37/7.72 | 28.4 | 304.9 | 2794118/2800498 | 0.998
Ch21 IS95 Low | 96.3 to 151.0 | 121.89 | 0.36/5.19 | 74.5 | 199.1 | 2796040/2800388 | 0.998
Ch15 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 2800510/2800510 | 1.000
Male
Ch07 IS95 High | 192.2 to 323.4 | 289.61 | 0.31/10.58 | 120.2 | 395.7 | 2800580/2800648 | 1.000
Ch08 IS95 Med | 136.2 to 233.4 | 197.37 | 0.33/7.73 | 102.5 | 288.1 | 2799062/2800638 | 0.999
Ch10 IS95 Low | 96.3 to 163.7 | 144.71 | 0.32/5.37 | 77.3 | 193.5 | 2800404/2800524 | 1.000
Ch04 Sham Control | 0.0 to 0.0 | 0.00 | –/0.00 | 0.0 | 0.0 | 2800844/2800844 | 1.000

Ch = chamber (e.g., Ch19 = Chamber 19).

Table I‑8 Summary of CDMA-modulated Cell Phone RFR Exposure Data in Rats – H-Field

Chamber | Target Range [V/m] | Mean [V/m] | Stdev [dB]/[V/m] | Min [V/m] | | | Max [V/m] | | In Range/Total | | Ratio
August 8 to 31, 2012
Female
Ch19 IS95 High | 0.65 to 0.75 | 0.699 | 0.15/0.012 | 0.45 | | | 0.83 | | 85780/85786 | | 1.000
Ch18 IS95 Med | 0.46 to 0.53 | 0.510 | 0.17/0.010 | 0.35 | | | 0.62 | | 85780/85786 | | 1.000
Ch21 IS95 Low | 0.33 to 0.38 | 0.342 | 0.16/0.006 | 0.22 | | | 0.42 | | 85780/85786 | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | | 0.00 | | 85786/85786 | | 1.000
September 1 to 30, 2012
Female
Ch19 IS95 High | 0.51 to 0.71 | 0.627 | 0.21/0.016 | 0.46 | | | 0.81 | | 105918/105918 | | 1.000
Ch18 IS95 Med | 0.36 to 0.51 | 0.469 | 0.31/0.017 | 0.34 | | | 0.58 | | 105798/105918 | | 0.999
Ch21 IS95 Low | 0.26 to 0.36 | 0.324 | 0.49/0.019 | 0.24 | | | 0.43 | | 105844/105918 | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | | 0.00 | | 105918/105918 | | 1.000
Male
Ch07 IS95 High | 0.51 to 0.71 | 0.650 | 0.25/0.019 | 0.49 | | | 1.07 | | 105906/105918 | | 1.000
Ch08 IS95 Med | 0.36 to 0.51 | 0.456 | 0.31/0.016 | 0.34 | | | 0.75 | | 105820/105918 | | 0.999
Ch10 IS95 Low | 0.26 to 0.36 | 0.319 | 0.27/0.010 | 0.22 | | | 0.53 | | 105758/105918 | | 0.998
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | | 0.00 | | 105918/105918 | | 1.000
October 1 to 31, 2012
Female
Ch19 IS95 High | 0.51 to 0.61 | 0.555 | 0.25/0.016 | 0.45 | | | 0.67 | | 110670/110670 | | 1.000
Ch18 IS95 Med | 0.37 to 0.44 | 0.435 | 0.25/0.013 | 0.35 | | | 0.53 | | 110668/110670 | | 1.000
Ch21 IS95 Low | 0.26 to 0.31 | 0.322 | 0.25/0.009 | 0.26 | | | 0.40 | | 110606/110670 | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | | 0.00 | | 110678/110678 | | 1.000
Male
Ch07 IS95 High | 0.53 to 0.71 | 0.663 | 0.23/0.018 | 0.50 | | | 0.82 | | 110702/110702 | | 1.000
Ch08 IS95 Med | 0.39 to 0.51 | 0.516 | 0.27/0.017 | 0.38 | | | 0.65 | | 110676/110702 | | 1.000
Ch10 IS95 Low | 0.27 to 0.36 | 0.329 | 0.28/0.011 | 0.24 | | | 0.42 | | 110678/110678 | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | | 0.00 | | 110702/110702 | | 1.000
November 1 to 30, 2012
Female
Ch19 IS95 High | 0.62 to 0.65 | 0.625 | 0.26/0.019 | 0.54 | | | 0.78 | | 107706/107706 | | 1.000
Ch18 IS95 Med | 0.45 to 0.47 | 0.498 | 0.23/0.013 | 0.44 | | | 0.58 | | 107706/107706 | | 1.000
Ch21 IS95 Low | 0.31 to 0.33 | 0.369 | 0.24/0.011 | 0.32 | | | 0.45 | | 107640/107706 | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | | 0.00 | | 107706/107706 | | 1.000
Male
Ch07 IS95 High | 0.72 to 0.78 | 0.772 | 0.20/0.018 | 0.69 | | | 0.87 | | 107706/107706 | | 1.000
Ch08 IS95 Med | 0.52 to 0.55 | 0.607 | 0.27/0.019 | 0.51 | | | 0.71 | | 107688/107706 | | 1.000
Ch10 IS95 Low | 0.36 to 0.39 | 0.396 | 0.25/0.012 | 0.35 | | | 0.46 | | 107706/107706 | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | | 0.00 | | 107706/107706 | | 1.000
December 1 to 31, 2012
Female
Ch19 IS95 High | 0.65 to 0.68 | 0.644 | 0.24/0.018 | 0.56 | | 0.74 | | 111216/111216 | | | 1.000
Ch18 IS95 Med | 0.47 to 0.49 | 0.519 | 0.24/0.015 | 0.45 | | 0.61 | | 111214/111216 | | | 1.000
Ch21 IS95 Low | 0.33 to 0.34 | 0.385 | 0.24/0.011 | 0.33 | | 0.47 | | 111128/111216 | | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111216/111216 | | | 1.000
Male
Ch07 IS95 High | 0.78 to 0.79 | 0.817 | 0.21/0.020 | 0.74 | | 0.95 | | 111216/111216 | | | 1.000
Ch08 IS95 Med | 0.55 to 0.56 | 0.630 | 0.28/0.020 | 0.56 | | 0.72 | | 111210/111216 | | | 1.000
Ch10 IS95 Low | 0.39 to 0.40 | 0.415 | 0.26/0.013 | 0.37 | | 0.48 | | 111216/111216 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111216/111216 | | | 1.000
January 1 to 31, 2013
Female
Ch19 IS95 High | 0.68 to 0.69 | 0.665 | 0.22/0.017 | 0.59 | | 0.77 | | 111234/111234 | | | 1.000
Ch18 IS95 Med | 0.49 to 0.50 | 0.536 | 0.31/0.019 | 0.38 | | 0.81 | | 111018/111234 | | | 0.998
Ch21 IS95 Low | 0.34 to 0.35 | 0.392 | 0.25/0.011 | 0.35 | | 0.46 | | 111170/111234 | | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111238/111238 | | | 1.000
Male
Ch07 IS95 High | 0.79 to 0.80 | 0.830 | 0.21/0.021 | 0.76 | | 0.92 | | 111238/111238 | | | 1.000
Ch08 IS95 Med | 0.56 to 0.57 | 0.622 | 0.27/0.020 | 0.57 | | 0.70 | | 111238/111238 | | | 1.000
Ch10 IS95 Low | 0.40 to 0.40 | 0.425 | 0.25/0.013 | 0.38 | | 0.48 | | 111238/111238 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111238/111238 | | | 1.000
February 1 to 28, 2013
Female
Ch19 IS95 High | 0.69 to 0.69 | 0.678 | 0.21/0.017 | 0.60 | | 0.77 | | 100164/100164 | | | 1.000
Ch18 IS95 Med | 0.50 to 0.50 | 0.536 | 0.20/0.012 | 0.48 | | 0.60 | | 100164/100164 | | | 1.000
Ch21 IS95 Low | 0.35 to 0.35 | 0.394 | 0.24/0.011 | 0.34 | | 0.47 | | 100088/100164 | | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 100164/100164 | | | 1.000
Male
Ch07 IS95 High | 0.80 to 0.81 | 0.835 | 0.23/0.023 | 0.75 | | 0.92 | | 100164/100164 | | | 1.000
Ch08 IS95 Med | 0.57 to 0.57 | 0.611 | 0.26/0.018 | 0.55 | | 0.71 | | 100164/100164 | | | 1.000
Ch10 IS95 Low | 0.40 to 0.40 | 0.435 | 0.25/0.013 | 0.39 | | 0.50 | | 100164/100164 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 100164/100164 | | | 1.000
March 1 to 31, 2013
Female
Ch19 IS95 High | 0.69 to 0.70 | 0.683 | 0.21/0.017 | 0.61 | | 0.76 | | 111408/111408 | | | 1.000
Ch18 IS95 Med | 0.50 to 0.51 | 0.544 | 0.22/0.014 | 0.50 | | 0.64 | | 111406/111408 | | | 1.000
Ch21 IS95 Low | 0.35 to 0.35 | 0.399 | 0.24/0.011 | 0.35 | | 0.49 | | 111336/111408 | | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111408/111408 | | | 1.000
Male
Ch07 IS95 High | 0.81 to 0.81 | 0.835 | 0.21/0.021 | 0.76 | | 0.92 | | 111408/111408 | | | 1.000
Ch08 IS95 Med | 0.57 to 0.58 | 0.610 | 0.22/0.016 | 0.56 | | 0.67 | | 111408/111408 | | | 1.000
Ch10 IS95 Low | 0.40 to 0.41 | 0.433 | 0.25/0.013 | 0.39 | | 0.50 | | 111408/111408 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111408/111408 | | | 1.000
April 1 to 30, 2013
Female
Ch19 IS95 High | 0.70 to 0.71 | 0.684 | 0.24/0.019 | 0.61 | | 0.78 | | 107438/107438 | | | 1.000
Ch18 IS95 Med | 0.51 to 0.51 | 0.546 | 0.20/0.013 | 0.49 | | 0.61 | | 107438/107438 | | | 1.000
Ch21 IS95 Low | 0.35 to 0.36 | 0.404 | 0.25/0.012 | 0.36 | | 0.49 | | 107356/107438 | | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107438/107438 | | | 1.000
Male
Ch07 IS95 High | 0.81 to 0.81 | 0.847 | 0.25/0.024 | 0.73 | | 1.04 | | 107426/107442 | | | 1.000
Ch08 IS95 Med | 0.58 to 0.58 | 0.616 | 0.23/0.016 | 0.56 | | 0.70 | | 107442/107442 | | | 1.000
Ch10 IS95 Low | 0.41 to 0.41 | 0.441 | 0.25/0.013 | 0.39 | | 0.51 | | 107438/107438 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107444/107444 | | | 1.000
May 1 to 31, 2013
Female
Ch19 IS95 High | 0.71 to 0.71 | 0.686 | 0.23/0.019 | 0.62 | | 0.79 | | 105524/105524 | | | 1.000
Ch18 IS95 Med | 0.51 to 0.52 | 0.559 | 0.22/0.014 | 0.50 | | 0.65 | | 105520/105524 | | | 1.000
Ch21 IS95 Low | 0.36 to 0.36 | 0.407 | 0.26/0.013 | 0.35 | | 0.49 | | 105446/105524 | | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 105524/105524 | | | 1.000
Male
Ch07 IS95 High | 0.81 to 0.82 | 0.853 | 0.23/0.022 | 0.41 | | 0.95 | | 105576/105578 | | | 1.000
Ch08 IS95 Med | 0.58 to 0.58 | 0.619 | 0.24/0.018 | 0.55 | | 0.69 | | 105576/105576 | | | 1.000
Ch10 IS95 Low | 0.41 to 0.41 | 0.439 | 0.27/0.014 | 0.38 | | 0.51 | | 105524/105524 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 105580/105580 | | | 1.000
June 1 to 30, 2013
Female
Ch19 IS95 High | 0.71 to 0.72 | 0.691 | 0.22/0.018 | 0.63 | | 0.80 | | 107074/107074 | | | 1.000
Ch18 IS95 Med | 0.52 to 0.52 | 0.563 | 0.23/0.015 | 0.50 | | 0.64 | | 107074/107074 | | | 1.000
Ch21 IS95 Low | 0.36 to 0.36 | 0.412 | 0.27/0.013 | 0.36 | | 0.50 | | 106962/107074 | | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107074/107074 | | | 1.000
Male
Ch07 IS95 High | 0.82 to 0.82 | 0.858 | 0.22/0.022 | 0.78 | | 0.95 | | 107084/107084 | | | 1.000
Ch08 IS95 Med | 0.58 to 0.59 | 0.643 | 0.34/0.025 | 0.44 | | 0.74 | | 107080/107084 | | | 1.000
Ch10 IS95 Low | 0.41 to 0.42 | 0.445 | 0.29/0.015 | 0.40 | | 0.51 | | 107074/107074 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107088/107088 | | | 1.000
July 1 to 31, 2013
Female
Ch19 IS95 High | 0.72 to 0.74 | 0.695 | 0.22/0.017 | 0.63 | | 0.78 | | 111054/111054 | | | 1.000
Ch18 IS95 Med | 0.52 to 0.53 | 0.573 | 0.20/0.013 | 0.52 | | 0.66 | | 111054/111054 | | | 1.000
Ch21 IS95 Low | 0.36 to 0.37 | 0.415 | 0.25/0.012 | 0.36 | | 0.50 | | 110982/111054 | | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111054/111054 | | | 1.000
Male
Ch07 IS95 High | 0.82 to 0.83 | 0.860 | 0.23/0.023 | 0.78 | | 0.97 | | 111056/111056 | | | 1.000
Ch08 IS95 Med | 0.59 to 0.59 | 0.649 | 0.23/0.018 | 0.59 | | 0.73 | | 111056/111056 | | | 1.000
Ch10 IS95 Low | 0.42 to 0.42 | 0.446 | 0.25/0.013 | 0.40 | | 0.51 | | 111054/111054 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111062/111062 | | | 1.000
August 1 to 31, 2013
Female
Ch19 IS95 High | 0.74 to 0.75 | 0.717 | 0.23/0.019 | 0.63 | | 0.82 | | 111904/111904 | | 1.000
Ch18 IS95 Med | 0.53 to 0.54 | 0.574 | 0.20/0.014 | 0.52 | | 0.66 | | 111904/111904 | | 1.000
Ch21 IS95 Low | 0.37 to 0.38 | 0.420 | 0.25/0.012 | 0.37 | | 0.49 | | 111844/111904 | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111904/111904 | | 1.000
Male
Ch07 IS95 High | 0.83 to 0.84 | 0.871 | 0.24/0.024 | 0.80 | | 0.98 | | 111904/111904 | | 1.000
Ch08 IS95 Med | 0.59 to 0.60 | 0.649 | 0.24/0.019 | 0.53 | | 0.82 | | 111894/111904 | | 1.000
Ch10 IS95 Low | 0.42 to 0.42 | 0.453 | 0.28/0.015 | 0.40 | | 0.53 | | 111904/111904 | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111910/111910 | | 1.000
September 1 to 30, 2013
Female
Ch19 IS95 High | 0.75 to 0.75 | 0.715 | 0.22/0.018 | 0.64 | | 0.82 | | 107392/107392 | | 1.000
Ch18 IS95 Med | 0.54 to 0.54 | 0.584 | 0.21/0.015 | 0.53 | | 0.67 | | 107392/107392 | | 1.000
Ch21 IS95 Low | 0.38 to 0.38 | 0.426 | 0.25/0.013 | 0.37 | | 0.52 | | 107314/107392 | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107392/107392 | | 1.000
Male
Ch07 IS95 High | 0.84 to 0.84 | 0.871 | 0.24/0.024 | 0.70 | | 1.01 | | 107392/107392 | | 1.000
Ch08 IS95 Med | 0.60 to 0.60 | 0.650 | 0.23/0.017 | 0.59 | | 0.72 | | 107392/107392 | | 1.000
Ch10 IS95 Low | 0.42 to 0.43 | 0.452 | 0.27/0.014 | 0.39 | | 0.51 | | 107392/107392 | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107406/107406 | | 1.000
October 1 to 31, 2013
Female
Ch19 IS95 High | 0.75 to 0.75 | 0.720 | 0.22/0.019 | 0.52 | | 0.82 | | 113492/113494 | | 1.000
Ch18 IS95 Med | 0.54 to 0.54 | 0.604 | 0.33/0.024 | 0.40 | | 0.69 | | 113448/113496 | | 1.000
Ch21 IS95 Low | 0.38 to 0.38 | 0.429 | 0.28/0.014 | 0.30 | | 0.54 | | 113444/113494 | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 113496/113496 | | 1.000
Male
Ch07 IS95 High | 0.84 to 0.84 | 0.880 | 0.23/0.024 | 0.70 | | 1.04 | | 113496/113496 | | 1.000
Ch08 IS95 Med | 0.60 to 0.60 | 0.651 | 0.25/0.019 | 0.48 | | 0.73 | | 113494/113496 | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.458 | 0.26/0.014 | 0.34 | | 0.52 | | 113496/113496 | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 113614/113614 | | 1.000
November 1 to 30, 2013
Female
Ch19 IS95 High | 0.75 to 0.76 | 0.723 | 0.25/0.021 | 0.57 | | 0.84 | | 110644/110646 | | 1.000
Ch18 IS95 Med | 0.54 to 0.55 | 0.622 | 0.25/0.018 | 0.33 | | 0.93 | | 110634/110646 | | 1.000
Ch21 IS95 Low | 0.38 to 0.39 | 0.433 | 0.31/0.016 | 0.33 | | 0.53 | | 110610/110646 | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 110646/110646 | | 1.000
Male
Ch07 IS95 High | 0.84 to 0.85 | 0.887 | 0.25/0.026 | 0.54 | | 0.99 | | 110658/110660 | | 1.000
Ch08 IS95 Med | 0.60 to 0.61 | 0.666 | 0.30/0.024 | 0.55 | | 0.87 | | 110572/110658 | | 0.999
Ch10 IS95 Low | 0.43 to 0.43 | 0.461 | 0.29/0.016 | 0.39 | | 0.53 | | 110658/110658 | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 110664/110664 | | 1.000
December 1 to 31, 2013
Female
Ch19 IS95 High | 0.76 to 0.77 | 0.738 | 0.23/0.020 | 0.62 | 0.84 | | | 106114/106114 | | | 1.000
Ch18 IS95 Med | 0.55 to 0.55 | 0.639 | 0.24/0.018 | 0.55 | 0.72 | | | 106170/106198 | | | 1.000
Ch21 IS95 Low | 0.39 to 0.39 | 0.440 | 0.27/0.014 | 0.36 | 0.52 | | | 106088/106114 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | | 106198/106198 | | | 1.000
Male
Ch07 IS95 High | 0.85 to 0.85 | 0.889 | 0.25/0.026 | 0.34 | 0.99 | | | 106212/106216 | | | 1.000
Ch08 IS95 Med | 0.61 to 0.61 | 0.670 | 0.29/0.023 | 0.48 | 0.88 | | | 106204/106212 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.458 | 0.29/0.016 | 0.37 | 0.52 | | | 106198/106198 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | | 106222/106222 | | | 1.000
January 1 to 31, 2014
Female
Ch19 IS95 High | 0.77 to 0.78 | 0.748 | 0.22/0.019 | 0.65 | 0.84 | | | 111242/111242 | | | 1.000
Ch18 IS95 Med | 0.55 to 0.56 | 0.641 | 0.21/0.016 | 0.58 | 0.71 | | | 111246/111252 | | | 1.000
Ch21 IS95 Low | 0.39 to 0.39 | 0.443 | 0.24/0.012 | 0.37 | 0.52 | | | 111212/111242 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | | 111252/111252 | | | 1.000
Male
Ch07 IS95 High | 0.85 to 0.85 | 0.890 | 0.25/0.026 | 0.77 | 1.00 | | | 111254/111254 | | | 1.000
Ch08 IS95 Med | 0.61 to 0.61 | 0.671 | 0.24/0.019 | 0.59 | 0.74 | | | 111254/111254 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.462 | 0.26/0.014 | 0.40 | 0.54 | | | 111254/111254 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | | 111258/111258 | | | 1.000
February 1 to 28, 2014
Female
Ch19 IS95 High | 0.78 to 0.79 | 0.748 | 0.21/0.018 | 0.63 | 0.84 | | | 103948/103948 | | | 1.000
Ch18 IS95 Med | 0.56 to 0.56 | 0.634 | 0.22/0.016 | 0.55 | 0.71 | | | 103946/103948 | | | 1.000
Ch21 IS95 Low | 0.39 to 0.40 | 0.446 | 0.25/0.013 | 0.37 | 0.54 | | | 103908/103948 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | | 103948/103948 | | | 1.000
Male
Ch07 IS95 High | 0.85 to 0.85 | 0.884 | 0.25/0.026 | 0.79 | 0.98 | | | 103948/103948 | | | 1.000
Ch08 IS95 Med | 0.61 to 0.61 | 0.675 | 0.22/0.018 | 0.58 | 0.76 | | | 103948/103948 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.457 | 0.27/0.014 | 0.40 | 0.52 | | | 103948/103948 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | | 103960/103960 | | | 1.000
March 1 to 31, 2014
Female
Ch19 IS95 High | 0.79 to 0.79 | 0.761 | 0.22/0.020 | 0.68 | 0.87 | | | 111408/111408 | | | 1.000
Ch18 IS95 Med | 0.56 to 0.56 | 0.642 | 0.22/0.016 | 0.59 | 0.72 | | | 111404/111408 | | | 1.000
Ch21 IS95 Low | 0.40 to 0.40 | 0.448 | 0.23/0.012 | 0.40 | 0.52 | | | 111388/111408 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | | 111408/111408 | | | 1.000
Male
Ch07 IS95 High | 0.85 to 0.86 | 0.895 | 0.25/0.026 | 0.80 | 1.02 | | | 111408/111408 | | | 1.000
Ch08 IS95 Med | 0.61 to 0.61 | 0.678 | 0.23/0.018 | 0.62 | 0.75 | | | 111408/111408 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.460 | 0.25/0.013 | 0.41 | 0.52 | | | 111408/111408 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | 0.00 | | | 111408/111408 | | | 1.000
April 1 to 30, 2014
Female
Ch19 IS95 High | 0.79 to 0.80 | 0.772 | 0.22/0.020 | 0.69 | | 0.89 | | 107286/107286 | | | 1.000
Ch18 IS95 Med | 0.56 to 0.57 | 0.650 | 0.20/0.015 | 0.37 | | 0.72 | | 107284/107288 | | | 1.000
Ch21 IS95 Low | 0.40 to 0.40 | 0.447 | 0.24/0.012 | 0.39 | | 0.53 | | 107262/107286 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107288/107288 | | | 1.000
Male
Ch07 IS95 High | 0.86 to 0.86 | 0.897 | 0.22/0.023 | 0.43 | | 0.99 | | 107292/107294 | | | 1.000
Ch08 IS95 Med | 0.61 to 0.62 | 0.680 | 0.22/0.017 | 0.61 | | 0.74 | | 107292/107292 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.460 | 0.24/0.013 | 0.36 | | 0.53 | | 107288/107288 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107298/107298 | | | 1.000
May 1 to 31, 2014
Female
Ch19 IS95 High | 0.80 to 0.80 | 0.766 | 0.20/0.018 | 0.69 | | 0.86 | | 111204/111204 | | | 1.000
Ch18 IS95 Med | 0.57 to 0.57 | 0.646 | 0.21/0.016 | 0.59 | | 0.74 | | 111204/111208 | | | 1.000
Ch21 IS95 Low | 0.40 to 0.40 | 0.451 | 0.25/0.013 | 0.40 | | 0.55 | | 111114/111204 | | | 0.999
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111208/111208 | | | 1.000
Male
Ch07 IS95 High | 0.86 to 0.86 | 0.907 | 0.24/0.025 | 0.81 | | 1.01 | | 111208/111208 | | | 1.000
Ch08 IS95 Med | 0.62 to 0.62 | 0.679 | 0.23/0.018 | 0.60 | | 0.74 | | 111208/111208 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.452 | 0.28/0.015 | 0.40 | | 0.52 | | 111208/111208 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111208/111208 | | | 1.000
June 1 to 30, 2014
Female
Ch19 IS95 High | 0.80 to 0.80 | 0.778 | 0.24/0.022 | 0.57 | | 1.00 | | 107446/107534 | | | 0.999
Ch18 IS95 Med | 0.57 to 0.57 | 0.649 | 0.21/0.016 | 0.60 | | 0.72 | | 107540/107542 | | | 1.000
Ch21 IS95 Low | 0.40 to 0.40 | 0.450 | 0.23/0.012 | 0.40 | | 0.52 | | 107524/107534 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107542/107542 | | | 1.000
Male
Ch07 IS95 High | 0.85 to 0.86 | 0.902 | 0.22/0.023 | 0.82 | | 1.01 | | 107546/107546 | | | 1.000
Ch08 IS95 Med | 0.62 to 0.62 | 0.683 | 0.24/0.019 | 0.62 | | 0.75 | | 107546/107546 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.454 | 0.25/0.013 | 0.41 | | 0.51 | | 107542/107542 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 107548/107548 | | | 1.000
July 1 to 31, 2014
Female
Ch19 IS95 High | 0.80 to 0.80 | 0.776 | 0.22/0.019 | 0.71 | | 0.88 | | 111202/111202 | | | 1.000
Ch18 IS95 Med | 0.57 to 0.57 | 0.653 | 0.20/0.015 | 0.61 | | 0.73 | | 111188/111202 | | | 1.000
Ch21 IS95 Low | 0.40 to 0.40 | 0.444 | 0.23/0.012 | 0.40 | | 0.62 | | 111186/111202 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111202/111202 | | | 1.000
Male
Ch07 IS95 High | 0.85 to 0.85 | 0.909 | 0.23/0.024 | 0.84 | | 1.03 | | 111202/111202 | | | 1.000
Ch08 IS95 Med | 0.61 to 0.62 | 0.681 | 0.22/0.017 | 0.61 | | 0.75 | | 111202/111202 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.457 | 0.24/0.013 | 0.42 | | 0.51 | | 111202/111202 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 111206/111206 | | | 1.000
August 1 to 31, 2014
Female
Ch19 IS95 High | 0.80 to 0.80 | 0.797 | 0.22/0.020 | 0.67 | | 0.91 | | 108708/108708 | | | 1.000
Ch18 IS95 Med | 0.57 to 0.57 | 0.647 | 0.22/0.016 | 0.58 | | 0.73 | | 108702/108708 | | | 1.000
Ch21 IS95 Low | 0.40 to 0.40 | 0.448 | 0.27/0.014 | 0.38 | | 0.54 | | 108676/108708 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 108708/108708 | | | 1.000
Male
Ch07 IS95 High | 0.85 to 0.85 | 0.909 | 0.24/0.025 | 0.80 | | 1.01 | | 108708/108708 | | | 1.000
Ch08 IS95 Med | 0.61 to 0.61 | 0.671 | 0.26/0.020 | 0.57 | | 0.77 | | 108708/108708 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.454 | 0.25/0.013 | 0.39 | | 0.53 | | 108708/108708 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 108716/108716 | | | 1.000
September 1 to 30, 2014
Female
Ch19 IS95 High | 0.80 to 0.80 | 0.801 | 0.23/0.022 | 0.65 | | 1.06 | | 104152/104176 | | | 1.000
Ch18 IS95 Med | 0.57 to 0.57 | 0.636 | 0.25/0.018 | 0.52 | | 0.77 | | 104166/104176 | | | 1.000
Ch21 IS95 Low | 0.40 to 0.40 | 0.429 | 0.33/0.017 | 0.31 | | 0.55 | | 104170/104176 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 104176/104176 | | | 1.000
Male
Ch07 IS95 High | 0.85 to 0.85 | 0.902 | 0.20/0.021 | 0.76 | | 1.12 | | 104170/104176 | | | 1.000
Ch08 IS95 Med | 0.61 to 0.61 | 0.648 | 0.32/0.024 | 0.53 | | 0.80 | | 104174/104176 | | | 1.000
Ch10 IS95 Low | 0.43 to 0.43 | 0.451 | 0.24/0.013 | 0.38 | | 0.55 | | 104174/104176 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 104176/104176 | | | 1.000
August 8, 2012 to September 30, 2014
Female
Ch19 IS95 High | 0.51 to 0.80 | 0.711 | 0.25/0.021 | 0.45 | | 1.06 | | 2800266/2800388 | | | 1.000
Ch18 IS95 Med | 0.36 to 0.57 | 0.582 | 0.38/0.026 | 0.33 | | 0.93 | | 2800006/2800498 | | | 1.000
Ch21 IS95 Low | 0.26 to 0.40 | 0.413 | 0.38/0.019 | 0.22 | | 0.62 | | 2799016/2800388 | | | 1.000
Ch15 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 2800510/2800510 | | | 1.000
Male
Ch07 IS95 High | 0.51 to 0.86 | 0.849 | 0.24/0.024 | 0.34 | | 1.12 | | 2800596/2800648 | | | 1.000
Ch08 IS95 Med | 0.36 to 0.62 | 0.633 | 0.32/0.024 | 0.29 | | 0.88 | | 2800368/2800638 | | | 1.000
Ch10 IS95 Low | 0.26 to 0.43 | 0.434 | 0.29/0.015 | 0.21 | | 0.55 | | 2800350/2800524 | | | 1.000
Ch04 Sham Control | 0.00 to 0.00 | 0.000 | –/0.000 | 0.00 | | 0.00 | | 2800844/2800844 | | | 1.000

Ch = chamber (e.g., Ch19 = Chamber 19).