# Appendix H Reproductive Tissue Evaluations

Table H‑1 Summary of Reproductive Tissue Evaluations for Male Rats Exposed to GSM-modulated Cell Phone RFR for 14 Weeks^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 444 ± 9 | 426 ± 10 | 430 ± 7 | 410 ± 7*
L. Cauda epididymis | 0.266 ± 0.011 | 0.271 ± 0.008 | 0.257 ± 0.009 | 0.269 ± 0.011
L. Epididymis | 0.640 ± 0.021 | 0.643 ± 0.018 | 0.622 ± 0.017 | 0.643 ± 0.029
L. Testis | 2.083 ± 0.059 | 2.028 ± 0.051 | 2.049 ± 0.039 | 1.954 ± 0.055
Spermatid measurements
Spermatid heads (106/testis) | 305.1 ± 11.2 | 280.3 ± 8.9 | 263.4 ± 12.3 | 297.4 ± 12.5
Spermatid heads (106/g testis) | 147.3 ± 6.0 | 138.6 ± 4.2 | 128.5 ± 5.2 | 152.7 ± 6.8
Epididymal spermatozoal measurements
Sperm motility (%) | 91.5 ± 1.4 | 74.0 ± 8.0 | 91.5 ± 1.4 | 89.4 ± 2.2
Sperm (106/cauda epididymis) | 247.7 ± 68.9 | 285.5 ± 71.3 | 283.7 ± 57.5 | 220.3 ± 34.9
Sperm (106/g cauda epididymis) | 909.3 ± 243.5 | 1,081.1 ± 282.6 | 1,085.0 ± 210.7 | 834.8 ± 139.5

* Significantly different (P ≤ 0.05) from the sham control group by Williams’ or Dunnett’s test.

^a^ Data are presented as mean ± standard error. Differences from the sham control group are not significant by Williams’ or Dunnett’s test (tissue weights) or by Shirley’s or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table H‑2 Summary of Reproductive Tissue Evaluations for Male Rats Exposed to CDMA-modulated Cell Phone RFR for 14 Weeks^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
N | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 444 ± 9 | 440 ± 8 | 435 ± 4 | 411 ± 8**
L. Cauda epididymis | 0.266 ± 0.011 | 0.284 ± 0.008 | 0.274 ± 0.009 | 0.249 ± 0.017
L. Epididymis | 0.640 ± 0.021 | 0.667 ± 0.014 | 0.649 ± 0.015 | 0.587 ± 0.043
L. Testis | 2.083 ± 0.059 | 2.116 ± 0.055 | 2.102 ± 0.036 | 1.836 ± 0.160
Spermatid measurements
Spermatid heads (106/testis) | 305.1 ± 11.2 | 281.0 ± 12.5 | 280.7 ± 10.1 | 253.7 ± 30.1
Spermatid heads (106/g testis) | 147.3 ± 6.0 | 133.9 ± 7.6 | 133.6 ± 4.5 | 129.5 ± 12.9
Epididymal spermatozoal measurements
Sperm motility (%) | 91.5 ± 1.4 | 90.9 ± 1.0 | 88.7 ± 4.0 | 81.9 ± 9.2
Sperm (106/cauda epididymis) | 247.7 ± 68.9 | 206.0 ± 36.4 | 243.9 ± 36.4 | 201.8 ± 29.7
Sperm (106/g cauda epididymis) | 909.3 ± 243.5 | 742.9 ± 140.7 | 906.2 ± 144.4 | 775.8 ± 106.6

** Significantly different (P ≤ 0.01) from the sham control group by Williams’ test.

^a^ Data are presented as mean ± standard error. Differences from the sham control group are tested for significance by Williams’ or Dunnett’s test (tissue weights) or by Shirley’s or Dunn’s test (spermatid and epididymal spermatozoal measurements).