# Appendix G Mean Body Temperatures, Organ Weights, and Organ-Weight-to-Body-Weight Ratios

Table G‑1 Mean Body Temperatures for Rats by Litter in the 28-day GSM-modulated Cell Phone RFR Study^a^

Day^b^ | Sham Control | | 3 W/kg | | 6 W/kg | | 9 W/kg
Day^b^ | Temperature (°C) | No. Litters Measured | Temperature (°C) | No. Litters Measured | Temperature (°C) | No. Litters Measured | Temperature (°C) | No. Litters Measured
Male
16 | 37.3 ± 0.1 | 4 | 37.1 ± 0.1 | 4 | 37.3 ± 0.1 | 4 | 37.3 ± 0.1 | 4
20 | 37.6 ± 0.1 | 4 | 37.0 ± 0.1** | 4 | 37.3 ± 0.1 | 4 | 37.4 ± 0.1 | 4
27 | 37.2 ± 0.1 | 4 | 37.0 ± 0.1 | 4 | 37.2 ± 0.1 | 3 | 37.4 ± 0.1 | 4
16–27^c^ | 37.4 ± 0.1 | 4 | 37.0 ± 0.1* | 4 | 37.3 ± 0.1 | 4^d^ | 37.4 ± 0.1 | 4
Female
16 | 37.9 ± 0.2 | 4 | 37.0 ± 0.2** | 4 | 37.1 ± 0.1* | 4 | 37.4 ± 0.1 | 4
20 | 38.0 ± 0.2 | 4 | 37.5 ± 0.2 | 4 | 37.1 ± 0.1** | 4 | 37.6 ± 0.2 | 4
27 | 37.9 ± 0.2 | 4 | 38.0 ± 0.2 | 4 | 37.4 ± 0.3 | 4 | 37.6 ± 0.2 | 4
16–27^c^ | 37.9 ± 0.1^▲^ | 4 | 37.5 ± 0.1 | 4 | 37.2 ± 0.1** | 4 | 37.5 ± 0.1 | 4

^▲^Significant trend (P ≤ 0.05) by Jonckheere’s test.

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Temperatures are given as mean ± standard error. Statistical analysis for linear trends was performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dosed groups to the sham control group were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett-Hsu adjustment method.

^b^ Postnatal day.

^c^ Average was calculated as the mean of the litter means of the individual animal averages over the time range.

^d^ There were three litters on day 27.

Table G‑2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats by Litter in the 28‑day GSM-modulated Cell Phone RFR Study^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
n | 4 | 4 | 4 | 4
Males
Necropsy body wt. | 251 ± 6 | 230 ± 2* | 227 ± 2* | 202 ± 7**
R. Adrenal gland
Absolute | 0.0253 ± 0.0012 | 0.0236 ± 0.0009 | 0.0240 ± 0.0006 | 0.0198 ± 0.0021
Relative | 0.10 ± 0.00 | 0.10 ± 0.00 | 0.11 ± 0.00 | 0.10 ± 0.01
Brain
Absolute | 1.76 ± 0.02 | 1.78 ± 0.02 | 1.75 ± 0.03 | 1.66 ± 0.05
Relative | 7.02 ± 0.08 | 7.73 ± 0.12* | 7.73 ± 0.11* | 8.25 ± 0.21**
Heart
Absolute | 1.02 ± 0.03 | 0.94 ± 0.02 | 0.88 ± 0.03* | 0.80 ± 0.04**
Relative | 4.06 ± 0.08 | 4.07 ± 0.11 | 3.89 ± 0.11 | 3.97 ± 0.09
R. Kidney
Absolute | 1.10 ± 0.05 | 1.04 ± 0.01 | 0.98 ± 0.03 | 0.84 ± 0.03**
Relative | 4.36 ± 0.12 | 4.52 ± 0.02 | 4.30 ± 0.12 | 4.16 ± 0.06
Liver
Absolute | 12.05 ± 0.35 | 11.04 ± 0.36 | 10.77 ± 0.16 | 9.75 ± 0.40**
Relative | 47.93 ± 0.66 | 47.99 ± 1.17 | 47.47 ± 0.69 | 48.30 ± 1.18
Lung
Absolute | 2.23 ± 0.13 | 1.93 ± 0.07 | 1.77 ± 0.09 | 1.81 ± 0.17
Relative | 8.93 ± 0.69 | 8.40 ± 0.36 | 7.82 ± 0.43 | 9.00 ± 0.96
R. Testis
Absolute | 1.473 ± 0.056 | 1.504 ± 0.038 | 1.455 ± 0.047 | 1.324 ± 0.028
Relative | 5.86 ± 0.14 | 6.54 ± 0.13* | 6.42 ± 0.23* | 6.56 ± 0.10*
Thymus
Absolute | 0.742 ± 0.060 | 0.520 ± 0.027* | 0.672 ± 0.068 | 0.584 ± 0.017
Relative | 2.95 ± 0.23 | 2.26 ± 0.10 | 2.96 ± 0.31 | 2.91 ± 0.14
Females
Necropsy body wt. | 168 ± 3 | 161 ± 5 | 167 ± 5 | 155 ± 4
R. Adrenal gland
Absolute | 0.0299 ± 0.0027 | 0.0263 ± 0.0019 | 0.0280 ± 0.0004 | 0.0253 ± 0.0017
Relative | 0.18 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.01
Brain
Absolute | 1.64 ± 0.01 | 1.64 ± 0.02 | 1.68 ± 0.03 | 1.61 ± 0.02
Relative | 9.77 ± 0.22 | 10.27 ± 0.30 | 10.05 ± 0.22 | 10.36 ± 0.16
Heart
Absolute | 0.73 ± 0.02 | 0.69 ± 0.02 | 0.71 ± 0.02 | 0.68 ± 0.02
Relative | 4.35 ± 0.09 | 4.31 ± 0.07 | 4.27 ± 0.04 | 4.37 ± 0.06
R. Kidney
Absolute | 0.76 ± 0.02 | 0.73 ± 0.02 | 0.75 ± 0.02 | 0.68 ± 0.01
Relative | 4.49 ± 0.10 | 4.53 ± 0.10 | 4.47 ± 0.07 | 4.38 ± 0.04
Liver
Absolute | 7.65 ± 0.20 | 7.29 ± 0.28 | 7.74 ± 0.21 | 7.10 ± 0.21
Relative | 45.53 ± 0.65 | 45.36 ± 0.78 | 46.28 ± 0.22 | 45.71 ± 0.88
Lung
Absolute | 1.52 ± 0.08 | 1.52 ± 0.03 | 1.50 ± 0.10 | 1.38 ± 0.04
Relative | 9.03 ± 0.51 | 9.49 ± 0.51 | 8.93 ± 0.56 | 8.92 ± 0.43
Thymus
Absolute | 0.453 ± 0.059 | 0.344 ± 0.015 | 0.444 ± 0.032 | 0.405 ± 0.035
Relative | 2.71 ± 0.38 | 2.13 ± 0.05 | 2.64 ± 0.15 | 2.61 ± 0.23

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams as means of litter means; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Statistical analysis is for linear trends performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dosed groups to the sham control group were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett-Hsu adjustment method.

Table G‑3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day GSM-modulated Cell Phone RFR Study^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
N | 10 | 10 | 10 | 10
Males
Necropsy body wt. | 249 ± 3 | 231 ± 2* | 227 ± 2* | 205 ± 6**
R. Adrenal gland
Absolute | 0.0247 ± 0.0011 | 0.0237 ± 0.0012 | 0.0238 ± 0.0009 | 0.0206 ± 0.0013
Relative | 0.10 ± 0.00 | 0.10 ± 0.00 | 0.11 ± 0.00 | 0.10 ± 0.01
Brain
Absolute | 1.75 ± 0.01 | 1.77 ± 0.02 | 1.75 ± 0.02 | 1.69 ± 0.03
Relative | 7.05 ± 0.07 | 7.68 ± 0.12* | 7.73 ± 0.08* | 8.29 ± 0.17**
Heart
Absolute | 1.02 ± 0.02 | 0.94 ± 0.02 | 0.90 ± 0.02* | 0.82 ± 0.03**
Relative | 4.09 ± 0.06 | 4.06 ± 0.08 | 3.95 ± 0.06 | 4.02 ± 0.08
R. Kidney
Absolute | 1.08 ± 0.03 | 1.04 ± 0.01 | 0.98 ± 0.02 | 0.85 ± 0.03**
Relative | 4.32 ± 0.09 | 4.51 ± 0.04 | 4.33 ± 0.08 | 4.17 ± 0.05
Liver
Absolute | 11.85 ± 0.22 | 11.25 ± 0.22 | 10.86 ± 0.18 | 9.81 ± 0.30**
Relative | 47.66 ± 0.63 | 48.61 ± 0.66 | 47.84 ± 0.56 | 47.98 ± 0.77
Lung
Absolute | 2.24 ± 0.12 | 1.90 ± 0.09 | 1.81 ± 0.08 | 1.87 ± 0.12
Relative | 9.05 ± 0.56 | 8.24 ± 0.40 | 8.00 ± 0.37 | 9.25 ± 0.70
R. Testis
Absolute | 1.464 ± 0.036 | 1.516 ± 0.039 | 1.482 ± 0.029 | 1.330 ± 0.041
Relative | 5.88 ± 0.11 | 6.55 ± 0.14* | 6.54 ± 0.14* | 6.50 ± 0.09*
Thymus
Absolute | 0.757 ± 0.041 | 0.536 ± 0.019* | 0.637 ± 0.036 | 0.576 ± 0.013
Relative | 3.04 ± 0.15 | 2.31 ± 0.07 | 2.81 ± 0.16 | 2.83 ± 0.10
Females
Necropsy body wt. | 167 ± 2 | 163 ± 4 | 168 ± 3 | 156 ± 3
R. Adrenal gland
Absolute | 0.0285 ± 0.0019 | 0.0266 ± 0.0016 | 0.0280 ± 0.0012 | 0.0259 ± 0.0017
Relative | 0.17 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.17 ± 0.01
Brain
Absolute | 1.64 ± 0.01 | 1.64 ± 0.02 | 1.67 ± 0.02 | 1.60 ± 0.02
Relative | 9.86 ± 0.15 | 10.13 ± 0.23 | 9.96 ± 0.14 | 10.31 ± 0.14
Heart
Absolute | 0.72 ± 0.01 | 0.70 ± 0.02 | 0.72 ± 0.02 | 0.68 ± 0.01
Relative | 4.34 ± 0.07 | 4.26 ± 0.05 | 4.25 ± 0.05 | 4.34 ± 0.05
R. Kidney
Absolute | 0.74 ± 0.02 | 0.73 ± 0.02 | 0.74 ± 0.02 | 0.68 ± 0.01
Relative | 4.46 ± 0.06 | 4.48 ± 0.07 | 4.43 ± 0.05 | 4.38 ± 0.07
Liver
Absolute | 7.55 ± 0.14 | 7.44 ± 0.24 | 7.80 ± 0.19 | 7.04 ± 0.14
Relative | 45.35 ± 0.44 | 45.56 ± 0.64 | 46.38 ± 0.40 | 45.18 ± 0.42
Lung
Absolute | 1.52 ± 0.07 | 1.50 ± 0.05 | 1.54 ± 0.09 | 1.36 ± 0.04
Relative | 9.11 ± 0.40 | 9.22 ± 0.37 | 9.16 ± 0.44 | 8.78 ± 0.38
Thymus
Absolute | 0.474 ± 0.036 | 0.349 ± 0.017 | 0.444 ± 0.025 | 0.386 ± 0.021
Relative | 2.86 ± 0.23 | 2.13 ± 0.07 | 2.63 ± 0.12 | 2.48 ± 0.13

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Statistical analysis is for linear trends performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dosed groups to the sham control group were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett-Hsu adjustment method.

Table G‑4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats at the 14‑week Interim Evaluation in the Two-year GSM-modulated Cell Phone RFR Study^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
n | 10 | 10 | 10 | 10
Males
Necropsy body wt. | 444 ± 9 | 426 ± 10 | 430 ± 7 | 410 ± 7*
Brain
Absolute | 1.92 ± 0.02 | 1.94 ± 0.02 | 1.94 ± 0.02 | 1.88 ± 0.02
Relative | 4.34 ± 0.08 | 4.58 ± 0.11 | 4.53 ± 0.06 | 4.59 ± 0.06
R. Epididymis
Absolute | 0.6423 ± 0.0278 | 0.6370 ± 0.0191 | 0.6245 ± 0.0173 | 0.6332 ± 0.0312
Relative | 1.45 ± 0.06 | 1.50 ± 0.05 | 1.46 ± 0.06 | 1.54 ± 0.06
L. Epididymis
Absolute | 0.6404 ± 0.0208 | 0.6430 ± 0.0178 | 0.6219 ± 0.0168 | 0.6435 ± 0.0290
Relative | 1.44 ± 0.05 | 1.51 ± 0.04 | 1.45 ± 0.05 | 1.56 ± 0.05
Heart
Absolute | 1.52 ± 0.03 | 1.46 ± 0.03 | 1.42 ± 0.04 | 1.44 ± 0.03
Relative | 3.42 ± 0.06 | 3.42 ± 0.04 | 3.30 ± 0.05 | 3.51 ± 0.04
R. Kidney
Absolute | 1.59 ± 0.04 | 1.43 ± 0.06* | 1.50 ± 0.02 | 1.41 ± 0.04*
Relative | 3.58 ± 0.09 | 3.37 ± 0.11 | 3.50 ± 0.06 | 3.44 ± 0.07
L. Kidney
Absolute | 1.58 ± 0.04 | 1.43 ± 0.05* | 1.47 ± 0.02* | 1.35 ± 0.05**
Relative | 3.57 ± 0.09 | 3.34 ± 0.09 | 3.42 ± 0.05 | 3.28 ± 0.09*
Liver
Absolute | 16.49 ± 0.31 | 14.97 ± 0.46 | 15.23 ± 0.35 | 14.85 ± 0.59*
Relative | 37.17 ± 0.61 | 35.12 ± 0.63 | 35.47 ± 0.73 | 36.12 ± 0.97
Lung
Absolute | 2.20 ± 0.06 | 2.08 ± 0.06 | 2.03 ± 0.06 | 2.00 ± 0.08
Relative | 4.96 ± 0.15 | 4.89 ± 0.13 | 4.73 ± 0.16 | 4.88 ± 0.17
R. Testis
Absolute | 2.071 ± 0.051 | 1.982 ± 0.049 | 2.055 ± 0.041 | 1.930 ± 0.056
Relative | 4.68 ± 0.16 | 4.66 ± 0.11 | 4.80 ± 0.15 | 4.70 ± 0.10
L. Testis
Absolute | 2.083 ± 0.059 | 2.028 ± 0.051 | 2.049 ± 0.039 | 1.954 ± 0.055
Relative | 4.71 ± 0.17 | 4.77 ± 0.11 | 4.79 ± 0.15 | 4.76 ± 0.08
Thymus
Absolute | 0.349 ± 0.023 | 0.361 ± 0.026 | 0.372 ± 0.024 | 0.360 ± 0.017
Relative | 0.79 ± 0.05 | 0.84 ± 0.04 | 0.86 ± 0.05 | 0.87 ± 0.03
Females
Necropsy body wt. | 274 ± 8 | 249 ± 6* | 265 ± 8 | 244 ± 5**
Brain
Absolute | 1.79 ± 0.02 | 1.80 ± 0.03 | 1.81 ± 0.02 | 1.78 ± 0.02
Relative | 6.58 ± 0.18 | 7.28 ± 0.14** | 6.90 ± 0.18 | 7.33 ± 0.11**
Heart
Absolute | 1.02 ± 0.03 | 0.95 ± 0.02 | 0.98 ± 0.03 | 0.94 ± 0.03
Relative | 3.74 ± 0.09 | 3.84 ± 0.08 | 3.70 ± 0.06 | 3.87 ± 0.04
R. Kidney
Absolute | 0.97 ± 0.03 | 0.91 ± 0.02 | 0.89 ± 0.02* | 0.85 ± 0.02**
Relative | 3.54 ± 0.08 | 3.65 ± 0.05 | 3.37 ± 0.10 | 3.50 ± 0.07
L. Kidney
Absolute | 0.97 ± 0.04 | 0.87 ± 0.02* | 0.88 ± 0.02* | 0.83 ± 0.02**
Relative | 3.53 ± 0.11 | 3.51 ± 0.04 | 3.33 ± 0.08 | 3.41 ± 0.08
Liver
Absolute | 10.07 ± 0.56 | 8.41 ± 0.25* | 9.36 ± 0.40 | 8.03 ± 0.22**
Relative | 36.55 ± 1.16 | 33.85 ± 0.61 | 35.27 ± 0.63 | 32.94 ± 0.46**
Lung
Absolute | 1.85 ± 0.05 | 1.67 ± 0.05 | 1.90 ± 0.07 | 1.56 ± 0.03**
Relative | 6.79 ± 0.24 | 6.74 ± 0.18 | 7.22 ± 0.29 | 6.42 ± 0.11
R. Ovary
Absolute | 0.0598 ± 0.0042 | 0.0581 ± 0.0047 | 0.0569 ± 0.0038 | 0.0565 ± 0.0025
Relative | 0.22 ± 0.02 | 0.23 ± 0.02 | 0.21 ± 0.01 | 0.23 ± 0.01
L. Ovary
Absolute | 0.0511 ± 0.0031 | 0.0496 ± 0.0040 | 0.0532 ± 0.0045 | 0.0521 ± 0.0035
Relative | 0.19 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01
Thymus
Absolute | 0.299 ± 0.016 | 0.244 ± 0.013* | 0.274 ± 0.020 | 0.234 ± 0.013*
Relative | 1.10 ± 0.06 | 0.98 ± 0.05 | 1.03 ± 0.07 | 0.96 ± 0.04

* Significantly different (P ≤ 0.05) from the sham control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G‑5 Mean Body Temperatures for Rats by Litter in the 28-day CDMA-modulated Cell Phone RFR Study^a^

Day^b^ | Sham Control | | 3 W/kg | | 6 W/kg | | 9 W/kg
Day^b^ | Temperature (°C) | No. Litters Measured | Temperature (°C) | No. Litters Measured | Temperature (°C) | No. Litters Measured | Temperature (°C) | No. Litters Measured
Male
16 | 37.3 ± 0.1 | 4 | 37.0 ± 0.1 | 4 | 37.1 ± 0.1 | 4 | 37.3 ± 0.1 | 4
20 | 37.6 ± 0.1 | 4 | 37.2 ± 0.1 | 4 | 37.1 ± 0.1 | 4 | 37.5 ± 0.2 | 4
27 | 37.2 ± 0.1 | 4 | 36.8 ± 0.1 | 4 | 37.0 ± 0.1 | 4 | 37.4 ± 0.2 | 4
16–27^c^ | 37.4 ± 0.1 | 4 | 37.0 ± 0.1 | 4 | 37.1 ± 0.1 | 4 | 37.5 ± 0.2 | 4
Female
16 | 37.9 ± 0.2 | 4 | 37.2 ± 0.2* | 3 | 37.5 ± 0.1 | 4 | 37.5 ± 0.1 | 4
20 | 38.0 ± 0.2^▲^ | 4 | 38.0 ± 0.1 | 4 | 37.6 ± 0.2 | 4 | 37.6 ± 0.2 | 4
27 | 37.9 ± 0.2 | 4 | 37.1 ± 0.2 | 4 | 38.0 ± 0.2 | 4 | 38.0 ± 0.2 | 4
16–27^c^ | 37.9 ± 0.1 | 4 | 37.4 ± 0.1 | 4d | 37.7 ± 0.1 | 4 | 37.7 ± 0.1 | 4

^▲^Significant trend (P ≤ 0.05) by Jonckheere’s test.

* Significantly different (P ≤ 0.05) from the sham control group.

^a^ Temperatures are given as mean ± standard error. Statistical analysis for linear trends was performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dosed groups to the sham control group were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett-Hsu adjustment method.

^b^ Postnatal day.

^c^ Average was calculated as the mean of the litter means of the individual animal averages over the time range.

^d^ There were three litters on day 16.

Table G‑6 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats by Litter in the 28‑day CDMA-modulated Cell Phone RFR Study^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
N | 4 | 4 | 4 | 4
Males
Necropsy body wt. | 251 ± 6 | 232 ± 4 | 234 ± 7 | 216 ± 3**
R. Adrenal gland
Absolute | 0.0253 ± 0.0012 | 0.0242 ± 0.0021 | 0.0249 ± 0.0019 | 0.0228 ± 0.0008
Relative | 0.10 ± 0.00 | 0.10 ± 0.01 | 0.11 ± 0.00 | 0.11 ± 0.00
Brain
Absolute | 1.76 ± 0.02 | 1.75 ± 0.02 | 1.74 ± 0.02 | 1.72 ± 0.02
Relative | 7.02 ± 0.08 | 7.53 ± 0.13* | 7.47 ± 0.19 | 7.98 ± 0.06**
Heart
Absolute | 1.02 ± 0.03 | 0.92 ± 0.01 | 0.95 ± 0.05 | 0.89 ± 0.04
Relative | 4.06 ± 0.08 | 3.95 ± 0.06 | 4.05 ± 0.12 | 4.12 ± 0.13
R. Kidney
Absolute | 1.10 ± 0.05 | 1.04 ± 0.02 | 1.00 ± 0.03 | 0.91 ± 0.04*
Relative | 4.36 ± 0.12 | 4.46 ± 0.04 | 4.27 ± 0.09 | 4.20 ± 0.13
Liver
Absolute | 12.05 ± 0.35 | 10.97 ± 0.22 | 11.25 ± 0.38 | 10.23 ± 0.17**
Relative | 47.93 ± 0.66 | 47.20 ± 0.99 | 48.11 ± 0.68 | 47.49 ± 0.74
Lung
Absolute | 2.23 ± 0.13 | 1.98 ± 0.16 | 1.94 ± 0.09 | 1.96 ± 0.04
Relative | 8.93 ± 0.69 | 8.53 ± 0.76 | 8.30 ± 0.49 | 9.13 ± 0.26
R. Testis
Absolute | 1.473 ± 0.056 | 1.444 ± 0.024 | 1.456 ± 0.050 | 1.410 ± 0.038
Relative | 5.86 ± 0.14 | 6.22 ± 0.08 | 6.23 ± 0.04 | 6.54 ± 0.08**
Thymus
Absolute | 0.742 ± 0.060 | 0.639 ± 0.011 | 0.646 ± 0.023 | 0.553 ± 0.025**
Relative | 2.95 ± 0.23 | 2.75 ± 0.04 | 2.77 ± 0.11 | 2.57 ± 0.12
Females
Necropsy body wt. | 168 ± 3 | 165 ± 5 | 169 ± 8 | 161 ± 4
R. Adrenal gland
Absolute | 0.0299 ± 0.0027 | 0.0250 ± 0.0003 | 0.0268 ± 0.0009 | 0.0242 ± 0.0016
Relative | 0.18 ± 0.01 | 0.15 ± 0.00 | 0.16 ± 0.01 | 0.15 ± 0.01
Brain
Absolute | 1.64 ± 0.01 | 1.68 ± 0.02 | 1.63 ± 0.01 | 1.63 ± 0.03
Relative | 9.77 ± 0.22 | 10.23 ± 0.21 | 9.76 ± 0.42 | 10.14 ± 0.14
Heart
Absolute | 0.73 ± 0.02 | 0.71 ± 0.02 | 0.72 ± 0.03 | 0.70 ± 0.01
Relative | 4.35 ± 0.09 | 4.34 ± 0.07 | 4.29 ± 0.10 | 4.33 ± 0.08
R. Kidney
Absolute | 0.76 ± 0.02 | 0.75 ± 0.02 | 0.73 ± 0.03 | 0.69 ± 0.02*
Relative | 4.49 ± 0.10 | 4.53 ± 0.03 | 4.32 ± 0.07 | 4.26 ± 0.08
Liver
Absolute | 7.65 ± 0.20 | 7.50 ± 0.16 | 7.87 ± 0.42 | 7.25 ± 0.07
Relative | 45.53 ± 0.65 | 45.64 ± 1.19 | 46.54 ± 0.53 | 45.11 ± 0.70
Lung
Absolute | 1.52 ± 0.08 | 1.48 ± 0.06 | 1.46 ± 0.06 | 1.41 ± 0.04
Relative | 9.03 ± 0.51 | 8.98 ± 0.45 | 8.78 ± 0.73 | 8.76 ± 0.34
Thymus
Absolute | 0.453 ± 0.059 | 0.444 ± 0.030 | 0.388 ± 0.024 | 0.380 ± 0.024
Relative | 2.71 ± 0.38 | 2.69 ± 0.10 | 2.31 ± 0.17 | 2.36 ± 0.09

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams as means of litter means; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Statistical analysis is for linear trends performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dosed groups to the sham control group were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett‑Hsu adjustment method.

Table G‑7 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the 28-day CDMA-modulated Cell Phone RFR Study^a^

| Sham Control | 3 W/kg | 6 W/kg | 9 W/kg
N | 10 | 10 | 10 | 10
Males
Necropsy body wt. | 249 ± 3 | 231 ± 3 | 236 ± 6 | 215 ± 3**
R. Adrenal gland
Absolute | 0.0247 ± 0.0011 | 0.0254 ± 0.0016 | 0.0253 ± 0.0013 | 0.0223 ± 0.0007
Relative | 0.10 ± 0.00 | 0.11 ± 0.01 | 0.11 ± 0.00 | 0.10 ± 0.00
Brain
Absolute | 1.75 ± 0.01 | 1.75 ± 0.01 | 1.75 ± 0.01 | 1.72 ± 0.02
Relative | 7.05 ± 0.07 | 7.59 ± 0.11* | 7.43 ± 0.14 | 8.01 ± 0.07**
Heart
Absolute | 1.02 ± 0.02 | 0.91 ± 0.01 | 0.97 ± 0.04 | 0.90 ± 0.02
Relative | 4.09 ± 0.06 | 3.95 ± 0.05 | 4.08 ± 0.09 | 4.16 ± 0.09
R. Kidney
Absolute | 1.08 ± 0.03 | 1.03 ± 0.02 | 1.00 ± 0.03 | 0.91 ± 0.03*
Relative | 4.32 ± 0.09 | 4.46 ± 0.05 | 4.22 ± 0.07 | 4.24 ± 0.08
Liver
Absolute | 11.85 ± 0.22 | 11.05 ± 0.21 | 11.38 ± 0.33 | 10.29 ± 0.17**
Relative | 47.66 ± 0.63 | 47.80 ± 0.58 | 48.13 ± 0.59 | 47.88 ± 0.47
Lung
Absolute | 2.24 ± 0.12 | 1.92 ± 0.10 | 1.91 ± 0.09 | 1.95 ± 0.08
Relative | 9.05 ± 0.56 | 8.34 ± 0.49 | 8.07 ± 0.35 | 9.10 ± 0.42
R. Testis
Absolute | 1.464 ± 0.036 | 1.438 ± 0.023 | 1.473 ± 0.036 | 1.407 ± 0.034
Relative | 5.88 ± 0.11 | 6.22 ± 0.08 | 6.23 ± 0.06 | 6.54 ± 0.12**
Thymus
Absolute | 0.757 ± 0.041 | 0.639 ± 0.017 | 0.658 ± 0.026 | 0.568 ± 0.022**
Relative | 3.04 ± 0.15 | 2.77 ± 0.06 | 2.79 ± 0.10 | 2.64 ± 0.11
Females
Necropsy body wt. | 167 ± 2 | 163 ± 4 | 172 ± 6 | 159 ± 3
R. Adrenal gland
Absolute | 0.0285 ± 0.0019 | 0.0250 ± 0.0007 | 0.0265 ± 0.0012 | 0.0236 ± 0.0011
Relative | 0.17 ± 0.01 | 0.15 ± 0.00 | 0.16 ± 0.01 | 0.15 ± 0.01
Brain
Absolute | 1.64 ± 0.01 | 1.67 ± 0.01 | 1.64 ± 0.01 | 1.61 ± 0.01
Relative | 9.86 ± 0.15 | 10.33 ± 0.19 | 9.62 ± 0.33 | 10.15 ± 0.16
Heart
Absolute | 0.72 ± 0.01 | 0.71 ± 0.02 | 0.74 ± 0.02 | 0.69 ± 0.01
Relative | 4.34 ± 0.07 | 4.34 ± 0.06 | 4.29 ± 0.08 | 4.33 ± 0.06
R. Kidney
Absolute | 0.74 ± 0.02 | 0.73 ± 0.02 | 0.74 ± 0.02 | 0.67 ± 0.01*
Relative | 4.46 ± 0.06 | 4.51 ± 0.03 | 4.32 ± 0.06 | 4.23 ± 0.06
Liver
Absolute | 7.55 ± 0.14 | 7.52 ± 0.16 | 8.04 ± 0.32 | 7.23 ± 0.17
Relative | 45.35 ± 0.44 | 46.25 ± 0.64 | 46.77 ± 0.55 | 45.45 ± 0.74
Lung
Absolute | 1.52 ± 0.07 | 1.50 ± 0.07 | 1.44 ± 0.04 | 1.41 ± 0.06
Relative | 9.11 ± 0.40 | 9.23 ± 0.37 | 8.45 ± 0.41 | 8.85 ± 0.37
Thymus
Absolute | 0.474 ± 0.036 | 0.432 ± 0.021 | 0.400 ± 0.025 | 0.369 ± 0.017
Relative | 2.86 ± 0.23 | 2.65 ± 0.08 | 2.35 ± 0.16 | 2.32 ± 0.10

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Statistical analysis is for linear trends performed using mixed models with continuous dose and dam ID (litter) as a random effect. Multiple pairwise comparisons of dosed groups to the sham control group were performed using mixed models with categorical dose and dam ID (litter) as a random effect with Dunnett-Hsu adjustment method.

Table G‑8 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats at the 14-week Interim Evaluation in the Two-year CDMA-modulated Cell Phone RFR Study^a^

| Sham Control | 1.5 W/kg | 3 W/kg | 6 W/kg
N | 10 | 10 | 10 | 10
Males
Necropsy body wt. | 444 ± 9 | 440 ± 8 | 435 ± 4 | 411 ± 8**
Brain
Absolute | 1.92 ± 0.02 | 1.96 ± 0.02 | 1.97 ± 0.04 | 1.92 ± 0.02
Relative | 4.34 ± 0.08 | 4.47 ± 0.08 | 4.53 ± 0.10 | 4.67 ± 0.08*
R. Epididymis
Absolute | 0.6423 ± 0.0278 | 0.6298 ± 0.0256 | 0.6370 ± 0.0162b | 0.5817 ± 0.0353
Relative | 1.45 ± 0.06 | 1.44 ± 0.07 | 1.46 ± 0.04b | 1.42 ± 0.09
L. Epididymis
Absolute | 0.6404 ± 0.0208 | 0.6673 ± 0.0137 | 0.6491 ± 0.0155 | 0.5866 ± 0.0428
Relative | 1.44 ± 0.05 | 1.52 ± 0.05 | 1.49 ± 0.03 | 1.43 ± 0.11
Heart
Absolute | 1.52 ± 0.03 | 1.52 ± 0.04 | 1.51 ± 0.03 | 1.43 ± 0.04
Relative | 3.42 ± 0.06 | 3.46 ± 0.06 | 3.47 ± 0.06 | 3.49 ± 0.07
R. Kidney
Absolute | 1.59 ± 0.04 | 1.51 ± 0.04 | 1.51 ± 0.05 | 1.38 ± 0.05**
Relative | 3.58 ± 0.09 | 3.45 ± 0.09 | 3.47 ± 0.11 | 3.36 ± 0.13
L. Kidney
Absolute | 1.58 ± 0.04 | 1.53 ± 0.04 | 1.49 ± 0.04 | 1.35 ± 0.04**
Relative | 3.57 ± 0.09 | 3.49 ± 0.06 | 3.43 ± 0.09 | 3.29 ± 0.12
Liver
Absolute | 16.49 ± 0.31 | 15.66 ± 0.39 | 15.57 ± 0.37 | 14.13 ± 0.36**
Relative | 37.17 ± 0.61 | 35.64 ± 0.57 | 35.79 ± 0.64 | 34.35 ± 0.45**
Lung
Absolute | 2.20 ± 0.06 | 2.06 ± 0.07 | 2.29 ± 0.12 | 2.09 ± 0.09
Relative | 4.96 ± 0.15 | 4.70 ± 0.18 | 5.26 ± 0.25 | 5.12 ± 0.30
R. Testis
Absolute | 2.071 ± 0.051 | 2.104 ± 0.045 | 2.087 ± 0.044 | 1.784 ± 0.152
Relative | 4.68 ± 0.16 | 4.80 ± 0.14 | 4.81 ± 0.12 | 4.37 ± 0.38
L. Testis
Absolute | 2.083 ± 0.059 | 2.116 ± 0.055 | 2.102 ± 0.036 | 1.836 ± 0.160
Relative | 4.71 ± 0.17 | 4.83 ± 0.14 | 4.84 ± 0.10 | 4.50 ± 0.40
Thymus
Absolute | 0.349 ± 0.023 | 0.368 ± 0.018 | 0.387 ± 0.026 | 0.364 ± 0.031
Relative | 0.79 ± 0.05 | 0.84 ± 0.04 | 0.89 ± 0.06 | 0.88 ± 0.07
Females
Necropsy body wt. | 274 ± 8 | 264 ± 5 | 264 ± 6 | 252 ± 4*
Brain
Absolute | 1.79 ± 0.02 | 1.79 ± 0.02 | 1.85 ± 0.02 | 1.77 ± 0.02
Relative | 6.58 ± 0.18 | 6.81 ± 0.13 | 7.02 ± 0.15 | 7.05 ± 0.09
Heart
Absolute | 1.02 ± 0.03 | 0.97 ± 0.01 | 0.98 ± 0.02 | 0.94 ± 0.02*
Relative | 3.74 ± 0.09 | 3.67 ± 0.05 | 3.73 ± 0.07 | 3.73 ± 0.08
R. Kidney
Absolute | 0.97 ± 0.03 | 0.91 ± 0.02 | 0.91 ± 0.02 | 0.84 ± 0.02**
Relative | 3.54 ± 0.08 | 3.45 ± 0.07 | 3.47 ± 0.06 | 3.35 ± 0.08
L. Kidney
Absolute | 0.97 ± 0.04 | 0.87 ± 0.02* | 0.89 ± 0.02* | 0.82 ± 0.02**
Relative | 3.53 ± 0.11 | 3.28 ± 0.05 | 3.38 ± 0.06 | 3.26 ± 0.09
Liver
Absolute | 10.07 ± 0.56 | 8.92 ± 0.28 | 9.19 ± 0.28 | 8.76 ± 0.20*
Relative | 36.55 ± 1.16 | 33.72 ± 0.59 | 34.80 ± 0.64 | 34.82 ± 0.76
Lung
Absolute | 1.85 ± 0.05 | 1.80 ± 0.07 | 1.75 ± 0.08 | 1.72 ± 0.06
Relative | 6.79 ± 0.24 | 6.83 ± 0.26 | 6.68 ± 0.35 | 6.84 ± 0.25
R. Ovary
Absolute | 0.0598 ± 0.0042 | 0.0578 ± 0.0039 | 0.0587 ± 0.0029 | 0.0566 ± 0.0053
Relative | 0.22 ± 0.02 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.22 ± 0.02
L. Ovary
Absolute | 0.0511 ± 0.0031 | 0.0521 ± 0.0030 | 0.0547 ± 0.0035 | 0.0495 ± 0.0055
Relative | 0.19 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01 | 0.20 ± 0.02
Thymus
Absolute | 0.299 ± 0.016 | 0.282 ± 0.008 | 0.274 ± 0.015 | 0.278 ± 0.015
Relative | 1.10 ± 0.06 | 1.07 ± 0.03 | 1.04 ± 0.05 | 1.11 ± 0.06

* Significantly different (P ≤ 0.05) from the sham control group.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Statistical analysis performed by Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^b^ n = 9.